# REFERENCES

1 Department of Veterans Affairs. Women Veterans Health Care: Facts and Statistics. [Website] Available at: https://www.womenshealth.va.gov/materials-and-resources/facts-and-statistics.asp. Accessed May 3, 2024.
2 Labor USDo. Veterans’ Employment and Training Service: Demographics. Vol. 2024.
3 Department of Veterans Affairs. Sourcebook Volume 4: Women Veterans in the Veterans Health Administration. Longitudinal Trends in Sociodemographics, Utilization, Health Profile, and Geographic Distribution. February 2018.
4 Affairs DoV. Sourcebook Volume 5: Women Veterans in the Veterans Health Administration. Longitudinal Trends in Sociodemographics, Utilization, Health Profile, and Geographic Distribution. [in preparation].
5 Yano EM, Bastian LA, Bean-Mayberry B, . Using research to transform care for women veterans: advancing the research agenda and enhancing research-clinical partnerships. Womens Health Issues. 2011;21(4 Suppl):S73–83.21724148
6 Department of Veterans Affairs. VA Women’s Health Research Network (WHRN). [Website] Available at: https://www.hsrd.research.va.gov/centers/womens_health/WHRN-Exec-Summary.pdf. Accessed May 3, 2024.
7 Goldzweig CL, Balekian TM, Rolón C, . The state of women veterans’ health research. Results of a systematic literature review. J Gen Intern Med. 2006;21 Suppl 3(Suppl 3):S82–92.16637952
8 Department of Veterans Affairs. Systematic Review of Women Veterans Health Research 2004-2008. Available at: https://www.hsrd.research.va.gov/publications/esp/womens-health.pdf. Accessed May 3, 2024.
9 Department of Veterans Affairs. An Evidence Map of the Women Veterans’ Health Research Literature (2008-2015). Available at: https://www.hsrd.research.va.gov/publications/esp/womens-health2.pdf. Accessed May 3, 2024.
10 McGowan J, Sampson M, Salzwedel DM, . PRESS Peer Review of Electronic Search Strategies: 2015 Guideline Statement. J Clin Epidemiol. 2016;75:40–6.27005575
11 EPOC CEPaOoC-. Cochrane Effective Practice and Organisation of Care (EPOC). What study designs can be considered for inclusion in an EPOC review and what should they be called? EPOC Resources for review authors. Vol. 2024; 2017.
12 Caloudas AB, Amspoker AB, Stanley M, . Prevalence of sexual desire and arousal difficulties among women veterans: A retrospective cohort design. Psychological services. 2022.
13 Graham SE, Coleman BC, Zhao X, Lisi AJ. Evaluating rates of chiropractic use and utilization by patient sex within the United States Veterans Health Administration: a serial cross-sectional analysis. Chiropractic & Manual Therapies. 2023;31(1):1–8.36635694
14 Amsalem D, Lazarov A, Markowitz JC, . Increasing treatment-seeking intentions of US veterans in the Covid-19 era: A randomized controlled trial. Depression & Anxiety (1091-4269). 2021;38(6):639–647.33734539
15 Fenton BT, Goulet JL, Bair MJ, . Relationships Between Temporomandibular Disorders, MSD Conditions, and Mental Health Comorbidities: Findings from the Veterans Musculoskeletal Disorders Cohort. Pain Medicine. 2018;19:S61–S68.30203016
16 Serier KN, Vogt D, Pandey S, Smith BN. Analysis of the bidirectional relationships between posttraumatic stress and depression symptoms with physical health functioning in post-9/11 veteran men and women deployed to a war zone. Journal of Psychosomatic Research. 2022;162:N.PAG-N.PAG.
17 Creech SK, Pulverman CS, Crawford JN, . Clinical Complexity in Women Veterans: A Systematic Review of the Recent Evidence on Mental Health and Physical Health Comorbidities. Behavioral Medicine. 2021;47(1):69–87.31403895
18 King PR, Buchholz LJ, Tauriello S, Wray LO. Qualitative Exploration of Factors Influencing Women Veterans’ Disordered Eating Symptoms and Treatment Preferences in VHA Primary Care. Families, Systems & Health: The Journal of Collaborative Family HealthCare. 2023;41(2):214–221.
19 Breland JY, Donalson R, Dinh J, . Women Veterans’ Treatment Preferences for Disordered Eating. Women’s Health Issues. 2016;26(4):429–436.27264912
20 Orshak J, Alexander L, Gilmore-Bykovskyi A, Lauver D. Interventions for Women Veterans with Mental Health Care Needs: Findings from a Scoping Review. Issues in mental health nursing. 2022;43(6):516–527.35025699
21 Godier-McBard LR, Wood A, Kohomange M, . Barriers and facilitators to mental healthcare for women veterans: a scoping review. Journal of Mental Health. 2023;32(5):951–961.36062860
22 Davis TD, Campbell DG, Bonner LM, . Women Veterans with Depression in Veterans Health Administration Primary Care: An Assessment of Needs and Preferences. Women’s Health Issues. 2016;26(6):656–666.27697494
23 Lam CA, Sherbourne C, Gelberg L, . Differences in Depression Care for Men and Women among Veterans with and without Psychiatric Comorbidities. Women’s Health Issues. 2017;27(2):206–213.28007391
24 Jones GL, Hanley T. The psychological health and well-being experiences of female military veterans: a systematic review of the qualitative literature. Journal of the Royal Army Medical Corps. 2017;163(5):311–318.28356493
25 Saban KL, Collins EG, Mathews HL, . Impact of a Mindfulness-Based Stress Reduction Program on Psychological Well-Being, Cortisol, and Inflammation in Women Veterans. JGIM: Journal of General Internal Medicine. 2022;37:751–761.36042095
26 Vogt D, Borowski SC, Godier-McBard LR, . Changes in the health and broader well-being of U.S. veterans in the first three years after leaving military service: Overall trends and group differences. Social Science & Medicine. 2022;294:N.PAG-N.PAG.
27 Lawrence KA, Matthieu MM, Robertson-Blackmore E. Civic Service as an Intervention to Promote Psychosocial Health and Implications for Mental Health in Post-9/11/01 Era Women Veterans. Journal of Women’s Health (15409996). 2019;28(8):1133–1142.
28 Vogt D, Borowski S, Maguen S, . Strengths and vulnerabilities: Comparing post-9/11 U.S. veterans’ and non-veterans’ perceptions of health and broader well-being. SSM - Population Health. 2022;19.
29 Barnes HA, Hurley RA, Taber KH. Moral Injury and PTSD: Often Co-Occurring Yet Mechanistically Different. J Neuropsychiatry Clin Neurosci. 2019;31(2):A4–103.
30 Groër MW, Kostas-Polston EA, Dillahunt-Aspillaga C, . Allostatic Perspectives in Women Veterans With a History of Childhood Sexual Assault. Biological Research for Nursing. 2016;18(4):454–464.27067613
31 Beckie TM, Duffy A, Groer MW. The Relationship between Allostatic Load and Psychosocial Characteristics among Women Veterans. Women’s Health Issues. 2016;26(5):555–563.27444339
32 Wang HL, Visovsky C, Ji M, Groer M. Stress-related biobehavioral responses, symptoms, and physical activity among female veterans in the community: An exploratory study. Nurse education today. 2016;47:2–9.27372810
33 Lwi SJ, Barnes DE, Xia F, . Ten-Year Prevalence of Cognitive Impairment Diagnoses and Associated Medical and Psychiatric Conditions in a National Cohort of Older Female Veterans. American Journal of Geriatric Psychiatry. 2019;27(4):417–425.
34 Fox AB, Walker BE, Smith BN, . Understanding how deployment experiences change over time: Comparison of female and male OEF/OIF and Gulf War veterans. Psychological trauma : theory, research, practice and policy. 2016;8(2):135–140.25866959
35 Sullivan-Baca E, Naylon K, Zartman A, . Gender Differences in Veterans Referred for Neuropsychological Evaluation in an Outpatient Neuropsychology Consultation Service. Archives of clinical neuropsychology : the official journal of the National Academy of Neuropsychologists. 2020;35(5):562–575.32128586
36 Galovski TE, Street AE, McCaughey VK, . WoVeN, the Women Veterans Network: an Innovative Peer Support Program for Women Veterans. JGIM: Journal of General Internal Medicine. 2022;37:842–847.36042082
37 Leslie LA, Koblinsky SA. Returning to civilian life: Family reintegration challenges and resilience of women veterans of the Iraq and Afghanistan wars. Journal of Family Social Work. 2017;20(2):106–123.
38 Katz LS, Park SE, Cojucar G, . Improved Attachment Style for Female Veterans Who Graduated Warrior Renew Sexual Trauma Treatment. Violence & Victims. 2016;31(4):680–691.27302913
39 Simpson T, Sistad R, Brooks JT, . Seeking care where they can: A systematic review of global trends in online alcohol treatment utilization among non-veteran and veteran women. Drug and Alcohol Dependence Reports. 2022;5.
40 Weinberger AH, Esan H, Hunt MG, Hoff RA. A review of research on smoking behavior in three demographic groups of veterans: women, racial/ethnic minorities, and sexual orientation minorities. Am J Drug Alcohol Abuse. 2016;42(3):254–268.26151807
41 Fink DS, Malte C, Cerdá M, . Trends in Cannabis-positive Urine Toxicology Test Results: US Veterans Health Administration Emergency Department Patients, 2008 to 2019. J Addict Med. 2023.
42 Livingston NA, Simpson T, Lehavot K, . Differential alcohol treatment response by gender following use of VetChange. Drug Alcohol Depend. 2021;221:N.PAG-N.PAG.
43 Stefanovics EA, Rosenheck RA. Gender Difference in Substance Use and Psychiatric Outcomes Among Dually Diagnosed Veterans Treated in Specialized Intensive PTSD Programs. J Dual Diagn. 2020;16(4):382–391.33002376
44 Danan ER, Sherman SE, Clothier BA, . Smoking Cessation among Female and Male Veterans before and after a Randomized Trial of Proactive Outreach. Womens Health Issues. 2019;29 Suppl 1:S15–S23.31253237
45 Pedersen ER, Parast L, Marshall GN, . A randomized controlled trial of a web-based, personalized normative feedback alcohol intervention for young-adult veterans. J Consult Clin Psychol. 2017;85(5):459–470.28287799
46 Simpson TL, Rillamas-Sun E, Lehavot K, . Alcohol Consumption Levels and All-Cause Mortality Among Women Veterans and Non-Veterans Enrolled in the Women’s Health Initiative. Gerontologist. 2016;56 Suppl 1:S138–49.26768387
47 Schweizer CA, Hoggatt KJ, Washington DL, . Use of alcohol as a sleep aid, unhealthy drinking behaviors, and sleeping pill use among women veterans. Sleep health. 2019;5(5):495–500.31416799
48 Holzhauer CG, Epstein EE, Smelson DA, Mattocks K. Targeting women veteran’s stress-induced drinking with cognitive reappraisal: Mechanisms and moderators of change. J Subst Abuse Treat. 2021;130:N.PAG-N.PAG.
49 Matson TE, Harris AHS, Chen JA, . Influence of a national transgender health care directive on receipt of alcohol-related care among transgender Veteran Health Administration patients with unhealthy alcohol use. J Subst Abuse Treat. 2022;143:N.PAG-N.PAG.
50 Than CT, Bean-Mayberry B, Schweizer CA, . Ask and Ask Again: Repeated Screening for Smoking Increases Likelihood of Prescription for Cessation Treatment Among Women Veterans. JGIM: Journal of General Internal Medicine. 2023;38(11):2553–2559.37277666
51 Giannitrapani KF, Holliday JR, Dawson AW, . Provider perceptions of challenges to identifying women Veterans with hazardous substance use. BMC Health Serv Res. 2022;22(1):1–9.34974828
52 Abraham TH, Lewis ET, Drummond KL, . Providers’ perceptions of barriers and facilitators to disclosure of alcohol use by women veterans. Prim Health Care Res Dev. 2017;18(1):64–72.27692026
53 Cucciare MA, Lewis ET, Hoggatt KJ, . Factors Affecting Women’s Disclosure of Alcohol Misuse in Primary Care: A Qualitative Study with U.S. Military Veterans. Women’s Health Issues. 2016;26(2):232–239.26341569
54 Hoggatt KJ, Simpson T, Schweizer CA, . Identifying women veterans with unhealthy alcohol use using gender-tailored screening. American Journal on Addictions. 2018;27(2):97–100.29489045
55 Halverson TF, Mann AJD, Zelkowitz RL, . Nonsuicidal self-injury in veterans: Prevalence, clinical characteristics, and gender differences from a national cohort. Psychiatry Research. 2022;315.
56 Holliday R, Forster JE, Desai A, . Association of lifetime homelessness and justice involvement with psychiatric symptoms, suicidal ideation, and suicide attempt among post-9/11 veterans. Journal of Psychiatric Research. 2021;144:455–461.34752942
57 Montgomery AE, Dichter ME, Blosnich JR. Gender Differences in the Predictors of Suicide-related Morbidity Among Veterans Reporting Current Housing Instability. Medical Care. 2021;59(2):S36–S41.33438881
58 Aboussouan A, Snow A, Cerel J, Tucker RP. Non-suicidal self-injury, suicide ideation, and past suicide attempts: Comparison between transgender and gender diverse veterans and non-veterans. Journal of Affective Disorders. 2019;259:186–194.31446379
59 Blosnich JR, Boyer TL, Brown GR, . Differences in Methods of Suicide Death Among Transgender and Nontransgender Patients in the Veterans Health Administration, 1999-2016. Medical Care. 2021;59(2):S31–S35.33438880
60 Boyer TL, Youk AO, Haas AP, . Suicide, Homicide, and All-Cause Mortality Among Transgender and Cisgender Patients in the Veterans Health Administration. LGBT Health. 2021;8(3):173–180.33544021
61 Gibson CJ, Li Y, Jasuja GK, . Long-term Psychoactive Medications, Polypharmacy, and Risk of Suicide and Unintended Overdose Death Among Midlife and Older Women Veterans. JGIM: Journal of General Internal Medicine. 2022;37:770–777.36042093
62 Lawrence KA, Vogt D, Nigam S, . Temporal Sequencing of Mental Health Symptom Severity and Suicidal Ideation in Post-9/11 Men and Women Veterans Who Recently Separated from the Military. Chronic Stress. 2021:1–11.
63 Hoffmire CA, Monteith LL, Forster JE, . Gender Differences in Lifetime Prevalence and Onset Timing of Suicidal Ideation and Suicide Attempt Among Post-9/11 Veterans and Nonveterans. Medical Care. 2021;59(2):S84–S91.33438888
64 Hoffmire CA, Monteith LL, Denneson LM, . A sex-stratified analysis of suicidal ideation correlates among deployed post-9/11 veterans: Results from the survey of experiences of returning veterans. Journal of Affective Disorders. 2021;294:824–830.34375209
65 Polzer ER, Rohs CM, Thomas SM, . Women Veterans’ experiences discussing household firearms with their intimate partners: collaborative, devalued, and deferential relational types. Injury Epidemiology. 2023;10(1):1–14.36604736
66 Denneson LM, Tompkins KJ, McDonald KL, . Gender differences in the development of suicidal behavior among United States military veterans: A national qualitative study. Social Science & Medicine. 2020;260:N.PAG-N.PAG.
67 Denneson LM, Tompkins KJ, McDonald KL, . Gender Differences in Recovery Needs After a Suicide Attempt: A National Qualitative Study of US Military Veterans. Medical Care. 2021;59(2):S65–S69.33438885
68 Maguen S, Griffin BJ, Vogt D, . Moral injury and peri- and post-military suicide attempts among post-9/11 veterans. Psychological Medicine. 2023;53(7):3200–3209.35034682
69 Holliday R, Forster JE, Schneider AL, . Interpersonal Violence Throughout the Lifespan: Associations With Suicidal Ideation and Suicide Attempt Among a National Sample of Female Veterans. Medical Care. 2021;59(2):S77–S83.33438887
70 Günak MM, Barnes DE, Yaffe K, . Risk of Suicide Attempt in Patients With Recent Diagnosis of Mild Cognitive Impairment or Dementia. JAMA Psychiatry. 2021;78(6):659–666.33760039
71 Livingston WS, Tannahill HS, Meter DJ, . The Association of Military Sexual Harassment/Assault With Suicide Ideation, Plans, Attempts, and Mortality Among US Service Members/Veterans: A Meta-Analysis. Trauma, Violence & Abuse. 2023;24(4):2616–2629.
72 Krishnamurti LS, Denneson LM, Agha A, . Improving suicide prevention for women veterans: Recommendations from VHA suicide prevention coordinators. General Hospital Psychiatry. 2023;84:67–72.37393650
73 Carter SP, Malte CA, Rojas SM, . Examination of potential disparities in suicide risk identification and follow-up care within the Veterans Health Administration. Suicide & life-threatening behavior. 2020;50(6):1127–1139.33196113
74 Smolenski DJ, McDonald KL, Hoffmire CA, . Informing measurement of gender differences in suicide risk and resilience: A national study of United States military veterans. Journal of clinical psychology. 2023;79(5):1371–1385.36680761
75 Holliday R, Schneider AL, Miller C, . Factor Structure of the Suicide Cognitions Scale in a National Sample of Female Veterans. Archives of Suicide Research. 2022;26(3):1349–1361.33689600
76 Gaeddert LA, Schneider AL, Miller CN, . Recruitment of women veterans into suicide prevention research: Improving response rates with enhanced recruitment materials and multiple survey modalities. Research in Nursing & Health. 2020;43(5):538–547.32827237
77 Solness CL, Kroska EB, Holdefer PJ, O’Hara MW. Treating postpartum depression in rural veterans using internet delivered CBT: program evaluation of MomMoodBooster. Journal of Behavioral Medicine. 2021;44(4):454–466.33052526
78 Kroll-Desrosiers AR, Crawford SL, Moore Simas TA, . Bridging the Gap for Perinatal Veterans: Care by Mental Health Providers at the Veterans Health Administration. Women’s Health Issues. 2019;29(3):274–282.30954382
79 Gross GM, Kroll-Desrosiers A, Mattocks K. A Longitudinal Investigation of Military Sexual Trauma and Perinatal Depression. Journal of Women’s Health (15409996). 2020;29(1):38–45.
80 Coleman JN, DeRycke EC, Bastian LA, . Predictors of prenatal smoking among US women veterans. Journal of Health Psychology. 2021;26(13):2648–2655.32255376
81 Miller LJ, Ghadiali NY. Mental Health Across the Reproductive Cycle in Women Veterans. Military Medicine. 2018;183(5/6):e140–e146.
82 Katon JG, Callegari LS, Bossick AS, . Association of Depression and Post-Traumatic Stress Disorder with Receipt of Minimally Invasive Hysterectomy for Uterine Fibroids: Findings from the U.S. Department of Veterans Affairs. Women’s Health Issues. 2020;30(5):359–365.32712008
83 Blais RK, Bird E, Sartin-Tarm A, . Mechanisms of the association between PTSD and sexual arousal and lubrication functioning among trauma-exposed female service members/veterans. Journal of Affective Disorders. 2022;301:352–359.34965403
84 Xiaofei C, Bala R, Shirling T, . Differential Impact of Aging on Cardiovascular Risk in Women Military Service Members. Journal of the American Heart Association. 2020;9(12):1–24.
85 Jeon-Slaughter H, Xiaofei C, Shirling T, . Developing an Internally Validated Veterans Affairs Women Cardiovascular Disease Risk Score Using Veterans Affairs National Electronic Health Records. Journal of the American Heart Association. 2021;10(5):1–12.
86 Gerber MR, King MW, Iverson KM, . Association Between Mental Health Burden and Coronary Artery Disease in U.S. Women Veterans Over 45: A National Cross-Sectional Study. Journal of Women’s Health (15409996). 2018;27(3):238–244.
87 Aghazadehsanai N, Chang TI, Garrett NR, Friedlander AH. Prevalence of calcified carotid artery atheromas on digital panoramic images among perimenopausal and postmenopausal African American women. Oral Surgery, Oral Medicine, Oral Pathology & Oral Radiology. 2017;123(5):621–625.28407989
88 Cavanagh CE, Rosman L, Chui PW, . Barriers to Cardiovascular Disease Preventive Behaviors Among OEF/OIF/OND Women and Men Veterans. Health Psychology. 2020;39(4):298–306.31999178
89 Dawson DB, Mohankumar R, Puran D, . Weight Management Treatment Representations: A Novel Use of the Common Sense Model. Journal of Clinical Psychology in Medical Settings. 2023;30(4):884–892.36828990
90 Vimalananda V, Damschroder L, Janney CA, . Weight loss among women and men in the ASPIRE-VA behavioral weight loss intervention trial. Obesity (19307381). 2016;24(9):1884–1891.
91 Gray KE, Silvestrini M, Ma EW, . Gender differences in social support for diabetes self-management: A qualitative study among veterans. Patient Education & Counseling. 2023;107:N.PAG-N.PAG.
92 Dyer KE, Moreau Jl PhD MPH, Finley E PhD MPH, . Tailoring an evidence-based lifestyle intervention to meet the needs of women Veterans with prediabetes. Women Health. 2020;60(7):748–762.31959089
93 Gatwood JD, Chisholm-Burns M, Davis R, . Differences in health outcomes associated with initial adherence to oral antidiabetes medications among veterans with uncomplicated Type 2 diabetes: a 5-year survival analysis. Diabetic Medicine. 2018;35(11):1571–1579.29978496
94 Gulanski B, Goulet J, Radhakrishnan K, . Metformin Prescription for U.S. Veterans with Prediabetes, 2010-2019. Journal of investigative medicine : the official publication of the American Federation for Clinical Research. 2023:10815589231201141.
95 Gray KE, Katon JG, Rillamas-Sun E, . Association Between Chronic Conditions and Physical Function Among Veteran and Non-Veteran Women With Diabetes. Gerontologist. 2016;56:S112–S125.26768385
96 Chang PY, Saechao FS, Lee J, . Prevalence and risk of fracture diagnoses in women across the adult life span: a national cross-sectional study. Osteoporosis International. 2016;27(11):3177–3186.27349559
97 Bethel M, Weaver FM, Bailey L, . Risk factors for osteoporotic fractures in persons with spinal cord injuries and disorders. Osteoporosis International. 2016;27(10):3011–3021.27230522
98 Chung JS, Jouk A, Licona NP, . In her own words: a phenomenological analysis of stories told by female service members and veterans after traumatic brain injury. Disability and rehabilitation. 2022:1–8.
99 Merritt VC, Gasperi M, Yim J, . Exploring Interactions Between Traumatic Brain Injury History and Gender on Medical Comorbidities in Military Veterans: An Epidemiological Analysis in the VA Million Veteran Program. Journal of Neurotrauma. 2023.
100 Lopez MR, VanCott AC, Amuan ME, . Prescribing Trends of Antiseizure Drugs in Women Veterans With Epilepsy. Military medicine. 2023.
101 Sico JJ, Seng EK, Wang K, . Characteristics and Gender Differences of Headache in the Veterans Health Administration: A National Cohort Study, Fiscal Year 2008-2019. Neurology. 2022;99(18):e1993–e2005.36100437
102 Russell Esposito E, Hansen AH, Slater BS, . Footwear limitations in women prosthesis users relate to more than preference. Prosthetics and orthotics international. 2023;47(5):511–518.36629586
103 Lehavot K, Young JP, Thomas RM, . Voices of Women Veterans with Lower Limb Prostheses: a Qualitative Study. JGIM: Journal of General Internal Medicine. 2022;37:799–805.36050521
104 Haskell SG, Brandt C, Bastian L, . Incident Musculoskeletal Conditions Among Men and Women Veterans Returning From Deployment. Medical Care. 2020;58(12):1082–1090.32925458
105 Vina ER, Youk AO, Quinones C, . Use of Complementary and Alternative Therapy for Knee Osteoarthritis: Race and Gender Variations. ACR Open Rheumatology. 2021;3(9):660–667.34535982
106 Fadhil AA, Al Rubaye AW, Alzubaidi MA, . Prevalence of neurological dysfunction and irregularities in people suffering from auto-immune conditions: An Iraqi perspective. Revista de Psiquiatria Clinica. 2022;49(5):148–154.
107 Coughlin SS, Krengel M, Sullivan K, . A Review of Epidemiologic Studies of the Health of Gulf War Women Veterans. J. 2017;3(2).
108 Lafferty M, Winchell K, Cottrell E, . Women of the Gulf War: Understanding Their Military and Health Experiences Over 30 Years. Military medicine. 2023;188(9–10):3191–3198.36179086
109 Clark E, Chen L, Dong Y, . Veteran Women Living With Human Immunodeficiency Virus Have Increased Risk of Human Papillomavirus (HPV)-Associated Genital Tract Cancers. Clinical Infectious Diseases. 2021;72(9):e359–e366.32785700
110 Hotton AL, Weber KM, Hershow RC, . Prevalence and Predictors of Hospitalizations among HIV-Infected and At-Risk HIV-Uninfected Women. Journal of Acquired Immune Deficiency Syndromes. 2017;75(2):e27–e35.28002184
111 Tsai S, Nguyen H, Ebrahimi R, . COVID-19 associated mortality and cardiovascular disease outcomes among US women veterans. Scientific reports. 2021;11(1):8497.33875764
112 Upchurch DM, Wong MS, Yuan AH, . COVID-19 Infection in the Veterans Health Administration: Gender-specific Racial and Ethnic Differences. Women’s Health Issues. 2022;32(1):41–50.34702652
113 Lynch KE, Shipherd JC, Gatsby E, . Sexual orientation-related disparities in health conditions that elevate COVID-19 severity. Annals of Epidemiology. 2022;66:5–12.34785397
114 Markland AD, Vaughan CP, Goldstein KM, . Optimizing remote access to urinary incontinence treatments for women veterans (PRACTICAL): Study protocol for a pragmatic clinical trial comparing two virtual care options. Contemporary Clinical Trials. 2023;133.
115 Tholemeier LN, Bresee C, De Hoedt AM, . Do medication prescription patterns follow guidelines in a cohort of women with interstitial cystitis/bladder pain syndrome? Neurourology and Urodynamics. 2022;41(5):1121–1126.35391498
116 Gregg LP, Ramsey DJ, Akeroyd JM, . Predictors, Disparities, and Facility-Level Variation: SGLT2 Inhibitor Prescription Among US Veterans With CKD. American Journal of Kidney Diseases. 2023;82(1):53–62.e1.36702340
117 Bade BC, DeRycke EC, Ramsey C, . Sex Differences in Veterans Admitted to the Hospital for Chronic Obstructive Pulmonary Disease Exacerbation. Annals of the American Thoracic Society. 2019;16(3):N.PAG-N.PAG.
118 Rinne ST, Elwy AR, Liu CF, . Implementation of guideline-based therapy for chronic obstructive pulmonary disease: Differences between men and women veterans. Chronic Respiratory Disease. 2017;14(4):385–391.28618875
119 Kaul B, Lee JS, Petersen LA, . Disparities in Antifibrotic Medication Utilization Among Veterans With Idiopathic Pulmonary Fibrosis. Chest. 2023;164(2):441–449.36801465
120 Heredia NI, Thrift AP, Ramsey DJ, . Association of Diet Quality with Metabolic (Dysfunction) Associated Fatty Liver Disease in Veterans in Primary Care. Nutrients. 2023;15(11):2598.37299561
121 Pandey N, Herrera HH, Johnson CM, . Preventative care for patients with inflammatory bowel disease in the Veterans Health Administration. Medicine. 2016;95(27):1–6.
122 MacGregor AJ, Zouris JM, Dougherty AL, Dye JL. Health Profiles of Military Women and the Impact of Combat-Related Injury. Women’s Health Issues. 2021;31(4):392–398.34059434
123 Maynard C, Nelson K, Fihn SD. Characteristics of younger women Veterans with service connected disabilities. Heliyon. 2019;5(3):e01284.30886930
124 Clifford RE, Ryan AF. The Interrelationship of Tinnitus and Hearing Loss Secondary to Age, Noise Exposure, and Traumatic Brain Injury. Ear & Hearing (01960202). 2022;43(4):1114–1124.
125 Katon JG, Shaw JG, Joyce VR, . Timeliness and Adequacy of Prenatal Care Among Department of Veterans Affairs–Enrolled Veterans: The First Step May Be the Biggest Hurdle. Women’s Health Issues. 2022;32(4):411–417.35074265
126 Friedman S, Shaw JG, Hamilton AB, . Gynecologist Supply Deserts Across the VA and in the Community. JGIM: Journal of General Internal Medicine. 2022;37:690–697.36042097
127 Dang S, Thavalathil B, Ruiz D, . A Patient Portal Intervention for Menopause Knowledge and Shared Decision-Making. Journal of Women’s Health (15409996). 2019;28(12):1614–1622.
128 Blais RK, Monson CM, Livingston WS, Maguen S. The association of disordered eating and sexual health with relationship satisfaction in female service members/veterans. Journal of Family Psychology. 2019;33(2):176–182.30702307
129 Borrero S, Callegari LS, Zhao X, . Unintended Pregnancy and Contraceptive Use Among Women Veterans: The ECUUN Study. J Gen Intern Med. 2017;32(8):900–908.28432564
130 Katon JG, Ma EW, Sayre G, . Women Veterans’ Experiences with Department of Veterans Affairs Maternity Care: Current Successes and Targets for Improvement. Women’s Health Issues. 2018;28(6):546–552.30279054
131 Gopisetty DD, Shaw JG, Gray C, . Veteran Postpartum Health: VA Care Team Perspectives on Care Coordination, Health Equity, and Trauma-Informed Care. Mil Med. 2022;16:16.
132 Mattocks KM, Kroll-Desrosiers A, Kinney R, Singer S. Understanding Maternity Care Coordination for Women Veterans Using an Integrated Care Model Approach. JGIM: Journal of General Internal Medicine. 2019;34(1):50–57.31098973
133 Mattocks KM, Kuzdeba J, Baldor R, . Implementing and Evaluating a Telephone-Based Centralized Maternity Care Coordination Program for Pregnant Veterans in the Department of Veterans Affairs. Women’s Health Issues. 2017;27(5):579–585.28709785
134 Cordasco KM, Katzburg JR, Katon JG, . Care coordination for pregnant veterans: VA’s Maternity Care Coordinator Telephone Care Program. Translational Behavioral Medicine. 2018;8(3):419–428.29800406
135 Shroff S, McNeil M, Borrero S. An Innovative Framework to Improve Teratogenic Medication Risk Counseling. Journal of Midwifery & Women’s Health. 2017;62(3):353–357.
136 Gawron LM, Pettey WBP, Redd AM, . Distance Matters: Geographic barriers to long acting reversible and permanent contraception for homeless women Veterans. J Soc Distress Homeless. 2019;28(2):139–148.31656390
137 Gawron LM, Redd A, Ying S, . Long-acting Reversible Contraception Among Homeless Women Veterans With Chronic Health Conditions: A Retrospective Cohort Study. Medical Care. 2017;55:S111–S120.28806374
138 Gawron L, Pettey WBP, Redd A, . The “Safety Net” of Community Care: Leveraging GIS to Identify Geographic Access Barriers to Texas Family Planning Clinics for Homeless Women Veterans. AMIA … Annual Symposium proceedings. AMIA Symposium. 2017;2017:750–759.29854141
139 Rosenfeld E, Callegari LS, Sileanu FE, . Racial and ethnic disparities in contraceptive knowledge among women veterans in the ECUUN study. Contraception. 2017;96(1):54–61.28322769
140 Callegari LS, Zhao X, Schwarz EB, . Racial/ethnic differences in contraceptive preferences, beliefs, and self-efficacy among women veterans. American Journal of Obstetrics & Gynecology. 2017;216(5):504.e1–504.e10.
141 MacDonald S, Hausmann LRM, Sileanu FE, . Associations Between Perceived Race-based Discrimination and Contraceptive Use Among Women Veterans in the ECUUN Study. Med Care. 2017;55 Suppl 9 Suppl 2:S43–S49.28806365
142 Judge-Golden CP, Smith KJ, Mor MK, Borrero S. Financial Implications of 12-Month Dispensing of Oral Contraceptive Pills in the Veterans Affairs Health Care System. JAMA Internal Medicine. 2019;179(9):1201–1208.31282923
143 Callegari LS, Tartaglione EV, Magnusson SL, . Understanding Women Veterans’ Family Planning Counseling Experiences and Preferences to Inform Patient-Centered Care. Women’s Health Issues. 2019;29(3):283–289.30981559
144 Wolgemuth TE, Cuddeback M, Callegari LS, . Perceived Barriers and Facilitators to Contraceptive Use Among Women Veterans Accessing the Veterans Affairs Healthcare System. Women’s Health Issues. 2020;30(1):57–63.31558352
145 Judge-Golden CP, Wolgemuth TE, Zhao X, . Agreement between Self-Reported “Ideal” and Currently Used Contraceptive Methods among Women Veterans Using the Veterans Affairs Healthcare System. Women’s Health Issues. 2020;30(4):283–291.32321666
146 Goossen RP, Summers KM, Ryan GL, . Ethnic Minority Status and Experiences of Infertility in Female Veterans. Journal of Women’s Health (15409996). 2019;28(1):63–68.
147 Callegari LS, Gray KE, Zephyrin LC, . Hysterectomy and Bilateral Salpingo-Oophorectomy: Variations by History of Military Service and Birth Cohort. Gerontologist. 2016;56 Suppl 1:S67–77.26768393
148 Bossick AS, Katon JG, Gray KE, . Concomitant Bilateral Salpingo-Oophorectomy at Hysterectomy: Differences by Race and Menopausal Status in the Veterans Affairs Health Care System, 2007–2014. Journal of Women’s Health (15409996). 2020;29(12):1513–1519.
149 Carey C, Silvestrini M, Callegari LS, . “I Wasn’t Presented With Options”: Perspectives of Black Veterans Receiving Care for Uterine Fibroids in the Veterans Health Administration. Women’s Health Issues. 2023.
150 Katon JG, Bossick A, Carey C, . Racial Disparities in Uterine Fibroid Treatment Among Veterans Using VA Health Care. Women’s Health Issues. 2023;33(4):405–413.37105835
151 Washington DL, Danz M, Jackson L, Cordasco KM. Development of Quality Indicators for the Care of Women with Abnormal Uterine Bleeding by Primary Care Providers in the Veterans Health Administration. Women’s Health Issues. 2019;29(2):135–143.30563732
152 Cordasco KM, Yuan AH, Danz MJ, . Guideline Adherence of Veterans Health Administration Primary Care for Abnormal Uterine Bleeding. Women’s Health Issues. 2019;29(2):144–152.30723059
153 Cordasco KM, Yuan AH, Danz MJ, . Veterans Health Administration Primary Care Provider Adherence to Prescribing Guidelines for Systemic Hormone Therapy in Menopausal Women. Journal for Healthcare Quality: Promoting Excellence in Healthcare. 2019;41(2):99–109.
154 Blondon M, Timmons AK, Baraff AJ, . Comparative venous thromboembolic safety of oral and transdermal postmenopausal hormone therapies among women Veterans. Menopause (10723714). 2021;28(10):1125–1129.
155 Gibson CJ, Yixia L, Jasuja GK, . Menopausal Hormone Therapy and Suicide in a National Sample of Midlife and Older Women Veterans. Medical Care. 2021;59:S70–S76.33438886
156 Blanken A, Gibson CJ, Li Y, . Racial/ethnic disparities in the diagnosis and management of menopause symptoms among midlife women veterans. Menopause (10723714). 2022;29(7):877–882.
157 Dietz NA, Mijares-Cantrell T, Acevedo D, . Women veterans and menopause: Knowledge and preferences. Women & Health. 2018;58(8):898–914.28805533
158 Breyer BN, Fang SC, Seal KH, . Sexual Health in Male and Female Iraq and Afghanistan U. S. War Veterans With and Without PTSD: Findings From the VALOR Cohort. Journal of Traumatic Stress. 2016;29(3):229–236.27128485
159 Garneau-Fournier J, Habarth J, Turchik JA. Factors Associated with Sexual Dysfunction Symptoms among Veterans who Have Experienced Military Sexual Trauma. International Journal of Sexual Health. 2018;30(1):28–41.
160 DiMauro J, Renshaw KD, Blais RK. Sexual vs. Non-sexual trauma, sexual satisfaction and function, and mental health in female veterans. Journal of Trauma & Dissociation. 2018;19(4):403–416.29601287
161 Vinekar K, Chu K, Tan GJ, . Using Primary Care Geographic Network Adequacy Metrics for VA Obstetric Referrals: a Foundation for Equitable, Timely, and Veteran-Centered Care. JGIM: Journal of General Internal Medicine. 2023;38:829–831.37340261
162 Schwarz EB, Sileanu FE, Zhao X, . Induced abortion among women veterans: data from the ECUUN study. Contraception. 2018;97(1):41–47.29055781
163 Judge-Golden C, Kroll-Desrosiers A, Mattocks K, Borrero S. Prior Abortions and Barriers to Abortion Access Reported by Pregnant Women Veterans. JGIM: Journal of General Internal Medicine. 2022;37:816–818.
164 Goyal V, Mengeling MA, Booth BM, . Lifetime Sexual Assault and Sexually Transmitted Infections Among Women Veterans. Journal of Women’s Health (15409996). 2017;26(7):745–754.
165 Coady-Fariborzian L, Anstead C. Twenty Years of Breast Reduction Surgery at a Veterans Affairs Medical Center. Fed. 2021;38(7):311–315.
166 Katon JG, Zephyrin L, Meoli A, . Reproductive Health of Women Veterans: A Systematic Review of the Literature from 2008 to 2017. Seminars in Reproductive Medicine. 2018;36(6):315–322.31003246
167 Schuttner L, Haraldsson B, Maynard C, . Factors Associated With Low-Value Cancer Screenings in the Veterans Health Administration. JAMA Network Open. 2021;4(10):e2130581–e2130581.34677595
168 Keddem S, Maier M, Gardella C, . Gonorrhea and Chlamydia Testing and Case Rates Among Women Veterans in the Veterans Health Administration. JGIM: Journal of General Internal Medicine. 2022;37:706–713.36042092
169 Marcotte LM, Deeds S, Wheat C, . Automated Opt-Out vs Opt-In Patient Outreach Strategies for Breast Cancer Screening: A Randomized Clinical Trial. JAMA Internal Medicine. 2023.
170 Reddy SM, Portnoy GA, Bathulapalli H, . Screening for Military Sexual Trauma Is Associated With Improved HIV Screening in Women Veterans. Medical Care. 2019;57(7):536–543.31194701
171 Albright DL, Landor AM, McDaniel JT, . Sexual Behaviors and Health Practices Among Student Service Members and Veterans. Archives of Sexual Behavior. 2019;48(8):2595–2604.30874977
172 Syler LB, Stobaugh CL, Foulis PR, . Cervical Cancer Screening in South Florida Veteran Population, 2014 to 2020: Cytology and High-Risk Human Papillomavirus Correlation and Epidemiology. Cureus. 2021;13(8):e17247.34540473
173 Bidassie B, Kovach A, Vallette MA, . Breast Cancer Risk Assessment and Chemoprevention Use Among Veterans Affairs Primary Care Providers: A National Online Survey. Military medicine. 2020;185(3–4):512–518.31865375
174 Sullivan-Baca E, Rehman R, Haneef Z. An Update on the Healthy Soldier Effect in U.S. Veterans. Military medicine. 2023;188(9–10):3199–3204.35652579
175 Trowbridge ER, Kim D, Barletta K, . Prevalence of positive screening test for cognitive impairment among elderly urogynecologic patients. American Journal of Obstetrics & Gynecology. 2016;215(5):663.e1–663.e6.
176 Beste LA, Keddem S, Borgerding J, . Sexually Transmitted Infection Testing in the National Veterans Health Administration Patient Cohort During the Coronavirus Disease 2019 Pandemic. Open Forum Infectious Diseases. 2022;9(12).
177 Beste LA, Maier MM, Borgerding J, . Testing Practices and Incidence of Chlamydial and Gonococcal Infection in the Veterans Health Administration, 2009-2019. Clinical Infectious Diseases. 2021;73(9):E3235–E3243.32975293
178 Monty GR, Benson SK, Deeds SA, . “We Are Working Harder, Not Smarter”: A Qualitative Inquiry into Care Coordination for Department of Veterans Affairs Mammograms Referred to the Community. Women’s Health Issues. 2023;33(4):414–421.36528428
179 Bean-Mayberry B, Moreau J, Hamilton AB, . Cardiovascular Risk Screening among Women Veterans: Identifying Provider and Patient Barriers and Facilitators to Develop a Clinical Toolkit. Women’s Health Issues. 2022;32(3):284–292.35115227
180 Hardin S, Vogt D, Smith BN, . Male and Female Veterans’ Preferences for Eating Disorders Screening. JGIM: Journal of General Internal Medicine. 2022;37:819–822.36042094
181 Jeon-Slaughter H, Chen X, Ramanan B, Tsai S. Assessing performance of the veterans affairs women cardiovascular risk model in predicting a short-term risk of cardiovascular disease incidence using united states veterans affairs covid-19 shared data. International Journal of Environmental Research and Public Health. 2021;18(19).
182 Sternke LM, Serpi T, Spiro A, . Assessment of a Revised Wartime Experiences Scale for Vietnam-Era Women: The Health of Vietnam-Era Women’s Study (HealthViEWS). Women’s Health Issues. 2017;27(4):471–477.28438646
183 Bovin MJ, Kimerling R, Weathers FW, . Diagnostic Accuracy and Acceptability of the Primary Care Posttraumatic Stress Disorder Screen for the Diagnostic and Statistical Manual of Mental Disorders (Fifth Edition) Among US Veterans. JAMA Network Open. 2021;4(2):e2036733–e2036733.33538826
184 Batch BC, Brown CS, Goldstein KM, . Women Veterans Experience with the VA MOVE! Weight Management Program. Womens Health Rep (New Rochelle). 2020;1(1):65–72.33786475
185 Zenk SN, Tarlov E, Wing C, . Does the built environment influence the effectiveness of behavioral weight management interventions? Preventive Medicine. 2019;126:N.PAG-N.PAG.
186 Zenk SN, Tarlov E, Wing C, . Long-term weight loss effects of a behavioral weight management program: Does the community food environment matter? International Journal of Environmental Research and Public Health. 2018;15(2).
187 Zenk SN, Tarlov E, Powell LM, . Weight and Veterans’ Environments Study (WAVES) I and II: Rationale, Methods, and Cohort Characteristics. American Journal of Health Promotion. 2018;32(3):779–794.29214851
188 Tarlov E, Silva A, Wing C, . Neighborhood Walkability and BMI Change: A National Study of Veterans in Large Urban Areas. Obesity (19307381). 2020;28(1):46–54.
189 Powell LM, Jones K, Duran AC, . The price of ultra-processed foods and beverages and adult body weight: Evidence from U.S. veterans. Economics and Human Biology. 2019;34:39–48.31204255
190 Whitbourne SB, Nguyen XT, Song RJ, . Million Veteran Program’s response to COVID-19: Survey development and preliminary findings. PLoS One. 2022;17(4):e0266381.35468170
191 Nguyen XT, Quaden RM, Song RJ, . Baseline Characterization and Annual Trends of Body Mass Index for a Mega-Biobank Cohort of US Veterans 2011-2017. J Health Res Rev Dev Ctries. 2018;5(2):98–107.33117892
192 Washington DL, Gray K, Hoerster KD, . Trajectories in Physical Activity and Sedentary Time Among Women Veterans in the Women’s Health Initiative. The Gerontologist. 2016;56:S27–S39.26768390
193 Kreyenbuhl J, Lucksted A, Despeaux K, Sykes VM. Understanding Women Veterans’ Experiences With and Management of Weight Gain From Medications for Serious Mental Illness: A Qualitative Study. Psychiatric Rehabilitation Journal. 2019;42(3):238–245.30920258
194 Goldstein KM, Zullig LL, Oddone EZ, . Understanding women veterans’ preferences for peer support interventions to promote heart healthy behaviors: A qualitative study. Preventive Medicine Reports. 2018;10:353–358.29868391
195 Hamilton AB, Finley EP, Bean-Mayberry B, . Enhancing Mental and Physical Health of Women through Engagement and Retention (EMPOWER) 2.0 QUERI: study protocol for a cluster-randomized hybrid type 3 effectiveness-implementation trial. Implement. 2023;4(1):23.
196 Bernstein E, DeRycke EC, Han L, . Racial, Ethnic, and Rural Disparities in US Veteran COVID-19 Vaccine Rates. AJPM Focus. 2023:100094.37362395
197 Mattocks KM, Kroll-Desrosiers A, Moore Simas TA, . Examining Pregnant Veterans’ Acceptance and Beliefs Regarding the COVID-19 Vaccine. JGIM: Journal of General Internal Medicine. 2022;37:671–678.
198 Johnson NL, Steffensmeier KS, Garvin LA, . “It Made Me Not Want to See him…”: The Role of Patient-Provider Communication in Influencing Rural-Dwelling Women Veterans’ Motivation to Seek Health Care for Managing Chronic Pain. Health Commun. 2023:1–14.33947309
199 Buttner MM, Godfrey KM, Floto E, . Combat exposure and pain in male and female Afghanistan and Iraq veterans: The role of mediators and moderators. Psychiatry Research. 2017;257:7–13.28709118
200 Rogers RG, Clark EA, Murata E, . Military Sexual Trauma in Female Veterans is Associated With Chronic Pain Conditions. Military Medicine. 2017;182(9):e1895–e1899.28885952
201 Arout CA, Sofuoglu M, Bastian LA, Rosenheck RA. Gender Differences in the Prevalence of Fibromyalgia and in Concomitant Medical and Psychiatric Disorders: A National Veterans Health Administration Study. Journal of Women’s Health (15409996). 2018;27(8):1035–1044.
202 Boyer TL, Blosnich JR, Hubbard CC, . Comparing Outpatient Opioids, High-Risk Prescribing, and Opioid Poisoning Between Transgender and Cisgender Veterans: A Cross-sectional Analysis. American Journal of Preventive Medicine. 2022;63(2):168–177.35396161
203 Vigil JM, Coulombe P, Alcock J, . How nurse gender influences patient priority assignments in US emergency departments. Pain. 2017;158(3):377–382.28187101
204 Driscoll MA, Knobf MT, Higgins DM, . Patient Experiences Navigating Chronic Pain Management in an Integrated Health Care System: A Qualitative Investigation of Women and Men. Pain Medicine. 2018;19:S19–S29.30203009
205 Hadlandsmyth K, Driscoll MA, Mares JG, . Rurality impacts pain care for female veterans similarly to male veterans. Journal of Rural Health. 2023;39(2):313–319.
206 Lehavot K, Rillamas-Sun E, Weitlauf J, . Mortality in Postmenopausal Women by Sexual Orientation and Veteran Status. The Gerontologist. 2016;56:S150–S162.26768389
207 Wong MS, Hoggatt KJ, Steers WN, . Racial/Ethnic Disparities in Mortality Across the Veterans Health Administration. Health Equity. 2019;3(1):99–108.31289768
208 Bernstein J, Lee A, Xi IL, Ahn J. Estimating Median Survival Following Hip Fracture Among Geriatric Females: (100 - Patient Age) / 4. Cureus. 2022;14(6):e26299.35911335
209 Orkaby AR, Nussbaum L, Ho YL, . The Burden of Frailty Among U.S. Veterans and Its Association With Mortality, 2002-2012. The journals of gerontology. Series A, Biological sciences and medical sciences. 2019;74(8):1257–1264.30307533
210 Washington DL, Bird CE, LaMonte MJ, . Military Generation and Its Relationship to Mortality in Women Veterans in the Women’s Health Initiative. The Gerontologist. 2016;56:S126–S137.26768386
211 Cho J, Copeland LA, Stock EM, . Protective and Risk Factors for 5-Year Survival in the Oldest Veterans: Data from the Veterans Health Administration. Journal of the American Geriatrics Society. 2016;64(6):1250–1257.27321603
212 Gonsoulin ME, Durazo-Arvizu RA, Goldstein KM, . A Health Profile of Senior-Aged Women Veterans: A Latent Class Analysis of Condition Clusters. Innov Aging. 2017;1(2):01.
213 Howard JT, Janak JC, Santos-Lozada AR, . Telomere shortening and accelerated aging in US military veterans. International Journal of Environmental Research and Public Health. 2021;18(4):1–13.
214 Weitlauf JC, Cypel YS, Davey VJ. Mortality of Women Vietnam War–Era Veterans. Women’s Health Issues. 2023;33(4):391–404.37088602
215 Dinesh D, Shao Q, Palnati M, . The epidemiology of mild cognitive impairment, Alzheimer’s disease and related dementia in U.S. veterans. Alzheimer’s and Dementia. 2023;19(9):3977–3984.
216 Bahorik A, Bobrow K, Hoang T, Yaffe K. Increased risk of dementia in older female US veterans with alcohol use disorder. Addiction. 2021;116(8):2049–2055.33449402
217 Kornblith E, Peltz CB, Xia F, . Sex, race, and risk of dementia diagnosis after traumatic brain injury among older veterans. Neurology. 2020;95(13):E1768–E1775.32887780
218 Yaffe K, Lwi SJ, Hoang TD, . Military-related risk factors in female veterans and risk of dementia. Neurology. 2019;92(3):126–126.
219 Cheng Y, Zamrini E, Faselis C, . Cardiorespiratory fitness and risk of Alzheimer’s disease and related dementias among American veterans. Alzheimer’s and Dementia. 2023.
220 Padula CB, Weitlauf JC, Rosen AC, . Longitudinal Cognitive Trajectories of Women Veterans from the Women’s Health Initiative Memory Study. The Gerontologist. 2016;56(1):115–125.26615021
221 Varilek BM, Da Rosa P. Analysis of Palliative Care Knowledge and Symptom Burden Among Female Veterans With Serious Illness: A Cross-Sectional Study. The American journal of hospice & palliative care. 2023:10499091231187341.
222 West SK, Peek B, Al-Achi A, LeCompte D. Advance Care Directive Preferences in Women Veterans: A Snapshot. Omega. 2022:302228221130115.
223 Varilek BM, Isaacson MJ. Female Veteran Use of Palliative and Hospice Care: A Scoping Review. Military Medicine. 2021;186(11/12):1100–1105.33512462
224 Tabio L, Walker RL, Crane PK, . Association of Lifetime TBI and Military Employment with Late Life ADL Functioning: A Population-Based Prospective Cohort Study. Archives of Physical Medicine & Rehabilitation. 2021;102(12):2316–2316.34283993
225 LaCroix AZ, Rillamas-Sun E, Woods NF, . Aging Well Among Women Veterans Compared With Non-Veterans in the Women’s Health Initiative. Gerontologist. 2016;56 Suppl 1:S14–26.26768388
226 Jeon CY, Kim S, Lin YC, . Prediction of Pancreatic Cancer in Diabetes Patients with Worsening Glycemic Control. Cancer Epidemiology Biomarkers and Prevention. 2022;31(1):242–253.
227 Demb J, Liu L, Murphy CC, . Young-onset colorectal cancer risk among individuals with iron-deficiency anaemia and haematochezia. Gut. 2021;70(8):1529–1537.
228 Gaffey AE, Han L, Ramsey CM, . Post-9/11 deployment history and the incidence of breast cancer among women Veterans. Annals of Epidemiology. 2023;77:98–102.36470323
229 Hull LE, Lynch JA, Berse BB, . Clinical Impact of 21-Gene Recurrence Score Test Within the Veterans Health Administration: Utilization and Receipt of Guideline-Concordant Care. Clinical Breast Cancer. 2018;18(2):135–143.29306660
230 Johnson KE, Siewert KM, Klarin D, . The relationship between circulating lipids and breast cancer risk: A Mendelian randomization study. PLoS Medicine. 2020;17(9).
231 Zullig LL, Sims KJ, McNeil R, . Cancer Incidence Among Patients of the U.S. Veterans Affairs Health Care System: 2010 Update. Military medicine. 2017;182(7):e1883–e1891.
232 Zullig LL, Goldstein KM, Sims KJ, . Cancer Among Women Treated in the Veterans Affairs Healthcare System. Journal of Women’s Health (15409996). 2019;28(2):268–275.
233 Oppegaard KR, Dunn LB, Kober KM, . Gender Differences in the Use of Engagement and Disengagement Coping Strategies in Patients With Cancer Receiving Chemotherapy. Oncology Nursing Forum. 2020;47(5):586–594.32830804
234 Iverson KM, Stolzmann KL, Brady JE, . Integrating Intimate Partner Violence Screening Programs in Primary Care: Results from a Hybrid-II Implementation-Effectiveness RCT. American Journal of Preventive Medicine. 2023;65(2):251–260.37031032
235 Wilson LC. The Prevalence of Military Sexual Trauma: A Meta-Analysis. Trauma, Violence & Abuse. 2018;19(5):584–597.
236 Pulverman CS, Christy AY, Kelly UA. Military Sexual Trauma and Sexual Health in Women Veterans: A Systematic Review. Sexual Medicine Reviews. 2019;7(3):393–407.31029620
237 Katz LS. Delivering brief warrior renew over video teleconferencing to women veterans with military sexual trauma: A pragmatic trial. Psychological services. 2023.
238 Gilmore AK, Davis MT, Grubaugh A, . “Do you expect me to receive PTSD care in a setting where most of the other patients remind me of the perpetrator?”: Home-based telemedicine to address barriers to care unique to military sexual trauma and veterans affairs hospitals. Contemporary Clinical Trials. 2016;48:59–64.26992740
239 Gilmore AK, Lopez C, Muzzy W, . Emotion Dysregulation Predicts Dropout from Prolonged Exposure Treatment among Women Veterans with Military Sexual Trauma-Related Posttraumatic Stress Disorder. Women’s Health Issues. 2020;30(6):462–469.32843240
240 Sparrow K, Kwan J, Howard L, . Systematic review of mental health disorders and intimate partner violence victimisation among military populations. Social Psychiatry & Psychiatric Epidemiology. 2017;52(9):1059–1080.28748307
241 Iverson KM, Danitz SB, Shayani DR, . Recovering From Intimate Partner Violence Through Strengths and Empowerment: Findings From a Randomized Clinical Trial. J Clin Psychiatry. 2021;83(1):23.
242 Danan ER, Brunner J, Bergman A, . The Relationship Between Sexual Assault History and Cervical Cancer Screening Completion Among Women Veterans in the Veterans Health Administration. Journal of Women’s Health (15409996). 2022;31(7):1040–1047.
243 Vander Weg MW, Sadler AG, Abrams TE, . Lifetime History of Sexual Assault and Emergency Department Service Use among Women Veterans. Women’s Health Issues. 2020;30(5):374–383.32571623
244 Edmonds SW, Mengeling MA, Syrop CH, . Associations Between Sexual Assault and Reproductive and Family Planning Behaviors and Outcomes in Female Veterans. Obstetrics & Gynecology. 2021;137(3):461–470.33543896
245 Dognin J, Sedlander E, Jay M, Ades V. Group education sessions for women veterans who experienced sexual violence: Qualitative findings. Families, Systems & Health: The Journal of Collaborative Family HealthCare. 2017;35(3):360–372.
246 Brandt CA, Workman TE, Farmer MM, . Documentation of Screening for Firearm Access by Healthcare Providers in the Veterans Healthcare System: A Retrospective Study. West J Emerg Med. 2021;22(3):525–532.34125022
247 Morgan NR, Aronson KR, Perkins DF, . The interaction of exposure to adverse childhood and combat experiences on the current mental health of new post-9/11 veterans. Journal of community psychology. 2022;50(1):204–220.33624843
248 Murdoch M, Kehle-Forbes SM, Partin MR. Changes in affect after completing a mailed survey about trauma: two pre- and post-test studies in former disability applicants for posttraumatic stress disorder. BMC Medical Research Methodology. 2017;17:1–9.28056835
249 Zhao Z, Serier KN, Smith BN, . Gender similarities and differences in associations between weight discrimination, shape/weight concerns, and eating disorder symptoms among post-9/11 veterans. Eating Behaviors. 2023;51.
250 Stanton K, Creech SK, Snyder DK, McKee GB. Combat exposure and mental health outcomes: The incremental impact of nonsexual harassment on women veterans. Psychological Trauma: Theory, Research, Practice & Policy. 2022;14(4):597–604.34242046
251 Mattocks K, Casares J, Brown A, . Women Veterans’ Experiences with Perceived Gender Bias in U.S. Department of Veterans Affairs Specialty Care. Women’s Health Issues. 2020;30(2):113–119.31735581
252 Klap R, Darling JE, Hamilton AB, . Prevalence of Stranger Harassment of Women Veterans at Veterans Affairs Medical Centers and Impacts on Delayed and Missed Care. Women’s Health Issues. 2019;29(2):107–115.30686577
253 MacDonald S, Judge-Golden C, Borrero S, . Experiences of Perceived Gender-based Discrimination Among Women Veterans: Data From the ECUUN Study. Medical Care. 2020;58(5):483–490.32000171
254 Dyer KE, Potter SJ, Hamilton AB, . Gender Differences in Veterans’ Perceptions of Harassment on Veterans Health Administration Grounds. Women’s Health Issues. 2019;29:S83–S93.31253247
255 Cannedy S, Dyer KE, Oishi A, . Managers’ and Leaders’ Perceptions of Sexual and Gender-Based Public Harassment in the Veterans Health Administration. Women’s Health Issues. 2022;32(4):395–401.35277335
256 Fenwick KM, Potter SJ, Klap R, . Staff and Patient Perspectives on Bystander Intervention Training to Address Patient-Initiated Sexual Harassment in Veterans Affairs Healthcare Settings. Women’s Health Issues. 2021;31(6):576–585.34452824
257 Fenwick KM, Golden RE, Frayne SM, . Women Veterans’ Experiences of Harassment and Perceptions of Veterans Affairs Health Care Settings During a National Anti-Harassment Campaign. Women’s Health Issues. 2021;31(6):567–575.34238668
258 Reddy MK, Murdoch M. Does the Factor Structure of Military Sexual Stressors in Men Correspond to Women’s? A Confirmatory Factor Analysis Using the Sexual Harassment Inventory. Military Medicine. 2016;181(2):161–166.26837085
259 Lynch KE, Viernes B, Schliep KC, . Variation in Sexual Orientation Documentation in a National Electronic Health Record System. LGBT Health. 2021;8(3):201–208.33625876
260 Trentalange M, Bielawski M, Murphy TE, . Patient Perception of Enough Time Spent With Provider Is a Mechanism for Improving Women Veterans’ Experiences With VA Outpatient Health Care. Evaluation & the Health Professions. 2016;39(4):460–474.26908572
261 Yano EM, Darling JE, Hamilton AB, . Cluster randomized trial of a multilevel evidence-based quality improvement approach to tailoring VA Patient Aligned Care Teams to the needs of women Veterans. Implementation Science. 2016;11(1):1–14.26727969
262 Hamilton AB, Brunner J, Cain C, . Engaging multilevel stakeholders in an implementation trial of evidence-based quality improvement in VA women’s health primary care. Translational Behavioral Medicine. 2017;7(3):478–485.28585163
263 Gawron LM, Young J, Yang S, . Women’s Health Provider Perspectives on Reproductive Services Provision in the Veterans Health Administration. Southern Medical Journal. 2023;116(2):181–187.36724533
264 Chanfreau-Coffinier C, Gordon HS, Schweizer CA, . Mental Health Screening Results Associated with Women Veterans’ Ratings of Provider Communication, Trust, and Care Quality. Women’s Health Issues. 2018;28(5):430–438.30017475
265 Carlson GC, Than CT, Rose D, . What Drives Women Veterans’ Trust in VA Healthcare Providers? Women’s Health Issues. 2022;32(5):499–508.35367107
266 Jones AL, Fine MJ, Taber PA, . National Media Coverage of the Veterans Affairs Waitlist Scandal: Effects on Veterans’ Distrust of the VA Health Care System. Medical Care. 2021;59:S322–S326.33976083
267 Shamaskin-Garroway AM, Knobf MT, Adams LJ, Haskell SG. “I Think It’s Pretty Much the Same, as It Should Be”: Perspectives of Inpatient Care Among Women Veterans. Qualitative Health Research. 2018;28(4):600–609.29231129
268 Mattocks KM, Yano EM, Brown A, . Examining Women Veteran’s Experiences, Perceptions, and Challenges With the Veterans Choice Program. Medical Care. 2018;56(7):557–560.29768310
269 Cannedy S, McCoy M, Oishi K, . Coping with disruptive patients: Perspectives of primary care employees. Work (Reading, Mass.). 2023.
270 Chuang E, Brunner J, Mak S, . Challenges with Implementing a Patient-Centered Medical Home Model for Women Veterans. Women’s Health Issues. 2017;27(2):214–220.28063848
271 Meredith LS, Wang Y, Okunogbe A, . Attitudes, Practices, and Experiences with Implementing a Patient-Centered Medical Home for Women Veterans. Women’s Health Issues. 2017;27(2):221–227.28087130
272 Vincent A, Ballard I, Farkas KJ. Mind Full or Mindful? A Cohort Study of Equine-Facilitated Therapy for Women Veterans. Journal of Creativity in Mental Health. 2023;18(3):367–382.
273 Shipherd JC, Kauth MR, Firek AF, . Interdisciplinary Transgender Veteran Care: Development of a Core Curriculum for VHA Providers. Transgender Health. 2016;1(1):54–62.29159298
274 Sanders AM, Golden RE, Kolehmainen C, . Implementation experience and initial assessment of a rural women’s health training program in support of the U.S. Department of Veterans Affairs as a learning health system. Learn. 2022;6(4):e10334.
275 Schwartz R, Frayne SM, Friedman S, . Retaining VA Women’s Health Primary Care Providers: Work Setting Matters. J Gen Intern Med. 2021;36(3):614–621.33063204
276 Farkas AH, Merriam S, Frayne S, . Retaining Providers with Women’s Health Expertise: Decreased Provider Loss Among VHA Women’s Health Faculty Development Program Attendees. JGIM: Journal of General Internal Medicine. 2022;37:786–790.36042098
277 Fried D, Rajan M, Tseng C, Helmer D. Total and Per-Patient Fiscal Year 2013 VA Disability Compensation and Medical Care Expenditures and Utilization for Vietnam Era Veterans with Service-Connected Disabilities. Journal of Military & Veterans’ Health. 2021;29(1):15–25.
278 Blosnich JR, Cashy J, Gordon AJ, . Using clinician text notes in electronic medical record data to validate transgender-related diagnosis codes. Journal of the American Medical Informatics Association. 2018;25(7):905–908.29635362
279 Nik-Ahd F, Waller J, De Hoedt AM, . Seeing the unseen: how can we best identify transgender women within the Veterans Affairs healthcare system’s electronic medical record? The journal of sexual medicine. 2023;20(4):559–567.36814112
280 Wolfe HL, Reisman JI, Yoon SS, . Validating Data-Driven Methods for Identifying Transgender Individuals in the Veterans Health Administration of the US Department of Veterans Affairs. American Journal of Epidemiology. 2021;190(9):1928–1934.34467408
281 Blosnich JR, Boyer TL. Concordance of Data About Sex From Electronic Health Records and the National Death Index: Implications for Transgender Populations. Epidemiology. 2022;33(3):383–385.35067566
282 Danan ER, Ullman K, Klap RS, . Evidence Map: Reporting of Results by Sex or Gender in Randomized, Controlled Trials with Women Veteran Participants (2008 to 2018). Women’s Health Issues. 2019;29:S112–S120.31253234
283 Goldstein KM, Duan-Porter W, Alkon A, . Enrollment and Retention of Men and Women in Health Services Research and Development Trials. Womens Health Issues. 2019;29 Suppl 1:S121–S130.31253236
284 Fan CA, Upham M, Beaver K, . Recruiting Sexual and Gender Minority Veterans for Health Disparities Research: Recruitment Protocol of a Web-Based Prospective Cohort Study. JMIR Res Protoc. 2023;12:e43824.37782536
285 Chrystal JG, Dyer KE, Gammage CE, . Increasing Engagement of Women Veterans in Health Research. JGIM: Journal of General Internal Medicine. 2022;37(1):42–49.35349014
286 Whitbourne SB, Li Y, Brewer JVV, . Overview of Efforts to Increase Women Enrollment in the Veterans Affairs Million Veteran Program. Health Equity. 2023;7(1):324–332.37284530
287 Golden RE, Klap R, Carney DV, . Promoting learning health system feedback loops: Experience with a VA practice-based research network card study: VA Card Study Promotes Learning Health System. Healthcare. 2021;8.
288 Flike K, Byrne T. Systematic review of access to healthcare and social services among US women Veterans experiencing homelessness. Women’s Health (17455057). 2023:1–17.
289 Blosnich JR, Rodriguez KL, Hruska KL, . Utilization of the Veterans Affairs’ Transgender E-consultation Program by Health Care Providers: Mixed-Methods Study. JMIR Med Inform. 2019;7(1):e11695.31344672
290 Chrystal JG, Frayne S, Dyer KE, . Women Veterans’ Attrition from the VA Health Care System. Women’s Health Issues. 2022;32(2):182–193.34972600
291 Narain K, Bean-Mayberry B, Washington DL, . Access to Care and Health Outcomes Among Women Veterans Using Veterans Administration Health Care: Association With Food Insufficiency. Women’s Health Issues. 2018;28(3):267–272.29475630
292 Baldomero AK, Kunisaki KM, Wendt CH, . Drive Time and Receipt of Guideline-Recommended Screening, Diagnosis, and Treatment. JAMA Network Open. 2022;5(11):e2240290–e2240290.36331503
293 Davies ML, Goffman RM, May JH, . Large-Scale No-Show Patterns and Distributions for Clinic Operational Research. Healthcare (Basel). 2016;4(1):16.27417604
294 Copeland LA, Finley EP, Vogt D, . Gender Differences in Newly Separated Veterans’ Use of Healthcare. American Journal of Managed Care. 2020;26(3):97–104.32181624
295 Weitlauf JC, Ortiz A, Kroll-Desrosiers AR, . Characterization and Comparison of Physical and Mental Health Profiles and Department of Veterans Affairs Health Care Utilization Patterns among Operation Iraqi Freedom/Operation Enduring Freedom Women Veterans in Puerto Rico versus the United States. Women’s Health Issues. 2020;30(1):49–56.31796346
296 Haskell SG, Han L, Abel EA, . Sex Differences in Use of a Clinical Complexity Measure to Predict Primary Care Utilization. Journal of Women’s Health (15409996). 2022;31(1):71–78.
297 Moore CL, Wang N, Johnson J, . Return-to-Work Outcome Rates of African American Versus White Veterans Served by State Vocational Rehabilitation Agencies. Rehabilitation Counseling Bulletin. 2016;59(3):158–171.
298 Williams L, Pavlish C, Maliski S, Washington D. Clearing Away Past Wreckage: A Constructivist Grounded Theory of Identity and Mental Health Access by Female Veterans. Advances in Nursing Science. 2018;41(4):327–339.30383561
299 Murdoch M, Spoont MR, Sayer NA, . Reversals in initially denied Department of Veterans Affairs’ PTSD disability claims after 17 years: a cohort study of gender differences. BMC Women’s Health. 2021;21(1):1–8.33388051
300 Tsai J, Pietrzak RH, Szymkowiak D. The Problem of Veteran Homelessness: An Update for the New Decade. American Journal of Preventive Medicine. 2021;60(6):774–780.33583678
301 Montgomery AE, Dichter ME, Thomasson AM, Roberts CB. Services Receipt Following Veteran Outpatients’ Positive Screen for Homelessness. American Journal of Preventive Medicine. 2016;50(3):336–343.26564329
302 Short M, Felder S, Garland Baird L, Gamble B. Female Veterans’ risk factors for homelessness: A scoping review. Journal of Military, Veteran & Family Health. 2023;9(4):29–38.
303 Brignone E, Gundlapalli AV, Blais RK, . Differential Risk for Homelessness Among US Male and Female Veterans With a Positive Screen for Military Sexual Trauma. JAMA Psychiatry. 2016;73(6):582–589.27096847
304 Liu S, Silanskis E, Knetig J, Holliday R. Intimate Partner Violence Screening for Veterans Accessing Homelessness Services. Journal of Aggression, Maltreatment & Trauma. 2023;32(7/8):989–1004.
305 Kondo K, Low A, Everson T, . Health Disparities in Veterans: A Map of the Evidence. Med Care. 2017;55 Suppl 9 Suppl 2:S9–S15.28806361
306 Nillni YI, Horenstein A, McClendon J, . The impact of perceived everyday discrimination and income on racial and ethnic disparities in PTSD, depression, and anxiety among veterans. PLoS One. 2023;18(9 September).
307 Blosnich JR, Montgomery AE, Taylor LD, Dichter ME. Adverse social factors and all-cause mortality among male and female patients receiving care in the Veterans Health Administration. Preventive Medicine. 2020;141:N.PAG-N.PAG.
308 Gaska KA, Kimerling R. Patterns of Adverse Experiences and Health Outcomes Among Women Veterans. American Journal of Preventive Medicine. 2018;55(6):803–811.30454638
309 Tynan M, Wooldridge JS, Rossi F, . Latent Class Patterns of Adverse Childhood Experiences and Their Relationship to Veteran Status and Sex in the National Epidemiologic Survey of Alcohol and Related Conditions Wave III. Military Medicine. 2022;187(3/4):304–312.34977940
310 Doucette CE, Morgan NR, Aronson KR, . The Effects of Adverse Childhood Experiences and Warfare Exposure on Military Sexual Trauma Among Veterans. Journal of Interpersonal Violence. 2023;38(3/4):3777–3805.35962589
311 Masheb RM, Sala M, Marsh AG, . Associations between adverse childhood experiences and weight, weight control behaviors and quality of life in Veterans seeking weight management services. Eating Behaviors. 2021;40:N.PAG-N.PAG.
312 Wooldridge JS, Bosch J, Crawford JN, . Relationships among adverse childhood experiences, posttraumatic stress disorder symptom clusters, and health in women veterans. Stress & Health: Journal of the International Society for the Investigation of Stress. 2020;36(5):596–605.32369234
313 Aronson KR, Perkins DF, Morgan NR, . The Impact of Adverse Childhood Experiences (ACEs) and Combat Exposure on Mental Health Conditions Among New Post-9/11 Veterans. Psychological Trauma: Theory, Research, Practice & Policy. 2020;12(7):698–706.32614200
314 Scoglio AAJ, Molnar BE, Lincoln AK, . Social support over time for men and women veterans with and without complex trauma histories. Psychological services. 2023;20(3):516–524.35201813
315 McCall JD, Tsai J. Characteristics and Health Needs of Veterans in Jails and Prisons: What We Know and Do Not Know about Incarcerated Women Veterans. Women’s Health Issues. 2018;28(2):172–180.29217313
316 Narain K, Jeffers KS, Bean-Mayberry B, . The Association of Food Insufficiency with Patient Activation Among Women Veterans Using Veterans Administration Healthcare: a Cross-Sectional Analysis. J Gen Intern Med. 2018;33(9):1417–1418.29766383
317 Hill BJ, Bouris A, Barnett JT, Walker D. Fit to Serve? Exploring Mental and Physical Health and Well-Being among Transgender Active-Duty Service Members and Veterans in the U.S. Military. Transgender Health. 2016;1(1):4–11.29159293
318 Carter A, Borrero S, Wessel C, . Racial and Ethnic Health Care Disparities Among Women in the Veterans Affairs Healthcare System: A Systematic Review. Women’s Health Issues. 2016;26(4):401–409.27138241
319 Hawkins BL, Crowe BM. Contextual Facilitators and Barriers of Community Reintegration Among Injured Female Military Veterans: A Qualitative Study. Archives of Physical Medicine & Rehabilitation. 2018;99:S65–S71.28866010
320 Krengel M, Sullivan K, Heboyan V, . Neurotoxicant exposures and rates of Chronic Multisymptom Illness and Kansas Gulf War Illness criteria in Gulf War deployed women veterans. Life Sciences. 2021;280.
321 Shinawi MS, Alpern R, Toomey R, . Birth Defects Among 788 Children Born to Gulf War Veterans Based on Physical Examination. Journal of Occupational & Environmental Medicine. 2019;61(4):263–270.30489351
322 Barth SK, Kang HK, Bullman T. All-CauseMortality Among US Veterans of the Persian Gulf War: 13-Year Follow-up. Public Health Reports. 2016;131(6):822–830.28123229
323 Sullivan K, Krengel M, Heboyan V, . Prevalence and Patterns of Symptoms Among Female Veterans of the 1991 Gulf War Era: 25 Years Later. Journal of Women’s Health (15409996). 2020;29(6):819–826.
324 Mancuso AC, Mengeling MA, Holcombe A, Ryan GL. Lifetime infertility and environmental, chemical, and hazardous exposures among female and male US veterans. American Journal of Obstetrics & Gynecology. 2022;227(5):744.e1–744.e12.
325 Dursa EK, Barth SK, Porter BW, Schneiderman AI. Health Status of Female and Male Gulf War and Gulf Era Veterans: A Population-Based Study. Women’s Health Issues. 2019;29:S39–S46.31253241
326 Services VsAaA. H.R.3967 - Honoring our PACT Act of 2022. 2022.
327 Frayne SM PC, Saechao F, Maisel NC, Friedman SA, Finlay A, Berg E, Balasubramanian V, Dally SK, Ananth L, Romodan Y, Lee J, Iqbal S, Hayes PM, Zephyrin L, Whitehead A, Torgal A, Katon JG, Haskell S. Sourcebook: Women Veterans in the Veterans Health Administration. Volume 3: Sociodemographics, Utilization, Costs of Care, and Health Profile. US Department of Veterans Affairs; 2014.
328 Goldstein K. Examining Sex/Gender Differences in Veterans Affairs Research. Women’s Health Issues. 2019;29:S1–S130.31253232
329 Hoffmire CA, Denneson LM, Monteith LL, . Accelerating Research on Suicide Risk and Prevention in Women Veterans Through Research-Operations Partnerships. Med Care. 2021;59:S11–S16.33438877
330 Hamilton AB, Schwarz EB, Thomas HN, Goldstein KM. Moving Women Veterans’ Health Research Forward: a Special Supplement. J Gen Intern Med. 2022;37(Suppl 3):665–667.36042081
331 Meffert BN, Morabito DM, Sawicki DA, . US Veterans Who Do and Do Not Utilize Veterans Affairs Health Care Services: Demographic, Military, Medical, and Psychosocial Characteristics. Prim Care Companion CNS Disord. 2019;21(1).
332 Oxman MN, Levin MJ, Johnson GR, . A vaccine to prevent herpes zoster and postherpetic neuralgia in older adults. N Engl J Med. 2005;352(22):2271–84.15930418
333 House TW. The White House Initiative on Women’s Health Research. 2024.
334 Webermann AR, Relyea MR, Portnoy GA, . The Role of Unit and Interpersonal Support in Military Sexual Trauma and Posttraumatic Stress Disorder Symptoms. Journal of Interpersonal Violence. 2023;38(15/16):9514–9535.37005795
335 Higgins DM, Han L, Kerns RD, . Risk Factors Associated with Healthcare Utilization for Spine Pain. Pain Medicine. 2022;23(8):1423–1433.34999899
336 Kroll-Desrosiers A, Kinney RL, Marteeny V, Mattocks KM. Exploring the Acceptability of Expanded Perinatal Depression Care Practices Among Women Veterans. JGIM: Journal of General Internal Medicine. 2022;37:762–769.36042083
337 Quinn DA, Sileanu FE, Borrero S, Callegari LS. Reproductive health services: A missed opportunity in VA primary care? Contraception. 2023;120.
338 Callegari LS, Mahorter SS, Benson SK, . Perceived Contraceptive Counseling Quality Among Veterans Using VA Primary Care: Data from the ECUUN Study. JGIM: Journal of General Internal Medicine. 2022;37:698–705.36042079
339 Domecq JP, Prutsky G, Elraiyah T, . Patient engagement in research: a systematic review. BMC Health Serv Res. 2014;14:89.24568690
340 O’Mara-Eves A, Brunton G, Oliver S, . The effectiveness of community engagement in public health interventions for disadvantaged groups: a meta-analysis. BMC Public Health. 2015;15:129.25885588
341 Affairs USDoV. Growing Rural Outreach through Veteran Engagement (GROVE). Vol. 2024.
342 Acierno R, Jaffe AE, Gilmore AK, . A randomized clinical trial of in-person vs. home-based telemedicine delivery of Prolonged Exposure for PTSD in military sexual trauma survivors. Journal of Anxiety Disorders. 2021;83.
343 Castillo DT, Chee CL, Nason E, . Group-Delivered Cognitive/Exposure Therapy for PTSD in Women Veterans: A Randomized Controlled Trial. Psychological Trauma: Theory, Research, Practice & Policy. 2016;8(3):404–412.26854355
344 Creech SK, Pulverman CS, Kahler CW, . Computerized Intervention in Primary Care for Women Veterans with Sexual Assault Histories and Psychosocial Health Risks: a Randomized Clinical Trial. JGIM: Journal of General Internal Medicine. 2022;37(5):1097–1107.34013470
345 Gobin RL, Strauss JL, Golshan S, . Gender Differences in Response to Acceptance and Commitment Therapy Among Operation Enduring Freedom/Operation Iraqi Freedom/Operation New Dawn Veterans. Women’s Health Issues. 2019;29(3):267–273.31060890
346 Kelly U, Haywood T, Segell E, Higgins M. Trauma-Sensitive Yoga for Post-Traumatic Stress Disorder in Women Veterans who Experienced Military Sexual Trauma: Interim Results from a Randomized Controlled Trial. Journal of Alternative & Complementary Medicine. 2021;27:S-45.33788599
347 Lehavot K, Millard SP, Thomas RM, . A randomized trial of an online, coach-assisted self-management PTSD intervention tailored for women veterans. J Consult Clin Psychol. 2021;89(2):134–141.33705169
348 Lopez CM, Gilmore AK, Brown WJ, . Effects of Emotion Dysregulation on Post-treatment Post-traumatic Stress Disorder and Depressive Symptoms Among Women Veterans With Military Sexual Trauma. Journal of Interpersonal Violence. 2022;37(15/16):NP13143–NP13161.33775153
349 Martin JL, Carlson GC, Kelly MR, . Novel treatment based on acceptance and commitment therapy versus cognitive behavioral therapy for insomnia: A randomized comparative effectiveness trial in women veterans. J Consult Clin Psychol. 2023.
350 Murdoch M, Clothier BA, Kehle-Forbes S, . Impact of different cover letter information and incentives on Veterans’ emotional responses to an unsolicited mailed survey about military traumas: a randomized, 3x2x2 factorial trial. BMC Medical Research Methodology. 2022;22(1):308–308.36456912
351 Thompson-Hollands J, Lunney CA, Sloan DM, . Treatment length and symptom improvement in prolonged exposure and present-centered therapy for posttraumatic stress disorder: Comparing dose-response and good-enough level models in two manualized interventions. J Consult Clin Psychol. 2023;91(10):596–605.37471022
352 Zaccari B, Loftis JM, Haywood T, . Synchronous Telehealth Yoga and Cognitive Processing Group Therapies for Women Veterans with Posttraumatic Stress Disorder: A Multisite Randomized Controlled Trial Adapted for COVID-19. Telemedicine journal and e-health : the official journal of the American Telemedicine Association. 2022.
353 Najavits LM, Enggasser J, Brief D, Federman E. A randomized controlled trial of a gender-focused addiction model versus 12-step facilitation for women veterans. American Journal on Addictions. 2018;27(3):210–216.29596724
354 Bauer A, Amspoker AB, Fletcher TL, . A Resource Building Virtual Care Programme: improving symptoms and social functioning among female and male rural veterans. Eur J Psychotraumatol. 2021;12(1):1860357.34025913
355 Green JD, Annunziata A, Kleiman SE, . Examining the diagnostic utility of the DSM-5 PTSD symptoms among male and female returning veterans. Depression & Anxiety (1091-4269). 2017;34(8):752–760.28763159
356 Laws HB, Glynn SM, McCutcheon SJ, . Posttraumatic stress symptom change after family involvement in veterans’ mental health care. Psychological services. 2018;15(4):520–528.29265842
357 Menefee DS, Leopoulos WS, Tran JK, . Inpatient Trauma-Focused Treatment for Veterans: Implementation and Evaluation of Patient Perceptions and Outcomes of an Integrated Evidence-Based Treatment Approach. Military Medicine. 2016;181(11):e1590–e1599.27849494
358 Mengeling MA, Torner JC, Smith JL, . Online Screening and Personalized Education to Identify Post-Deployment Mental Health Need and Facilitate Access to Care. Military medicine. 2022.
359 Pebole MM, VanVoorhees EE, Chaudhry N, . Patient-centered behavioral services for women veterans with mental health conditions. Translational Behavioral Medicine. 2021;11(9):1676–1681.34080638
360 Stefanovics EA, Rosenheck RA. Gender Differences in Outcomes Following Specialized Intensive PTSD Treatment in the Veterans Health Administration. Psychological Trauma: Theory, Research, Practice & Policy. 2020;12(3):272–280.31282719
361 Berg KM, Smith SS, Cook JW, . Identifying Opportunities to Improve Smoking Cessation Among Women Veterans at a Veterans Hospital. Military Medicine. 2016;181(10):1340–1347.27753573
362 Timko C, Hoggatt KJ, Wu FM, . Substance Use Disorder Treatment Services for Women in the Veterans Health Administration. Women’s Health Issues. 2017;27(6):639–645.28602581
363 Dichter ME, Iverson KM, Montgomery AE, Sorrentino A. Clinical Response to Positive Screens for Intimate Partner Violence in the Veterans Health Administration: Findings from Review of Medical Records. Journal of Aggression, Maltreatment & Trauma. 2023;32(7/8):1005–1021.
364 Portnoy GA, Iverson KM, Haskell SG, . A Multisite Quality Improvement Initiative to Enhance the Adoption of Screening Practices for Intimate Partner Violence Into Routine Primary Care for Women Veterans. Public Health Reports. 2021;136(1):52–60.33207128
365 Kumpula MJ, Wagner HR, Dedert EA, . An Evaluation of the Effectiveness of Evidence-Based Psychotherapies for Depression to Reduce Suicidal Ideation among Male and Female Veterans. Women’s Health Issues. 2019;29:S103–S111.31253233
366 Gisseman J, Fletcher T, Schmolze A, . Depression Screening During Pregnancy: Compliance and Effectiveness in a Military Population. Military Medicine. 2021;186(9/10):e951–e955.33242062
367 Batch BC, Goldstein K, Yancy WS, . Outcome by Gender in the Veterans Health Administration Motivating Overweight/Obese Veterans Everywhere Weight Management Program. Journal of Women’s Health (15409996). 2018;27(1):32–39.
368 Combellick JL, Bastian LA, Altemus M, . Severe Maternal Morbidity Among a Cohort of Post-9/11 Women Veterans. Journal of Women’s Health (15409996). 2020;29(4):577–584.
369 Avery TJ, Schulz-Heik RJ, Friedman M, . Clinical yoga program utilization in a large health care system. Psychological services. 2021;18(3):389–397.32134306
370 Okvat HA, Davis MC, Mistretta EG, Mardian AS. Mindfulness-based training for women veterans with chronic pain: A retrospective study. Psychological services. 2022;19:106–119.34807665
371 Baier Manwell L, McNeil M, Gerber MR, . Mini-Residencies to Improve Care for Women Veterans: A Decade of Re-Educating Veterans Health Administration Primary Care Providers. Journal of Women’s Health (15409996). 2022;31(7):991–1002.
372 Moreau JL, Dyer KE, Hamilton AB, . Women Veterans’ Perspectives on How to Make Veterans Affairs Healthcare Settings More Welcoming to Women. Women’s Health Issues. 2020;30(4):299–305.32340897
373 Rose DE, Oishi SM, Farmer MM, . Association Between Availability of Women’s Health Services and Women Veterans’ Care Experiences. Women’s Health Issues. 2022;32(6):623–632.36115812
374 Liu Y, Collins C, Wang K, . The prevalence and trend of depression among veterans in the United States. Journal of Affective Disorders. 2019;245:724–727.30699861
375 Sairsingh H, Solomon P, Helstrom A, Treglia D. Depression in Female Veterans Returning from Deployment: The Role of Social Factors. Military Medicine. 2018;183(3/4):e133–e139.29514350
376 Anderson GM, Ramsey CM, Lynch KG, . Baseline platelet serotonin in a multi-site treatment study of depression in veterans administration patients: Distribution and effects of demographic variables and serotonin reuptake inhibitors. Journal of Affective Disorders. 2023;327:368–377.36754092
377 Thomas KH, Albright DL, Shields MM, . Predictors of Depression Diagnoses and Symptoms in United States Female Veterans: Results from a National Survey and Implications for Programming. Journal of Military & Veterans’ Health. 2016;24(3):6–16.
378 Borowski S, Smith BN, McClendon J, Vogt D. Work-family conflict and subsequent depressive symptoms among war-exposed post-9/11 U.S. military Veterans. Journal of Military, Veteran & Family Health. 2021;7:58–68.
379 Curry JF, Shepherd-Banigan M, Van Voorhees E, . Sex differences in predictors of recurrent major depression among current-era military veterans. Psychological services. 2021;18(2):275–284.31750696
380 Breland JY, Donalson R, Nevedal A, . Military experience can influence Women’s eating habits. Appetite. 2017;118:161–167.28802575
381 Vaught AS, Piazza V, Raines AM. Prevalence of eating disorders and comorbid psychopathology in a US sample of treatment-seeking veterans. International Journal of Eating Disorders. 2021;54(11):2009–2014.34338326
382 Buchholz LJ, King PR, Wray LO. Rates and correlates of disordered eating among women veterans in primary care. Eating Behaviors. 2018;30:28–34.29777967
383 Rosenbaum DL, Kimerling R, Pomernacki A, . Binge Eating among Women Veterans in Primary Care: Comorbidities and Treatment Priorities. Women’s Health Issues. 2016;26(4):420–428.26972486
384 Masheb RM, Ramsey CM, Marsh AG, . Atypical Anorexia Nervosa, not so atypical after all: Prevalence, correlates, and clinical severity among United States military Veterans. Eating Behaviors. 2021;41:N.PAG-N.PAG.
385 Masheb RM, Ramsey CM, Marsh AG, . DSM-5 eating disorder prevalence, gender differences, and mental health associations in United States military veterans. International Journal of Eating Disorders. 2021;54(7):1171–1180.33665848
386 Slane JD, Levine MD, Borrero S, . Eating Behaviors: Prevalence, Psychiatric Comorbidity, and Associations With Body Mass Index Among Male and Female Iraq and Afghanistan Veterans. Military Medicine. 2016;181(11):e1650–e1656.27849502
387 Krupp MB, King PR, Wade M, Buchholz LJ. Health service utilization among women veterans who report eating disorder symptoms. International Journal of Eating Disorders. 2023;56(8):1593–1602.37166105
388 Sienkiewicz ME, Iverson KM, Smith BN, Mitchell KS. Associations between eating disorder symptoms, employment status, and occupational functioning among female veterans. Eating Behaviors. 2021;42:N.PAG-N.PAG.
389 Huston JC, Iverson KM, Mitchell KS. Associations between healthcare use and disordered eating among female veterans. International Journal of Eating Disorders. 2018;51(8):978–983.29846012
390 Breland JY, Donalson R, Yongmei L, . Military sexual trauma is associated with eating disorders, while combat exposure is not. Psychological Trauma: Theory, Research, Practice & Policy. 2018;10(3):276–281.28493727
391 Zelkowitz RL, Sienkiewicz ME, Vogt DS, . Gender differences in direct and indirect associations of trauma types with disordered eating in a national U.S. veteran sample. Psychological trauma : theory, research, practice and policy. 2022.
392 Arditte Hall KA, Bartlett BA, Iverson KM, Mitchell KS. Eating disorder symptoms in female veterans: The role of childhood, adult, and military trauma exposure. Psychological Trauma: Theory, Research, Practice & Policy. 2018;10(3):345–351.28682107
393 Mitchell KS, Sienkiewicz M, Smith BN, . Associations between probable eating disorders and healthcare use among post-9/11 veteran men and women. Journal of Psychosomatic Research. 2022;157:N.PAG-N.PAG.
394 Serier KN, Smith BN, Cooper Z, . Disordered eating in sexual minority post-9/11 United States veterans. International Journal of Eating Disorders. 2022;55(4):470–480.35092637
395 Ziobrowski H, Sartor CE, Tsai J, Pietrzak RH. Gender differences in mental and physical health conditions in U.S. veterans: Results from the National Health and Resilience in Veterans Study. Journal of Psychosomatic Research. 2017;101:110–113.28867415
396 Brown GR, Jones KT. Mental Health and Medical Health Disparities in 5135 Transgender Veterans Receiving Healthcare in the Veterans Health Administration: A Case-Control Study. LGBT health. 2016;3(2):122–131.26674598
397 Fitzke RE, Bouskill KE, Sedano A, . Barriers and Facilitators to Behavioral Healthcare for Women Veterans: a Mixed-Methods Analysis of the Current Landscape. The journal of behavioral health services & research. 2023.
398 Ingelse K, Messecar D. Rural Women Veterans’ Use and Perception of Mental Health Services. Archives of Psychiatric Nursing. 2016;30(2):244–248.26992878
399 Rossi FS, Javier SJ, Kimerling R. An Examination of the Association Between Patient Experience and Quality of Mental Health Care Among Women Veterans. Administration and policy in mental health. 2021;48(1):61–69.32415345
400 Brunner J, Schweizer CA, Canelo IA, . Timely access to mental health care among women veterans. Psychological services. 2019;16(3):498–503.29620391
401 Lindsay JA, Caloudas A, Hogan J, . Getting Connected: a Retrospective Cohort Investigation of Video-to-Home Telehealth for Mental Health Care Utilization Among Women Veterans. JGIM: Journal of General Internal Medicine. 2022;37:778–785.36042096
402 Williston SK, Bramande EA, Vogt DS, . An Examination of the Roles of Mental Health Literacy, Treatment-Seeking Stigma, and Perceived Need for Care in Female Veterans’ Service Use. Psychiatric Services. 2020;71(2):144–150.31658896
403 Lilienthal KR, Buchholz LJ, King PR, . Mental health measurement among women veterans receiving co-located, collaborative care services. Psychology, Health & Medicine. 2017;22(10):1192–1202.
404 Kimerling R, Pavao J, Wong A. Patient Activation and Mental Health Care Experiences Among Women Veterans. Administration and policy in mental health. 2016;43(4):506–513.25917224
405 Tsai J, Hoff RA, Harpaz-Rotem I. One-year incidence and predictors of homelessness among 300,000 U.S. Veterans seen in specialty mental health care. Psychological services. 2017;14(2):203–207.28481605
406 Fischer EP, Curran GM, Fortney JC, . Impact of Attitudes and Rurality on Veterans’ Use of Veterans Health Administration Mental Health Services. Psychiatric Services. 2021;72(5):521–529.33691490
407 Harper KL, Thompson-Hollands J, Keane TM, Marx BP. Mental health treatment utilization and relationship functioning among male and female OEF/OIF veterans. Psychological services. 2022;19(3):597–603.34081522
408 Kotzias V, Engel CC, Ramchand R, . Mental Health Service Preferences and Utilization Among Women Veterans in Crisis: Perspectives of Veterans Crisis Line Responders. Journal of Behavioral Health Services & Research. 2019;46(1):29–42.30298442
409 Sayer NA, Orazem RJ, Mitchell LL, . What the public should know about veterans returning from combat deployment to support reintegration: A qualitative analysis. American Journal of Orthopsychiatry. 2021;91(3):398–406.33914556
410 Breland JY, Frayne SM, Timko C, . Mental Health and Obesity Among Veterans: A Possible Need for Integrated Care. Psychiatric Services. 2020;71(5):506–509.31996116
411 Wilson SM, Burroughs TK, Newins AR, . The Association Between Alcohol Consumption, Lifetime Alcohol Use Disorder, and Psychiatric Distress Among Male and Female Veterans. Journal of Studies on Alcohol & Drugs. 2018;79(4):591–600.30079875
412 Desai A, Holliday R, Borges LM. Racial, ethnic, and sex differences in psychiatric diagnosis, mental health sequelae, and VHA service utilization among justice-involved veterans. Law and human behavior. 2023;47(1):260–274.36931862
413 Ramsey C, Dziura J, Justice AC, . Incidence of Mental Health Diagnoses in Veterans of Operations Iraqi Freedom, Enduring Freedom, and New Dawn, 2001-2014. American Journal of Public Health. 2017;107(2):329–335.27997229
414 Merians AN, Gross G, Spoont MR, . Racial and ethnic mental health disparities in U.S. Military Veterans: Results from the National Health and Resilience in Veterans Study. Journal of Psychiatric Research. 2023;161:71–76.36905842
415 Blosnich JR, Marsiglio MC, Gao S, . Mental Health of Transgender Veterans in US States With and Without Discrimination and Hate Crime Legal Protection. American Journal of Public Health. 2016;106(3):534–540.26794162
416 Smith BN, Spiro A, Frayne SM, . Impact of Wartime Stress Exposures and Mental Health on Later-Life Functioning and Disability in Vietnam-Era Women Veterans: Findings From the Health of Vietnam-Era Women’s Study. Psychosomatic Medicine. 2020;82(2):147–157.31714370
417 Maiocco G, Smith MJ. The Experience of Women Veterans Coming Back from War. Archives of Psychiatric Nursing. 2016;30(3):393–399.27256947
418 Pless Kaiser A, Wang J, Davison EH, . Stressful and positive experiences of women who served in Vietnam. Journal of Women & Aging. 2017;29(1):26–38.27428167
419 Quinn DA, Hollis BF, Dichter ME, Blosnich JR. Recent and Frequent Mental Distress Among Women with a History of Military Service, 2003-2019. The journal of behavioral health services & research. 2023;50(1):119–127.36369432
420 Albright DL, Hendricks Thomas K, McDaniel J, . When women veterans return: The role of postsecondary education in transition in their civilian lives. Journal of American College Health. 2019;67(5):479–485.30724680
421 Vanneman ME, Harris AHS, Chen C, . Postdeployment Behavioral Health Screens and Linkage to the Veterans Health Administration for Army Reserve Component Members. Psychiatric Services. 2017;68(8):803–809.28412888
422 Scoglio AAJ, Shirk SD, Hoff RA, . Gender-Specific Risk Factors for Psychopathology and Reduced Functioning in a Post-9/11 Veteran Sample. Journal of Interpersonal Violence. 2021;36(3/4):NP1359–1374NP.29295023
423 Muralidharan A, Austern D, Hack S, Vogt D. Deployment Experiences, Social Support, and Mental Health: Comparison of Black, White, and Hispanic U.S. Veterans Deployed to Afghanistan and Iraq. Journal of Traumatic Stress. 2016;29(3):273–278.27191777
424 Lawrence KA, Vogt D, Dugan AJ, . Mental health and psychosocial functioning in recently separated U.S. women veterans: Trajectories and bi-directional relationships. International Journal of Environmental Research and Public Health. 2021;18(3):1–15.
425 Adams RE, Hu Y, Figley CR, . Risk and protective factors associated with mental health among female military veterans: results from the veterans’ health study. BMC Women’s Health. 2021;21(1):1–10.33388051
426 Creech SK, Zlotnick C, Swift R, . Combat exposure, mental health, and relationship functioning among women veterans of the Afghanistan and Iraq wars. Journal of Family Psychology. 2016;30(1):43–51.26348108
427 Lehavot K, Beckman KL, Chen JA, . Race/Ethnicity and Sexual Orientation Disparities in Mental Health, Sexism, and Social Support among Women Veterans. Psychol Sex Orientat Gend Divers. 2019;6(3):347–358.31435497
428 Lehavot K, Beaver K, Rhew I, . Disparities in Mental Health and Health Risk Behaviors for LGBT Veteran Subgroups in a National U.S. Survey. LGBT Health. 2022;9(8):543–554.35766966
429 Hamrick HC, Ehlke SJ, Davies RL, . Moral Injury as a Mediator of the Associations Between Sexual Harassment and Mental Health Symptoms and Substance Use Among Women Veterans. Journal of Interpersonal Violence. 2022;37(11/12):NP10007–NP10035.33435809
430 Ranney RM, Maguen S, Bernhard PA, . Moral injury and chronic pain in veterans. Journal of Psychiatric Research. 2022;155:104–111.36027646
431 Maguen S, Griffin BJ, Copeland LA, . Gender differences in prevalence and outcomes of exposure to potentially morally injurious events among post-9/11 veterans. Journal of Psychiatric Research. 2020;130:97–103.32805522
432 Kehle-Forbes SM, Gerould H, Polusny MA, . “It leaves me very skeptical” messaging in marketing prolonged exposure and cognitive processing therapy to veterans with PTSD. Psychological trauma : theory, research, practice and policy. 2022;14(5):849–852.31961163
433 Wilson SR, Hintz EA, MacDermid Wadsworth SM, . Female U.S. Military Veterans’ (Non)Disclosure of Mental Health Issues with Family and Friends: Privacy Rules and Boundary Management. Health Communication. 2021;36(4):412–423.31752542
434 Kehle-Forbes SM, Harwood EM, Spoont MR, . Experiences with VHA care: a qualitative study of U.S. women veterans with self-reported trauma histories. BMC Women’s Health. 2017;17:1–8.28049464
435 Haun JN, Duffy A, Lind JD, . Qualitative Inquiry Explores Health-Related Quality of Life of Female Veterans With Post-Traumatic Stress Disorder. Military Medicine. 2016;181(11):e1470–e1475.27849478
436 Krupnick JL. Gender Differences in Trauma Types and Themes in Veterans with Posttraumatic Stress Disorder. Journal of Loss & Trauma. 2017;22(6):514–525.
437 Valenstein-Mah H, Kehle-Forbes S, Nelson D, . Gender Differences in Rates and Predictors of Individual Psychotherapy Initiation and Completion Among Veterans Health Administration Users Recently Diagnosed With PTSD. Psychological Trauma: Theory, Research, Practice & Policy. 2019;11(8):811–819.30688508
438 Farmer CC, Rossi FS, Michael EM, Kimerling R. Psychotherapy Utilization, Preferences, and Retention among Women Veterans with Post-traumatic Stress Disorder. Women’s Health Issues. 2020;30(5):366–373.32680627
439 Lehavot K, Litz B, Millard SP, . Study adaptation, design, and methods of a web-based PTSD intervention for women Veterans. Contemporary Clinical Trials. 2017;53:68–79.27940187
440 Murdoch M, Kehle-Forbes S, Spoont M, . Changes in Post-traumatic Stress Disorder Service Connection Among Veterans Under Age 55: An 18-Year Ecological Cohort Study. Military Medicine. 2019;184(11/12):715–722.30938816
441 Hadlandsmyth K, Bernardy NC, Lund BC. Gender differences in medication prescribing patterns for veterans with posttraumatic stress disorder: A 10-year follow-up study. Journal of Traumatic Stress. 2022;35(6):1586–1597.35797242
442 Wisco BE, Marx BP, Miller MW, . Probable posttraumatic stress disorder in the US veteran population according to DSM-5: Results from the national health and resilience in veterans study. Journal of Clinical Psychiatry. 2016;77(11):1503–1510.27631148
443 Davin KR, Dardis CM, Barth MR, Iverson KM. Prospective mental health effects of intimate partner stalking among women veterans. Psychological trauma : theory, research, practice and policy. 2022;14(5):751–758.34735188
444 Webermann AR, Gianoli MO, Rosen MI, . Military sexual trauma-related posttraumatic stress disorder service-connection award denial across gender and race. 2023.
445 Moye J, Kaiser AP, Cook J, Pietrzak RH. Post-traumatic Stress Disorder in Older U.S. Military Veterans: Prevalence, Characteristics, and Psychiatric and Functional Burden. American Journal of Geriatric Psychiatry. 2022;30(5):606–618.
446 Schnurr PP, Lunney CA. Residual symptoms following prolonged exposure and present-centered therapy for PTSD in female veterans and soldiers. Depression & Anxiety (1091-4269). 2019;36(2):162–169.30576030
447 Andresen FJ, Monteith LL, Kugler J, . Institutional betrayal following military sexual trauma is associated with more severe depression and specific posttraumatic stress disorder symptom clusters. Journal of clinical psychology. 2019;75(7):1305–1319.30947374
448 Stainbrook K, Hartwell S, James A. Female Veterans in Jail Diversion Programs: Differences From and Similarities to Their Male Peers. Psychiatric Services. 2016;67(1):133–136.26234331
449 Tsai J, Pietrzak RH, Hoff RA, Harpaz-Rotem I. Accuracy of screening for posttraumatic stress disorder in specialty mental health clinics in the U.S. Veterans Affairs Healthcare System. Psychiatry Research. 2016;240:157–162.27107669
450 Murdoch M, Spoont MR, Kehle-Forbes SM, . Persistent Serious Mental Illness Among Former Applicants for VA PTSD Disability Benefits and Long-Term Outcomes: Symptoms, Functioning, and Employment. Journal of Traumatic Stress. 2017;30(1):36–44.28099769
451 McClendon J, Perkins D, Copeland LA, . Patterns and correlates of racial/ethnic disparities in posttraumatic stress disorder screening among recently separated veterans. Journal of Anxiety Disorders. 2019;68.
452 Shipherd JC, Lynch K, Gatsby E, . Estimating Prevalence of PTSD Among Veterans With Minoritized Sexual Orientations Using Electronic Health Record Data. J Consult Clin Psychol. 2021;89(10):856–868.34807660
453 Shastry N, Sultana E, Jeffrey M, . The impact of post-traumatic stress on quality of life and fatigue in women with Gulf War Illness. BMC psychology. 2022;10(1):42.35216624
454 James LM, Georgopoulos AP. Immunogenetics of posttraumatic stress disorder (PTSD) in women veterans. Brain, Behavior, and Immunity - Health. 2022;26.
455 Kimbrel NA, Thomas SP, Hicks TA, . Wall/Object Punching: An Important but Under-Recognized Form of Nonsuicidal Self-Injury. Suicide & Life-Threatening Behavior. 2018;48(5):501–511.28925016
456 Schnurr PP, Lunney CA. SYMPTOM BENCHMARKS OF IMPROVED QUALITY OF LIFE IN PTSD. Depression & Anxiety (1091-4269). 2016;33(3):247–255.26882293
457 Maguen S, Holder N, Li Y, . Factors associated with PTSD symptom improvement among Iraq and Afghanistan veterans receiving evidenced-based psychotherapy. Journal of Affective Disorders. 2020;273:1–7.32421589
458 Vogt D, King MW, Borowski S, . Identifying factors that contribute to military veterans’ post-military well-being. Applied psychology. Health and well-being. 2021;13(2):341–356.33595207
459 Shiner B, Leonard Westgate C, Harik JM, . Effect of Patient-Therapist Gender Match on Psychotherapy Retention Among United States Veterans with Posttraumatic Stress Disorder. Administration and policy in mental health. 2017;44(5):642–650.27530121
460 Lehavot K, Goldberg SB, Chen JA, . Do trauma type, stressful life events, and social support explain women veterans’ high prevalence of PTSD? Social Psychiatry & Psychiatric Epidemiology. 2018;53(9):943–953.29936598
461 Lehavot K, Katon JG, Chen JA, . Post-traumatic Stress Disorder by Gender and Veteran Status. American Journal of Preventive Medicine. 2018;54(1):e1–e9.29254558
462 James LM, Leuthold AF, Georgopoulos AP. Classification of posttraumatic stress disorder and related outcomes in women veterans using magnetoencephalography. Experimental Brain Research. 2022;240(4):1117–1125.35133447
463 Stefanovics EA, Rosenheck RA. Comparing Outcomes of Women-Only and Mixed-Gender Intensive Posttraumatic Stress Disorder Treatment for Female Veterans. Journal of Traumatic Stress. 2019;32(4):606–615.31361360
464 Harper KL, Vogt D, Fox A, . The Role of PTSD Symptom Severity and Relationship Functioning in Male and Female Veterans’ Mental Health Service Use. Psychological Trauma: Theory, Research, Practice & Policy. 2023;15(4):690–696.36174158
465 Christ NM, Blain RC, Pukay-Martin ND, . Comparing Veterans with Posttraumatic Stress Disorder Related to Military Sexual Trauma or Other Trauma Types: Baseline Characteristics and Residential Cognitive Processing Therapy Outcomes. Journal of Interpersonal Violence. 2022;37(21/22):NP20701–NP20723.34787530
466 Rosen CS, Bernardy NC, Chard KM, . Which patients initiate cognitive processing therapy and prolonged exposure in department of veterans affairs PTSD clinics? Journal of Anxiety Disorders. 2019;62:53–60.30550959
467 Shapiro MO, Short NA, Raines AM, . Pain and posttraumatic stress: Associations among women veterans with a history of military sexual trauma. Psychological trauma : theory, research, practice and policy. 2022.
468 Wolf EJ, Lunney CA, Schnurr PP. The Influence of the Dissociative Subtype of Posttraumatic Stress Disorder on Treatment Efficacy in Female Veterans and Active Duty Service Members. J Consult Clin Psychol. 2016;84(1):95–100.26167946
469 Miles SR, Menefee DS, Wanner J, . The Relationship Between Emotion Dysregulation and Impulsive Aggression in Veterans With Posttraumatic Stress Disorder Symptoms. Journal of Interpersonal Violence. 2016;31(10):1795–1816.25681165
470 Buta E, Masheb R, Gueorguieva R, . Posttraumatic stress disorder diagnosis and gender are associated with accelerated weight gain trajectories in veterans during the post-deployment period. Eating Behaviors. 2018;29:8–13.29413821
471 Smith BN, Wang JM, Vaughn-Coaxum RA, . The role of postdeployment social factors in linking deployment experiences and current posttraumatic stress disorder symptomatology among male and female veterans. Anxiety, Stress & Coping. 2017;30(1):39–51.27232981
472 Zelkowitz RL, Archibald EA, Gradus JL, Street AE. Postdeployment Mental Health Concerns and Family Functioning in Veteran Men and Women. Psychological Trauma: Theory, Research, Practice & Policy. 2023;15(4):705–714.35311338
473 Meyer EC, Konecky B, Kimbrel NA, . Gender differences in associations between DSM-5 posttraumatic stress disorder symptom clusters and functional impairment in war veterans. Psychological services. 2018;15(2):230–237.29723025
474 Vogt D, Smith BN, Fox AB, . Consequences of PTSD for the work and family quality of life of female and male U.S. Afghanistan and Iraq War veterans. Social psychiatry and psychiatric epidemiology. 2017;52(3):341–352.28040826
475 Burg MM, Brandt C, Buta E, . Risk for Incident Hypertension Associated With Posttraumatic Stress Disorder in Military Veterans and the Effect of Posttraumatic Stress Disorder Treatment. Psychosomatic Medicine. 2017;79(2):181–188.27490852
476 Janke-Stedronsky SR, Greenawalt DS, Stock EM, . Association of parental status and diagnosis of posttraumatic stress disorder among veterans of Operations Iraqi and Enduring Freedom. Psychological trauma : theory, research, practice and policy. 2016;8(1):72–79.25793320
477 McClendon J, Kressin N, Perkins D, . The Impact of Discriminatory Stress on Changes in Posttraumatic Stress Severity at the Intersection of Race/Ethnicity and Gender. Journal of Trauma & Dissociation. 2021;22(2):170–187.33460360
478 Ceja A, Yalch MM, Maguen S. Posttraumatic stress disorder symptom expression in racially and ethnically diverse women veterans. Psychiatry Research. 2022;309.
479 Koo KH, Hebenstreit CL, Madden E, Maguen S. PTSD detection and symptom presentation: Racial/ethnic differences by gender among veterans with PTSD returning from Iraq and Afghanistan. Journal of Affective Disorders. 2016;189:10–16.26402342
480 Caska-Wallace CM, Katon JG, Lehavot K, . Posttraumatic Stress Disorder Symptom Severity and Relationship Functioning Among Partnered Heterosexual and Lesbian Women Veterans. LGBT health. 2016;3(3):186–192.26895547
481 Sripada RK, Hannemann CM, Schnurr PP, . Mental Health Service Utilization before and after Receipt of a Service-Connected Disability Award for PTSD: Findings from a National Sample. Health Services Research. 2018;53(6):4565–4583.29667171
482 Benfer N, Darnell BC, Rusowicz-Orazem L, . An examination of the criterion-related validity of varying methods of indexing clinically significant change in posttraumatic stress disorder treatment. Psychological trauma : theory, research, practice and policy. 2023.
483 Reuman L, Thompson-Hollands J. Women veterans’ attitudes toward family involvement in PTSD treatment: A mixed-methods examination. Psychological services. 2022.
484 Gros DF, Allan NP, Koscinski B, . Influence of comorbid social anxiety disorder in PTSD treatment outcomes for Prolonged Exposure in female military sexual trauma survivors with PTSD. Journal of clinical psychology. 2023;79(4):1039–1050.36399326
485 Banducci AN, McCaughey VK, Gradus JL, Street AE. The associations between deployment experiences, PTSD, and alcohol use among male and female veterans. Addictive Behaviors. 2019;98:N.PAG-N.PAG.
486 Olmos-Ochoa TT, Speicher S, Ong LE, . Supporting Equitable Engagement and Retention of Women Patients in a Trauma-Informed Virtual Mental Health Intervention: Acceptability and Needed Adaptations. Psychiatric Rehabilitation Journal. 2023;46(1):26–35.36809014
487 Goldstein LA, Dinh J, Donalson R, . Impact of military trauma exposures on posttraumatic stress and depression in female veterans. Psychiatry Research. 2017;249:281–285.28135599
488 Lucas CL, Cederbaum JA, Kintzle S, Castro CA. An Examination of Stalking Experiences During Military Service Among Female and Male Veterans and Associations With PTSD and Depression. Journal of Interpersonal Violence. 2021;36(21/22):NP11894–NP11915.31789112
489 Gross GM, Spiller TR, Carretta R, . Clinical outcomes of veterans affairs residential PTSD treatment for PTSD and depressive symptoms: 1-year follow-up outcomes and gender differences. Psychological trauma : theory, research, practice and policy. 2023.
490 Arditte Hall KA, Davison EH, Galovski TE, . Associations Between Trauma-Related Rumination and Symptoms of Posttraumatic Stress and Depression in Treatment-Seeking Female Veterans. Journal of Traumatic Stress. 2019;32(2):260–268.31009555
491 Holliday R, Hoffmire CA, Martin WB, . Associations between justice involvement and PTSD and depressive symptoms, suicidal ideation, and suicide attempt among post-9/11 veterans. Psychological trauma : theory, research, practice and policy. 2021;13(7):730–739.34323570
492 Welsh JA, Olson JR, Perkins DF. Gender Differences in Post-deployment Adjustment of Air Force Personnel: The Role of Wartime Experiences, Unit Cohesion, and Self-efficacy. Military Medicine. 2019;184(1/2):e229–e234.30371812
493 Smith BN, Taverna EC, Fox AB, . The Role of PTSD, Depression, and Alcohol Misuse Symptom Severity in Linking Deployment Stressor Exposure and Post-Military Work and Family Outcomes in Male and Female Veterans. Clin. 2017;5(4):664–682.
494 Vogt D, Danitz SB, Fox AB, . Do functional impairments promote or hinder mental health treatment seeking: Differential results for women and men. Psychiatry Research. 2019;271:614–620.30791333
495 Gorman KR, Kearns JC, Pantalone DW, . The impact of deployment-related stressors on the development of PTSD and depression among sexual minority and heterosexual female veterans. Psychological trauma : theory, research, practice and policy. 2022;14(5):747–750.34398629
496 Finkelstein-Fox L, Sinnott SM, Lee SY, . Meaningful military engagement among male and female post-9/11 veterans: An examination of correlates and implications for resilience. Journal of clinical psychology. 2021;77(10):2167–2186.33960411
497 Gutner CA, Pedersen ER, Drummond SPA. Going direct to the consumer: Examining treatment preferences for veterans with insomnia, PTSD, and depression. Psychiatry Research. 2018;263:108–114.29524908
498 Sandhu D, Dougherty EN, Haedt-Matt A. PTSD symptoms as a potential mediator of associations between military sexual assault and disordered eating. Eating Disorders. 2023;31(3):285–299.36239705
499 Stojek MM, Lipka J, Maples-keller JM, . Investigating sex differences in rates and correlates of food addiction status in women and men with ptsd. Nutrients. 2021;13(6).
500 Webermann AR, Dardis CM, Iverson KM. The role of general self-efficacy in intimate partner violence and symptoms of posttraumatic stress disorder among women veterans. Journal of Traumatic Stress. 2022;35(3):868–878.35099821
501 C’De Baca J, Nason E, Castillo DT, . Examining Relationships Among Ethnicity, PTSD, Life Functioning, and Comorbidity in Female OEF/OIF Veterans. Journal of Loss & Trauma. 2016;21(5):350–359.
502 Williams R, Holliday R, Clem M, . Borderline Personality Disorder and Military Sexual Trauma: Analysis of Previous Traumatization and Current Psychiatric Presentation. Journal of Interpersonal Violence. 2017;32(15):2223–2236.26198645
503 Creech SK, Benzer JK, Meyer EC, . Longitudinal associations in the direction and prediction of PTSD symptoms and romantic relationship impairment over one year in post 9/11 veterans: A comparison of theories and exploration of potential gender differences. Journal of Abnormal Psychology. 2019;128(3):245–255.30920234
504 James LM, Leuthold AF, Georgopoulos AP. MEG neural signature of sexual trauma in women veterans with PTSD. Experimental Brain Research. 2022;240(7–8):2135–2142.35786746
505 Saba SK, Davis JP, Prindle JJ, . Associations between symptoms of posttraumatic stress disorder, pain, and alcohol use disorder among OEF/OIF/OND veterans. Addictive Behaviors. 2021;122.
506 Epstein EL, Martindale SL, Workgroup VAM-AM, Miskey HM. Posttraumatic stress disorder and traumatic brain Injury: Sex differences in veterans. Psychiatry Research. 2019;274:105–111.30784779
507 Jackson CE, Green JD, Bovin MJ, . Mild Traumatic Brain Injury, PTSD, and Psychosocial Functioning Among Male and Female U.S. OEF/OIF Veterans. Journal of Traumatic Stress. 2016;29(4):309–316.27405050
508 Portnoy GA, Relyea MR, Decker S, . Understanding Gender Differences in Resilience Among Veterans: Trauma History and Social Ecology. Journal of Traumatic Stress. 2018;31(6):845–855.30431668
509 Sexton MB, Davis MT, Bennett DC, . A psychometric evaluation of the Posttraumatic Cognitions Inventory with Veterans seeking treatment following military trauma exposure. Journal of Affective Disorders. 2018;226:232–238.29017066
510 Schuman DL, Bricout J, Peterson HL, Barnhart S. A systematic review of the psychosocial impact of emotional numbing in US combat veterans. Journal of clinical psychology. 2019;75(4):644–663.30597543
511 Trivedi RB, Post EP, Piegari R, . Mortality Among Veterans with Major Mental Illnesses Seen in Primary Care: Results of a National Study of Veteran Deaths. JGIM: Journal of General Internal Medicine. 2020;35(1):112–118.31667746
512 Holliday R, Desai A, Edwards ER, Borges LM. Personality Disorder Diagnosis among Justice-Involved Veterans: An Investigation of VA Using Veterans. Journal of Nervous and Mental Disease. 2023;211(5):402–406.37040142
513 Goodsmith N, Cohen AN, Pedersen ER, . Predictors of Functioning and Recovery Among Men and Women Veterans with Schizophrenia. Community Mental Health Journal. 2023;59(1):110–121.35643881
514 Saldana KS, Carlson GC, Revolorio K, . Values Expressed by Women Veterans Receiving Treatment for Chronic Insomnia Disorder. Behavioral sleep medicine. 2023:1–13.
515 Carlson GC, Kelly MR, Mitchell M, . Benefits of Cognitive Behavioral Therapy for Insomnia for Women Veterans with and without Probable Post-Traumatic Stress Disorder. Women’s Health Issues. 2022;32(2):194–202.34815139
516 Jasuja GK, Reisman JI, Wiener RS, . Gender differences in prescribing of zolpidem in the Veterans Health Administration. American Journal of Managed Care. 2019;25(3):E58–E65.30875172
517 Babson KA, Wong AC, Morabito D, Kimerling R. Insomnia symptoms among female veterans: Prevalence, risk factors, and the impact on psychosocial functioning and health care utilization. Journal of Clinical Sleep Medicine. 2018;14(6):931–939.29852900
518 Martin JL, Schweizer CA, Hughes JM, . Estimated Prevalence of Insomnia among Women Veterans: Results of a Postal Survey. Women’s Health Issues. 2017;27(3):366–373.28110799
519 Culver NC, Song Y, Kate McGowan S, . Acceptability of Medication and Nonmedication Treatment for Insomnia Among Female Veterans: Effects of Age, Insomnia Severity, and Psychiatric Symptoms. Clinical Therapeutics. 2016;38(11):2373–2385.28314434
520 Taylor KA, Mysliwiec V, Kimbrel NA, . Probable trauma associated sleep disorder in post-9/11 US Veterans. Sleep Adv. 2023;4(1):zpad001.37193287
521 Colvonen PJ, Almklov E, Tripp JC, . Prevalence rates and correlates of insomnia disorder in post-9/11 veterans enrolling in VA healthcare. Sleep. 2020;43(12).
522 Carlson G, Kelly M, Grinberg A, . Trauma as an insomnia precipitating event among women Veterans. Sleep Medicine. 2019;64:S54–S55.
523 Kim HM, Gerlach LB, Yosef M, . Responsiveness of veterans affairs health care system to zolpidem safety warnings. Journal of Clinical Sleep Medicine. 2018;14(7):1135–1141.29991420
524 Rosen RC, Cikesh B, Fang S, . Posttraumatic Stress Disorder Severity and Insomnia-Related Sleep Disturbances: Longitudinal Associations in a Large, Gender-Balanced Cohort of Combat-Exposed Veterans. Journal of Traumatic Stress. 2019;32(6):936–945.31800135
525 Kim HM, Gerlach LB, Van T, . Predictors of long-term and high-dose use of zolpidem in veterans. Journal of Clinical Psychiatry. 2019;80(2).
526 Song Y, Washington DL, Yano EM, . Caregiving-Related Sleep Problems and Their Relationship to Mental Health and Daytime Function in Female Veterans. Behavioral sleep medicine. 2018;16(4):371–379.27690634
527 Carlson GC, Kelly MR, Grinberg AM, . Insomnia Precipitating Events among Women Veterans: The Impact of Traumatic and Nontraumatic Events on Sleep and Mental Health Symptoms. Behavioral sleep medicine. 2021;19(5):672–688.33251855
528 Mahoney CT, Shayani DR, Iverson KM. Longing for sleep after violence: The impact of PTSD symptoms, avoidance, and pain on insomnia among female veterans. Psychiatry Research. 2022;313.
529 Gaffey AE, Redeker NS, Rosman L, . The role of insomnia in the association between posttraumatic stress disorder and hypertension. Journal of Hypertension. 2020;38(4):641–648.31725076
530 Webermann A, Dardis C, Shipherd J, Iverson K. A Two-Year Examination of Intimate Partner Violence and Associated Mental and Physical Health among Sexual Minority and Heterosexual Women Veterans. Journal of Aggression, Maltreatment & Trauma. 2023;32(7/8):1124–1141.
531 Tuepker A, Newell S, Sorrentino A, . High-Risk Encounters: Primary Care Experiences of Women Living with Intimate Partner Violence, and Implications for the Patient Centered Medical Home. Journal of Aggression, Maltreatment & Trauma. 2023;32(7/8):1041–1054.
532 Miller CJ, Stolzmann K, Dichter ME, . Intimate Partner Violence Screening for Women in the Veterans Health Administration: Temporal Trends from the Early Years of Implementation 2014-2020. Journal of Aggression, Maltreatment & Trauma. 2023;32(7/8):960–978.
533 Kim S, Currao A, Fonda JR, . Experience of Intimate Partner Violence and Associated Psychiatric, Neurobehavioral, and Functional Burden in Male and Female Veterans: Implications for Treatment. Journal of Aggression, Maltreatment & Trauma. 2023;32(7/8):1022–1040.
534 Goldstein LA, Jakubowski KP, Huang AJ, . Lifetime history of interpersonal partner violence is associated with insomnia among midlife women veterans. Menopause (10723714). 2023;30(4):370–375.
535 Shayani DR, Danitz SB, Low SK, . Women Tell All: A Comparative Thematic Analysis of Women’s Perspectives on Two Brief Counseling Interventions for Intimate Partner Violence. International Journal of Environmental Research and Public Health. 2022;19(5).
536 Iverson KM, Rossi FS, Nillni YI, . PTSD and Depression Symptoms Increase Women’s Risk for Experiencing Future Intimate Partner Violence. International Journal of Environmental Research and Public Health. 2022;19(19).
537 Iverson KM, Dardis CM, Cowlishaw S, . Effects of Intimate Partner Violence During COVID-19 and Pandemic-Related Stress on the Mental and Physical Health of Women Veterans. JGIM: Journal of General Internal Medicine. 2022;37:724–733.36042090
538 Watkins LE, Laws HB. A Dyadic Analysis of PTSD and Psychological Partner Aggression Among U.S. Iraq and Afghanistan Veterans: The Impact of Gender and Dual-Veteran Couple Status. Journal of Interpersonal Violence. 2021;36(5/6):2393–2408.29502510
539 Sorrentino AE, Iverson KM, Tuepker A, . Mental health care in the context of intimate partner violence: Survivor perspectives. Psychological services. 2021;18(4):512–522.32237873
540 Creech SK, Pulverman CS, Kroll-Desrosiers A, . Intimate Partner Violence Among Pregnant Veterans: Prevalence, Associated Mental Health Conditions, and Health Care Utilization. JGIM: Journal of General Internal Medicine. 2021;36(10):2982–2988.33464464
541 Adjognon OL, Brady JE, Gerber MR, . Getting routine intimate partner violence screening right: Implementation strategies used in Veterans Health Administration (VHA) primary care. Journal of the American Board of Family Medicine. 2021;34(2):346–356.33833003
542 Portnoy GA, Relyea MR, Street AE, . A Longitudinal Analysis of Women Veterans’ Partner Violence Perpetration: the Roles of Interpersonal Trauma and Posttraumatic Stress Symptoms. Journal of Family Violence. 2020;35(4):361–372.
543 Makaroun LK, Brignone E, Rosland AM, Dichter ME. Association of Health Conditions and Health Service Utilization with Intimate Partner Violence Identified via Routine Screening among Middle-Aged and Older Women. JAMA Network Open. 2020.
544 Iverson KM, Sayer NA, Meterko M, . Intimate Partner Violence Among Female OEF/OIF/OND Veterans Who Were Evaluated for Traumatic Brain Injury in the Veterans Health Administration: A Preliminary Investigation. Journal of Interpersonal Violence. 2020;35(13/14):2422–2445.29294714
545 Dichter ME, Ogden SN, Clyatt KJ, Roberts CB. Missed Opportunity for HIV Prevention Among a High-Risk Population of Women Experiencing Intimate Partner Violence. J Gen Intern Med. 2020;35(1):392–393.31621047
546 Dichter ME, Makaroun L, Tuepker A, . Middle-aged Women’s Experiences of Intimate Partner Violence Screening and Disclosure: “It’s a private matter. It’s an embarrassing situation”. J Gen Intern Med. 2020;35(9):2655–2661.32514900
547 Iverson KM, Adjognon O, Grillo AR, . Intimate Partner Violence Screening Programs in the Veterans Health Administration: Informing Scale-up of Successful Practices. JGIM: Journal of General Internal Medicine. 2019;34(11):2435–2442.31420827
548 Iovine-Wong PE, Nichols-Hadeed C, Thompson Stone J, . Intimate Partner Violence, Suicide, and Their Overlapping Risk in Women Veterans: A Review of the Literature. Military medicine. 2019;184(5–6):e201–e210.30690471
549 Huston JC, Grillo AR, Iverson KM, Mitchell KS. Associations between disordered eating and intimate partner violence mediated by depression and posttraumatic stress disorder symptoms in a female veteran sample. General Hospital Psychiatry. 2019;58:77–82.30965163
550 Danitz SB, Stirman SW, Grillo AR, . When user-centered design meets implementation science: integrating provider perspectives in the development of an intimate partner violence intervention for women treated in the United States’ largest integrated healthcare system. BMC Women’s Health. 2019;19(1):N.PAG-N.PAG.
551 Rosenfeld EA, Miller E, Zhao X, . Male partner reproductive coercion among women veterans. American Journal of Obstetrics & Gynecology. 2018;218(2):239.e1–239.e8.
552 Portnoy GA, Haskell SG, King MW, . Accuracy and Acceptability of a Screening Tool for Identifying Intimate Partner Violence Perpetration among Women Veterans: A Pre-Implementation Evaluation. Women’s Health Issues. 2018;28(5):439–445.29885901
553 Iverson KM, Sorrentino AE, Bellamy SL, . Adoption, penetration, and effectiveness of a secondary risk screener for intimate partner violence: Evidence to inform screening practices in integrated care settings. General Hospital Psychiatry. 2018;51:79–84.29353128
554 Dichter ME, Sorrentino AE, Haywood TN, . Women’s Healthcare Utilization Following Routine Screening for Past-Year Intimate Partner Violence in the Veterans Health Administration. JGIM: Journal of General Internal Medicine. 2018;33(6):936–941.29423623
555 Dardis CM, Dichter ME, Iverson KM. Empowerment, PTSD and revictimization among women who have experienced intimate partner violence. Psychiatry Research. 2018;266:103–110.29859496
556 Bartlett BA, Iverson KM, Mitchell KS. Intimate partner violence and disordered eating among male and female veterans. Psychiatry Research. 2018;260:98–104.29179017
557 Meredith LS, Azhar G, Okunogbe A, . Primary Care Providers with More Experience and Stronger Self-Efficacy Beliefs Regarding Women Veterans Screen More Frequently for Interpersonal Violence. Women’s Health Issues. 2017;27(5):586–591.28754476
558 Iverson KM, Vogt D, Maskin RM, Smith BN. Intimate Partner Violence Victimization and Associated Implications for Health and Functioning Among Male and Female Post-9/11 Veterans. Med Care. 2017;55 Suppl 9 Suppl 2:S78–S84.28806369
559 Dichter ME, Sorrentino A, Bellamy S, . Disproportionate Mental Health Burden Associated With Past-Year Intimate Partner Violence Among Women Receiving Care in the Veterans Health Administration. Journal of Traumatic Stress. 2017;30(6):555–563.29193289
560 Dichter ME, Haywood TN, Butler AE, . Intimate Partner Violence Screening in the Veterans Health Administration: Demographic and Military Service Characteristics. American Journal of Preventive Medicine. 2017;52(6):761–768.28209282
561 Dardis CM, Shipherd JC, Iverson KM. Intimate partner violence among women veterans by sexual orientation. Women & Health. 2017;57(7):775–791.27322372
562 Dardis CM, Amoroso T, Iverson KM. Intimate partner stalking: Contributions to PTSD symptomatology among a national sample of women veterans. Psychological trauma : theory, research, practice and policy. 2017;9:67–73.27414469
563 Creech SK, Macdonald A, Taft C. Use and Experience of Recent Intimate Partner Violence Among Women Veterans Who Deployed to Iraq and Afghanistan. Partner Abuse. 2017;8(3):251–271.
564 Kimerling R, Iverson KM, Dichter ME, . Prevalence of Intimate Partner Violence among Women Veterans who Utilize Veterans Health Administration Primary Care. J Gen Intern Med. 2016;31(8):888–894.27130619
565 Iverson KM, Stirman SW, Street AE, . Female veterans’ preferences for counseling related to intimate partner violence: Informing patient-centered interventions. General Hospital Psychiatry. 2016;40:33–38.27083252
566 Rodriguez L, King PR, Buchholz LJ. Associations among military sexual trauma, positive alcohol expectancies, and coping behaviors in female veterans. Psychological trauma : theory, research, practice and policy. 2023.
567 Reinhardt KM, McCaughey VK, Vento SA, Street AE. In Their Own Words: Women Veterans Identify the Personal Consequences of Military Sexual Trauma Victimization. Violence against women. 2023:10778012221147909.
568 Monteith LL, Kittel JA, Schneider AL, . Military Sexual Trauma Among Women Veterans Using Veterans Health Administration Reproductive Health Care: Screening Challenges and Associations with Post-Military Suicidal Ideation and Suicide Attempts. Journal of Interpersonal Violence. 2023;38(11/12):7578–7601.36695157
569 Kalvesmaki AF, Trevino AY, Charron E, . The Impact of Resilience on Employment Among Post-9/11 Veterans With and Without Military Sexual Trauma Exposure. Military medicine. 2023.
570 Holliday R, Holder N, Smith AA, . Military sexual trauma among Veterans using and not using VA justice-related programing: A national examination. Journal of Psychiatric Research. 2023;164:46–50.37311403
571 Hargrave AS, Danan ER, Than CT, . Factors Associated with Military Sexual Trauma (MST) Disclosure During VA Screening Among Women Veterans. J Gen Intern Med. 2023.
572 Galovski TE, McSweeney LB, Woolley MG, . The Relative Impact of Different Types of Military Sexual Trauma on Long-Term PTSD, Depression, and Suicidality. Journal of Interpersonal Violence. 2023;38(15/16):9465–9491.37102588
573 R K B, A K Z, W S L. Interpersonal Trauma and Sexual Function and Satisfaction: The Mediating Role of Negative Affect Among Survivors of Military Sexual Trauma. J Interpers Violence. 2022;37(7–8):NP5517–NP5537.32990170
574 Preston AM, Saigal S, Barrie R, . Defeated No More: Meaning-Making After Military Sexual Trauma. Military medicine. 2022.
575 Paulson JL, Florimbio AR, Rogers TA, . Contrasting ecological contexts among treatment-seeking military sexual assault survivors: Consideration of relationships with sexual and gender minority identification. Psychological services. 2022.
576 Patel TA, Mann AJ, Nomamiukor FO, . Correlates and clinical associations of military sexual assault in Gulf War era U.S. veterans: Findings from a national sample. Journal of Traumatic Stress. 2022;35(4):1240–1251.35355332
577 Nichter B, Holliday R, Monteith LL, . Military sexual trauma in the United States: Results from a population-based study. Journal of Affective Disorders. 2022;306:19–27.35301038
578 Monteith LL, Holder N, Iglesias CD, Holliday R. Institutional Betrayal and Closeness Among Women Veteran Survivors of Military Sexual Trauma: Associations with Self-Directed Violence and Mental Health Symptoms. Journal of Trauma and Dissociation. 2022.
579 McBain SA, Garneau-Fournier J, Turchik JA. The Relationship Between Provider Gender Preferences and Perceptions of Providers Among Veterans Who Experienced Military Sexual Trauma. Journal of Interpersonal Violence. 2022;37(5/6):NP2868–NP2890.32741237
580 Hargrave AS, Maguen S, Inslicht SS, . Veterans Health Administration Screening for Military Sexual Trauma May Not Capture Over Half of Cases Among Midlife Women Veterans. Women’s Health Issues. 2022;32(5):509–516.35821182
581 Gaffey AE, Rosman L, Sico JJ, . Military sexual trauma and incident hypertension: a 16-year cohort study of young and middle-aged men and women. Journal of Hypertension. 2022;40(11):2307–2315.35983872
582 Wiblin J, Holder N, Holliday R, Surís A. Predictors of Unbearability, Unlovability, and Unsolvability in Veterans With Military-Sexual-Trauma-Related Posttraumatic Stress Disorder. Journal of Interpersonal Violence. 2021;36(7/8):3814–3830.29848187
583 Wiblin J, Holder N, Holliday R, . A Factor Analysis of the Suicide Cognitions Scale in Veterans with Military Sexual Trauma-Related Posttraumatic Stress Disorder. Journal of Trauma & Dissociation. 2021;22(3):319–331.33460353
584 Tannahill HS, Fargo JD, Barrett TS, Blais RK. Gender as a moderator of the association of military sexual trauma and posttraumatic stress symptoms. Journal of clinical psychology. 2021;77(10):2262–2287.33991354
585 Sumner JA, Lynch KE, Viernes B, . Military Sexual Trauma and Adverse Mental and Physical Health and Clinical Comorbidity in Women Veterans. Women’s Health Issues. 2021;31(6):586–595.34479786
586 Street AE, Shin MH, Marchany KE, . Veterans’ perspectives on military sexual trauma-related communication with VHA providers. Psychological services. 2021;18(2):249–259.31621356
587 Newins AR, Glenn JJ, Wilson LC, . Psychological outcomes following sexual assault: Differences by sexual assault setting. Psychological services. 2021;18(4):504–511.32271049
588 Monteith LL, Schneider AL, Holliday R, Bahraini NH. Assessing Institutional Betrayal Among Female Veterans Who Experienced Military Sexual Trauma: A Rasch Analysis of the Institutional Betrayal Questionnaire.2. Journal of Interpersonal Violence. 2021;36(23/24):10861–10883.33403916
589 Monteith LL, Holliday R, Schneider AL, . Institutional betrayal and help-seeking among women survivors of military sexual trauma. Psychological trauma : theory, research, practice and policy. 2021;13(7):814–823.33764096
590 Kelly UA. Barriers to PTSD treatment-seeking by women veterans who experienced military sexual trauma decades ago: The role of institutional betrayal. Nursing Outlook. 2021;69(3):458–470.33863545
591 Hannan SM, Thomas KB, Allard CB. Posttraumatic Stress Symptom Severity Mediates the Relationship Between Military Sexual Trauma and Tension Reduction Behaviors in Male and Female Veterans. Journal of Interpersonal Violence. 2021;36(17/18):NP10035–NP10054.31315500
592 Felder S, Delany PJ. Life course perspective on the role of military sexual trauma as a pathway to homelessness for female Veterans. Journal of Military, Veteran & Family Health. 2021;7:69–75.
593 Blais RK, Livingston WS. The association of assault military sexual trauma and sexual function among partnered female service members and veterans: the mediating roles of depression and sexual self-schemas. European journal of psychotraumatology. 2021;12(1):1872964.34531961
594 Monteith LL, Bahraini NH, Gerber HR, . Military sexual trauma survivors’ perceptions of veterans health administration care: A qualitative examination. Psychological services. 2020;17(2):178–186.30265071
595 Khan AJ, Holder N, Li Y, . How do gender and military sexual trauma impact PTSD symptoms in cognitive processing therapy and prolonged exposure? Journal of Psychiatric Research. 2020;130:89–96.32798774
596 Gross GM, Ronzitti S, Combellick JL, . Sex Differences in Military Sexual Trauma and Severe Self-Directed Violence. American Journal of Preventive Medicine. 2020;58(5):675–682.32037020
597 Gibson CJ, Maguen S, Xia F, . Military Sexual Trauma in Older Women Veterans: Prevalence and Comorbidities. JGIM: Journal of General Internal Medicine. 2020;35(1):207–213.31713042
598 Garneau-Fournier J, McBain S, Turchik JA. Factors Associated with Sexual Satisfaction among Veterans Who Have Experienced Military Sexual Trauma. Journal of Sex & Marital Therapy. 2020;46(8):721–735.32847446
599 Pulverman CSP, Creech SKP, Mengeling MAP, . Sexual Assault in the Military and Increased Odds of Sexual Pain Among Female Veterans. Obstetrics & Gynecology. 2019;134(1):63–71.31188311
600 Holder N, Holliday R, Wiblin J, . Predictors of dropout from a randomized clinical trial of cognitive processing therapy for female veterans with military sexual trauma-related PTSD. Psychiatry Research. 2019;276:87–93.31030005
601 Gundlapalli AV, Jones AL, Redd A, . Combining Natural Language Processing of Electronic Medical Notes With Administrative Data to Determine Racial/Ethnic Differences in the Disclosure and Documentation of Military Sexual Trauma in Veterans. Medical Care. 2019;57:S149–S156.31095054
602 Gross GM, Laws H, Park CL, . Meaning in life following deployment sexual trauma: Prediction of posttraumatic stress symptoms, depressive symptoms, and suicidal ideation. Psychiatry Research. 2019;278:78–85.31158725
603 Dichter ME, Sorrentino AE, Haywood TN, . Women’s Participation in Research on Intimate Partner Violence: Findings on Recruitment, Retention, and Participants’ Experiences. Women’s Health Issues. 2019;29(5):440–446.31072755
604 Cichowski S, Ashley M, Ortiz O, Dunivan G. Female Veterans’ Experiences With VHA Treatment for Military Sexual Trauma. Fed. 2019;36(1):41–47.
605 Bovin MJ, Black SK, Kleiman SE, . The Impact of Assessment Modality and Demographic Characteristics on Endorsement of Military Sexual Trauma. Women’s Health Issues. 2019;29:S67–S73.31253245
606 Bergman AA, Hamilton AB, Chrystal JG, . Primary Care Providers’ Perspectives on Providing Care to Women Veterans with Histories of Sexual Trauma. Women’s Health Issues. 2019;29(4):325–332.31027706
607 Averill LA, Smith NB, Holens PL, . Sex Differences in Correlates of Risk and Resilience Associated with Military Sexual Trauma. Journal of Aggression, Maltreatment & Trauma. 2019;28(10):1199–1215.
608 Pandey N, Ashfaq SN, Dauterive EW, . Military Sexual Trauma and Obesity Among Women Veterans. Journal of Women’s Health (15409996). 2018;27(3):305–310.
609 Gross GM, Cunningham KC, Moore DA, . Does Deployment-Related Military Sexual Assault Interact with Combat Exposure to Predict Posttraumatic Stress Disorder in Female Veterans? Traumatology. 2018.
610 Freysteinson WM, Mellott S, Celia T, . Body Image Perceptions of Women Veterans With Military Sexual Trauma. Issues in Mental Health Nursing. 2018;39(8):623–632.29648911
611 Foynes MM, Street AE, Dardis CM, . “Who Are You Going to Tell? Who’s Going to Believe You?”. Psychology of Women Quarterly. 2018;42(4):414–429.
612 Dardis CM, Vento SA, Gradus JL, Street AE. Labeling of deployment sexual harassment experiences among male and female veterans. Psychological Trauma: Theory, Research, Practice & Policy. 2018;10(4):452–455.29154590
613 Calhoun PS, Schry AR, Dennis PA, . The Association Between Military Sexual Trauma and Use of VA and Non-VA Health Care Services Among Female Veterans With Military Service in Iraq or Afghanistan. Journal of Interpersonal Violence. 2018;33(15):2439–2464.26802046
614 Brownstone LM, Gerber HR, Holliman BD, Monteith LL. The Phenomenology of Military Sexual Trauma Among Women Veterans. Psychology of Women Quarterly. 2018;42(4):399–413.
615 Blais RK, Brignone E, Fargo JD, . Assailant identity and self-reported nondisclosure of military sexual trauma in partnered women veterans. Psychological Trauma: Theory, Research, Practice & Policy. 2018;10(4):470–474.29016157
616 Beckman K, Shipherd J, Simpson T, Lehavot K. Military Sexual Assault in Transgender Veterans: Results From a Nationwide Survey. Journal of Traumatic Stress. 2018;31(2):181–190.29603392
617 Story KM, Beck BD. Guided Imagery and Music with female military veterans: An intervention development study. Arts in Psychotherapy. 2017;55:93–102.
618 Katz LS, Huffman C, Cojucar G. In Her Own Words: Semi-structured Interviews of Women Veterans Who Experienced Military Sexual Assault. Journal of Contemporary Psychotherapy. 2017;47(3):181–189.
619 Gundlapalli AV, Brignone E, Divita G, . Using Structured and Unstructured Data to Refine Estimates of Military Sexual Trauma Status Among US Military Veterans. Studies in health technology and informatics. 2017;238:128–131.28679904
620 Brignone E, Gundlapalli AV, Blais RK, . Increased Health Care Utilization and Costs Among Veterans With a Positive Screen for Military Sexual Trauma. Med Care. 2017;55 Suppl 9 Suppl 2:S70–S77.28806368
621 Blais RK, Brignone E, Maguen S, . Military sexual trauma is associated with post-deployment eating disorders among Afghanistan and Iraq veterans. International Journal of Eating Disorders. 2017;50(7):808–816.28401580
622 Wolff KB, Mills PD. Reporting Military Sexual Trauma: A Mixed-Methods Study of Women Veterans’ Experiences Who Served From World War II to the War in Afghanistan. Military Medicine. 2016;181(8):840–848.27483522
623 Laws H, Mazure CM, McKee SA, . Within-unit relationship quality mediates the association between military sexual trauma and posttraumatic stress symptoms in veterans separating from military service. Psychological trauma : theory, research, practice and policy. 2016;8(5):649–656.26963956
624 Kimerling R, Makin-Byrd K, Louzon S, . Military Sexual Trauma and Suicide Mortality. American Journal of Preventive Medicine. 2016;50(6):684–691.26699249
625 Gilmore AK, Brignone E, Painter JM, . Military Sexual Trauma and Co-occurring Posttraumatic Stress Disorder, Depressive Disorders, and Substance Use Disorders among Returning Afghanistan and Iraq Veterans. Women’s Health Issues. 2016;26(5):546–554.27528358
626 Gibson CJ, Gray KE, Katon JG, . Sexual Assault, Sexual Harassment, and Physical Victimization during Military Service across Age Cohorts of Women Veterans. Women’s Health Issues. 2016;26(2):225–231.26632005
627 Gaher RM, O’Brien C, Smiley P, Hahn AM. Alexithymia, Coping Styles and Traumatic Stress Symptoms in a Sample of Veterans Who Experienced Military Sexual Trauma. Stress & Health: Journal of the International Society for the Investigation of Stress. 2016;32(1):55–62.25393043
628 Barth SK, Kimerling RE, Pavao J, . Military Sexual Trauma Among Recent Veterans: Correlates of Sexual Assault and Sexual Harassment. American Journal of Preventive Medicine. 2016;50(1):77–86.26232906
629 Rossi FS, Nillni Y, Fox AB, Galovski TE. The association between lifetime trauma exposure typologies and mental health outcomes among veterans. Psychiatry Research. 2023;326.
630 Esopenko C, de Souza N, Wilde EA, . Characterizing the Influence of Exposure to Military Sexual Trauma and Intimate Partner Violence on Mental Health Outcomes among Female Veterans. Journal of Interpersonal Violence. 2023;38(13/14):8476–8499.36866584
631 Relyea MR, Portnoy GA, Combellick JL, . Military Sexual Trauma and Intimate Partner Violence: Subtypes, Associations, and Gender Differences. Journal of Family Violence. 2020;35(4):349–360.
632 Combellick JL, Dziura J, Portnoy GA, . Trauma and Sexual Risk: Do Men and Women Veterans Differ? Womens Health Issues. 2019;29 Suppl 1:S74–S82.31253246
633 Dichter ME, Wagner C, True G. Women Veterans’ Experiences of Intimate Partner Violence and Non-Partner Sexual Assault in the Context of Military Service: Implications for Supporting Women’s Health and Well-Being. Journal of Interpersonal Violence. 2018;33(6):843–864.27655865
634 Bomyea J, Allard CB. Trauma-Related Disgust in Veterans With Interpersonal Trauma. Journal of Traumatic Stress. 2017;30(2):149–156.28429858
635 Schry AR, Beckham JC, The Va Mid-Atlantic Mirecc W, Calhoun PS. Sexual revictimization among Iraq and Afghanistan war era veterans. Psychiatry Res. 2016;240:406–411.27149409
636 Monteith LL, Miller CN, Polzer E, . “Feel the need to prepare for Armageddon even though I do not believe it will happen”: Women Veterans’ Firearm Beliefs and Behaviors during the COVID-19 Pandemic, Associations with Military Sexual Assault and Posttraumatic Stress Disorder Symptoms. PLoS One. 2023;18(2 February).
637 Monteith LL, Kinney AR, Holliday R, . Associations between deployment experiences, safety-related beliefs, and firearm ownership among women Veterans. Journal of Psychiatric Research. 2023;157:72–81.36442409
638 Monteith LL, Holliday R, Dorsey Holliman BA, . Understanding female veterans’ experiences and perspectives of firearms. Journal of clinical psychology. 2020;76(9):1736–1753.32227687
639 Williams EC, Fletcher OV, Frost MC, . Comparison of Substance Use Disorder Diagnosis Rates From Electronic Health Record Data With Substance Use Disorder Prevalence Rates Reported in Surveys Across Sociodemographic Groups in the Veterans Health Administration. JAMA Network Open. 2022;5(6):e2219651–e2219651.35771574
640 Waddell JT, Gress-Smith JL, Hartman JD, . Age, sex, and race-varying rates of alcohol use, cannabis use, and alcohol and cannabis co-use in veterans vs. non-veterans. Addictive Behaviors. 2022;134:N.PAG-N.PAG.
641 Stefanovics EA, Rhee TG, Rosenheck RA. Long-term impact of the U.S. Armed forces Zero-Tolerance drug policy on female veterans. Journal of Addictive Diseases. 2022;40(1):26–34.33988491
642 Hasin DS, Saxon AJ, Malte C, . Trends in Cannabis Use Disorder Diagnoses in the U.S. Veterans Health Administration, 2005-2019. American Journal of Psychiatry. 2022;179(10):748–757.35899381
643 Begley MR, Ravindran C, Peltzman T, . Veteran drug overdose mortality, 2010-2019. Drug Alcohol Depend. 2022;233:N.PAG-N.PAG.
644 Peltier MR, Sofuoglu M, Petrakis IL, . Sex Differences in Opioid Use Disorder Prevalence and Multimorbidity Nationally in the Veterans Health Administration. J Dual Diagn. 2021;17(2):124–134.33982642
645 Peltzman T, Ravindran C, Schoen PM, . Brief Report: Opioid-Involved Overdose Mortality in United States Veterans. American Journal on Addictions. 2020;29(4):340–344.32223045
646 Agaku I, Odani S, Nelson JR. U.S. Military Veteran Versus Nonveteran Use of Licit and Illicit Substances. American Journal of Preventive Medicine. 2020;59(5):733–741.33012620
647 Kalpakci A, Sofuoglu M, Petrakis I, Rosenheck RA. Gender differences among Veterans with alcohol use disorder nationally in the Veterans Health Administration. Journal of Addictive Diseases. 2018;37(3/4):185–194.31429377
648 Hoggatt KJ, Lehavot K, Krenek M, . Prevalence of substance misuse among US veterans in the general population. American Journal on Addictions. 2017;26(4):357–365.28370701
649 Grossbard J, Malte CA, Lapham G, . Prevalence of Alcohol Misuse and Follow-Up Care in a National Sample of OEF/OIF VA Patients With and Without TBI. Psychiatric Services. 2017;68(1):48–55.27476804
650 Williams EC, Gupta S, Rubinsky AD, . Racial/Ethnic Differences in the Prevalence of Clinically Recognized Alcohol Use Disorders Among Patients from the U.S. Veterans Health Administration. Alcoholism: Clinical & Experimental Research. 2016;40(2):359–366.26842254
651 Shahoumian TA, Phillips BR, Backus LI. Cigarette Smoking, Reduction and Quit Attempts: Prevalence Among Veterans With Coronary Heart Disease. Preventing Chronic Disease. 2016;13:1–12.
652 Bastian LA, Gray KE, DeRycke E, . Differences in Active and Passive Smoking Exposures and Lung Cancer Incidence Between Veterans and Non-Veterans in the Women’s Health Initiative. Gerontologist. 2016;56 Suppl 1:S102–11.26768384
653 Bachrach RL, Blosnich JR, Williams EC. Alcohol screening and brief intervention in a representative sample of veterans receiving primary care services. J Subst Abuse Treat. 2018;95:18–25.30352666
654 Williams EC, Lapham GT, Rubinsky AD, . Influence of a targeted performance measure for brief intervention on gender differences in receipt of brief intervention among patients with unhealthy alcohol use in the Veterans Health Administration. J Subst Abuse Treat. 2017;81:11–16.28847450
655 Buckheit KA, Pengelly C, Ramon A, . Rates and Correlates of Alcohol and Substance Use Among Women Veterans During the COVID-19 Pandemic: The Moderating Role of COVID-Specific Anxiety. Women’s Health Issues. 2023;33(3):250–257.37003919
656 Beckman KL, Williams EC, Hebert PL, . Associations Among Military Sexual Trauma, Opioid Use Disorder, and Gender. American Journal of Preventive Medicine. 2022;62(3):377–386.34742619
657 Beckman KL, Williams EC, Hebert P, . The impact of military sexual trauma and gender on receipt of evidence-based medication treatment among veterans with opioid use disorder. J Subst Abuse Treat. 2022;139:N.PAG-N.PAG.
658 Livingston NA, Lee DJ, Mahoney CT, . Longitudinal assessment of PTSD and illicit drug use among male and female OEF-OIF veterans. Addictive Behaviors. 2021;118:N.PAG-N.PAG.
659 Mahoney CT, Zweig IR, Marx BP, Keane TM. Cross-lagged effects of posttraumatic stress disorder symptom severity and cigarette smoking among OEF/OIF/OND veterans. Depression and Anxiety. 2020;37(11):1118–1126.32851756
660 Mahoney CT, Iverson KM. The Roles of Alcohol Use Severity and Posttraumatic Stress Disorder Symptoms as Risk Factors for Women’s Intimate Partner Violence Experiences. Journal of Women’s Health (15409996). 2020;29(6):827–836.
661 Gross GM, Bastian LA, Smith NB, . Sex Differences in Associations between Depression and Posttraumatic Stress Disorder Symptoms and Tobacco Use among Veterans of Recent Conflicts. Journal of Women’s Health. 2020;29(5):677–685.
662 Gross GM, Colon R, Bastian LA, Hoff R. Perceived Stress Mediates the Association between Deployment Sexual Trauma and Nicotine Dependence in Women Veterans. Women’s Health Issues. 2020;30(3):214–220.32317136
663 Goldberg SB, Livingston WS, Blais RK, . A positive screen for military sexual trauma is associated with greater risk for substance use disorders in women veterans. Psychology of Addictive Behaviors. 2019;33(5):477–483.31246067
664 Yalch MM, Hebenstreit CL, Maguen S. Influence of military sexual assault and other military stressors on substance use disorder and PTS symptomology in female military veterans. Addictive Behaviors. 2018;80:28–33.29310004
665 Evans EA, Upchurch DM, Simpson T, . Differences by Veteran/civilian status and gender in associations between childhood adversity and alcohol and drug use disorders. Social Psychiatry & Psychiatric Epidemiology. 2018;53(4):421–435.29188311
666 Browne KC, Dolan M, Simpson TL, . Regular past year cannabis use in women veterans and associations with sexual trauma. Addictive Behaviors. 2018;84:144–150.29684763
667 Gradus JL, Leatherman S, Curreri A, . Gender differences in substance abuse, PTSD and intentional self-harm among veterans health administration patients. Drug Alcohol Depend. 2017:66–69.
668 Japuntich SJ, Gregor K, Pineles SL, . Deployment stress, tobacco use, and postdeployment posttraumatic stress disorder: Gender differences. Psychological trauma : theory, research, practice and policy. 2016;8(2):123–126.26654688
669 Ruiz RA, Lehavot K, Heffner JL, . Cigarette Smoking Motives and Stages of Change in Smoking Cessation Among Veterans: Differences by Gender and Sexual Orientation. American journal of health promotion : AJHP. 2023:8901171231197147.
670 Livingston NA, Gatsby E, Shipherd JC, Lynch KE. Causes of alcohol-attributable death and associated years of potential life lost among LGB and non-LGB veteran men and women in Veterans Health Administration. Addictive Behaviors. 2023;139:N.PAG-N.PAG.
671 Lynch KE, Livingston NA, Gatsby E, . Alcohol-attributable deaths and years of potential life lost due to alcohol among veterans: Overall and between persons with minoritized and non-minoritized sexual orientations. Drug Alcohol Depend. 2022;237:N.PAG-N.PAG.
672 Fletcher OV, Chen JA, van Draanen J, . Prevalence of social and economic stressors among transgender veterans with alcohol and other drug use disorders. SSM - Population Health. 2022;19.
673 Williams EC, Frost MC, Rubinsky AD, . Patterns of Alcohol Use Among Transgender Patients Receiving Care at the Veterans Health Administration: Overall and Relative to Nontransgender Patients. Journal of Studies on Alcohol & Drugs. 2021;82(1):132–141.33573731
674 Williams EC, Chen JA, Frost MC, . Receipt of evidence-based alcohol-related care in a national sample of transgender patients with unhealthy alcohol use: Overall and relative to non-transgender patients. J Subst Abuse Treat. 2021;131:N.PAG-N.PAG.
675 Frost MC, Blosnich JR, Lehavot K, . Disparities in Documented Drug Use Disorders Between Transgender and Cisgender U.S. Veterans Health Administration Patients. J Addict Med. 2021;15(4):334–340.33252409
676 Dawson DB, White DL, Chiao E, . Mental and Physical Health Correlates of Tobacco Use Among Transgender Veterans of the Iraq and Afghanistan Conflicts. Transgender Health. 2021;6(5):290–295.34993301
677 Anderson-Carpenter KD, Rutledge JD, Mitchell K. Prescription opioid misuse among heterosexual versus lesbian, gay, and bisexual military veterans: Evidence from the 2015-2017 national survey of drug use and health. Drug Alcohol Depend. 2020;207:N.PAG-N.PAG.
678 Bukowski LA, Blosnich J, Shipherd JC, . Exploring Rural Disparities in Medical Diagnoses Among Veterans With Transgender-related Diagnoses Utilizing Veterans Health Administration Care. Med Care. 2017;55 Suppl 9 Suppl 2:S97–S103.28806372
679 Lehavot K, Williams EC, Millard SP, . Association of Alcohol Misuse With Sexual Identity and Sexual Behavior in Women Veterans. Substance Use & Misuse. 2016;51(2):216–229.26800263
680 Bachrach RL, Quinn DA. The role of gender and veteran status in healthcare access among a national sample of U.S. adults with unhealthy alcohol use. Substance Use & Misuse. 2023;58(4):491–499.36722613
681 Pugatch M, Chang G, Garnick D, . Rates and predictors of brief intervention for women veterans returning from recent wars: Examining gaps in service delivery for unhealthy alcohol use. J Subst Abuse Treat. 2021;123:N.PAG-N.PAG.
682 Meshberg-Cohen S, Gross GM, Kachadourian LK, Harpaz-Rotem I. Binge drinking following residential treatment for posttraumatic stress disorder among veterans with and without alcohol use disorder. Journal of Psychiatric Research. 2021;143:202–208.34500350
683 Chen JA, Glass JE, Bensley KMK, . Racial/ethnic and gender differences in receipt of brief intervention among patients with unhealthy alcohol use in the U.S. Veterans Health Administration. J Subst Abuse Treat. 2020;119:N.PAG-N.PAG.
684 Berg KM, Gruber SJ, Jorenby DE. Helping women veterans quit smoking: a qualitative analysis of successful and unsuccessful attempts. BMC Women’s Health. 2020;20(1):1–7.31898500
685 Wilson SM, Medenblik AM, Neal JM, . Lifetime Smoking Patterns and Preferences for Smoking Cessation Among Women Veterans Receiving Veterans Health Administration Care. Qualitative Health Research. 2019;29(14):2096–2107.31307290
686 Taylor E, Timko C, Harris AHS, . Receipt of pharmacotherapy for alcohol use disorder by justice-involved women in the Veterans Health Administration. Addiction science & clinical practice. 2019;14(1):1.30602392
687 Painter JM, Brignone E, Gilmore AK, . Gender differences in service utilization among Operations Enduring Freedom, Iraqi Freedom, and New Dawn Veterans Affairs patients with severe mental illness and substance use disorders. Psychological services. 2018;15(1):11–20.28517950
688 Abraham TH, Lewis ET, Cucciare MA. Providers’ Perspectives on Barriers and Facilitators to Connecting Women Veterans to Alcohol-Related Care From Primary Care. Military medicine. 2017;182(9):e1888–e1894.28885951
689 Myers MG, Chen T, Schweizer CA. Factors Associated With Accepting Assistance for Smoking Cessation Among Military Veterans. Nicotine & Tobacco Research. 2016;18(12):2288–2292.27613903
690 Lewis ET, Jamison AL, Ghaus S, . Receptivity to alcohol-related care among U.S. women Veterans with alcohol misuse. Journal of Addictive Diseases. 2016;35(4):226–237.27049338
691 Chen JI, Cameron DC, Laliberte AZ, . Assessment of Suicidal Intent in Self-directed Violence and Subsequent Care Received Among Military Veterans: A National Study of Gender Differences. Medical Care. 2021;59(2):S17–S22.33438878
692 Krishnamurti LS, Agha A, Denneson LM, . Gender Differences in Connecting Veterans to Care Through the Veterans Crisis Line: A Mixed Methods Evaluation of Referrals to Suicide Prevention Coordinators. Medical Care. 2023;61(1):50–53.36477620
693 Chhatre S, Hoffmire CA, Bellamy SL, . Relationship between Veterans Crisis Line risk rating and subsequent suicidal self-directed violence among veteran callers: A gender comparison. Suicide & life-threatening behavior. 2023.
694 Dichter ME, Krishnamurti LS, Chhatre S, . Gender differences in veterans’ use of the Veterans Crisis Line (VCL): Findings from VCL call data. General Hospital Psychiatry. 2022;74:65–70.34923376
695 Dichter ME, Chhatre S, Hoffmire C, . Variation in call volume to the Veterans Crisis Line by women and men veterans prior to and following onset of the COVID-19 pandemic. Journal of Psychiatric Research. 2022;151:561–563.35636032
696 Hoffmire CA, Barth SK, Bossarte RM. Reevaluating Suicide Mortality for Veterans With Data From the VA-DoD Mortality Data Repository, 2000-2010. Psychiatric Services. 2020;71(6):612–615.32089080
697 Stefanovics EA, Potenza MN, Tsai J, . Sex-specific risk and resilience correlates of suicidal ideation in U.S. military veterans. Journal of Affective Disorders. 2023;328:303–311.36775254
698 Zelkowitz RL, Mitchell KS, Grossman SL, . Latent Class Analysis of Self-directed Violence and Indirect Self-harm Behaviors: Gender Differences and Associations With Mental Health Symptoms. Medical Care. 2021;59(2):S51–S57.33438883
699 Androulakis XM, Guo S, Zhang J, . Suicide attempts in us veterans with chronic headache disorders: A 10-year retrospective cohort study. Journal of Pain Research. 2021;14:2629–2639.34466030
700 Aslan M, Radhakrishnan K, Rajeevan N, . Suicidal ideation, behavior, and mortality in male and female US veterans with severe mental illness. Journal of Affective Disorders. 2020;267:144–152.32063566
701 Bohnert KM, Ilgen MA, Louzon S, . Substance use disorders and the risk of suicide mortality among men and women in the US Veterans Health Administration. Addiction. 2017;112(7):1193–1201.28301070
702 Blosnich JR, Brenner LA, Bossarte RM. Population mental health among U.S. military veterans: results of the Veterans Health Module of the Behavioral Risk Factor Surveillance System, 2011-2012. Annals of Epidemiology. 2016;26(8):592–596.27448820
703 Monteith LL, Smith NB, Holliday R, Pietrzak RH. Psychiatric and Interpersonal Correlates of Suicide Ideation in Military Sexual Trauma Survivors: The National Health and Resilience in Veterans Study. Chronic Stress. 2018;2:1–1.
704 Zelkowitz RL, Kehle-Forbes SM, Smith BN, . Associations between DSM-5 posttraumatic stress disorder Criterion E2 endorsement and selected self-destructive behaviors in recent-era veterans: A focus on disordered eating. Journal of traumatic stress. 2023.
705 Decker SE, Ramsey CM, Ronzitti S, . Military sexual trauma and suicidal ideation in VHA-care-seeking OEF/OIF/OND veterans without mental health diagnosis or treatment. Psychiatry Research. 2021;303.
706 Bullman T, Schneiderman A. Risk of suicide among U.S. veterans who deployed as part of Operation Enduring Freedom, Operation Iraqi Freedom, and Operation New Dawn. Injury Epidemiology. 2021;8(1):1–9.33423690
707 Ronzitti S, Loree AM, Potenza MN, . Gender Differences in Suicide and Self-Directed Violence Risk Among Veterans With Post-traumatic Stress and Substance Use Disorders. Womens Health Issues. 2019;29 Suppl 1:S94–S102.31253249
708 Monteith LL, Hoffmire CA, Holliday R, . Do unit and post-deployment social support influence the association between deployment sexual trauma and suicidal ideation? Psychiatry Research. 2018;270:673–681.30384288
709 Gradus JL, King MW, Galatzer-Levy I, . Gender Differences in Machine Learning Models of Trauma and Suicidal Ideation in Veterans of the Iraq and Afghanistan Wars. Journal of Traumatic Stress. 2017;30(4):362–371.28741810
710 Blosnich JR, Garfin DR, Maguen S, . Differences in childhood adversity, suicidal ideation, and suicide attempt among veterans and nonveterans. American Psychologist. 2021;76(2):284–299.33734795
711 Horwitz AG, Smith DL, Held P, Zalta AK. Characteristics of Veteran and Civilian Suicide Decedents: A Sex-Stratified Analysis. American Journal of Preventive Medicine. 2019;56(5):e163–e168.30898537
712 Monteith LL, Holliday R, Miller C, . Suicidal ideation, suicide attempt, and non-suicidal self-injury among female veterans: Prevalence, timing, and onset. Journal of Affective Disorders. 2020;273:350–357.32560928
713 Monteith LL, Holliday R, Hoffmire CA, Bahraini NH. Female Veterans’ Willingness to Seek Veterans Health Administration and Non-Veterans Health Administration Services for Suicidal Thoughts and Mental Health Concerns. Medical Care. 2021;59(2):S23–S30.33438879
714 Brignone E, Sorrentino AE, Roberts CB, Dichter ME. Suicidal ideation and behaviors among women veterans with recent exposure to intimate partner violence. General Hospital Psychiatry. 2018;55:60–64.30412860
715 Monteith LL, Bahraini NH, Menefee DS. Perceived Burdensomeness, Thwarted Belongingness, and Fearlessness about Death: Associations With Suicidal Ideation among Female Veterans Exposed to Military Sexual Trauma. Journal of clinical psychology. 2017;73(12):1655–1669.28186637
716 Khan AJ, Li Y, Dinh JV, . Examining the impact of different types of military trauma on suicidality in women veterans. Psychiatry Research. 2019;274:7–11.30776710
717 Monteith LL, Holliday R, Miller CN, . Prevalence and Correlates of Firearm Access Among Post-9/11 US Women Veterans Using Reproductive Healthcare: a Cross-Sectional Survey. JGIM: Journal of General Internal Medicine. 2022;37:714–723.
718 Lawrence KA, Vogt D, Dugan AJ, . Psychosocial functioning deficits impact and are impacted by suicidal ideation in post-9/11 women veterans. J Affect Disord Rep. 2022;9.
719 Tucker RP, Testa RJ, Reger MA, . Current and Military-Specific Gender Minority Stress Factors and Their Relationship with Suicide Ideation in Transgender Veterans. Suicide & Life-Threatening Behavior. 2019;49(1):155–166.29327446
720 Carter SP, Allred KM, Tucker RP, . Discrimination and Suicidal Ideation Among Transgender Veterans: The Role of Social Support and Connection. LGBT Health. 2019;6(2):43–50.30714839
721 Tucker RP, Testa RJ, Simpson TL, . Hormone therapy, gender affirmation surgery, and their association with recent suicidal ideation and depression symptoms in transgender veterans. Psychological Medicine. 2018;48(14):2329–2336.29331161
722 Sayer NA, Nelson DB, Gradus JL, . The Effects of Suicide Exposure on Mental Health Outcomes Among Post-9/11 Veterans: Protocol for an Explanatory, Sequential, Mixed Methods Study. JMIR Res Protoc. 2023;12:e51324.37751271
723 Solness CL, Holdefer PJ, Hsu T, . Relationship Factors in Internet-Delivered Psychological Interventions for Veterans Experiencing Postpartum Depression: Qualitative Analysis. JMIR Mental Health. 2023;10.
724 Howard M, Ledoux T, Llaneza D, . Exploring the prevalence of antidepressant medication discontinuation among pregnant veterans. Archives of Women’s Mental Health. 2023.
725 Anderson EH, Morrow C, Mattocks KM, Shivakumar G. Perinatal Symptoms and Treatment Engagement in Female Veterans. Military Medicine. 2023;188(3/4):e468–e472.34244790
726 Kroll-Desrosiers A, Copeland LA, Kuzdeba J, . Exploring the Extent of Perinatal Depression Screening in the Health Records of Veterans. Administration and policy in mental health. 2021;48(4):608–618.33140222
727 Kroll-Desrosiers AR, Crawford SL, Moore Simas TA, . Treatment and Management of Depression Symptoms in Pregnant Veterans: Varying Experiences of Mental Health Care in the Prenatal Period. Psychiatric Quarterly. 2020;91(2):475–493.32008211
728 Pratt AA, Sadler AG, Thomas EBK, . Incidence and risk factors for postpartum mood and anxiety disorders among women veterans. General Hospital Psychiatry. 2023;84:112–124.37433239
729 Mattocks KM, Kroll-Desrosiers A, Marteeny V, . Veterans’ Perinatal Care and Mental Health Experiences During the COVID-19 Pandemic: An Examination of the Role of Prior Trauma and Pandemic-Related Stressors. Journal of Women’s Health (15409996). 2022;31(10):1507–1517.
730 Creech SK, Kroll-Desrosiers A, Benzer JK, . The impact of military sexual trauma on parent-infant bonding in a sample of perinatal women veterans. Depression & Anxiety (1091-4269). 2022;39(3):201–210.34633137
731 Holzhauer CG, Kroll-Desrosiers A, Kinney RL, . Prenatal Stress Exposure and Post-traumatic Stress Disorder Associated With Risk of Postpartum Alcohol Misuse Among Women Veterans. Women’s Health Issues. 2021;31(6):596–602.34148828
732 Kroll-Desrosiers AR, Crawford SL, Moore Simas TA, . Rates and Correlates of Depression Symptoms in a Sample of Pregnant Veterans Receiving Veterans Health Administration Care. Women’s Health Issues. 2019;29(4):333–340.31105035
733 Shepardson RL, Mitzel LD, Trabold N, . Sexual dysfunction and preferences for discussing sexual health concerns among veteran primary care patients. Journal of the American Board of Family Medicine. 2021;34(2):357–367.33833004
734 Vassy JL, Posner DC, Ho YL, . Cardiovascular Disease Risk Assessment Using Traditional Risk Factors and Polygenic Risk Scores in the Million Veteran Program. JAMA Cardiology. 2023;8(6):564–574.37133828
735 Maskoun W, Alqam B, Habash F, . Sex Differences in Stress-Induced (Takotsubo) Cardiomyopathy. CJC Open. 2023;5(2):120–127.36880077
736 Zheutlin AR, Derington CG, Herrick JS, . Lipid-Lowering Therapy Use and Intensification among United States Veterans Following Myocardial Infarction or Coronary Revascularization between 2015 and 2019. Circulation: Cardiovascular Quality and Outcomes. 2022;15(12):E008861.36252093
737 Lu B, Posner D, Vassy JL, . Prediction of Cardiovascular and All-Cause Mortality After Myocardial Infarction in US Veterans. American Journal of Cardiology. 2022;169:10–17.35063273
738 Dhruva SS, Dziura J, Bathulapalli H, . Gender Differences in Guideline-Directed Medical Therapy for Cardiovascular Disease Among Young Veterans. JGIM: Journal of General Internal Medicine. 2022;37:806–815.36042086
739 Mahtta D, Ramsey D, Krittanawong C, . Recreational substance use among patients with premature atherosclerotic cardiovascular disease. Heart. 2021;107(8):650–656.33589427
740 Lee MT, Mahtta D, Ramsey DJ, . Sex-Related Disparities in Cardiovascular Health Care among Patients with Premature Atherosclerotic Cardiovascular Disease. JAMA Cardiology. 2021;6(7):782–790.33881448
741 Gaziano L, Cho K, Djousse L, . Risk factors and prediction models for incident heart failure with reduced and preserved ejection fraction. ESC Heart Failure. 2021;8(6):4893–4903.34528757
742 Gaffey AE, Haskell SG, Brandt CA, . Post-9/11 veterans’ heart disease knowledge, self-perceived risk, and prevention beliefs and behaviors. Health Psychology. 2021;40(11):737–746.34780203
743 Ebrahimi R, Lynch KE, Beckham JC, . Association of Posttraumatic Stress Disorder and Incident Ischemic Heart Disease in Women Veterans. JAMA Cardiology. 2021;6(6):642–651.33729463
744 Weeda ER, Bishu KG, Ward R, . Joint effect of race/ethnicity or location of residence and sex on low density lipoprotein-cholesterol among veterans with type 2 diabetes: a 10-year retrospective cohort study. BMC Cardiovascular Disorders. 2020;20(1):N.PAG-N.PAG.
745 Vassy JL, Lu B, Ho YL, . Estimation of Atherosclerotic Cardiovascular Disease Risk among Patients in the Veterans Affairs Health Care System. JAMA Network Open. 2020.
746 Mahtta D, Ahmed ST, Ramsey DJ, . Statin Prescription Rates, Adherence, and Associated Clinical Outcomes Among Women with PAD and ICVD. Cardiovasc Drugs Ther. 2020;34(6):745–754.32840709
747 Ajam T, Devaraj S, Fudim M, . Lower Post Myocardial Infarction Mortality Among Women Treated at Veterans Affairs Hospitals Compared to Men. American Journal of the Medical Sciences. 2020;360(5):537–542.31982101
748 Vance MC, Wiitala WL, Sussman JB, . Increased Cardiovascular Disease Risk in Veterans With Mental Illness. Circulation: Cardiovascular Quality & Outcomes. 2019;12(10):e005563–e005563.31547692
749 Rodriguez F, Maron DJ, Knowles JW, . Association of Statin Adherence with Mortality in Patients with Atherosclerotic Cardiovascular Disease. JAMA Cardiology. 2019;4(3):206–213.30758506
750 Mattingly AS, Lerman BJ, Popat R, Wren SM. Association of Sex With Postoperative Mortality Among Patients With Heart Failure Who Underwent Elective Noncardiac Operations. JAMA Network Open. 2019;2(11):e1914420–e1914420.31675085
751 Hinojosa R. Sex, Age, Race/Ethnicity, Veteran Status, and the Likelihood of Reporting Cardiovascular Conditions in the National Health Interview Survey. Journal of Cardiovascular Nursing. 2019;34(3):215–221.30973492
752 Gibson CJ, Li Y, Inslicht SS, . Gender Differences in Cardiovascular Risk Related to Diabetes and Posttraumatic Stress Disorder. American Journal of Geriatric Psychiatry. 2018;26(12):1268–1272.
753 Ajam T, Ajam S, Devaraj S, . Effect of carvedilol vs metoprolol succinate on mortality in heart failure with reduced ejection fraction. American Heart Journal. 2018;199:1–6.29754646
754 Ventetuolo CE, Hess E, Austin ED, . Sex-based differences in veterans with pulmonary hypertension: Results from the veterans affairs-clinical assessment reporting and tracking database. PLoS One. 2017;12(11).
755 Sussman JB, Wiitala WL, Zawistowski M, . The Veterans Affairs Cardiac Risk Score: Recalibrating the Atherosclerotic Cardiovascular Disease Score for Applied Use. Medical Care. 2017;55(9):864–870.28763374
756 Haskell SG, Brandt C, Burg M, . Incident Cardiovascular Risk Factors Among Men and Women Veterans After Return From Deployment. Medical Care. 2017;55(11):948–955.28984707
757 Goldstein KM, Stechuchak KM, Zullig LL, . Impact of Gender on Satisfaction and Confidence in Cholesterol Control Among Veterans at Risk for Cardiovascular Disease. Journal of Women’s Health (15409996). 2017;26(7):806–814.
758 Goldstein KM, Oddone EZ, Bastian LA, . Characteristics and Health Care Preferences Associated with Cardiovascular Disease Risk among Women Veterans. Women’s Health Issues. 2017;27(6):700–706.28890128
759 Farmer MM, Stanislawski MA, Plomondon ME, . Sex Differences in 1-Year Outcomes After Percutaneous Coronary Intervention in the Veterans Health Administration. Journal of Women’s Health (15409996). 2017;26(10):1062–1068.
760 Whitehead AM, Maher NH, Goldstein K, . Sex Differences in Veterans’ Cardiovascular Health. J Womens Health (Larchmt). 2019;28(10):1418–1427.30839237
761 Lee DC, Orstad SL, Kanchi R, . Demographic, social and geographic factors associated with glycaemic control among US Veterans with new onset type 2 diabetes: a retrospective cohort study. BMJ Open. 2023;13(10):e075599.
762 Inoue K, Guo R, Lee ML, . Iodine-Induced Hypothyroidism and Long-Term Risks of Incident Heart Failure. J Am Heart Assoc. 2023:e030511.37815042
763 Inoue K, Guo R, Lee ML, . Iodinated Contrast Administration and Risks of Thyroid Dysfunction: A Retrospective Cohort Analysis of the U.S. Veterans Health Administration System. Thyroid. 2023;33(2):230–238.36173108
764 Inoue K, Guo R, Lee ML, . Iodine-Induced Hyperthyroidism and Long-term Risks of Incident Atrial Fibrillation and Flutter. The Journal of clinical endocrinology and metabolism. 2023;108(10):e956–e962.37146179
765 Wander PL, Lowy E, Beste LA, . The Incidence of Diabetes Among 2,777,768 Veterans With and Without Recent SARS-CoV-2 Infection. Diabetes Care. 2022;45(4):782–788.35085391
766 Breland JY, Joyce VR, Frayne SM, Phibbs C. Differences in body mass index based on self-reported versus measured data from women veterans. Obesity Science and Practice. 2020;6(4):434–438.32874677
767 Schmidt EM, Magruder K, Kilbourne AM, . Four Decades after War: Incident Diabetes among Women Vietnam-Era Veterans in the HealthViEWS Study. Women’s Health Issues. 2019;29(6):471–479.31519465
768 Santhiveeran J. The influence of obesity and sociodemographic factors on the health hardships among women veterans. Social Work in Health Care. 2019;58(5):459–470.30901287
769 Breland JY, Wong MS, Frayne SM, . Obesity and Health Care Experiences among Women and Men Veterans. Women’s Health Issues. 2019;29:S32–S38.31253240
770 Breland JY, Phibbs CS, Hoggatt KJ, . The Obesity Epidemic in the Veterans Health Administration: Prevalence Among Key Populations of Women and Men Veterans. J Gen Intern Med. 2017;32:11–17.
771 LaFleur J, Rillamas-Sun E, Colon-Emeric CS, . Fracture Rates and Bone Density Among Postmenopausal Veteran and Non-Veteran Women From the Women’s Health Initiative. Gerontologist. 2016;56 Suppl 1:S78–90.26768394
772 Goodrich DE, Klingaman EA, Verchinina L, . Sex Differences in Weight Loss among Veterans with Serious Mental Illness: Observational Study of a National Weight Management Program. Women’s Health Issues. 2016;26(4):410–419.27365284
773 Dursa EK, Cao G, Culpepper WJ, Schneiderman A. Comparison of Health Outcomes Over Time Among Women 1990–1991 Gulf War Veterans, Women 1990–1991 Gulf Era Veterans, and Women in the U.S. General Population. Women’s Health Issues. 2023.
774 Cypel YS, Vogt D, Maguen S, . Physical health of Post-9/11 U.S. Military veterans in the context of Healthy People 2020 targeted topic areas: Results from the Comparative Health Assessment Interview Research Study. Preventive Medicine Reports. 2023;32.
775 Gaffey AE, Burg MM, Rosman L, . Baseline Characteristics from the Women Veterans Cohort Study: Gender Differences and Similarities in Health and Healthcare Utilization. Journal of Women’s Health (15409996). 2021;30(7):944–955.
776 Bullman T, Schneiderman A, Dursa E. Cause-specific mortality risks among U.S. veterans: 25 years after their service in the 1990-1991 gulf war. Annals of Epidemiology. 2021;57:1–6.33581241
777 Heboyan V, Krengel MH, Sullivan K, . Sex Differences in Gulf War Illness: A Reanalysis of Data From the CDC Air Force Study Using CDC and Modified Kansas Case Definitions. Journal of Occupational & Environmental Medicine. 2019;61(7):610–616.31090678
778 Brown MC, Sims KJ, Gifford EJ, . Gender-based Differences among 1990-1991 Gulf War Era Veterans: Demographics, Lifestyle Behaviors, and Health Conditions. Womens Health Issues. 2019;29 Suppl 1:S47–S55.31253242
779 Coughlin SS, Sullivan K. Study Protocol: Southern Women Veterans’ Health Study. Ann Epidemiol Public Health. 2018;1(1).
780 Kilbourne AM, Schumacher K, Frayne SM, . Physical Health Conditions Among a Population-Based Cohort of Vietnam-Era Women Veterans: Agreement Between Self-Report and Medical Records. Journal of Women’s Health (15409996). 2017;26(11):1244–1251.
781 Harfouch O, Comstock E, Kaplan R, . Impact of the COVID-19 Pandemic on the PrEP Cascade at Two Veterans Affairs Healthcare Systems. AIDS and behavior. 2023.
782 McGinnis KA, Skanderson M, Justice AC, . HIV care using differentiated service delivery during the COVID-19 pandemic: a nationwide cohort study in the US Department of Veterans Affairs. J Int AIDS Soc. 2021;24 Suppl 6:e25810.34713585
783 Matson TE, McGinnis KA, Rubinsky AD, . Gender and alcohol use: Influences on HIV care continuum in a national cohort of patients with HIV. AIDS. 2018;32(15):2247–2253.30005010
784 Kramer JR, El-Serag HB, Taylor TJ, . Hepatitis C virus-related complications are increasing in women veterans: A national cohort study. Journal of Viral Hepatitis. 2017;24(11):955–965.28815822
785 Kanwal F, Kramer JR, El-Serag HB, . Race and Gender Differences in the Use of Direct Acting Antiviral Agents for Hepatitis C Virus. Clinical Infectious Diseases. 2016;63(3):291–299.27131869
786 Webster J, Borgia M, Resnik L. Prosthesis nonuse and discontinuation in United States veterans with major limb amputation: Results of a national survey. Prosthetics and orthotics international. 2023.
787 Norvell DC, Turner AP, Morgenroth DC, . The effect of depression on prosthesis prescription in men and women who have undergone a lower limb amputation. Disability and rehabilitation. 2023:1–8.
788 Littman AJ, Peterson AC, Korpak A, . Differences in Prosthetic Prescription Between Men and Women Veterans After Transtibial or Transfemoral Lower-Extremity Amputation: A Longitudinal Cohort Study (2005-2018). Archives of Physical Medicine & Rehabilitation. 2023;104(8):1274–1281.36906098
789 Kuo PB, Lehavot K, Thomas RM, . Gender differences in prosthesis-related outcomes among veterans: Results of a national survey of U.S. veterans. PM and R. 2023.
790 Meadows M, Peterson A, Boyko EJ, Littman AJ. Validity of Methods to Identify Individuals With Lower Extremity Amputation Using Department of Veterans Affairs Electronic Medical Records. Archives of Rehabilitation Research and Clinical Translation. 2022;4(1).
791 Aday AW, Duncan MS, Patterson OV, . Association of Sex and Race With Incident Peripheral Artery Disease Among Veterans With Normal Ankle-Brachial Indices. JAMA Network Open. 2022;5(11):e2240188–e2240188.36326762
792 Higgins DM, Fenton BT, Driscoll MA, . Gender Differences in Demographic and Clinical Correlates among Veterans with Musculoskeletal Disorders. Women’s Health Issues. 2017;27(4):463–470.28325585
793 Goulet JL, Kerns RD, Bair M, . The musculoskeletal diagnosis cohort: Examining pain and pain care among veterans. Pain. 2016;157(8):1696–1703.27023420
794 Quiñones ME, Joseph JK, Dowell S, . Hydroxychloroquine and Risk of Long QT Syndrome in Rheumatoid Arthritis: A Veterans Cohort Study With Nineteen-Year Follow-up. Arthritis Care and Research. 2023;75(7):1571–1579.36039941
795 England BR, Yang Y, Roul P, . Identification of Multimorbidity Patterns in Rheumatoid Arthritis Through Machine Learning. Arthritis Care and Research. 2023;75(2):220–230.35588095
796 Sullivan-Baca E, Rehman R, Towne AR, Haneef Z. Psychiatric co-morbidity of drug-resistant epilepsy in Veterans. Epilepsy and Behavior. 2023;139.
797 Sullivan-Baca E, Lorkiewicz SA, Rehman R, . Utilization of epilepsy care among Women Veterans: A population-based study. Epilepsy Research. 2023;192.
798 Sofer T, Kurniansyah N, Murray M, . Genome-wide association study of obstructive sleep apnoea in the Million Veteran Program uncovers genetic heterogeneity by sex. eBioMedicine. 2023;90.
799 Moghtaderi I, Kelly MR, Carlson GC, . Identifying gaps in clinical evaluation and treatment of sleep-disordered breathing in women veterans. Sleep and Breathing. 2023;27(5):1929–1933.36525174
800 Sullivan-Baca E, Weitzner DS, Choudhury TK, . Characterizing differences in psychiatric profiles between male and female veterans with epilepsy and psychogenic non-epileptic seizures. Epilepsy Research. 2022;186.
801 Sullivan-Baca E, Modiano YA, Miller BI, . Characterizing women veterans receiving seizure care in the veterans affairs healthcare system. Epilepsy Research. 2022;180.
802 Seng EK, Fenton BT, Wang K, . Frequency, Demographics, Comorbidities, and Health Care Utilization by Veterans With Migraine: A VA Nationwide Cohort Study. Neurology. 2022;13:13.
803 Merritt VC, Chanfreau-Coffinier C, Sakamoto MS, . Characterizing Sex Differences in Clinical and Functional Outcomes Among Military Veterans with a Comprehensive Traumatic Brain Injury Evaluation (CTBIE): A Million Veteran Program (MVP) Study. Clin. 2022;21:21.
804 Song Y, Carlson GC, McGowan SK, . Sleep Disruption Due to Stress in Women Veterans: A Comparison between Caregivers and Noncaregivers. Behavioral sleep medicine. 2021;19(2):243–254.32116050
805 Martin JL, Carlson G, Kelly M, . Sleep apnea in women veterans: Results of a national survey of VA health care users. Journal of Clinical Sleep Medicine. 2021;17(3):555–565.33124975
806 Cogan AM, Smith B, Bender Pape TL, . Self-reported Participation Restrictions Among Male and Female Veterans With Traumatic Brain Injury in Veterans Health Administration Outpatient Polytrauma Programs. Archives of Physical Medicine & Rehabilitation. 2020;101(12):2071–2079.32795563
807 Rosman L, Sico JJ, Lampert R, . Posttraumatic Stress Disorder and Risk for Stroke in Young and Middle-Aged Adults: A 13-Year Cohort Study. Stroke (00392499). 2019;50(11):2996–3003.
808 Amara JH, Stolzmann KL, Iverson KM, Pogoda TK. Predictors of Employment Status in Male and Female Post-9/11 Veterans Evaluated for Traumatic Brain Injury. Journal of Head Trauma Rehabilitation. 2019;34(1):11–20.29863619
809 Nelson LM, Topol B, Kaye W, . Estimation of the Prevalence of Amyotrophic Lateral Sclerosis in the United States Using National Administrative Healthcare Data from 2002 to 2004 and Capture-Recapture Methodology. Neuroepidemiology. 2018;51(3–4):149–157.30092573
810 Iverson KM, Dardis CM, Pogoda TK. Traumatic brain injury and PTSD symptoms as a consequence of intimate partner violence. Comprehensive Psychiatry. 2017;74:80–87.28126481
811 Rissling MB, Gray KE, Ulmer CS, . Sleep Disturbance, Diabetes, and Cardiovascular Disease in Postmenopausal Veteran Women. The Gerontologist. 2016;56:S54–S66.26768391
812 Harrington KM, Nguyen XT, Song RJ, . Gender Differences in Demographic and Health Characteristics of the Million Veteran Program Cohort. Womens Health Issues. 2019;29 Suppl 1:S56–S66.31253243
813 Maynard C, Trivedi R, Nelson K, Fihn SD. Disability Rating, Age at Death, and Cause of Death in U.S. Veterans with Service-Connected Conditions. Military Medicine. 2018;183(11/12):e371–e376.29590473
814 Hassan W, Shrestha P, Sumida K, . Association of Uric Acid–Lowering Therapy With Incident Chronic Kidney Disease. JAMA Network Open. 2022;5(6):e2215878–e2215878.35657621
815 Akwo EA, Chen HC, Liu G, . Phenome-Wide Association Study of UMOD Gene Variants and Differential Associations With Clinical Outcomes Across Populations in the Million Veteran Program a Multiethnic Biobank. Kidney International Reports. 2022;7(8):1802–1818.35967117
816 You AS, Kalantar-Zadeh K, Streja E, . Mortality Risk in Chronic Kidney Disease Patients Transitioning to Dialysis: Impact of Opiate and Non-Opiate Use. American Journal of Nephrology. 2020;51(9):715–725.32777779
817 Soohoo M, Moradi H, Obi Y, . Statin Therapy Before Transition to End-Stage Renal Disease With Posttransition Outcomes. Journal of the American Heart Association. 2019;8(6).
818 Kim JE, Scherzer R, Estrella MM, . Tenofovir exposure alters associations of serum bicarbonate with chronic kidney disease risk in HIV-infected veterans. AIDS (02699370). 2016;30(7):1049–1057.
819 Dubinskaya A, Tholemeier LN, Erickson T, . Prevalence of Overactive Bladder Symptoms among Women with Interstitial Cystitis/Bladder Pain Syndrome. Female Pelvic Medicine and Reconstructive Surgery. 2022;28(3):E115–E119.35272344
820 Dallas KB, Bresee C, De Hoedt A, . Demographic Differences and Disparities in the Misdiagnosis of Interstitial Cystitis/Bladder Pain Syndrome in a National Cohort of VA Patients. Urology. 2022;163:22–28.34348123
821 Welch E, Sheth S, Ashong CN, Pham C. Retrospective Review on the Safety and Efficacy of Nitrofurantoin for the Treatment of Cystitis in the Veteran Population with or without Renal Insufficiency. Open Forum Infectious Diseases. 2021;8(9).
822 Laden BF, Bresee C, De Hoedt A, . Comorbidities in a Nationwide, Heterogenous Population of Veterans with Interstitial Cystitis/Bladder Pain Syndrome. Urology. 2021;156:37–43.33901534
823 Volpe KA, Cichowski SB, Komesu YK, . Female Veterans with Diagnoses of Both Chronic Pelvic Pain and Overactive Bladder; How Do They Compare to Women Diagnosed with Interstitial Cystitis? Female Pelvic Medicine and Reconstructive Surgery. 2020;26(9):591–593.29746393
824 Lynch KE, Viernes B, Khader K, . Sex and the Diagnostic Pathway to Bladder Cancer among Veterans: No Evidence of Disparity. Women’s Health Issues. 2020;30(2):128–135.31870696
825 Ninivaggio C, Riese H, Dunivan GC, . One and the Same? Nocturnal Enuresis and Overactive Bladder in the Female Veteran Population: Evaluation of a Large National Database. Female Pelvic Medicine and Reconstructive Surgery. 2018;24(4):307–311.28657995
826 Bradley CS, Nygaard IE, Hillis SL, . Longitudinal associations between mental health conditions and overactive bladder in women veterans. American Journal of Obstetrics & Gynecology. 2017;217(4):430.e1–430.e8.
827 Gawron LM, He T, Lewis L, . Oral Emergency Contraception Provision in the Veterans Health Administration: a Retrospective Cohort Study. JGIM: Journal of General Internal Medicine. 2022;37:685–689.36042074
828 Mahorter S, Vinekar K, Shaw JG, . Variations in Provision of Long-Acting Reversible Contraception Across Veterans Health Administration Facilities. JGIM: Journal of General Internal Medicine. 2023;38:865–867.
829 Arora KS, Zhao X, Judge-Golden C, . Factors Associated with Choice of Sterilization Among Women Veterans. Journal of Women’s Health (15409996). 2020;29(7):989–995.
830 Judge CP, Zhao X, Sileanu FE, . Medical contraindications to estrogen and contraceptive use among women veterans. American Journal of Obstetrics & Gynecology. 2018;218(2):234.e1–234.e9.
831 Britton LE, Judge-Golden CP, Wolgemuth TE, . Associations Between Perceived Susceptibility to Pregnancy and Contraceptive Use in a National Sample of Women Veterans. Perspectives on Sexual & Reproductive Health. 2019;51(4):211–218.31749310
832 Wolgemuth T, Judge-Golden C, Callegari L, . Associations between Pregnancy Intention, Attitudes, and Contraceptive Use among Women Veterans in the ECUUN Study. Women’s Health Issues. 2018;28(6):480–487.30241794
833 Koenig AF, Borrero S, Zhao X, . Factors associated with long-acting reversible contraception use among women Veterans in the ECUUN study. Contraception. 2019;100(3):234–240.31152697
834 Schexnayder CD, King S, Emelogu O. Documentation of contraceptive counseling in female veterans of reproductive age. American Journal of Health-System Pharmacy. 2020;77:S71–S77.32706019
835 Kroll-Desrosiers A, Copeland LA, Mengeling MA, Mattocks KM. Infertility Services for Veterans Enrolled in Veterans Health Administration Care. JGIM: Journal of General Internal Medicine. 2023;38(10):2347–2353.36810630
836 Mancuso AC, Summers KM, Mengeling MA, . Infertility and Health-Related Quality of Life in United States Women Veterans. Journal of Women’s Health (15409996). 2020;29(3):412–419.
837 Judge-Golden CP, Borrero S, Zhao X, . The Association between Mental Health Disorders and History of Unintended Pregnancy among Women Veterans. JGIM: Journal of General Internal Medicine. 2018;33(12):2092–2099.30187377
838 Quinn DA, Sileanu FE, Zhao X, . History of unintended pregnancy and patterns of contraceptive use among racial and ethnic minority women veterans. American Journal of Obstetrics & Gynecology. 2020;223(4):564.e1–564.e13.
839 Friedman A, Janulewicz Lloyd PA, Carlson J, . Preliminary Findings from the Gulf War Women’s Cohort: Reproductive and Children’s Health Outcomes among Women Veterans. International Journal of Environmental Research and Public Health. 2022;19(14).
840 Shaw JG, Joyce VR, Schmitt SK, . Selection of Higher Risk Pregnancies into Veterans Health Administration Programs: Discoveries from Linked Department of Veterans Affairs and California Birth Data. Health Serv Res. 2018;53 Suppl 3:5260–5284.30198185
841 Katon JG, Bossick AS, Tartaglione EV, . Assessing Racial Disparities in Access, Use, and Outcomes for Pregnant and Postpartum Veterans and Their Infants in Veterans Health Administration. Journal of Women’s Health (15409996). 2023;32(7):757–766.
842 Keddem S, Solomon P, Marcus SC, . Disparities in Breastfeeding Among Military Veterans. Journal of Human Lactation. 2020;36(1):64–73.31770049
843 Sheahan KL, Kroll-Desrosiers A, Goldstein KM, . Sufficiency of Health Information During Pregnancy: What’s Missing and for Whom? A Cross-Sectional Analysis Among Veterans. Journal of Women’s Health (15409996). 2022;31(11):1557–1566.
844 Mattocks KM, Baldor R, Bean-Mayberry B, . Factors Impacting Perceived Access to Early Prenatal Care among Pregnant Veterans Enrolled in the Department of Veterans Affairs. Women’s Health Issues. 2019;29(1):56–63.30446330
845 Katon J, Zephyrin L, Reiber G, . Deployment and Adverse Pregnancy Outcomes: Primary Findings and Methodological Considerations. Maternal & Child Health Journal. 2017;21(2):376–386.27449782
846 Grekin R, Zivin K, Hall SV, . Predictors of Veterans Affairs Health Service Utilization by Women Veterans during Pregnancy. Women’s Health Issues. 2020;30(4):292–298.32417074
847 Copeland LA, Kinney RL, Kroll-Desrosiers AR, . Medications with Potential for Fetal Risk Prescribed to Veterans. Journal of Women’s Health (15409996). 2022;31(10):1450–1458.
848 Nillni YI, Fox AB, Cox K, . The impact of military sexual trauma and warfare exposure on women veterans’ perinatal outcomes. Psychological trauma : theory, research, practice and policy. 2022;14(5):730–737.34410813
849 Shaw JG, Asch SM, Katon JG, . Post-traumatic Stress Disorder and Antepartum Complications: a Novel Risk Factor for Gestational Diabetes and Preeclampsia. Paediatric & Perinatal Epidemiology. 2017;31(3):185–194.28328031
850 Shivakumar G, Kroll-Desrosiers AR, Copeland L, . Patterns of Treatment Utilization Across the Perinatal Period in the Center for Maternal and Infant Outcomes and Research in Translation (COMFORT) Veterans Study. Journal of Women’s Health (15409996). 2021;30(6):882–890.
851 Shapiro MO, Kroll-Desrosiers A, Mattocks KM. Understanding the Mental Health Impact of Previous Pregnancy Loss Among Currently Pregnant Veterans. Women’s Health Issues. 2023;33(4):422–427.37100719
852 Nillni YI, Shayani DR, Finley E, . The Impact of Posttraumatic Stress Disorder and Moral Injury on Women Veterans’ Perinatal Outcomes Following Separation From Military Service. Journal of Traumatic Stress. 2020;33(3):248–256.32291816
853 Kinney RL, Copeland LA, Kroll-Desrosiers AR, . Newborn Outcomes Among Veterans Utilizing VHA Maternity Benefits, 2016-2020. Military medicine. 2023;188(5–6):e1252–e1259.34718702
854 Panelli DM, Chan CS, Shaw JG, . An Exploratory Analysis of Factors Associated With Spontaneous Preterm Birth Among Pregnant Veterans With Post-Traumatic Stress Disorder. Women’s Health Issues. 2023;33(2):191–198.37576490
855 Shankar M, Chan CS, Frayne SM, . Postpartum Transition of Care: Racial/Ethnic Gaps in Veterans’ Re-Engagement in VA Primary Care after Pregnancy. Women’s Health Issues. 2021;31(6):603–609.34229932
856 Lumsden RH, Goldstein KM, Shephard-Banigan M, . Racial Differences in Nontraditional Risk Factors Associated with Cardiovascular Conditions in Pregnancy Among U.S. Women Veterans. Journal of Women’s Health (15409996). 2022;31(5):706–714.
857 Hansen B, Picken LK, Gould S. Disparate Risk Factors Among Pregnant Veterans Using Veterans Administration Health Benefits for Community-Based Obstetrical Care. Military medicine. 2023.
858 Albright DL, McDaniel J, Suntai Z, . Pregnancy and Binge Drinking: An Intersectionality Theory Perspective Using Veteran Status and Racial/Ethnic Identity. Maternal & Child Health Journal. 2021;25(8):1345–1351.33945080
859 Kroll-Desrosiers A, Holzhauer CG, Russo L, . Factors Associated With Quitting Smoking During Pregnancy Among Women Veterans. Women’s Health Issues. 2021;31(4):408–413.34049763
860 Mattocks KM, Kroll-Desrosiers A, Kinney R, . Racial Differences in the Cesarean Section Rates Among Women Veterans Using Department of Veterans Affairs Community Care. Medical Care. 2021;59(2):131–138.33201084
861 Katon JG, Gray KE, Gerber MR, . Vasomotor Symptoms and Quality of Life Among Veteran and Non-Veteran Postmenopausal Women. Gerontologist. 2016;56 Suppl 1:S40–53.26220418
862 Quinn DA, Mor MK, Sileanu FE, . Measuring Female Veterans’ Prepregnancy Wellness Using Department of Veterans Affairs’ Health Record Data. Obstetrics and Gynecology. 2021;137(3):471–480.33543894
863 Quinn DA, Edmonds SW, Zhao X, . Veteran-Reported Receipt of Prepregnancy Care: Data from the Examining Contraceptive Use and Unmet Need (ECUUN) Study. Maternal and child health journal. 2021;25(8):1254–1264.33929654
864 Katon JG, Gray K, Callegari L, . Trends in hysterectomy rates among women veterans in the US Department of Veterans Affairs. American Journal of Obstetrics & Gynecology. 2017;217(4):428.e1–428.e11.
865 Katon JG, Bossick AS, Doll KM, . Contributors to Racial Disparities in Minimally Invasive Hysterectomy in the US Department of Veterans Affairs. Medical Care. 2019;57(12):930–936.31730567
866 Callegari LS, Katon JG, Gray KE, . Associations between Race/Ethnicity, Uterine Fibroids, and Minimally Invasive Hysterectomy in the VA Healthcare System. Women’s Health Issues. 2019;29(1):48–55.30293778
867 Ryan GL, Mengeling MA, Summers KM, . Hysterectomy risk in premenopausal-aged military veterans: associations with sexual assault and gynecologic symptoms. American Journal of Obstetrics & Gynecology. 2016;214(3):352.e1–352.e13.
868 Carey CM, Katon JG, Bossick AS, . Uterine Weight as a Modifier of Black/White Racial Disparities in Minimally Invasive Hysterectomy Among Veterans with Fibroids in the Veterans Health Administration. Health Equity. 2022;6(1):909–916.36636115
869 Blalock DV, Pura JA, Stechuchak KM, . BMI Trends for Veterans Up to 10 Years After VA Enrollment Following Military Discharge. J Gen Intern Med. 2023;38(6):1423–1430.36219304
870 Cohen AJ, Dosa DM, Rudolph JL, . Risk factors for Veteran food insecurity: findings from a National US Department of Veterans Affairs Food Insecurity Screener. Public Health Nutrition. 2022;25(4):819–828.34743780
871 Stefanovics EA, Edwards LM, Pietrzak RH. Personality and Body Mass Index in U.S. Military Veterans: Results from the National Health and Resilience in Veterans Study. Psychiatric Quarterly. 2021;92(3):917–923.33389478
872 Slater SJ, Tarlov E, Jones K, . Would increasing access to recreational places promote healthier weights and a healthier nation? Health & Place. 2019;56:127–134.30738347
873 Schult TM, Schmunk SK, Marzolf JR, Mohr DC. The Health Status of Veteran Employees Compared to Civilian Employees in Veterans Health Administration. Military Medicine. 2019;184(7/8):e218–e224.
874 Tarlov E, Wing C, Gordon HS, . Does Effectiveness of Weight Management Programs Depend on the Food Environment? Health Services Research. 2018;53(6):4268–4290.30246454
875 Tamas MJ, Khakharia A, Rothenberg RB, Phillips LS. Weight Trends in Veterans With and Without Diabetes, 2000 to 2014. Obesity (19307381). 2018;26(12):1949–1957.
876 Jay M, Mateo KF, Squires AP, . Military service and other socioecological factors influencing weight and health behavior change in overweight and obese Veterans: A qualitative study to inform intervention development within primary care at the United States Veterans Health Administrati. BMC Obesity. 2016;3(1).
877 Minnier J, Rajeevan N, Gao L, . Polygenic breast cancer risk for women veterans in the million veteran program. JCO Precision Oncology. 2021;5:1178–1191.
878 Imperiale TF, Daggy JK, Imler TD, . Prevalence of Advanced Colorectal Neoplasia in Veterans: Effects of Age, Sex, and Race/Ethnicity. Journal of Clinical Gastroenterology. 2021;55(10):876–883.34049372
879 Brunner J, Farmer MM, Bean-Mayberry B, . Implementing clinical decision support for reducing women Veterans’ cardiovascular risk in VA: A mixed-method, longitudinal study of context, adaptation, and uptake. Front Health Serv. 2022;2:946802.36925876
880 Hoffmire CA, Brenner LA, Katon J, . Women Veterans’ Perspectives on Suicide Prevention in Reproductive Health Care Settings: An Acceptable, Desired, Unmet Opportunity. Women’s Health Issues. 2022;32(4):418–425.35272885
881 Ferras M, Dye J, Ayala GX, Schmied E. An Examination of Factors That Influence Receipt of Reproductive Health Screenings Among Female Veterans. Military Medicine. 2023;188(1/2):42–48.35253065
882 Gibson CJ, Li Y, Huang AJ, . Menopausal Symptoms and Higher Risk Opioid Prescribing in a National Sample of Women Veterans with Chronic Pain. JGIM: Journal of General Internal Medicine. 2019;34(10):2159–2166.31414358
883 Salas J, Scherrer JF, Ahmedani BK, . Gender and the Association between Long-Term Prescription Opioid Use and New-Onset Depression. Journal of Pain. 2018;19(1):88–98.29030323
884 Cichowski SB, Rogers RG, Komesu Y, . A 10-yr Analysis of Chronic Pelvic Pain and Chronic Opioid Therapy in the Women Veteran Population. Military Medicine. 2018;183(11/12):e635–e640.29788455
885 Kroll-Desrosiers AR, Skanderson M, Bastian LA, . Receipt of Prescription Opioids in a National Sample of Pregnant Veterans Receiving Veterans Health Administration Care. Women’s Health Issues. 2016;26(2):240–246.26549242
886 Martinson A, Kutz A, Marchand W, . Factors associated with participation and nonparticipation in a VA Whole Health Primary Care Pain Education and Opioid Monitoring Program (PC-POP). Journal of Opioid Management. 2020;16(3):179–188.32421838
887 Goldsmith ES, MacLehose RF, Jensen AC, . Complementary, Integrative, and Nondrug Therapy Use for Pain Among US Military Veterans on Long-term Opioids. Med Care. 2020;58 Suppl 2 9S:S116–S124.32826781
888 Driscoll MA, Higgins D, Shamaskin-Garroway A, . Examining Gender as a Correlate of Self-Reported Pain Treatment Use Among Recent Service Veterans with Deployment-Related Musculoskeletal Disorders. Pain Medicine. 2017;18(9):1767–1777.28379576
889 Naylor JC, Wagner HR, Johnston C, . Pain Intensity and Pain Interference in Male and Female Iraq/Afghanistan-era Veterans. Women’s Health Issues. 2019;29:S24–S31.31253239
890 Nicosia FM, Gibson CJ, Purcell N, . Women Veterans’ Experiences with Integrated, Biopsychosocial Pain Care: A Qualitative Study. Pain Medicine. 2021;22(9):1954–1961.33547797
891 Evans EA, Herman PM, Washington DL, . Gender Differences in Use of Complementary and Integrative Health by U.S. Military Veterans with Chronic Musculoskeletal Pain. Women’s Health Issues. 2018;28(5):379–386.30174254
892 Corcoran KL, Dunn AS, Formolo LR, Beehler GP. Chiropractic Management for US Female Veterans With Low Back Pain: A Retrospective Study of Clinical Outcomes. Journal of Manipulative & Physiological Therapeutics. 2017;40(8):573–579.29187308
893 Murphy JL, Phillips KM, Rafie S. Sex differences between Veterans participating in interdisciplinary chronic pain rehabilitation. Journal of Rehabilitation Research & Development. 2016;53(1):83–94.27005932
894 Gibson CJ, Li Y, Bertenthal D, . Menopause symptoms and chronic pain in a national sample of midlife women veterans. Menopause (10723714). 2019;26(7):708–713.
895 Nahin RL. Severe Pain in Veterans: The Effect of Age and Sex, and Comparisons With the General Population. Journal of Pain. 2017;18(3):247–254.27884688
896 Patel KV, Cochrane BB, Turk DC, . Association of Pain With Physical Function, Depressive Symptoms, Fatigue, and Sleep Quality Among Veteran and non-Veteran Postmenopausal Women. Gerontologist. 2016;56 Suppl 1:S91–101.26768395
897 Higgins DM, Buta E, Dorflinger L, . Prevalence and correlates of painful conditions and multimorbidity in national sample of overweight/obese Veterans. Journal of Rehabilitation Research & Development. 2016;53(1):71–82.26933823
898 Naylor JC, Wagner HR, Brancu M, . Self-Reported Pain in Male and Female Iraq/Afghanistan-Era Veterans: Associations with Psychiatric Symptoms and Functioning. Pain Medicine. 2017;18(9):1658–1667.28122941
899 Green KT, Wilson SM, Dennis PA, . Cigarette Smoking and Musculoskeletal Pain Severity Among Male and Female Afghanistan/Iraq Era Veterans. Pain Medicine. 2017;18(9):1795–1804.28340108
900 Mohanty AF, Helmer DA, Muthukutty A, . Fibromyalgia syndrome care of Iraq- and Afghanistan-deployed Veterans in Veterans Health Administration. Journal of Rehabilitation Research & Development. 2016;53(1):45–57.26934034
901 Kroll-Desrosiers A, Wallace KF, Higgins DM, . Musculoskeletal Pain During Pregnancy Among Veterans: Associations With Health and Health Care Utilization. Women’s Health Issues. 2023.
902 Eastman J, Bahorik A, Kornblith E, . Sex Differences in the Risk of Dementia in Older Veterans. Journals of Gerontology Series A: Biological Sciences & Medical Sciences. 2022;77(6):1250–1253.35134198
903 Bihn JR, Cioffi G, Waite KA, . Brain Tumors in United States Military Veterans. Neuro-oncology. 2023.
904 Aggarwal A, Adepoju B, Yacur M, . Gender Disparity in Breast Cancer: A Veteran Population-Based Comparison. Clinical Breast Cancer. 2021;21(4):e471–e478.33619003
905 Azad AD, Bozkurt S, Wheeler AJ, . Acute pain after breast surgery and reconstruction: A two-institution study of surgical factors influencing short-term pain outcomes. J Surg Oncol. 2020;20:20.
906 Zuchowski JL, Chrystal JG, Hamilton AB, . Coordinating Care Across Health Care Systems for Veterans With Gynecologic Malignancies: A Qualitative Analysis. Med Care. 2017;55 Suppl 7 Suppl 1:S53–S60.28614184
907 Capitulo K, Olender L. Voices of women veterans: My Life, My Story. Nursing. 2023;53(5):55–60.
908 Sheahan KL, Goldstein KM, Than CT, . Women Veterans’ Healthcare Needs, Utilization, and Preferences in Veterans Affairs Primary Care Settings. JGIM: Journal of General Internal Medicine. 2022;37:791–798.36042076
909 Holzhauer CG, Byrne T, Simmons MM, . Profiles of Clinical Need Among Homeless Individuals with Dual Diagnoses. Community Mental Health Journal. 2019;55(8):1305–1312.31236735
910 Sedlander E, Barboza KC, Jensen A, . Veterans’ Preferences for Remote Management of Chronic Conditions. Telemedicine journal and e-health : the official journal of the American Telemedicine Association. 2018;24(3):229–235.28745941
911 Evans EA, Glover DL, Washington DL, Hamilton AB. Psychosocial Factors that Shape Substance Abuse and Related Mental Health of Women Military Veterans who Use Community-Based Services. Substance Use & Misuse. 2018;53(11):1878–1892.29485302
912 Brooks E, Dailey NK, Bair BD, Shore JH. Listening to the Patient: Women Veterans’ Insights About Health Care Needs, Access, and Quality in Rural Areas. Military Medicine. 2016;181(9):976–981.27612340
913 Tsui GO, Duncan G, Yu Y, . Patient inequities in affording surgical resident operative autonomy at Veterans Affairs teaching hospitals, does it extend to female patients? American Journal of Surgery. 2023;225(1):40–45.36192216
914 Scheuner MT, Huynh AK, Chanfreau-Coffinier C, . Demographic Differences Among US Department of Veterans Affairs Patients Referred for Genetic Consultation to a Centralized VA Telehealth Program, VA Medical Centers, or the Community. JAMA Network Open. 2022;5(1):e226687–e226687.35404460
915 Gray KE, Ma EW, Callegari LS, . Understanding Variation in Availability and Provision of Minimally Invasive Hysterectomy: A Qualitative Study of Department of Veterans Affairs Gynecologists. Women’s Health Issues. 2020;30(3):200–206.32253057
916 Zickmund SL, Burkitt KH, Gao S, . Racial, Ethnic, and Gender Equity in Veteran Satisfaction with Health Care in the Veterans Affairs Health Care System. JGIM: Journal of General Internal Medicine. 2018;33(3):305–331.29313226
917 Than CT, Washington DL, Vogt D, . Discontinuity of Women Veterans’ Care in Patient-Centered Medical Homes: Does Workforce Gender Sensitivity Matter? Women’s Health Issues. 2022;32(2):173–181.34930639
918 Reddy SM, Rose DE, Jr. Burgess JF, . The Role of Organizational Factors in the Provision of Comprehensive Women’s Health in the Veterans Health Administration. Women’s Health Issues. 2016;26(6):648–655.27745998
919 Devine DT, McMillan SC, Kip K, Powell-Cope G. Quality of life among women veterans. Journal of the American Association of Nurse Practitioners. 2020;32(11):745–755.32649382
920 Vance BS, Carpenter R. Women Veterans’ Descriptions of Interactions With Civilian Health Care Providers: A Qualitative Inquiry. ANS. Advances in nursing science. 2023.
921 Fleming L, Johnson A, Wells H, . An Exploration into the Experiences of Female Veterans Who Attended Higher Ground Military Programming. Therapeutic Recreation Journal. 2021;55(2):168–184.
922 Hamilton AB, Wiltsey-Stirman S, Finley EP, . Usual Care Among Providers Treating Women Veterans: Managing Complexity and Multimorbidity in the Era of Evidence-Based Practice. Administration and policy in mental health. 2020;47(2):244–253.31468284
923 Than C, Chuang E, Washington DL, . Understanding Gender Sensitivity of the Health Care Workforce at the Veterans Health Administration. Women’s Health Issues. 2020;30(2):120–127.32094056
924 Zuchowski JL, Hamilton AB, Washington DL, . Drivers of Continuing Education Learning Preferences for Veterans Affairs Women’s Health Primary Care Providers. Journal of Continuing Education in the Health Professions. 2017;37(3):168–172.28817394
925 Marshall V, Stryczek KC, Haverhals L, . The Focus They Deserve: Improving Women Veterans’ Health Care Access. Women’s Health Issues. 2021;31(4):399–407.33582001
926 Vance B, Alhussain K, Sambamoorthi U. Five-year trend in healthcare access and patient-reported health outcomes among women veterans. Nursing Forum. 2020;55(2):165–173.31729039
927 Brunner J, Rose DE, Chuang E, . The role of healthcare system hassles in delaying or forgoing care. Healthcare. 2020;8(2).
928 Newins AR, Wilson SM, Hopkins TA, . Barriers to the use of Veterans Affairs health care services among female veterans who served in Iraq and Afghanistan. Psychological services. 2019;16(3):484–490.29419309
929 Chanfreau-Coffinier C, Washington DL, Chuang E, . Exploring the association of care fragmentation and patient ratings of care quality: A mediation analysis of women Veterans’ experience with VA care. Health Services Research. 2019;54(4):816–826.30989651
930 Brunner J, Chuang E, Washington DL, . Patient-Rated Access to Needed Care: Patient-Centered Medical Home Principles Intertwined. Women’s Health Issues. 2018;28(2):165–171.29339012
931 Di Leone BAL, Wang JM, Kressin N, Vogt D. Women’s veteran identity and utilization of VA health services. Psychol Serv. 2016;13(1):60–68.25729892
932 Gawron LM, Pettey WBP, Redd AM, . Distance to Veterans Administration Medical Centers as a Barrier to Specialty Care for Homeless Women Veterans. Studies in health technology and informatics. 2017;238:112–115.28679900
933 Wolfe HL, Boyer TL, Shipherd JC, . Barriers and Facilitators to Gender-affirming Hormone Therapy in the Veterans Health Administration. Annals of behavioral medicine : a publication of the Society of Behavioral Medicine. 2023.
934 Rose AJ, Hughto JMW, Dunbar MS, . Trends in Feminizing Hormone Therapy for Transgender Patients, 2006–2017. Transgender Health. 2023;8(2):188–194.37013092
935 Hahn H, Burkitt KH, Kauth MR, . Primary sources of health care among LGBTQ+ veterans: Findings from the Behavioral Risk Factor Surveillance System. Health Services Research. 2023;58(2):392–401.36331086
936 Boyer TL, Wolfe HL, Littman AJ, . Patient Experiences and Provider Perspectives on Accessing Gender-Affirming Surgical Services in the Veterans Health Administration. J Gen Intern Med. 2023.
937 Wolfe HL, Vimalananda VG, Wong DH, . Patient Characteristics Associated with Receiving Gender-Affirming Hormone Therapy in the Veterans Health Administration. Transgender Health. 2022.
938 Shipherd JC, Darling JE, Klap RS, . Experiences in the Veterans Health Administration and Impact on Healthcare Utilization: Comparisons Between LGBT and Non-LGBT Women Veterans. LGBT Health. 2018;5(5):303–311.29979640
939 Dietert M, Dentice D, Keig Z. Addressing the Needs of Transgender Military Veterans: Better Access and More Comprehensive Care. Transgender Health. 2017;2(1):35–44.28861546
940 Rohs CM, Albright KR, Monteith LL, . Perspectives of VA healthcare from rural women veterans not enrolled in or using VA healthcare. PLoS One. 2023;18(8 August).
941 Cordasco KM, Mengeling MA, Yano EM, Washington DL. Health and Health Care Access of Rural Women Veterans: Findings From the National Survey of Women Veterans. Journal of Rural Health. 2016;32(4):397–406.
942 Ward RE, Nguyen XT, Li Y, . Racial and Ethnic Disparities in U.S. Veteran Health Characteristics. Int J Environ Res Public Health. 2021;18(5):02.
943 Tsai J, Mitchell L, Nakashima J, Blue-Howells J. Unmet needs of homeless U.S. veterans by gender and race/ethnicity: Data from five annual surveys. Psychological services. 2023;20(1):149–156.34780210
944 Tsai J, Szymkowiak D, Iheanacho T. Psychopharmacoepidemiology of antidepressant medications among homeless and unstably housed service users in the Veterans Affairs healthcare system. Human Psychopharmacology. 2022;37(4).
945 Spinola S, Hoff RA, Tsai J. A psychosocial mediational model of homelessness among U.S. male and female veterans who served in Iraq and Afghanistan. Health & Social Care in the Community. 2021;29(2):453–463.32662176
946 Mulcahy E, Szymkowiak D, Montgomery AE. Psychosocial risk factors for transitions into housing instability among women veterans. Journal of the American Board of Family Medicine. 2021;34(2):387–391.33833007
947 Yu B, True G, Chhabra M, . The Intersection of Interpersonal Violence and Housing Instability: Perspectives From Women Veterans. American Journal of Orthopsychiatry. 2020;90(1):63–69.30596443
948 Montgomery AE, Shipherd JC, Kauth MR, . Use of Veterans Health Administration Homeless Programs Among Transgender and Non-Transgender Veterans Experiencing Self-Reported Housing Instability. Journal of Health Care for the Poor & Underserved. 2020;31(2):909–919.33410815
949 Felder S, Delany PJ. The life course of homeless female Veterans: Qualitative study findings. Journal of Military, Veteran & Family Health. 2020;6:31–39.
950 Carter SP, Montgomery AE, Henderson ER, . Housing Instability Characteristics Among Transgender Veterans Cared for in the Veterans Health Administration, 2013–2016. American Journal of Public Health. 2019;109(10):1413–1418.31415197
951 Montgomery AE, Sorrentino AE, Cusack MC, . Recent Intimate Partner Violence and Housing Instability Among Women Veterans. American Journal of Preventive Medicine. 2018;54(4):584–590.29433952
952 Dichter ME, Wagner C, Borrero S, . Intimate partner violence, unhealthy alcohol use, and housing instability among women veterans in the Veterans Health Administration. Psychological services. 2017;14(2):246–249.28481611
953 Campbell SB, Gray KE, Hoerster KD, . Differences in functional and structural social support among female and male veterans and civilians. Social Psychiatry & Psychiatric Epidemiology. 2021;56(3):375–386.32249329
954 Boros P, Erolin KS. Women Veterans after Transition to Civilian Life: An Interpretative Phenomenological Analysis. Journal of Feminist Family Therapy. 2021;33(4):330–353.
955 Sienkiewicz ME, Amalathas A, Iverson KM, . Examining the association between trauma exposure and work-related outcomes in women veterans. International Journal of Environmental Research and Public Health. 2020;17(12):1–16.