# DISCUSSION

This evidence map identified 933 articles on WVs health published between 2016 and 2023, which was double the number published in the preceding 8 years. Similar to the 2008-2015 evidence map, most studies were observational and focused on mental health. Areas with the greatest growth were suicide/NSSI, reproductive mental health, reproductive health, chronic pain/opioids, and interpersonal violence. Within prioritized populations, there was an 8-fold increase in papers focusing on transgender and/or nonbinary Veterans; however, overall this remained an infrequent target population (k = 32). More commonly prioritized populations were OEF/OIF/OND Veterans and Veterans with a history of trauma. Emerging areas included harassment and discrimination experienced within the context of VA care, sleep disorders, disordered eating, and military-related toxic exposures. Literature areas with modest growth include long-term care/aging and access to care/utilization. Additional gaps in this literature included conditions common among women Veterans including hypertension, anxiety, and depression. As observed in the 2008-2015 map, we found that this overall body of literature remains primarily observational, though we identified 26 trials in the areas of general mental health and substance use, in addition to 11 implementation trials. Overall, there was also a similar portion of articles that exclusively included WVs (~44%) compared with articles with mixed samples of WVs and Veteran men or WVs and non-Veteran civilian women.

The areas of greatest growth for the WVs health literature are largely consistent with recent priority areas for VA research and major shifts in the overall population demographics. For example, pain, opioid use, and suicide prevention are all stated areas of emphasis in VA research. In addition, new areas of this literature map to previously underrecognized areas of importance, such as stranger harassment in VA facilities, or to areas of growing focus, such as military toxic exposures following the 2022 PACT Act.^326^ We also identified a growth in research regarding health issues of women in their reproductive years (eg, maternal health, family planning), perhaps reflecting the increase in reproductive-age WVs receiving care in the VA.^327^ This growth has been supported by multiple strategic actions from the WHRN^6^ including the organization and hosting of relevant national collaborative research workgroups (eg, reproductive mental health, suicide prevention, LGBTQ+ Veterans, SUD), sponsoring of multiple women Veteran’s health-focused journal supplements, and the direct involvement of congressionally mandated IPV work.^328–330^ In addition, new workgroups have been recently launched to address the information need around menopause, women, aging, and women’s military exposures which will support the needed growth in these areas.

In developing this map, we also explored the representation of prioritized populations within the field of WVs research by identifying both the area of focus for each article as well as the patient populations included. We observed an increase in the number of articles related to the health of transgender and/or nonbinary Veterans (4 to 32 articles), as well 156 articles focused on OEF/OIF/OND Veterans and 141 focused on Veterans with a history of trauma. We also identified 38 articles that specifically sought to include or focus on Veterans from racially and ethnically minoritized populations. We were unable to directly compare this finding to the 2008-2015 WVs health evidence map due to differences in categorization. Increases in research that investigates or accounts for the role of race, ethnicity, and gender identity in WVs health and VA health care align with the VA Office of Research and Development (ORD) strategic priority to actively promote diversity, equity, and inclusion.

Significant opportunities exist to leverage existing data sets to expand the impact of VA research and generate valuable information to inform patient-centered, personalized care for WVs.^328^ Similar to the 2008-2015 map, we excluded over 500 articles that did not report findings for WVs subsamples, representing an important missed opportunity since in many of these studies, it would likely have been feasible to disaggregate outcomes for WVs. These observations suggest that, in line with the VA ORD strategic priority to put VA data to work for Veterans, future research could better utilize VA data to explore differences in outcomes among Veteran women and Veteran men. Moreover, even when lacking statistical power to support subgroup analyses, investigators can still make retrospective or prospective data on WVs available for hypothesis generation or for contribution to future individual participant meta-analyses. A related strategy is to harmonize eligibility criteria, outcomes, and data collection strategies of prospective VA studies within the same research area to better enable pooling of findings across studies. These strategies could be useful, in particular, for building the limited literature on common but still understudied conditions impacting WVs, such as hypertension, anemia, lumbosacral disorders, and irritable bowel syndrome.^3^

Although there were relatively few randomized trials, we identified a notable number of program evaluations. This finding highlights the growth of VA clinical offerings and innovations designed to improve the health of WVs, as well as greater use of program evaluation resources available within VA’s Learning Health Care System model. Although resource-intensive and methodologically sophisticated trials are often warranted for higher-risk innovations, lower-risk innovations can likely advance more rapidly to clinical practice, along a pathway that includes pragmatic research studies and well-designed program evaluations. This is especially true when evidence on safety and benefits exists in other clinical settings and populations. As such, ongoing evaluation of the field of WVs health research should involve tracking the progress and outcomes of program evaluation efforts alongside findings from rigorous efficacy and implementation trials.

This evidence map is focused on WVs, but findings have implications beyond the VA setting.^330^ First, more WVs receive care outside of the VA than within the VA. While there are known differences in health status and demographics between VA users and non-users,^331^ many of the findings from this work can inform the care provided to WVs outside the VA. Second, a growing number of WVs receive dual care (simultaneous care from inside and outside the VA) due to the need to seek clinical expertise in women’s health from outside of the VA and in response to the expansion of VA-purchased care in the community. Clinicians in both settings could benefit from a richer understanding of the dynamics and prevalence of health issues and health care challenges experienced by this population. Finally, many of the health issues and complexities of health care for WVs are not unique to the Veteran population. Comorbid mental and physical health conditions, amputations, care barriers due to SDOH, and long-term effects of sexual trauma are also experienced by many men and women in the non-Veteran civilian population. The extensive expertise built in the VA research community has long supported clinical practice and professional guidelines used by non-Veteran civilian populations (eg, shingles vaccine) and WVs research offers similar benefits.^332^

## Limitations

These findings should be considered within the context of the limitations of our approach. First, the categorization of identified articles could have been conducted in multiple ways—both overall and with each individual article. We aimed to align our categorization with the existing structure and approach to WVs health research by the VA ORD and Women’s Health Research Network while expanding the opportunities to look for overlap and connections across areas of research. A different approach may have revealed different patterns in the literature. Although we made efforts to maintain comparability with earlier evidence maps and reviews, we acknowledge that some of our categorization and literature mapping approaches were not identical to those used in past mapping efforts. For example, we identified articles focused on OEF/OIF/OND Veterans as a population targeted for inclusion; however, this is not the same as being focused specifically on post-deployment issues (less than 10 of the 156 articles seeking to include this group of Veterans were framed around re-integration and fewer than 10 focused explicitly on ramifications of combat exposure). Second, we excluded articles that described single-site quality improvement projects to focus on recent and generalizable scientific literature designed to translate broadly. However, reports of these projects likely describe important efforts to improve the health and well-being of WVs and may merit future synthesis. Third, due to the volume of literature, we were unable to screen each citation in duplicate, which may have led to the incorrect exclusion or misclassification of articles. We quality checked 20% of each investigator’s citations (and up to 100% if needed). Lastly, given the volume of literature, we did not contact authors for clarification when aspects of study reporting or analyses were unclear; we described the study characteristics to the best of our abilities based on information in the primary literature.

## Future Research

The current map demonstrates advances on research recommendations made in the 2008-2015 evidence map. Specifically, there has been a greater intersectional focus on certain minoritized populations, research on emerging topic areas, and increased reporting of funding sources. In addition to identifying areas of WVs literature that have grown and are ready for a focused synthesis, another key value of an evidence map is its ability to identify areas warranting further investigation. We have thus highlighted gaps in the literature that could be areas for future scientific exploration (Table 19).

First, the largest portion of WVs who received care in the VA are middle aged or younger. There is a time-sensitive need to understand conditions affecting this subpopulation now and in coming years, including chronic conditions such as heart disease, cancer, menopause, caregiving, cognitive decline, and mental health conditions such as PTSD, depression, and anxiety. Additionally, the intersectional and cumulative toll, and long-term management of these conditions needs to be explored. Particularly for chronic diseases, military exposures, and cancer, there is a great opportunity to leverage VA data to explore how and when care should be tailored for women. Although we observed an increased number of articles related to CVD in this map compared to the 2008-2015 map, the volume of long-term care and aging-related articles saw nominal growth. The 2024 White House Initiative for Women’s Health Research underscores the importance of growing women’s health research, especially related to mid- and late-life health issues for women.^333^ Similarly, other conditions commonly affecting aging women such as menopausal symptoms, cancer, and dementia have been explored minimally in the WVs population and are identified as a priority for VA women’s health research. Evolving VA research activities, such as the newly established WHRN workgroups mentioned above, the Women’s Operational Military Exposure Network Center of Excellence (WOMEN CoE) and the recently established VA Center for Oncology oUtcomes Review And Gender Equity (COURAGE), are women’s health-focused research groups well positioned to address these existing gaps in a timely manner.

Second, this body of literature grew rapidly since the 2008-2015 map, and now presents a robust picture of many topics important to the health of WVs. Despite continued growth, it will be important for research efforts to continue to respond to evolving patterns of care, access, and utilization and to the emerging health care needs of an aging and changing WVs population. We noted gaps in areas that might inform how care is provided in the VA including the use of dual sources of care, comparisons to non-VA care received by WVs, and care coordination across sites. In addition, while research on many prioritized VA populations has increased, there will be a continued need to ensure representation of minoritized populations and intersectional identities in study samples and findings. In addition, we note that many articles^163,334–338^ identified in this map leveraged data from a collection of larger survey and cohort studies, which demonstrates a path for growth in the field and may suggest the benefits of more funding for similarly designed studies.

Third, we also highlighted several important study design and reporting considerations. Crucially, participant sex and gender identity were reported separately in only 61 included articles. Because patient sex and gender identity have been captured separately in VA medical records for only the last few years, studies based on administrative data have not had sufficient time to use this additional information. It will be critical to approach the thoughtful incorporation of these variables into future analyses. The relevance and importance of these variables will vary by topic, as will the ability to conduct meaningful sex- or gender identity-based analyses built on data availability. However, reporting of stratified outcomes for WVs as a standard practice would support future hypothesis generation and potential inclusion in meta-analyses. In addition, the prior 2008-2015 evidence map noted the importance of considering Veteran engagement to strengthen and advance the field of WVs health literature.^9^ While we sought to identify which articles noted the practice of WVs engagement during study conduct, this was rarely reported (only 28 articles). Aside from increasing engagement efforts, future research should articulate if, how, and when engagement with WVs was sought and implemented over the course of the research (eg, topic ideation, study implementation, interpretation of findings, dissemination). Engagement advances scientific rigor, feasibility, and acceptability^339,340^; however, there are still many unanswered questions in the field of engagement science. Thorough and appropriate documentation of patient partners and engagement activities could assist in advancing the field of engagement science, a strategic focus area of the VA Office of Research Development. The many existing resources in the VA through the WHRN^6^ and groups such as Growing Rural Outreach through Veteran Engagement (GROVE)^341^ may be leveraged to support WVs research moving forward.

Fourth, the vast majority of the existing WVs literature continues to be observational in nature. While there was a 3-fold increase in clinical trials since the 2008-2015 map, the percentage of articles with a RCT study design remains low (3%) and we identified only 11 implementation studies. One example of current VA efforts to increase clinical trials participation among WVs is the Women’s Enhanced Recruitment Process (WERP) which is funded through the Cooperative Studies Program. While not all innovations will require sophisticated trials prior to application in clinical practice, there may be other ways to improve inclusion of women in trials (eg, aligning recruitment activities with locations where women receive clinical care, tailoring study recruitment messaging and images to be inclusive of WVs) to assist with meeting the VA ORD strategic priority of increasing Veterans’ access to high-quality clinical trials.

Finally, we found 17 systematic reviews, scoping reviews, and evidence maps across areas of general mental health, interpersonal violence, and SDOH. Focus areas that could have sufficient evidence to support a future focused synthesis include MST, PTSD, substance use, and suicide/NSSI.

Table 19 Gap Analysis of Recent WVs Health Literature

Population | - Women with health issues common during midlife, peri-, and post-menopausal age; - Older WVs and their caregivers; - Rural-dwelling women; - Women from racially and ethnically minoritized populations; - Mixed-sex and mixed-gender populations
Intervention or phenomena | - Common chronic conditions impacting women including hypertension, anemia, lumbosacral disorders, asthma, and irritable bowel syndrome; - Gender-based differences in pain management including opioid prescribing and/or harm reduction strategies; - Toxic exposures; - Care received via dual site (eg, VA and non-VA); - Women’s health provider and staff retention; - SDOH impact; - Combat exposure impacts
Comparator | - Non-VA care; - Non-sex-based or gender-informed care
Outcomes | - Implementation outcomes
Setting | - Community-delivered care for Veterans
Other design and reporting considerations | - Collect and report self-identified gender and sex assigned at birth; - Explore experimental, interventional, and implementation studies; - Conduct sex and/or gender-based analyses appropriate to condition under study; when impacted by statistical limitations, stratify by sex and gender for hypothesis generation and future meta-analyses; - Report nature of any Veteran and partner engagement that occurs during a study

## CONCLUSIONS

A robust evidence base is critical to promote the overall health of WVs and improve their quality of life and well-being. The pace of growth of WVs health research has doubled and has expanded in important areas that align with VA research priorities. Further advancement of this field should include research on health issues pertinent to an aging WVs population and greater utilization of rigorous but pragmatic research and program evaluation approaches.