# METHODS

## REGISTRATION AND REVIEW

A preregistered protocol for this review can be found on OSF (https://doi.org/10.17605/OSF.IO/7VT5Z). A draft version of this report was reviewed by external peer reviewers; their comments and author responses are located in the Appendix.

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following key question was the focus of this evidence map: What is the scope and breadth of the literature on WVs health published since 2015? Study eligibility criteria are shown in Table 1.

Table 1 Study Eligibility Criteria

| Eligibility Criteria
Population | Included:; - Individuals who have served in the armed forces (including national guard and reserves) [underlined: and] who identify as women or who are transgender and/or non-binary and were assigned female at birth; - More than 75% of the study population comprised WVs [underlined: or] the study reported results separately for WVs as subgroup analysis or otherwise reported results separately for women. Included studies could:; ○ Stratify or disaggregate results by sex and/or gender (eg, report the effect separately for women only); ○ Report subgroup analysis by sex and/or gender by modeling results separately for men and women; ○ Include mediation modeling or interaction terms to evaluate the contribution of individual sex and/or gender factors to differences between men and women; - Health care team members who provided care to WVs if the focus of article was on provision of care to the WVs population; Excluded:; - Studies that did not include US WVs; - Studies that included only active-duty members of the military; - Animal studies
Intervention | Any or none
Comparator | Any or none
Outcomes | Any
Setting | Health care settings in the US (or US Veteran expats if outside the US)
Study design | Included:; - Trials, observational (prospective and retrospective) studies, systematic reviews (eg, scoping, mapping, umbrella, qualitative), protocols, qualitative studies, secondary analyses of trials, implementation studies, multisite or national program evaluations, measurement or methods studies if specifically used for WVs; - Designs other than qualitative or methods development, for which the total number of WVs was over 50; - Qualitative studies of only WVs [underlined: or] those with a qualifying subgroup analysis, which included either a specific plan outline to compare men and women or at least 1 theme broken out that was specific to WVs; Excluded:; - Letters, case reports and case series, meeting abstracts, dissertations not published in a peer reviewed journal, editorials, narrative review, comprehensive or narrative reviews, measurement development studies not specific to WVs, single-site QI projects, commentaries, opinion papers, feasibility studies, pilots; - Studies that used sex and/or gender as a component of the regression or propensity model; - Studies that treated sex and/or gender as a covariate only
Years | Published January 2016 to present
Language | English only

## SEARCHING AND SCREENING

We conducted a primary search from January 1, 2016, to October 2023 of MEDLINE (via Ovid), Embase (via Elsevier), and CINAHL (via EBSCO) (see Appendix for complete search strategies). We used terms for Veterans (eg, post-deployment) and women (eg, women’s health). To ensure completeness, search strategies were developed in consultation with an expert medical librarian and peer reviewed by a second librarian in accordance with PRESS guidance.^10^ After an initial pilot process with the whole team for calibration, we screened all identified citations with 2 reviewers at the title and abstract level. Although we identified a large number of mixed-sample studies that included both Veteran men and WVs, or WVs and non-Veteran civilian women, we were often unable to verify, based on title and abstract alone, whether studies reported results among WVs. While infeasible to review all mixed-sample studies at full text, we prioritized mixed-sample studies with at least 10,000 participants for a further full-text review. Our rationale for this choice was that, as WVs comprise ~10% of the Veteran populations, such studies would likely include ~1,000 WVs depending on the condition of study, would be more likely to report results separately for WVs, and would thus be more generalizable to the larger WVs population. We also reviewed an additional 20% of studies in duplicate that had been excluded at the title and abstract level for not disaggregating results for WVs. We conducted 3 pilot full-text review rounds of 10 studies each for team calibration, prior to independent full-text review. Full-text review was then conducted by a single reviewer. Twenty percent of studies excluded at full-text review by 1 reviewer were then reviewed in duplicate by a second reviewer [AAT]. We did not include individual studies from the 2008-2015 map within the current map, though we reference findings from that map throughout.

## DATA EXTRACTION

Citations meeting eligibility criteria at full-text review were included for extraction. Extraction was completed by an individual reviewer. Given the large volume of literature, we quality checked data extractions for up to 20% of each extracting reviewer. If significant accuracy concerns were identified, we reviewed further for correction as needed. In addition, we quality checked all included studies for focus areas and target populations. Primary focus area was assigned based on an assessment of the framing and emphasis of the article by drawing from the title, introduction, stated aim or objective, and analytic approach. When an article had multiple potential primary focus areas, we classified it based on relevant medical condition (eg, hypertension) rather than care delivery characteristic (eg, utilization). Each article was assigned to only 1 primary focus area (eg, reproductive mental health and reproductive health are mutually exclusive). We also assigned up to 2 secondary focus areas. We extracted key study characteristics such as the study population (eg, military service era, age), study focus areas, study design, population, and funding source. The internal validity (risk of bias) of each included study was not rated, in keeping with evidence map methodology.

## SYNTHESIS

We described key study characteristics of the included articles and investigated patterns across these characteristics to identify data-rich areas that warranted further investigation. In particular, we mapped the included articles across key categories considered of interest and a priority to the WVs research community. Articles were mainly grouped according to the primary focus area. We used visualizations to present important research and publication patterns for the overall evidence base and within primary focus areas.

Study designs and stages were classified, where possible, using the design declared by the study authors. The Cochrane Effective Practice and Organisation of Care (EPOC) suggests that 4 study designs should be considered for systematic review with multiple sites and data collection points: randomized trials with 2 intervention and 2 control sites, non-randomized trials with 2 intervention and 2 control sites, controlled before-after trials with 2 intervention and 2 control cites, and interrupted time series and repeated measure studies with 3 data collections before and 3 data collections after the intervention.^11^ In this report, however, experimental studies were not held to the full (EPOC) study design criteria requiring multiple sites or data collection time points, as the category was intended to capture interventional studies that did not employ a randomization process. Secondary analyses of RCT data that did not preserve random allocation (eg, comparisons of intervention-group participants by level of intervention adherence) were considered observational studies.