# BACKGROUND

Since its inception, the VA has aimed to provide high-quality care that recognizes and addresses the unique health care needs of all Veterans. For much of the history of the VA, however, women have made up a small proportion of the US armed forces and the scope of VA services has been largely tied to the health needs of Veteran men. Only in recent decades has the number of women Veterans (WVs) seeking care at the VA begun to steadily grow, and with that there is an increased demand for programs and services that meet the health and well-being needs of women.

WVs now comprise approximately 10% of the Veteran population and are expected to make up 18% of the Veteran population by 2040.^1,2^ The number of women using the VA for health care continues to increase every year and has seen a 1.8-fold increase since 2010, with WVs utilizing outpatient care at a higher frequency than Veteran men.^3,4^ WVs tend to be younger, more racially and ethnically diverse, and more likely to be service-connected than Veteran men.^3^ In fact, younger women VA users are more likely to be service-connected and have high service-connected disability ratings than older women VA users, making them eligible for lifelong VA care for service-connected conditions.^4^ It is thus critical that the VA utilize available research to understand best practices for providing evidence-based care to WVs across their lifespan—from reproductive years to perimenopause, geriatric years, and end of life.

In response to the unique health care needs and changing population demographics of WVs, the VA has prioritized initiatives to address knowledge gaps, improve care, and eliminate barriers to care for WVs as well as transgender and/or non-binary Veterans who may utilize VA women’s health services. In 2004, the first national VA Women’s Health Research Agenda^5^ was developed and provided a framework to drive new research addressing the specific health needs of WVs. In 2010, the VA funded the Women’s Health Research Network (WHRN) with 2 initial objectives: (1) build research capacity by supporting VA women’s health researchers and (2) support multisite studies and quality improvement projects that emphasize the recruitment of women, through the establishment of a Women’s Health Practice-based Research Network (WH-PBRN). The WHRN has been pivotal to the exponential amplification of women’s health research through the VA and has led to multiple trials and journal supplements focused on WVs health as well as expansion of the WH-PBRN to 76 VA medical centers across the country.^6^ Additionally, in 2010, the VA Women’s Health Services Research Conference, sponsored by the VA HSR&D Service and the VA Women Veterans Health Strategic Health Care Group, brought together researchers and leadership and resulted in the development of the VA Women’s Health Services Research Agenda. This new agenda outlined 6 research priority areas: access to care and rural health, primary care and prevention, mental health, post-deployment health, complex chronic conditions/aging and long-term care, and reproductive health.^5^

To date, there have been 3 articles^7–9^ which broadly summarize the field of WVs health research. The evidence map, developed in 2017 by the VA ESP, included 440 articles published between 2008-2015.^9^ More than 90% of identified studies were observational and nearly half were related to mental health. The 2017 ESP map showed dramatic growth in several critical research areas: access to care and rural health, post-deployment health, reproductive health, and mental health. Recommendations for improving WVs health research made by the map authors included reporting outcomes disaggregated for WVs, engaging WVs in research, conducting focused systematic reviews of evidence in certain research areas, expanding research to address vulnerable populations, and addressing the expanding role of women in combat.

In the 8 years since the 2008-2015 evidence map was published, there has been considerable growth in WVs health research. The present evidence map includes studies published from 2016 to the present. In addition to describing this new evidence and identifying research areas that have significantly grown from the 2008-2015 period, we revisited the future research recommendations of the earlier evidence map to clarify what questions about WVs health and health care have since been addressed, and what questions remain unanswered.