# Appendix

## SEARCH STRATEGIES

Database: MEDLINE (via Ovid)

Search date: 10/17/2023

Note: MEDLINE ALL 1946 to October 16, 2023

Search Set + Description | Search Strategy | Results
#1; Veteran terms | exp Veterans/ or exp Hospitals, Veterans/ or exp Veterans Health/ or exp Veterans Health Services/ or (veteran or veterans or ((former* or retir*) adj2 (military or “service member” or “service members” or servicemember or servicemembers)) or “post deployment” or post-deployment or VAMC or VAHCS or VHA).ti,ab. | 52093
#2; Women terms | exp Women/ or exp Women’s Health/ or exp Women’s Health Services/ or exp Health Services for Transgender Persons/ or exp Homosexuality, Female/ or exp Breast/ or exp Breast Diseases/ or exp Breast Neoplasms/ or exp Mammography/ or exp Mastectomy/ or exp Mammaplasty/ or exp Female Genitalia/ or exp Genital Diseases, Female/ or exp Genital Neoplasms, Female/ or exp Pregnant Women/ or exp Maternal Health/ or exp Maternal Health Services/ or exp Prenatal Care/ or exp Perinatal Care/ or exp Postnatal Care/ or exp Postpartum Period/ or exp Depression, Postpartum/ or exp Pregnancy/ or exp Pregnancy Complications/ or exp Breast Feeding/ or exp Lactation/ or exp Contraception/ or exp Hormonal Contraception/ or exp Contraceptives, Oral/ or exp “Contraceptive Devices, Female”/ or Reproductive Health Services/ or exp Preconception Care/ or exp Family Planning Services/ or exp Fertility/ or exp Infertility/ or exp Fertility Clinics/ or exp obstetrical surgical procedures/ or exp gynecologic surgical procedures/ or exp Abortion, Induced/ or exp Abortion, Spontaneous/ or exp Menstrual Cycle/ or exp Menstruation Disturbances/ or exp Menopause/ or exp Polycystic Ovary Syndrome/ or exp Domestic Violence/ or exp Intimate Partner Violence/ or exp Spousal Abuse/ or exp Battered Women/ or exp Rape/ or (woman or women or womens or womans or “women s” or “woman s” or female or females or “female s” or trans or transgender or transgendered or transfemale or “trans-female” or transman or trans-man or transmans or “transman s” or trans-mans or “trans-man s” or transmen or trans-men or transmens or trans-mens or “transmen s” or “transmen s” or transwoman or trans-woman or transwomans or “transwoman s” or trans-womans or “trans-woman s” or trans-women or transwomen or transwomens or “transwomen s” or trans-womens or “transwomen s” or gender-specific or “gender specific” or gender-related or “gender related” or “gender difference” or “gender differences” or sex-specific or “sex specific” or sex-related or “sex related” or “sex difference” or “sex differences” or lesbian or lesbians or non-binary or “non binary” or abortifacient or abortifacients or abortion or abortions or amenorrhea or breast or breasts or breastfeeding or cervix or cervical or climacteric or clitoris or clitoral or colposcop* or colpotom* or conception or contraception or contraceptive or contraceptives or culdoscop* or dysmenorrhea or dyspareunia or endometriosis or endometritis or endometrium or endometrial or endometrioid or episiotom* or fallopian or fallopians or “family planning” or fertility or gynecolog* or “hot flash” or “hot flashes” or hymen or hymens or hysterectom* or hysteroscop* or infertility or “intimate partner violence” or “intrauterine device” or “intrauterine devices” or IUD or IUDs or labia or labias or labial or lactation or lactating or mammaplast* or mammoplast* or mammogra* or mastectom* or maternal or maternally or menopaus* or menorrhagia or menstrua* or menses or menarche or “military sexual trauma” or “military sexual assault” or “morning after pill” or “morning after pills” or obstetric* or oligomenorrhea or oophorectom* or oophoritis or ovariectom* or ovary or ovaries or ovarian or “painful period” or “painful periods” or “irregular period” or “irregular periods” or PCOS or perimenopaus* or peri-menopaus* or perinatal or peri-natal or perinatally or peri-natally or PMDD or postmenopaus* or post-menopaus* or postnatal or post-natal or postnatally or post-natally or postpartum or post-partum or preconception or pre-conception or pregnancy or pregnancies or pregnant or pregnancy-induced or pregnancy-associated or prepregnancy or premenstrual or pre-menstrual or prenatal or pre-natal or prenatally or pre-natally or puerperium or rape or rapes or raped or “reproductive health” or “reproductive care” or “reproductive healthcare” or “reproductive plan” or “reproductive planning” or salpingectom* or salpingo-oophorectom* or uterus or uterine or vagina or vaginas or vaginal* or transvaginal* or vaginismus or vulva or vulvas or vulvar or vulvectom* or vulvitis or vulvodynia).ti,ab. or ((dilatation or vacuum) adj2 curettage).ti,ab. or ((sex or sexual or sexually or domestic or partner or spouse or spousal or physical or physically) adj3 (abuse or abuses or abused or abuser or abusers or abusive or violence or violent or assault or assaults or assaulted)).ti,ab. or (tubal adj2 (ligation* or sterilization* or sterilisation*)).ti,ab. | 4874513
#3; combination | 1 and 2 | 5729
#4; Date limit 2016 - present | Limit 3 to da=20160101-20231231 | 3156
#5; Study design exclusions | 4 not (case reports OR editorial OR letter OR comment OR congress).pt. | 3070
#6; Animal study exclusion | 5 not (exp animals/ not exp humans/) | 3063

Database: Embase (via Elsevier)

Search date: 10/17/2023

Note: Search from the Results page

Search Set + Description | Search Strategy | Results
#1; Veteran terms | ‘veteran’/exp OR ‘veterans health’/exp OR ‘veterans health service’/exp OR (veteran OR veterans OR ((former* OR retir*) NEAR/2 (military OR ‘service member’ OR ‘service members’ OR servicemember OR servicemembers)) OR ‘post deployment’ OR ‘post deployment’ OR VAMC OR VAHCS OR VHA):ti,ab | 67740
#2; Women terms | ‘women’s health’/exp OR ‘homosexual female’/exp OR ‘male to female transgender’/exp OR ‘breast’/exp OR ‘breast disease’/exp OR ‘breast cancer’/exp OR ‘mammography’/exp OR ‘mastectomy’/exp OR ‘breast reconstruction’/exp OR ‘female genital system’/exp OR ‘gynecologic disease’/exp OR ‘female genital tract tumor’/exp OR ‘pregnant woman’/exp OR ‘maternal care’/exp OR ‘maternal health service’/exp OR ‘prenatal care’/exp OR ‘perinatal care’/exp OR ‘postnatal care’/de OR ‘puerperium’/de OR ‘postnatal depression’/exp OR ‘pregnancy’/exp OR ‘pregnancy complication’/exp OR ‘breast feeding’/exp OR ‘lactation’/exp OR ‘lactation disorder’/exp OR ‘contraception’/exp OR ‘female contraceptive device’/exp OR ‘prepregnancy care’/exp OR ‘family planning’/exp OR ‘female fertility’/exp OR ‘female infertility’/exp OR ‘fertility clinic’/exp OR ‘obstetric procedure’/exp OR ‘obstetric operation’/exp OR ‘gynecologic disease’/exp OR ‘gynecologic surgery’/exp OR ‘abortion’/exp OR ‘menstrual cycle’/exp OR ‘menstrual cycle’/exp OR ‘menstruation disorder’/exp OR ‘menopause and climacterium’/exp OR ‘menopause related disorder’/exp OR ‘battered woman’/exp OR ‘partner violence’/exp OR ‘rape’/exp OR (woman OR women OR womens OR womans OR ‘women s’ OR ‘woman s’ OR female OR females OR ‘female s’ OR trans OR transgender OR transgendered OR transfemale OR ‘trans female’ OR transman OR ‘trans man’ OR transmans OR ‘transman s’ OR ‘trans mans’ OR ‘trans-man s’ OR transmen OR ‘trans men’ OR transmens OR ‘trans mens’ OR ‘transmen s’ OR ‘transmen s’ OR transwoman OR ‘trans woman’ OR transwomans OR ‘transwoman s’ OR ‘trans womans’ OR ‘trans-woman s’ OR ‘trans women’ OR transwomen OR transwomens OR ‘transwomen s’ OR ‘trans womens’ OR ‘transwomen s’ OR ‘genderspecific’ OR ‘gender specific’ OR ‘genderrelated’ OR ‘gender related’ OR ‘gender difference’ OR ‘gender differences’ OR ‘sexspecific’ OR ‘sex specific’ OR ‘sexrelated’ OR ‘sex related’ OR ‘sex difference’ OR ‘sex differences’ OR lesbian OR lesbians OR nonbinary OR ‘non binary’ OR abortifacient OR abortifacients OR abortion OR abortions OR amenorrhea OR breast OR breasts OR breastfeeding OR cervix OR cervical OR climacteric OR clitoris OR clitoral OR colposcop* OR colpotom* OR conception OR contraception OR contraceptive OR contraceptives OR culdoscop* OR dysmenorrhea OR dyspareunia OR endometriosis OR endometritis OR endometrium OR endometrial OR endometrioid OR episiotom* OR fallopian OR fallopians OR ‘family planning’ OR fertility OR gynecolog* OR ‘hot flash’ OR ‘hot flashes’ OR hymen OR hymens OR hysterectom* OR hysteroscop* OR infertility OR ‘intimate partner violence’ OR ‘intrauterine device’ OR ‘intrauterine devices’ OR IUD OR IUDs OR labia OR labias OR labial OR lactation OR lactating OR mammaplast* OR mammoplast* OR mammogra* OR mastectom* OR maternal OR maternally OR menopaus* OR menorrhagia OR menstrua* OR menses OR menarche OR ‘military sexual trauma’ OR ‘military sexual assault’ OR ‘morning after pill’ OR ‘morning after pills’ OR obstetric* OR oligomenorrhea OR oophorectom* OR oophoritis OR ovariectom* OR ovary OR ovaries OR ovarian OR ‘painful period’ OR ‘painful periods’ OR ‘irregular period’ OR ‘irregular periods’ OR PCOS OR perimenopaus* OR peri?menopaus* OR perinatal OR peri?natal OR perinatally OR peri?natally OR PMDD OR postmenopaus* OR post?menopaus* OR postnatal OR post?natal OR postnatally OR post?natally OR postpartum OR post?partum OR preconception OR pre?conception OR pregnancy OR pregnancies OR pregnant OR pregnancy?induced OR pregnancy?associated OR prepregnancy OR premenstrual OR pre?menstrual OR prenatal OR pre?natal OR prenatally OR pre?natally OR puerperium OR rape OR rapes OR raped OR ‘reproductive health’ OR ‘reproductive care’ OR ‘reproductive healthcare’ OR ‘reproductive plan’ OR ‘reproductive planning’ OR salpingectom* OR salpingo?oophorectom* OR uterus OR uterine OR vagina OR vaginas OR vaginal* OR transvaginal* OR vaginismus OR vulva OR vulvas OR vulvar OR vulvectom* OR vulvitis OR vulvodynia):ti,ab OR ((dilatation OR vacuum) NEAR/2 curettage):ti,ab OR ((sex OR sexual OR sexually OR domestic OR partner OR spouse OR spousal OR physical OR physically) NEAR/3 (abuse OR abuses OR abused OR abuser OR abusers OR abusive OR violence OR violent OR assault OR assaults OR assaulted)):ti,ab OR (tubal NEAR/2 (ligation* OR sterilization* OR sterilisation*)):ti,ab | 7127763
#3; combination | #1 AND #2 | 8591
#4; Date limit 2016 - present | #3 AND [01-01-2016]/sd | 5085
#5; Study design exclusions | #4 NOT (‘case report’/exp OR ‘case study’/exp OR ‘editorial’/exp OR [editorial]/lim OR ‘letter’/exp OR [letter]/lim OR ‘note’/exp OR [note]/lim OR [conference abstract]/lim OR ‘conference abstract’/exp OR ‘conference abstract’/it OR ‘case report’:ti OR editorial:ti OR letter:ti OR proceedings:ti OR conference:ti) | 3062
#6; Animal study exclusion | #5 AND [humans]/lim | 3017

Database: CINAHL Complete (via EBSCO)

Search date: 10/17/2023

Search Set + Description | Search Strategy | Results
#1; Veteran terms | (MH “Veterans Health Services”) OR (MH “Veterans+”) OR (MH “United States Department of Veterans Affairs”) OR (MH “Hospitals, Veterans”) OR ((TI veteran OR AB veteran) OR (TI veterans OR AB veterans) OR (((TI former* OR AB former*) OR (TI retir* OR AB retir*)) N2 ((TI military OR AB military) OR (TI “service member” OR AB “service member”) OR (TI “service members” OR AB “service members”) OR (TI servicemember OR AB servicemember) OR (TI servicemembers OR AB servicemembers))) OR (TI “post deployment” OR AB “post deployment”) OR (TI post-deployment OR AB post-deployment) OR (TI VAMC OR AB VAMC) OR (TI VAHCS OR AB VAHCS) OR (TI VHA OR AB VHA)) | 37061
#2; Women terms | (MH “Women+”) OR (MH “Battered Women”) OR (MH “Single Women”) OR (MH “Trans Women”) OR (MH “Expectant Mothers”) OR (MH “Intimate Partner Violence”) OR (MH “Women’s Health”) OR (MH “Women’s Health Services”) OR (MH “Lesbians”) OR (MH “Breast+”) OR (MH “Breast Neoplasms+”) OR (MH “Breast Self-Examination”) OR (MH “Breast Pumps”) OR (MH “Breast Tissue Density”) OR (MH “Breast Reconstruction”) OR (MH “Breast Examination+”) OR (MH “Breast Implants”) OR (MH “Breast Feeding+”) OR (MH “Mammography”) OR (MH “Mastectomy+”) OR (MH “Genitalia, Female+”) OR (MH “Genital Neoplasms, Female+”) OR (MH “Genital Diseases, Female+”) OR (MH “Female Urogenital Diseases and Pregnancy Complications+”) OR (MH “Sexual Dysfunction, Female+”) OR (MH “Maternal Health Services+”) OR (MH “Prenatal Care”) OR (MH “Prenatal Diagnosis+”) OR (MH “Perinatal Period”) OR (MH “Perinatal Care”) OR (MH “Postnatal Care+”) OR (MH “Postnatal Period+”) OR (MH “Depression, Postpartum”) OR (MH “Postpartum Psychosis”) OR (MH “Pregnancy+”) OR (MH “Pregnancy Outcomes”) OR (MH “Pregnancy Discomforts”) OR (MH “Lactation”) OR (MH “Lactation Disorders+”) OR (MH “Contraception+”) OR (MH “Hormonal Contraception”) OR (MH “Contraceptive Agents+”) OR (MH “Prepregnancy Care”) OR (MH “Family Planning+”) OR (MH “Fertility+”) OR (MH “Fertility Preservation”) OR (MH “Infertility+”) OR (MH “Obstetric Emergencies”) OR (MH “Delivery, Obstetric+”) OR (MH “Obstetric Patients”) OR (MH “Obstetric Service”) OR (MH “Obstetric Care+”) OR (MH “Surgery, Obstetrical+”) OR (MH “Gynecologic Examination”) OR (MH “Surgery, Gynecologic+”) OR (MH “Diagnosis, Gynecologic+”) OR (MH “Gynecologic Care”) OR (MH “Abortion, Incomplete”) OR (MH “Abortion, Induced+”) OR (MH “Abortion, Spontaneous+”) OR (MH “Menstrual Cycle+”) OR (MH “Dysmenorrhea”) OR (MH “Menstrual and Perimenopausal Disorders+”) OR (MH “Menstruation Disorders+”) OR (MH “Menstruation”) OR (MH “Menstruation Inducing Agents+”) OR (MH “Oligomenorrhea”) OR (MH “Menopause+”) OR (MH “Menarche”) OR (MH “Menopause, Premature”) OR (MH “Premenopause”) OR (MH “Postmenopause”) OR (MH “Postmenopausal Disorders”) OR (MH “Perimenopause”) OR (MH “Domestic Violence+”) OR (MH “Rape”) OR ((TI woman OR AB woman) OR (TI women OR AB women) OR (TI womens OR AB womens) OR (TI womans OR AB womans) OR (TI “women s” OR AB “women s”) OR (TI “woman s” OR AB “woman s”) OR (TI female OR AB female) OR (TI females OR AB females) OR (TI “female s” OR AB “female s”) OR (TI trans OR AB trans) OR (TI transgender OR AB transgender) OR (TI transgendered OR AB transgendered) OR (TI transfemale OR AB transfemale) OR (TI trans-female OR AB trans-female) OR (TI transman OR AB transman) OR (TI trans-man OR AB trans-man) OR (TI transmans OR AB transmans) OR (TI “transman s” OR AB “transman s”) OR (TI trans-mans OR AB trans-mans) OR (TI “trans-man s” OR AB “trans-man s”) OR (TI transmen OR AB transmen) OR (TI trans-men OR AB trans-men) OR (TI transmens OR AB transmens) OR (TI trans-mens OR AB trans-mens) OR (TI “transmen s” OR AB “transmen s”) OR (TI “transmen s” OR AB “transmen s”) OR (TI transwoman OR AB transwoman) OR (TI trans-woman OR AB trans-woman) OR (TI transwomans OR AB transwomans) OR (TI “transwoman s” OR AB “transwoman s”) OR (TI trans-womans OR AB trans-womans) OR (TI “trans-woman s” OR AB “trans-woman s”) OR (TI trans-women OR AB trans-women) OR (TI transwomen OR AB transwomen) OR (TI transwomens OR AB transwomens) OR (TI “transwomen s” OR AB “transwomen s”) OR (TI trans-womens OR AB trans-womens) OR (TI “transwomen s” OR AB “transwomen s”) OR (TI gender-specific OR AB gender-specific) OR (TI “gender specific” OR AB “gender specific”) OR (TI gender-related OR AB gender-related) OR (TI “gender related” OR AB “gender related”) OR (TI “gender difference” OR AB “gender difference”) OR (TI “gender differences” OR AB “gender differences”) OR (TI sex-specific OR AB sex-specific) OR (TI “sex specific” OR AB “sex specific”) OR (TI sex-related OR AB sex-related) OR (TI “sex related” OR AB “sex related”) OR (TI “sex difference” OR AB “sex difference”) OR (TI “sex differences” OR AB “sex differences”) OR (TI lesbian OR AB lesbian) OR (TI lesbians OR AB lesbians) OR (TI non-binary OR AB non-binary) OR (TI “non binary” OR AB “non binary”) OR (TI abortifacient OR AB abortifacient) OR (TI abortifacients OR AB abortifacients) OR (TI abortion OR AB abortion) OR (TI abortions OR AB abortions) OR (TI amenorrhea OR AB amenorrhea) OR (TI breast OR AB breast) OR (TI breasts OR AB breasts) OR (TI breastfeeding OR AB breastfeeding) OR (TI cervix OR AB cervix) OR (TI cervical OR AB cervical) OR (TI climacteric OR AB climacteric) OR (TI clitoris OR AB clitoris) OR (TI clitoral OR AB clitoral) OR (TI colposcop* OR AB colposcop*) OR (TI colpotom* OR AB colpotom*) OR (TI conception OR AB conception) OR (TI contraception OR AB contraception) OR (TI contraceptive OR AB contraceptive) OR (TI contraceptives OR AB contraceptives) OR (TI culdoscop* OR AB culdoscop*) OR (TI dysmenorrhea OR AB dysmenorrhea) OR (TI dyspareunia OR AB dyspareunia) OR (TI endometriosis OR AB endometriosis) OR (TI endometritis OR AB endometritis) OR (TI endometrium OR AB endometrium) OR (TI endometrial OR AB endometrial) OR (TI endometrioid OR AB endometrioid) OR (TI episiotom* OR AB episiotom*) OR (TI fallopian OR AB fallopian) OR (TI fallopians OR AB fallopians) OR (TI “family planning” OR AB “family planning”) OR (TI fertility OR AB fertility) OR (TI gynecolog* OR AB gynecolog*) OR (TI “hot flash” OR AB “hot flash”) OR (TI “hot flashes” OR AB “hot flashes”) OR (TI hymen OR AB hymen) OR (TI hymens OR AB hymens) OR (TI hysterectom* OR AB hysterectom*) OR (TI hysteroscop* OR AB hysteroscop*) OR (TI infertility OR AB infertility) OR (TI “intimate partner violence” OR AB “intimate partner violence”) OR (TI “intrauterine device” OR AB “intrauterine device”) OR (TI “intrauterine devices” OR AB “intrauterine devices”) OR (TI IUD OR AB IUD) OR (TI IUDs OR AB IUDs) OR (TI labia OR AB labia) OR (TI labias OR AB labias) OR (TI labial OR AB labial) OR (TI lactation OR AB lactation) OR (TI lactating OR AB lactating) OR (TI mammaplast* OR AB mammaplast*) OR (TI mammoplast* OR AB mammoplast*) OR (TI mammogra* OR AB mammogra*) OR (TI mastectom* OR AB mastectom*) OR (TI maternal OR AB maternal) OR (TI maternally OR AB maternally) OR (TI menopaus* OR AB menopaus*) OR (TI menorrhagia OR AB menorrhagia) OR (TI menstrua* OR AB menstrua*) OR (TI menses OR AB menses) OR (TI menarche OR AB menarche) OR (TI “military sexual trauma” OR AB “military sexual trauma”) OR (TI “military sexual assault” OR AB “military sexual assault”) OR (TI “morning after pill” OR AB “morning after pill”) OR (TI “morning after pills” OR AB “morning after pills”) OR (TI obstetric* OR AB obstetric*) OR (TI oligomenorrhea OR AB oligomenorrhea) OR (TI oophorectom* OR AB oophorectom*) OR (TI oophoritis OR AB oophoritis) OR (TI ovariectom* OR AB ovariectom*) OR (TI ovary OR AB ovary) OR (TI ovaries OR AB ovaries) OR (TI ovarian OR AB ovarian) OR (TI “painful period” OR AB “painful period”) OR (TI “painful periods” OR AB “painful periods”) OR (TI “irregular period” OR AB “irregular period”) OR (TI “irregular periods” OR AB “irregular periods”) OR (TI PCOS OR AB PCOS) OR (TI perimenopaus* OR AB perimenopaus*) OR (TI peri-menopaus* OR AB peri-menopaus*) OR (TI perinatal OR AB perinatal) OR (TI peri-natal OR AB peri-natal) OR (TI perinatally OR AB perinatally) OR (TI peri-natally OR AB peri-natally) OR (TI PMDD OR AB PMDD) OR (TI postmenopaus* OR AB postmenopaus*) OR (TI post-menopaus* OR AB post-menopaus*) OR (TI postnatal OR AB postnatal) OR (TI post-natal OR AB post-natal) OR (TI postnatally OR AB postnatally) OR (TI post-natally OR AB post-natally) OR (TI postpartum OR AB postpartum) OR (TI post-partum OR AB post-partum) OR (TI preconception OR AB preconception) OR (TI pre-conception OR AB pre-conception) OR (TI pregnancy OR AB pregnancy) OR (TI pregnancies OR AB pregnancies) OR (TI pregnant OR AB pregnant) OR (TI pregnancy-induced OR AB pregnancy-induced) OR (TI pregnancy-associated OR AB pregnancy-associated) OR (TI prepregnancy OR AB prepregnancy) OR (TI premenstrual OR AB premenstrual) OR (TI pre-menstrual OR AB pre-menstrual) OR (TI prenatal OR AB prenatal) OR (TI pre-natal OR AB pre-natal) OR (TI prenatally OR AB prenatally) OR (TI pre-natally OR AB pre-natally) OR (TI puerperium OR AB puerperium) OR (TI rape OR AB rape) OR (TI rapes OR AB rapes) OR (TI raped OR AB raped) OR (TI “reproductive health” OR AB “reproductive health”) OR (TI “reproductive care” OR AB “reproductive care”) OR (TI “reproductive healthcare” OR AB “reproductive healthcare”) OR (TI “reproductive plan” OR AB “reproductive plan”) OR (TI “reproductive planning” OR AB “reproductive planning”) OR (TI salpingectom* OR AB salpingectom*) OR (TI salpingo-oophorectom* OR AB salpingo-oophorectom*) OR (TI uterus OR AB uterus) OR (TI uterine OR AB uterine) OR (TI vagina OR AB vagina) OR (TI vaginas OR AB vaginas) OR (TI vaginal* OR AB vaginal*) OR (TI transvaginal* OR AB transvaginal*) OR (TI vaginismus OR AB vaginismus) OR (TI vulva OR AB vulva) OR (TI vulvas OR AB vulvas) OR (TI vulvar OR AB vulvar) OR (TI vulvectom* OR AB vulvectom*) OR (TI vulvitis OR AB vulvitis) OR (TI vulvodynia OR AB vulvodynia)) OR (((TI dilatation OR AB dilatation) OR (TI vacuum OR AB vacuum)) N2 (TI curettage OR AB curettage)) OR (((TI sex OR AB sex) OR (TI sexual OR AB sexual) OR (TI sexually OR AB sexually) OR (TI domestic OR AB domestic) OR (TI partner OR AB partner) OR (TI spouse OR AB spouse) OR (TI spousal OR AB spousal) OR (TI physical OR AB physical) OR (TI physically OR AB physically)) N3 ((TI abuse OR AB abuse) OR (TI abuses OR AB abuses) OR (TI abused OR AB abused) OR (TI abuser OR AB abuser) OR (TI abusers OR AB abusers) OR (TI abusive OR AB abusive) OR (TI violence OR AB violence) OR (TI violent OR AB violent) OR (TI assault OR AB assault) OR (TI assaults OR AB assaults) OR (TI assaulted OR AB assaulted))) OR ((TI tubal OR AB tubal) N2 ((TI ligation* OR AB ligation*) OR (TI sterilization* OR AB sterilization*) OR (TI sterilisation* OR AB sterilisation*))) | 1459233
#3; combination | S1 AND S2 | 4720
#4; Date limit 2016 - present | Limit 3 to da=20160101-20231231 | 2253
#5; Study design exclusions | 4 not (case reports OR editorial OR letter OR comment OR congress).pt. | 1996
#6; Animal study exclusion | 5 not (exp animals/ not exp humans/) | 1993

## STUDIES EXCLUDED DURING FULL-TEXT SCREENING

Citation | Exclude Reason
Zhu, 2023^1^ | 8
Yocum, 2023^2^ | 5
Yancey, 2023^3^ | 8
Yan, 2023^4^ | 8
Wong, 2023^5^ | 8
Womersley, 2023^6^ | 8
White, 2023^7^ | 8
Webermann, 2023^8^ | 8
Webermann, 2023^9^ | 8
Wang, 2023^10^ | 8
Walter, 2023^11^ | 5
Walker, 2023^12^ | 8
Villamagna, 2023^13^ | 6
Vashistha, 2023^14^ | 4
Thrift, 2023^15^ | 8
Tannahill, 2023^16^ | 8
Stryczek, 2023^17^ | 8
Spiller, 2023^18^ | 8
Shih, 2023^19^ | 1
Sherva, 2023^20^ | 8
Shenasa, 2023^21^ | 8
Serier, 2023^22^ | 8
Serbeniuk, 2023^23^ | 1
Schwartzenburg, 2023^24^ | 5
Schreiber, 2023^25^ | 8
Schneider, 2023^26^ | 8
Schapira, 2023^27^ | 4
Schafer, 2023^28^ | 8
Saenz de Viteri, 2023^29^ | 8
Saba, 2023^30^ | 8
Russell, 2023^31^ | 8
Ruiz, 2023^32^ | 6
Robison, 2023^33^ | 8
Robichaux, 2023^34^ | 8
Robertson, 2023^35^ | 8
Rizk, 2023^36^ | 8
Rich, 2023^37^ | 8
Resnik, 2023^38^ | 8
Relyea, 2023^39^ | 8
Rauch, 2023^40^ | 8
Ranney, 2023^41^ | 8
Ramsey, 2023^42^ | 8
Pundi, 2023^43^ | 8
Puckett, 2023^44^ | 7
Proctor, 2023^45^ | 4
Portnoy, 2023^46^ | 4
Peppard, 2023^47^ | 8
Pebole, 2023^48^ | 8
Patil, 2023^49^ | 8
Panelli, 2023^50^ | 7
Ozturk, 2023^51^ | 8
Olmos-Ochoa, 2023^52^ | 5
Oblea, 2023^53^ | 8
Nilaweera, 2023^54^ | 8
Nikolaidou, 2023^55^ | 3
Nik-Ahd, 2023^56^ | 6
Morgan-Lopez, 2023^57^ | 8
Monteith, 2023^58^ | 8
Mitchell, 2023^59^ | 8
Mills, 2023^60^ | 6
Miller, 2023^61^ | 8
Miller, 2023^62^ | 8
Mehta, 2023^63^ | 8
McNabb, 2023^64^ | 8
McCormack, 2023^65^ | 1
Mattocks, 2023^66^ | 8
Mattison, 2023^67^ | 7
Matthieu, 2023^68^ | 8
Maciejewski, 2023^69^ | 8
Ly, 2023^70^ | 8
Luoh, 2023^71^ | 7
Logan, 2023^72^ | 4
Lloyd, 2023^73^ | 6
Liao, 2023^74^ | 1
Liao, 2023^75^ | 1
Lavigne, 2023^76^ | 8
Landes, 2023^77^ | 8
Kviatkovsky, 2023^78^ | 4
Kulak, 2023^79^ | 8
Krebs, 2023^80^ | 7
Koutsouras, 2023^81^ | 8
Korona-Bailey, 2023^82^ | 5
Korem, 2023^83^ | 8
Kolaja, 2023^84^ | 8
Kochar, 2023^85^ | 4
Klote, 2023^86^ | 8
Kimbrel, 2023^87^ | 8
Kim, 2023^88^ | 8
Kidwai-Khan, 2023^89^ | 3
Katon, 2023^90^ | 7
Kanwal, 2023^91^ | 8
Kamdar, 2023^92^ | 8
Kalandari, 2023^93^ | 5
Jones, 2023^94^ | 8
Jasuja, 2023^95^ | 8
Iwashyna, 2023^96^ | 8
Ivey, 2023^97^ | 8
Huang, 2023^98^ | 1
Houghtaling, 2023^99^ | 8
Holliday, 2023^100^ | 8
Holder, 2023^101^ | 8
Hilgeman, 2023^102^ | 4
Hilgeman, 2023^103^ | 4
Herrick, 2023^104^ | 5
Hendrikx, 2023^105^ | 3
Hasin, 2023^106^ | 8
Harper, 2023^107^ | 6
Hamrick, 2023^108^ | 5
Hahn, 2023^109^ | 8
Gregg, 2023^110^ | 8
Goulet, 2023^111^ | 8
Gonugunta, 2023^112^ | 8
Goldstein, 2023^113^ | 7
Goldman, 2023^114^ | 8
Gelernter, 2023^115^ | 8
Gaffey, 2023^116^ | 8
Fox, 2023^117^ | 8
Fischer, 2023^118^ | 8
Evans, 2023^119^ | 6
Elsea, 2023^120^ | 8
Ellis, 2023^121^ | 7
Ebrahimi, 2023^122^ | 7
Duffy, 2023^123^ | 1
Deo, 2023^124^ | 8
Cunningham, 2023^125^ | 8
Copeland, 2023^126^ | 8
Clark, 2023^127^ | 8
Chu, 2023^128^ | 8
Chidambaram, 2023^129^ | 7
Chang, 2023^130^ | 8
Chang, 2023^131^ | 8
Carlson, 2023^132^ | 8
C Coleman, 2023^133^ | 8
Bail, 2023^134^ | 7
Buckholdt, 2023^135^ | 7
Brault, 2023^136^ | 5
Bovin, 2023^137^ | 8
Blais, 2023^138^ | 8
Blais, 2023^139^ | 8
Beagley, 2023^140^ | 8
Bajema, 2023^141^ | 8
Aunon, 2023^142^ | 8
Anderson, 2023^143^ | 8
Alpert, 2023^144^ | 6
Alemi, 2023^145^ | 8
Yarmolinsky, 2022^146^ | 8
Wooldridge, 2022^147^ | 4
West, 2022^148^ | 4
West, 2022^149^ | 7
Wang, 2022^150^ | 8
Vitzthum, 2022^151^ | 8
Velagaleti, 2022^152^ | 8
Tisdale, 2022^153^ | 8
Therkorn, 2022^154^ | 8
Szymkowiak, 2022^155^ | 8
Strewler, 2022^156^ | 7
Stacy, 2022^157^ | 6
Spinella, 2022^158^ | 6
Southwell, 2022^159^ | 8
Sou, 2022^160^ | 1
Soohoo, 2022^161^ | 8
Song, 2022^162^ | 8
Shah, 2022^163^ | 5
Scoglio, 2022^164^ | 8
Schnurr, 2022^165^ | 8
Schliep, 2022^166^ | 8
Scherrer, 2022^167^ | 7
Rufa, 2022^168^ | 8
Ross, 2022^169^ | 8
Romano, 2022^170^ | 5
Rockett, 2022^171^ | 8
Randles, 2022^172^ | 8
Radomski, 2022^173^ | 8
Prasad, 2022^174^ | 8
Pittaras, 2022^175^ | 6
Pierce, 2022^176^ | 4
Pewowaruk, 2022^177^ | 4
Petersen, 2022^178^ | 8
Perino, 2022^179^ | 8
Patel, 2022^180^ | 5
Oslin, 2022^181^ | 8
Oberlin, 2022^182^ | 4
O’Reilly, 2022^183^ | 6
Nolte, 2022^184^ | 8
Nichter, 2022^185^ | 8
Myers, 2022^186^ | 8
Mukherjee, 2022^187^ | 8
Mukand, 2022^188^ | 5
Monteith, 2022^189^ | 7
Mitzel, 2022^190^ | 4
Miller, 2022^191^ | 8
Michailidou, 2022^192^ | 6
Meyer, 2022^193^ | 8
Mehta, 2022^194^ | 8
Megan, 2022^195^ | 8
McLean, 2022^196^ | 8
McLean, 2022^197^ | 8
McLean, 2022^198^ | 8
McGinnis, 2022^199^ | 8
McDonald, 2022^200^ | 8
Mayor, 2022^201^ | 8
Mahtta, 2022^202^ | 8
Lundeen, 2022^203^ | 5
Livecchi, 2022^204^ | 8
Liu, 2022^205^ | 1
Liang, 2022^206^ | 8
Lee, 2022^207^ | 8
Lamprea-Montealegre, 2022^208^ | 8
Kornblith, 2022^209^ | 8
Knopp, 2022^210^ | 4
Kinney, 2022^211^ | 5
Kimbrel, 2022^212^ | 8
Kidwai, 2022^213^ | 8
Khalifian, 2022^214^ | 8
Kelton, 2022^215^ | 8
Kelton, 2022^216^ | 8
Kelly, 2022^217^ | 5
Keller, 2022^218^ | 7
Kaul, 2022^219^ | 8
Kasovic, 2022^220^ | 1
Kasovic, 2022^221^ | 1
Kachadourian, 2022^222^ | 8
Jalal, 2022^223^ | 4
Jackson, 2022^224^ | 4
Iverson, 2022^225^ | 4
Iverson, 2022^226^ | 6
Holzhauer, 2022^227^ | 6
Haun, 2022^228^ | 8
Hashemi, 2022^229^ | 8
Harris, 2022^230^ | 8
Harper, 2022^231^ | 8
Hadlandsmyth, 2022^232^ | 8
Guillot, 2022^233^ | 8
Gross, 2022^234^ | 8
Gromisch, 2022^235^ | 8
Grigoryan, 2022^236^ | 8
Grau, 2022^237^ | 8
Grau, 2022^238^ | 8
Graham, 2022^239^ | 8
Golla, 2022^240^ | 7
Goger, 2022^241^ | 4
Gardner, 2022^242^ | 8
Galovski, 2022^243^ | 7
Funk, 2022^244^ | 8
Fried, 2022^245^ | 8
Forkus, 2022^246^ | 8
Fletcher, 2022^247^ | 6
Etuk, 2022^248^ | 8
Elbogen, 2022^249^ | 8
Dodlapati, 2022^250^ | 8
Der-Martirosian, 2022^251^ | 8
Dennis, 2022^252^ | 8
Deitelzweig, 2022^253^ | 8
Davis, 2022^254^ | 8
Cucciare, 2022^255^ | 8
Crasta, 2022^256^ | 8
Cowlishaw, 2022^257^ | 8
Corey, 2022^258^ | 5
Coleman, 2022^259^ | 5
Chen, 2022^260^ | 8
Chandra, 2022^261^ | 8
Ceroni, 2022^262^ | 8
Carr, 2022^263^ | 8
Carey, 2022^264^ | 8
Carey, 2022^265^ | 3
Callegari, 2022^266^ | 6
Buchanan, 2022^267^ | 8
Bond, 2022^268^ | 8
Boice Jr, 2022^269^ | 7
Boice, 2022^270^ | 8
Betancourt, 2022^271^ | 8
Bernardy, 2022^272^ | 8
Bennett, 2022^273^ | 4
Belizaire, 2022^274^ | 7
Beagley, 2022^275^ | 4
Apaydin, 2022^276^ | 5
Ali, 2022^277^ | 6
Young-Xu, 2021^278^ | 8
Ye, 2021^279^ | 8
Xie, 2021^280^ | 8
Wilson, 2021^281^ | 8
Williams, 2021^282^ | 8
Wilkinson, 2021^283^ | 8
Wiemken, 2021^284^ | 8
Weygandt, 2021^285^ | 8
Wayne, 2021^286^ | 8
Ward, 2021^287^ | 8
Wang, 2021^288^ | 6
Vashi, 2021^289^ | 8
Van Voorhees, 2021^290^ | 4
Valera, 2021^291^ | 6
Torre, 2021^292^ | 1
Tirone, 2021^293^ | 8
Tcheung, 2021^294^ | 8
Tantisattamo, 2021^295^ | 8
Sumida, 2021^296^ | 8
Sugarman, 2021^297^ | 4
Stirman, 2021^298^ | 8
Steers, 2021^299^ | 8
Soohoo, 2021^300^ | 8
Simonov, 2021^301^ | 8
Shaine, 2021^302^ | 8
Shahait, 2021^303^ | 8
Seligman, 2021^304^ | 8
Seidenfeld, 2021^305^ | 8
Schirmer, 2021^306^ | 8
Scherrer, 2021^307^ | 8
Salloum, 2021^308^ | 8
Sadler, 2021^309^ | 8
Ryan, 2021^310^ | 7
Qiao, 2021^311^ | 8
Pundi, 2021^312^ | 8
Pulverman, 2021^313^ | 6
Pierce, 2021^314^ | 6
Perino, 2021^315^ | 8
Perino, 2021^316^ | 8
Pedersen, 2021^317^ | 8
Parrish, 2021^318^ | 5
Modiano, 2021^319^ | 4
Miller, 2021^320^ | 7
Miao, 2021^321^ | 8
McDaniel, 2021^322^ | 8
Martinez, 2021^323^ | 8
Marchand, 2021^324^ | 8
Mancuso, 2021^325^ | 6
Lynch, 2021^326^ | 8
Livingston, 2021^327^ | 8
Kumar, 2021^328^ | 8
Kosturakis, 2021^329^ | 7
Kolaja, 2021^330^ | 5
Koffel, 2021^331^ | 8
Kasovic, 2021^332^ | 1
Jones, 2021^333^ | 8
Jia, 2021^334^ | 8
Jasuja, 2021^335^ | 8
Ioannou, 2021^336^ | 8
Huang, 2021^337^ | 1
Hsiung, 2021^338^ | 7
Horseman, 2021^339^ | 8
Holens, 2021^340^ | 8
Harvey, 2021^341^ | 6
Hahn, 2021^342^ | 8
Grillo, 2021^343^ | 6
Greiner, 2021^344^ | 8
Greenhalgh, 2021^345^ | 4
Gomez, 2021^346^ | 5
Glynn, 2021^347^ | 8
George, 2021^348^ | 8
Gawron, 2021^349^ | 6
Gaffey, 2021^350^ | 8
Fortney, 2021^351^ | 8
Flores, 2021^352^ | 8
Flatt, 2021^353^ | 8
Finlay, 2021^354^ | 8
Ferguson, 2021^355^ | 8
Fenwick, 2021^356^ | 8
Eichler, 2021^357^ | 8
Ebrahimi, 2021^358^ | 7
Denneson, 2021^359^ | 7
Decker, 2021^360^ | 8
Davis, 2021^361^ | 8
Daphna-Tekoah, 2021^362^ | 1
Dallocchio, 2021^363^ | 7
Cunningham, 2021^364^ | 4
Cucciare, 2021^365^ | 8
Creech, 2021^366^ | 6
Conard, 2021^367^ | 6
Cohen, 2021^368^ | 7
Byrne, 2021^369^ | 8
Butt, 2021^370^ | 8
Brodhead, 2021^371^ | 7
Braun, 2021^372^ | 6
Bountress, 2021^373^ | 8
Boersma, 2021^374^ | 7
Blais, 2021^375^ | 8
Bhanegaonkar, 2021^376^ | 8
Balut, 2021^377^ | 8
Baca, 2021^378^ | 8
Avoundjian, 2021^379^ | 8
Appaneal, 2021^380^ | 8
Appaneal, 2021^381^ | 8
Alqam, 2021^382^ | 7
Allen, 2021^383^ | 8
Alcantara, 2021^384^ | 5
Akwo, 2021^385^ | 8
Agarwal, 2021^386^ | 8
Abou-Donia, 2021^387^ | 4
Yoon, 2020^388^ | 8
Xie, 2020^389^ | 8
Womack, 2020^390^ | 8
Wilson, 2020^391^ | 8
Werum, 2020^392^ | 4
Vogt, 2020^393^ | 8
Vassy, 2020^394^ | 4
Turner, 2020^395^ | 8
Timko, 2020^396^ | 8
Thakur, 2020^397^ | 8
Tan, 2020^398^ | 8
Taetzsch, 2020^399^ | 5
Stefanovics, 2020^400^ | 8
Skalitzky, 2020^401^ | 7
Siddiqi, 2020^402^ | 5
Seymour, 2020^403^ | 8
Serper, 2020^404^ | 8
Selby, 2020^405^ | 8
Sanchez, 2020^406^ | 8
Ryan, 2020^407^ | 7
Ryan, 2020^408^ | 7
Rubin, 2020^409^ | 8
Rossi, 2020^410^ | 6
Robbins, 2020^411^ | 8
Richardson, 2020^412^ | 8
Resnik, 2020^413^ | 4
Rentsch, 2020^414^ | 8
Relyea, 2020^415^ | 6
Redd, 2020^416^ | 8
Ravindran, 2020^417^ | 8
Raad, 2020^418^ | 6
Protsiv, 2020^419^ | 5
Portnoy, 2020^420^ | 8
Porter, 2020^421^ | 8
Podlogar, 2020^422^ | 8
Park, 2020^423^ | 1
Pak, 2020^424^ | 8
Norman, 2020^425^ | 6
Nelson, 2020^426^ | 5
Montgomery, 2020^427^ | 8
Molloy, 2020^428^ | 5
McGlade, 2020^429^ | 4
Mazzei, 2020^430^ | 4
Maynard, 2020^431^ | 8
Mancuso, 2020^432^ | 7
Mahtta, 2020^433^ | 8
Maguen, 2020^434^ | 8
Lord, 2020^435^ | 1
Livingston, 2020^436^ | 8
Lee, 2020^437^ | 8
Lamba, 2020^438^ | 6
LaFrance, 2020^439^ | 4
Lacefield, 2020^440^ | 6
Kwan, 2020^441^ | 8
Kumar, 2020^442^ | 8
Kobe, 2020^443^ | 8
Klapheke, 2020^444^ | 5
Kinzel, 2020^445^ | 4
Khalifian, 2020^446^ | 4
Keach, 2020^447^ | 8
Katon, 2020^448^ | 7
Jenkins, 2020^449^ | 5
Iverson, 2020^450^ | 6
Holliday, 2020^451^ | 8
Henderson, 2020^452^ | 8
Hausmann, 2020^453^ | 8
Haun, 2020^454^ | 6
Haun, 2020^455^ | 6
Hamilton, 2020^456^ | 6
Gundlapalli, 2020^457^ | 8
Gromisch, 2020^458^ | 8
Griffiths, 2020^459^ | 4
Graham, 2020^460^ | 8
Gosmanova, 2020^461^ | 8
Goode, 2020^462^ | 4
Gnall, 2020^463^ | 8
Drake, 2020^464^ | 8
Do, 2020^465^ | 5
Djousse, 2020^466^ | 8
Dionne-Odom, 2020^467^ | 5
Dent, 2020^468^ | 8
Damschroder, 2020^469^ | 8
Cypel, 2020^470^ | 8
Cucciare, 2020^471^ | 8
Chu, 2020^472^ | 8
Christiansen, 2020^473^ | 6
Chang, 2020^474^ | 8
Carbone, 2020^475^ | 4
Blais, 2020^476^ | 8
Blais, 2020^477^ | 8
Blais, 2020^478^ | 8
Blais, 2020^479^ | 8
Beach, 2020^480^ | 6
Baldassarri, 2020^481^ | 8
Bade, 2020^482^ | 8
Arya, 2020^483^ | 8
Aronson, 2020^484^ | 8
Anonymous, 2020^485^ | 6
Alemi, 2020^486^ | 8
Zundel, 2019^487^ | 4
Yoon, 2019^488^ | 8
Yecies, 2019^489^ | 6
Wooldridge, 2019^490^ | 8
Williams, 2019^491^ | 8
Wells, 2019^492^ | 8
Wells, 2019^493^ | 6
Weissman, 2019^494^ | 4
Weber, 2019^495^ | 8
Weaver, 2019^496^ | 8
Tsai, 2019^497^ | 8
Tsai, 2019^498^ | 8
Trbovich, 2019^499^ | 8
Thomas, 2019^500^ | 6
Thomas, 2019^501^ | 8
Taylor, 2019^502^ | 8
Tam-Seto, 2019^503^ | 8
Sutton, 2019^504^ | 7
Stroupe, 2019^505^ | 8
Sripada, 2019^506^ | 8
Soohoo, 2019^507^ | 8
Shuster, 2019^508^ | 8
Shue, 2019^509^ | 6
Shiner, 2019^510^ | 8
Segars, 2019^511^ | 8
Segars, 2019^512^ | 6
Scoglio, 2019^513^ | 6
Schmidt, 2019^514^ | 8
Schifman, 2019^515^ | 8
Ronzitti, 2019^516^ | 8
Rogal, 2019^517^ | 8
Riordan, 2019^518^ | 8
Piuzzi, 2019^519^ | 4
Peacock, 2019^520^ | 5
Park, 2019^521^ | 5
Papaleontiou, 2019^522^ | 1
Pan, 2019^523^ | 8
Ozieh, 2019^524^ | 1
Nouri, 2019^525^ | 8
Nenova, 2019^526^ | 8
Mull, 2019^527^ | 8
Morland, 2019^528^ | 8
Monteith, 2019^529^ | 4
Mikolic, 2019^530^ | 8
Meffert, 2019^531^ | 8
McCulley, 2019^532^ | 8
McCarthy, 2019^533^ | 8
Maskin, 2019^534^ | 8
Maguen, 2019^535^ | 8
Luciano, 2019^536^ | 8
Lifshitz, 2019^537^ | 4
Liang, 2019^538^ | 7
Lerman, 2019^539^ | 8
Lentscher, 2019^540^ | 8
Lee, 2019^541^ | 6
LaPosta, 2019^542^ | 8
Korinek, 2019^543^ | 8
Kim, 2019^544^ | 1
Kheirbek, 2019^545^ | 6
Kenny, 2019^546^ | 8
Kelley, 2019^547^ | 6
Kauth, 2019^548^ | 8
Juraschek, 2019^549^ | 8
Jackson, 2019^550^ | 5
Iverson, 2019^551^ | 6
Hung, 2019^552^ | 4
Hugin, 2019^553^ | 8
Huang, 2019^554^ | 6
Hsiung, 2019^555^ | 7
Holder, 2019^556^ | 8
Himmelstein, 2019^557^ | 8
Harrison-Brown, 2019^558^ | 6
Harris, 2019^559^ | 5
Harb, 2019^560^ | 8
Han, 2019^561^ | 8
Gyamlani, 2019^562^ | 8
Goldstein, 2019^563^ | 8
Gallegos Salazar, 2019^564^ | 6
Fredman, 2019^565^ | 8
Etingen, 2019^566^ | 8
Edmonds, 2019^567^ | 8
Demb, 2019^568^ | 6
Davis, 2019^569^ | 5
Coughlin, 2019^570^ | 8
Cooper, 2019^571^ | 7
Christy, 2019^572^ | 8
Christy, 2019^573^ | 7
Chermack, 2019^574^ | 7
Brunner, 2019^575^ | 4
Brickell, 2019^576^ | 5
Brickell, 2019^577^ | 5
Branch-Elliman, 2019^578^ | 8
Branch-Elliman, 2019^579^ | 5
Boehler, 2019^580^ | 8
Blais, 2019^581^ | 8
Blais, 2019^582^ | 8
Bevans, 2019^583^ | 8
Bennett, 2019^584^ | 7
Beckman, 2019^585^ | 8
Bauer, 2019^586^ | 8
Andresen, 2019^587^ | 8
Alore, 2019^588^ | 8
Wu, 2018^589^ | 8
Won, 2018^590^ | 8
Williams, 2018^591^ | 8
Westover, 2018^592^ | 8
Weisbord, 2018^593^ | 8
Wahl, 2018^594^ | 8
Vest, 2018^595^ | 8
Vassy, 2018^596^ | 4
Strigo, 2018^597^ | 8
Stoerkel, 2018^598^ | 8
Starr, 2018^599^ | 5
Srivastava, 2018^600^ | 8
Spece, 2018^601^ | 8
Sloan, 2018^602^ | 8
Singh, 2018^603^ | 5
Shea, 2018^604^ | 8
Shayegani, 2018^605^ | 6
Ross, 2018^606^ | 8
Rodriguez, 2018^607^ | 5
Rhee, 2018^608^ | 5
Raskind, 2018^609^ | 8
Pourafkari, 2018^610^ | 8
Patros, 2018^611^ | 8
Park, 2018^612^ | 8
Obi, 2018^613^ | 8
Niznik, 2018^614^ | 8
Najavits, 2018^615^ | 8
Nadpara, 2018^616^ | 4
Murff, 2018^617^ | 8
Mosher, 2018^618^ | 8
Morris, 2018^619^ | 8
Moreau, 2018^620^ | 8
Metrik, 2018^621^ | 5
McManus, 2018^622^ | 8
McCabe, 2018^623^ | 8
Maule, 2018^624^ | 8
Markossian, 2018^625^ | 8
Marcum, 2018^626^ | 8
Lucas, 2018^627^ | 8
Lippa, 2018^628^ | 8
Lerner, 2018^629^ | 5
Lee, 2018^630^ | 6
Leapman, 2018^631^ | 8
LaVaccare, 2018^632^ | 8
Kravitz, 2018^633^ | 8
Kleine, 2018^634^ | 8
Jones, 2018^635^ | 8
Hudson, 2018^636^ | 4
Hostetter, 2018^637^ | 8
Holliday, 2018^638^ | 8
Holder, 2018^639^ | 8
Hartz, 2018^640^ | 8
Hallett, 2018^641^ | 8
Ha, 2018^642^ | 6
Gupta, 2018^643^ | 8
Grubbs, 2018^644^ | 8
Goodman, 2018^645^ | 8
Gobin, 2018^646^ | 6
Gerber, 2018^647^ | 4
Gawron, 2018^648^ | 4
Garner, 2018^649^ | 7
Eyawo, 2018^650^ | 8
Elbogen, 2018^651^ | 8
Edmond, 2018^652^ | 8
Davis, 2018^653^ | 8
Davis, 2018^654^ | 4
Coughlin, 2018^655^ | 8
Connolly, 2018^656^ | 5
Conard, 2018^657^ | 8
Burney, 2018^658^ | 7
Bui, 2018^659^ | 6
Brickell, 2018^660^ | 5
Blais, 2018^661^ | 8
Blais, 2018^662^ | 8
Bekelman, 2018^663^ | 8
Barnes, 2018^664^ | 8
Bannister, 2018^665^ | 8
Arya, 2018^666^ | 8
Armenta, 2018^667^ | 8
Ahlin, 2018^668^ | 8
Abel, 2018^669^ | 8
Aase, 2018^670^ | 8
Anonymous, 2018^671^ | 4
Yano, 2017^672^ | 6
Wallace, 2017^673^ | 7
Wahl, 2017^674^ | 6
Vora, 2017^675^ | 8
Turban, 2017^676^ | 8
Tarlov, 2017^677^ | 4
Sumida, 2017^678^ | 8
Stroupe, 2017^679^ | 8
Stahlman, 2017^680^ | 8
Shivakumar, 2017^681^ | 5
Shirazipour, 2017^682^ | 6
Sexton, 2017^683^ | 8
Schroeck, 2017^684^ | 4
Savitz, 2017^685^ | 8
Ryan, 2017^686^ | 8
Rubenstein, 2017^687^ | 7
Ruben, 2017^688^ | 8
Roumie, 2017^689^ | 8
Rodriguez, 2017^690^ | 8
Radell, 2017^691^ | 8
Puttnam, 2017^692^ | 8
Puttnam, 2017^693^ | 8
Pogach, 2017^694^ | 8
Perino, 2017^695^ | 8
Park, 2017^696^ | 8
Odden, 2017^697^ | 8
McCabe, 2017^698^ | 5
Marshall, 2017^699^ | 8
Markland, 2017^700^ | 8
MacGregor, 2017^701^ | 8
London, 2017^702^ | 5
Leppert, 2017^703^ | 8
LeBlanc, 2017^704^ | 8
Kwon, 2017^705^ | 8
Koo, 2017^706^ | 5
Koenig, 2017^707^ | 8
Kleiber Balderrama, 2017^708^ | 7
Kinsinger, 2017^709^ | 8
Kim-Dopp, 2017^710^ | 8
Keiichi, 2017^711^ | 7
Jones, 2017^712^ | 8
Jeon-Slaughter, 2017^713^ | 8
Hoopsick, 2017^714^ | 5
Holliday, 2017^715^ | 8
Hauser, 2017^716^ | 4
Haun, 2017^717^ | 4
Harrison, 2017^718^ | 8
Hamilton, 2017^719^ | 5
Gustafson, 2017^720^ | 6
George, 2017^721^ | 5
Fox, 2017^722^ | 8
Falkenstein, 2017^723^ | 8
Erickson, 2017^724^ | 4
Doran, 2017^725^ | 8
Dixon, 2017^726^ | 8
DiNapoli, 2017^727^ | 8
D’Aoust, 2017^728^ | 8
Coughlin, 2017^729^ | 6
Conard, 2017^730^ | 8
Cleveland, 2017^731^ | 7
Chun, 2017^732^ | 4
Christie, 2017^733^ | 8
Ceylony, 2017^734^ | 4
Callegari, 2017^735^ | 6
Callegari, 2017^736^ | 7
Buchholz, 2017^737^ | 7
Branch-Elliman, 2017^738^ | 8
Bomyea, 2017^739^ | 8
Bastian, 2017^740^ | 8
Barry, 2017^741^ | 8
Anderson, 2017^742^ | 8
Altalib, 2017^743^ | 8
Abraham, 2017^744^ | 8
Zephyrin, 2016^745^ | 6
Yeomans, 2016^746^ | 6
Xie, 2016^747^ | 6
Wright, 2016^748^ | 8
Wright, 2016^749^ | 5
Whiting, 2016^750^ | 8
Wang, 2016^751^ | 8
Waltz, 2016^752^ | 1
Walser, 2016^753^ | 7
Wagner, 2016^754^ | 4
Wachterman, 2016^755^ | 1
Tsui, 2016^756^ | 8
Thomson, 2016^757^ | 8
Taber, 2016^758^ | 5
Sumida, 2016^759^ | 8
Sternke, 2016^760^ | 8
Smith, 2016^761^ | 8
Shimada, 2016^762^ | 8
Rossiter, 2016^763^ | 8
Rogal, 2016^764^ | 6
Rodriguez, 2016^765^ | 8
Robbins, 2016^766^ | 8
Ramchand, 2016^767^ | 5
Pugh, 2016^768^ | 5
Prentice, 2016^769^ | 8
Pierce, 2016^770^ | 8
Perez, 2016^771^ | 4
Park, 2016^772^ | 5
Park, 2016^773^ | 8
Naylor, 2016^774^ | 8
Mouilso, 2016^775^ | 7
Moore, 2016^776^ | 8
Montgomery, 2016^777^ | 8
Monteith, 2016^778^ | 8
Mehta, 2016^779^ | 8
McGinnis, 2016^780^ | 7
Mankowski, 2016^781^ | 8
Malaty, 2016^782^ | 6
Maguen, 2016^783^ | 8
Lonberger, 2016^784^ | 8
Lindsay, 2016^785^ | 7
Lederer, 2016^786^ | 7
Le, 2016^787^ | 8
Lawrence-Wood, 2016^788^ | 8
Latta, 2016^789^ | 8
Langdon, 2016^790^ | 6
Kopacz, 2016^791^ | 8
Kip, 2016^792^ | 8
Kazerooni, 2016^793^ | 8
Inacio, 2016^794^ | 8
Heung, 2016^795^ | 6
Halvorson, 2016^796^ | 8
Haaland, 2016^797^ | 8
Grams, 2016^798^ | 4
Gosmanova, 2016^799^ | 8
Gosmanov, 2016^800^ | 8
Gorman, 2016^801^ | 8
Ganzer, 2016^802^ | 8
Funderburk, 2016^803^ | 7
Finlay, 2016^804^ | 8
Echevarria Baez, 2016^805^ | 8
Copeland, 2016^806^ | 7
Connor, 2016^807^ | 8
Callegari, 2016^808^ | 5
Boos, 2016^809^ | 7
Bethel, 2016^810^ | 8
Ashrafioun, 2016^811^ | 4
Anker, 2016^812^ | 8
Anonymous, 2016^813^ | 8
Xue, 2015^814^ | 7
Simonetti, 2015^815^ | 8
Mosher, 2015^816^ | 2
McCauley, 2015^817^ | 2
Kimerling, 2015^818^ | 2
Fischer, 2015^819^ | 2
Fang, 2015^820^ | 2
Bullman, 2015^821^ | 2
Zullig, 2014^822^ | 2
Blosnich, 2014^823^ | 8
Sternke, 2011^824^ | 2
Oishi, 2011^825^ | 2
MacGregor, 2011^826^ | 2
Iverson, 2011^827^ | 2
Cone, 2011^828^ | 2
Curran, 2009^829^ | 2

Notes. 1 = Not US, 2 = ineligible year, 3 = ineligible setting, 4 = ineligible total N, 5 = ineligible population, 6 = ineligible study design, 7 = ineligible publication type, 8 = not stratified by women Veterans.

1 Zhu X, Hong X, Wu J, . The Association between Circulating Lipids and Female Infertility Risk: A Univariable and Multivariable Mendelian Randomization Analysis. Nutrients. 2023;15(14):3130.37513548
2 Yocum D, Elashoff B, Verta P, . Patient reported outcomes do not correlate to functional knee recovery and range of motion in total knee arthroplasty. Journal of Orthopaedics. 2023;43:36–40.37564705
3 Yancey JR, Carson CN, McGlade EC, Yurgelun-Todd DA. A Literature Review of Mental Health Symptom Outcomes in U.S. Veterans and Servicemembers Following Combat Exposure and Military Sexual Trauma. Trauma, violence & abuse. 2023:15248380231178764.
4 Yan Q, Kim J, Hall DE, . Association of Frailty and the Expanded Operative Stress Score with Preoperative Acute Serious Conditions, Complications, and Mortality in Males Compared to Females: A Retrospective Observational Study. Annals of Surgery. 2023;277(2):E294–E304.34183515
5 Wong RJ, Rupp L, Lu M, . Prevalence of hepatitis B virus (HBV) and latent tuberculosis co-infection and risk of drug-induced liver injury across two large HBV cohorts in the United States. Journal of Viral Hepatitis. 2023;30(6):512–519.36843435
6 Womersley JS, Du Plessis M, Greene MC, . Advances in the molecular neurobiology of posttraumatic stress disorder from global contexts: A systematic review of longitudinal studies. Global Mental Health. 2023.
7 White CN, Kauffman BY, Acierno R. Factors contributing to veterans’ satisfaction with PTSD treatment delivered in person compared to telehealth. Journal of telemedicine and telecare. 2023;29(6):426–434.33497311
8 Webermann AR, Nester MS, Gianoli MO, . Compensation and Pension Exams for Military Sexual Trauma–Related Posttraumatic Stress Disorder: Examiner Perspectives, Clinical Impacts on Veterans, and Strategies. Women’s Health Issues. 2023;33(4):428–434.37003918
9 Webermann AR, Merians AN, Gross GM, . Military Sexual Trauma and its Association with Mental Health Among Sexual Minority and Heterosexual Veterans in the United States. LGBT Health. 2023;10:S61–S69.37754922
10 Wang K, Fenton BT, Dao VX, . Trajectory of blood pressure after initiating anti-calcitonin gene-related peptide treatment of migraine: a target trial emulation from the veterans health administration. Journal of Headache & Pain. 2023;24(1):1–10.36597043
11 Walter KH, Hunt WM, Otis NP, . Comparison of behavioral activation-enhanced cognitive processing therapy and cognitive processing therapy among U.S. service members: A randomized clinical trial. Psychiatry Res. 2023;326:115330.37418778
12 Walker WC, Clark SW, Eppich K, . Headache among combat-exposed veterans and service members and its relation to mild traumatic brain injury history and other factors: a LIMBIC-CENC study. Front Neurol. 2023;14:1242871.37808506
13 Villamagna AH, Beste LA, Borgerding J, . Testing and Case Rates of Gonorrhea, Chlamydia, Syphilis, and HIV among People with Substance Use Disorders in the Veterans Health Administration. Journal of Addiction Medicine. 2023;17(4):387–393.37579093
14 Vashistha V, Katsoulakis E, Guo A, . Molecular-Guided Off-Label Targeted Therapy in a Large-Scale Precision Oncology Program. JCO precision oncology. 2023;7:e2200518.36787508
15 Thrift AP, Nguyen TH, Pham C, . The Prevalence and Determinants of NAFLD and MAFLD and Their Severity in the VA Primary Care Setting. Clinical Gastroenterology and Hepatology. 2023;21(5):1252–1260.e5.35811043
16 Tannahill HS, Barrett TS, Zalta AK, . Posttraumatic Cognitions Differ Between Men and Women after Military Sexual Assault Revictimization in Their Contribution to PTSD Symptoms. Journal of Interpersonal Violence. 2023;38(7/8):6038–6061.36210787
17 Stryczek KC, Honsberger M, Ball SL, . VA Outreach Is an Essential Area for Improving Veterans’ Health Care Accessibility. Military medicine. 2023.
18 Spiller TR, Duek O, Buta E, . Comparative effectiveness of group v. individual trauma-focused treatment for posttraumatic stress disorder in veterans. Psychological Medicine. 2023;53(10):4561–4568.35959560
19 Shih EJ, Chen JK, Tsai PJ, Bee YS. Differences in characteristics, aetiologies, isolated pathogens, and the efficacy of antibiotics in adult patients with preseptal cellulitis and orbital cellulitis between 2000-2009 and 2010-2019. The British journal of ophthalmology. 2023;107(3):331–336.34607790
20 Sherva R, Zhang R, Sahelijo N, . African ancestry GWAS of dementia in a large military cohort identifies significant risk loci. Molecular Psychiatry. 2023;28(3):1293–1302.36543923
21 Shenasa MA, Afshar HT, Miller EA, . Effects of cannabis use on antidepressant treatment response to repetitive transcranial magnetic stimulation and ketamine. 2023.
22 Serier KN, Zelkowitz RL, Smith BN, . The Posttraumatic Cognitions Inventory (PTCI): Psychometric evaluation in veteran men and women with trauma exposure. Psychological Assessment. 2023;35(2):140–151.36355692
23 Serbeniuk AV. FEATURES OF MENTAL AND REPRODUCTIVE HEALTH, FUNCTIONAL STATE OF THE ORGANISM OF FEMALE MILITARY SERVICEMEN WHO SUFFERED CONCUSSION DURING COMBAT ACTIONS. Reproductive Endocrinology. 2023;68:8–15.
24 Schwartzenburg JB, Cruise SC, Reed RE, . Neuropathological Outcomes of Traumatic Brain Injury and Alcohol Use in Males and Females: Studies Using Pre-Clinical Rodent and Clinical Human Specimens. Journal of Neurotrauma. 2023.
25 Schreiber AM, Cawood CD. Treatment outcomes of Veteran men in a comprehensive dialectical behavior therapy program: Characterizing sex differences in symptom trajectories. Journal of Psychiatric Research. 2023;164:90–97.37331262
26 Schneider ALC, Peltz CB, Li Y, . Traumatic Brain Injury and Long-Term Risk of Stroke Among US Military Veterans. Stroke. 2023;54(8):2059–2068.37334708
27 Schapira MM, Hubbard RA, Whittle J, . Lung Cancer Screening Decision Aid Designed for a Primary Care Setting: A Randomized Clinical Trial. JAMA Network Open. 2023;6(8):e2330452–e2330452.37647070
28 Schafer KM, Wilson E, Joiner T. Traumatic brain injury and suicidality among military veterans: The mediating role of social integration. Journal of Affective Disorders. 2023;338:414–421.37364657
29 Saenz de Viteri S, Zhang J, Johnson EC, . Genomic risk for post-traumatic stress disorder in families densely affected with alcohol use disorders. Molecular Psychiatry. 2023.
30 Saba SK, Davis JP, Bricker JB, . Pain Trajectories among U.S. Veterans During COVID-19. Journal of Pain. 2023.
31 Russell LE, Cohen AJ, Chrzas S, . Implementing a Social Needs Screening and Referral Program Among Veterans: Assessing Circumstances & Offering Resources for Needs (ACORN). Journal of General Internal Medicine. 2023.
32 Ruiz F, Burgo-Black L, Hunt SC, . A Practical Review of Suicide Among Veterans: Preventive and Proactive Measures for Health Care Institutions and Providers. Public Health Reports. 2023;138(2):223–231.35403486
33 Robison RD, Singh M, Jiang L, . Acute Antipsychotic Use and Presence of Dysphagia Among Older Veterans with Heart Failure. Journal of the American Medical Directors Association. 2023;24(9):1303–1310.37478895
34 Robichaux C, Aron J, Wendt CH, . Sociodemographic and Geographic Risk Factors for All-Cause Mortality in Patients with COPD. International Journal of COPD. 2023;18:1587–1593.37521023
35 Robertson DJ, Dominitz JA, Beed A, . Baseline Features and Reasons for Nonparticipation in the Colonoscopy Versus Fecal Immunochemical Test in Reducing Mortality From Colorectal Cancer (CONFIRM) Study, a Colorectal Cancer Screening Trial. JAMA network open. 2023;6(7):e2321730.37432690
36 Rizk JG, Hsiung JT, Arif Y, . Triglycerides and Renal Outcomes According to Albuminuria and in Consideration of Other Metabolic Syndrome Components in Diabetic US Veterans. American Journal of Nephrology. 2023;54(1–2):14–24.36889289
37 Rich TL, Phelan HL, Gravely AA, . Veteran Perspectives on Phantom Limb Pain and Non-Drug Interventions. Journal of Pain Research. 2023;16:1391–1400.37138954
38 Resnik L, Borgia M, Clark MA. Contralateral Limb Pain Is Prevalent, Persistent, and Impacts Quality of Life of Veterans with Unilateral Upper-Limb Amputation. Journal of Prosthetics & Orthotics (JPO). 2023;35(1):3–11.
39 Relyea MR, Presseau C, Runels T, . Understanding Veterans’ intimate partner violence use and patterns of healthcare utilization. Health Services Research. 2023.
40 Rauch SAM, Venners MR, Ragin C, . Treatment of posttraumatic stress disorder with prolonged exposure for primary care (PE-PC): Effectiveness and patient and therapist factors related to symptom change and retention. Psychological services. 2023.
41 Ranney RM, Bernhard PA, Holder N, . Factors associated with receipt of minimally adequate psychotherapy for PTSD at the Veterans Health Administration. Journal of Psychiatric Research. 2023;166:80–85.37741063
42 Ramsey CM, Gaffey AE, Brandt CA, . Depression, Insomnia, and Obesity Among Post-9/11 Veterans: Eating Pathology as a Distinct Health Risk Behavior. Military medicine. 2023;188(5–6):921–927.35726626
43 Pundi K, Fan J, Kabadi S, . Dronedarone Versus Sotalol in Antiarrhythmic Drug-Naive Veterans With Atrial Fibrillation. Circulation: Arrhythmia and Electrophysiology. 2023;16(8):456–467.37485722
44 Puckett LL, Kodali D, Solanki AA, . Consensus Quality Measures and Dose Constraints for Breast Cancer From the Veterans Affairs Radiation Oncology Quality Surveillance Program and American Society for Radiation Oncology Expert Panel. Practical Radiation Oncology. 2023;13(3):217–230.36115498
45 Proctor DM, Emmons KR, Scannell-Desch E. An Education Intervention to Improve Knowledge of Post-Traumatic Stress Disorder Symptoms and Treatments Among U.S. Women Service Members and Veterans. Military Medicine. 2023;188(1/2):368–373.34950958
46 Portnoy GA, Relyea MR, Presseau C, . Screening for Intimate Partner Violence Experience and Use in the Veterans Health Administration. JAMA netw. 2023;6(10):e2337685.
47 Peppard SW, Burkard J, Georges J, Dye J. The Lived Experience of Military Women With Chronic Pain: A Phenomenological Study. Military medicine. 2023;188(5–6):1199–1206.35596551
48 Pebole MM, Singleton CR, Hall KS, . Impact of Military Affiliation on Exercise Perceptions Among Survivors of Sexual Violence. Military medicine. 2023.
49 Patil T, Zysk SN, Akridge ME, . A Quasi-Experimental Evaluation of Single Trough-Based Area Under the Curve Guided Dosing on the Incidence of Vancomycin Associated Nephrotoxicity in Veteran Patients. Journal of Pharmacy Technology. 2023;39(3):123–133.
50 Panelli DM, Esmaeili A, Joyce V, . Impact of psychiatric conditions on the risk of severe maternal morbidity in veterans. American Journal of Obstetrics & Gynecology. 2023;228:S457–S458.
51 Ozturk ED, Zhang Y, Lai MHC, . Measurement Invariance of the Neurobehavioral Symptom Inventory in Male and Female Million Veteran Program Enrollees Completing the Comprehensive Traumatic Brain Injury Evaluation. Assessment. 2023:10731911231198214.
52 Olmos-Ochoa TT, Luger TM, Oishi A, . Challenges to Engaging Women Veterans in Quality Improvement From Patient Care to Policy: Women’s Health Managers’ Perspectives. Women’s Health Issues. 2023;33(2):199–207.36153165
53 Oblea PN, Adams AR, Nguyen-Wu ED, . Lesbian Gay Bisexual Transgender and Queer Health-Care Experiences in a Military Population. Journal of homosexuality. 2023;70(6):1098–1118.35007488
54 Nilaweera D, Phyo AZZ, Teshale AB, . Lifetime posttraumatic stress disorder as a predictor of mortality: a systematic review and meta-analysis. BMC Psychiatry. 2023;23(1).
55 Nikolaidou ME, Sotiropoulos K, Barzouka K. Postural balance ability and vertical jumping performance in female veteran volleyball athletes and non-athletes. Front. 2023;5:1109488.
56 Nik-Ahd F, De Hoedt A, Butler C, . Prostate Cancer in Transgender Women in the Veterans Affairs Health System, 2000-2022. JAMA: Journal of the American Medical Association. 2023;329(21):1877–1879.37119522
57 Morgan-López AA, Saavedra LM, Hien DA, . Differential symptom weighting in estimating empirical thresholds for underlying PTSD severity: Toward a “platinum” standard for diagnosis? International journal of methods in psychiatric research. 2023;32(3):e1963.36789653
58 Monteith LL, Kittel JA, Schneider AL, . Suicide among Asian American, Native Hawaiian, and Pacific Islander Veterans: Rates and Methods, 2005-2019. American journal of preventive medicine. 2023.
59 Mitchell KS, Smith BN, Masheb R, Vogt D. The impact of the COVID-19 pandemic on eating disorders in U.S. military veterans. International Journal of Eating Disorders. 2023;56(1):108–117.36239518
60 Mills J, Liebert C, Wren SM, . Robotic General Surgery Trends in the Veterans Health Administration, Community Practice, and Academic Centers from 2013 to 2021. JAMA Surgery. 2023;158(5):552–554.36790771
61 Miller MB, Monk JK, Flores LY, . Impact of Discrimination and Coping on Veterans’ Willingness to Seek Treatment for Physical and Mental Health Problems. Psychology of Addictive Behaviors. 2023;37(2):209–221.35787102
62 Miller MB, Freeman LK, Aranda A, . Prevalence and correlates of alcohol-induced blackout in a diverse sample of veterans. Alcohol: Clinical & Experimental Research. 2023;47(2):395–405.
63 Mehta P, Raymond J, Punjani R, . Prevalence of amyotrophic lateral sclerosis in the United States using established and novel methodologies, 2017. Amyotrophic Lateral Sclerosis and Frontotemporal Degeneration. 2023;24(1–2):108–116.35422180
64 McNabb M, Durante KA, Trocchio S, . Self-reported Medicinal Cannabis Use as an Alternative to Prescription and Over-the-counter Medication Use Among US Military Veterans. Clinical Therapeutics. 2023;45(6):562–577.37414507
65 McCormack L, Bennett NL. Relentless, aggressive, and pervasive: Exploring gender minimization and sexual abuse experienced by women ex-military veterans. Psychological trauma : theory, research, practice and policy. 2023;15(2):237–246.34843350
66 Mattocks KM, Marteeny V, Walker L, . Examining Veterans’ Experiences With In Vitro Fertilization Provided Under P.L. 114-223. Medical Care. 2023;61(4):192–199.36689683
67 Mattison CS, Wiese J. The Prevalence of the Female Athlete Triad in Female Service Members. 2023.
68 Matthieu MM, Ounpraseuth ST, Williams JS, . “Advancing” Advance Care Planning to Veterans in the Veterans Health Administration. Military Medicine. 2023;188(3/4):786–791.35801841
69 Maciejewski ML, Greene L, Grubber JM, . Association between patient-reported social and behavioral risks and health care costs in high-risk Veterans health administration patients. Health Services Research. 2023.
70 Ly DP, Shekelle PG, Song Z. Evidence for Anchoring Bias during Physician Decision-Making. JAMA Internal Medicine. 2023;183(8):818–823.37358843
71 Luoh SW, Minnier J, Zhao H, Gao L. Predicting Breast Cancer Risk for Women Veterans of African Ancestry in the Million Veteran Program. Health Equity. 2023;7(1):303–306.37284538
72 Logan CD, Hudnall MT, Schlick CJR, . Venous Thromboembolism Chemoprophylaxis Adherence Rates After Major Cancer Surgery. JAMA Network Open. 2023;6(9):e2335311–e2335311.37768664
73 Lloyd M, Amos ME, Milfred-Laforest S, . Residing in a Food Desert and Adverse Cardiovascular Events in US Veterans With Established Cardiovascular Disease. American Journal of Cardiology. 2023;196:70–76.37094491
74 Liao WK, Hsieh MS, Hu SY, . Predictive Performance of Scoring Systems for Mortality Risk in Patients with Cryptococcemia: An Observational Study. Journal of Personalized Medicine. 2023;13(9).
75 Liao LC, Jan SL, Lin MC, . Novel technique to reduce prolapsed device in atrial septal defect closure. Frontiers in Cardiovascular Medicine. 2023;10.
76 Lavigne JE, Gibbons JB. The association between vitamin D serum levels, supplementation, and suicide attempts and intentional self-harm. PLoS ONE. 2023;18(2 February).
77 Landes SJ, Abraham TH, Woods JA, . Qualitative Evaluation of a Caring Letters Suicide Prevention Intervention for the Veterans Crisis Line. Psychiatric services (Washington, D.C.). 2023:appips20220632.
78 Kviatkovsky SA, Hickner RC, Cabre HE, . Collagen peptides supplementation improves function, pain, and physical and mental outcomes in active adults. Journal of the International Society of Sports Nutrition. 2023;20(1):2243252.37551682
79 Kulak JA, Homish DL, Kozlowski LT, Homish GG. Cannabis Use and Perceptions Among Current and Former Military Service Members. Cannabis. 2023;6(2):104–112.37484055
80 Krebs EE, Becker WC, Nelson D, . Design, methods, and recruitment outcomes of the Veterans’ pain care organizational improvement comparative effectiveness (VOICE) study. Contemporary Clinical Trials. 2023;124.
81 Koutsouras GW, Wade M, Marawar S. Anterior cervical discectomy and fusion and pneumonia: use of the VASQIP database. Current Orthopaedic Practice. 2023;34(4):180–184.
82 Korona-Bailey J, Banaag A, Nguyen DR, . Free the Bun: Prevalence of Alopecia Among Active Duty Service Women, Fiscal Years 2010-2019. Military medicine. 2023;188(3–4):e492–e496.34244770
83 Korem N, Ben-Zion Z, Spiller TR, . Correlates of avoidance coping in trauma-exposed U.S. military veterans: Results from the National Health and Resilience in Veterans Study. Journal of Affective Disorders. 2023;339:89–97.37437721
84 Kolaja CA, Belding JN, Boparai SK, . Survey response over 15 years of follow-up in the Millennium Cohort Study. BMC medical research methodology. 2023;23(1):205.37689640
85 Kochar A, Deo SV, Charest B, . Preoperative frailty and adverse outcomes following coronary artery bypass grafting surgery in US veterans. Journal of the American Geriatrics Society. 2023;71(9):2736–2747.37083188
86 Klote MM, Gutierrez CG, Deen JE, . Best Practices in Recruitment and Outreach to Women and Diverse Veterans for Coronavirus Research at the U.S. Department of Veterans Affairs. Health Equity. 2023;7(1):351–355.37313134
87 Kimbrel NA, Ashley-Koch AE, Qin XJ, . Identification of Novel, Replicable Genetic Risk Loci for Suicidal Thoughts and Behaviors Among US Military Veterans. JAMA Psychiatry. 2023;80(2):135–145.36515925
88 Kim KM, Giannitrapani KF, Garcia A, . Patient Characteristics Associated With Occurrence of Preoperative Goals-of-Care Conversations. JAMA Network Open. 2023;6(2):e2255407–e2255407.36757697
89 Kidwai-Khan F, Wang R, Skanderson M, . A Roadmap to Artificial Intelligence (AI): Methods for Designing and Building AI ready Data for Women’s Health Studies. medRxiv. 2023;30:30.
90 Katon JG, Rodriguez A, Yano EM, . Research Priorities to Support Women Veterans’ Reproductive Health and Health Care Within a Learning Health Care System. Women’s Health Issues. 2023;33(3):215–221.36702724
91 Kanwal F, Khaderi S, Singal AG, . Risk Stratification Model for Hepatocellular Cancer in Patients With Cirrhosis. Clinical Gastroenterology and Hepatology. 2023.
92 Kamdar N, Hundt NE, Ramsey DJ, . Characteristics Associated with Persistent Versus Transient Food Insecurity Among US Veterans Screened in the Veterans Health Administration. Journal of the Academy of Nutrition & Dietetics. 2023;123(7):1044–1044.36898479
93 Kalandari E, Govina O, Tzonichaki I, . Exploration of the Relationship between the Burden and Family Support among Family Caregivers of Older Adults with Chronic Diseases: A Cross- Sectional Study. International Journal of Caring Sciences. 2023;16(1):51–61.
94 Jones BE, Sarvet AL, Ying J, . Incidence and Outcomes of Non–Ventilator-Associated Hospital-Acquired Pneumonia in 284 US Hospitals Using Electronic Surveillance Criteria. JAMA Network Open. 2023;6(5):e2314185–e2314185.37200031
95 Jasuja GK, Reisman JI, Rao SR, . Social Stressors and Health Among Older Transgender and Gender Diverse Veterans. LGBT Health. 2023;10(2):148–157.36454239
96 Iwashyna TJ, Seelye S, Berkowitz TS, . Late Mortality after COVID-19 Infection among US Veterans vs Risk-Matched Comparators: A 2-Year Cohort Analysis. JAMA Internal Medicine. 2023;183(10):1111–1119.37603339
97 Ivey KL, Nguyen XT, Li R, . Association of dietary fatty acids with the risk of atherosclerotic cardiovascular disease in a prospective cohort of United States veterans. Am J Clin Nutr. 2023;118(4):763–772.37479185
98 Huang CH, Hsiao FY, Wang TH. Risk Factors for Treatment Failure in Skin and Soft Tissue Infections Caused by Nontuberculous Mycobacteria. Annals of plastic surgery. 2023;90(1):S51–S54.37075294
99 Houghtaling L, Osypuk TL. Health disparities among millennial veterans by sexual orientation. Mil Psychol. 2023;35(3):204–214.37133547
100 Holliday R, Nichter B, Holder N, . Childhood Sexual Abuse and Military Sexual Trauma Interact to Increase Suicide Risk: Results from a Nationally Representative Veteran Sample. Journal of Interpersonal Violence. 2023;38(5/6):5354–5369.36124932
101 Holder N, Maguen S, Holliday R, . Psychosocial Outcomes Among Veteran and Non-Veteran Survivors of Sexual Assault. Journal of Interpersonal Violence. 2023;38(1/2):NP1569–NP1591.35465744
102 Hilgeman MM, Lange TM, Bishop T, Cramer RJ. Spreading pride in all who served: A health education program to improve access and mental health outcomes for sexual and gender minority veterans. Psychological services. 2023;20(3):596–608.35113622
103 Hilgeman MM, Cramer RJ, Kaniuka AR, . Moderators of Treatment Outcomes for LGBTQ+ Military Veterans in the PRIDE in All Who Served Health Promotion Group. 2023.
104 Herrick MSR, Chai W. Incidence of Postpartum Depression Decreases After Initial Expansion of Military Maternity Leave. Military medicine. 2023.
105 Hendrikx LJ, Williamson V, Murphy D. Adversity during military service: the impact of military sexual trauma, emotional bullying and physical assault on the mental health and well-being of women veterans. BMJ military health. 2023;169(5):419–424.34697241
106 Hasin DS, Wall MM, Alschuler DM, . Chronic pain, cannabis legalisation, and cannabis use disorder among patients in the US Veterans Health Administration system, 2005 to 2019: a repeated, cross-sectional study. Lancet Psychiatry. 2023;06:06.
107 Harper KL, Vogt D, Fox A, . “The role of PTSD symptom severity and relationship functioning in male and female veterans’ mental health service use”: Correction. Psychological trauma : theory, research, practice and policy. 2023;15(4):696.36342430
108 Hamrick L, Larsen SE, Sippel LM, . Benchmarking quality of life to posttraumatic stress disorder symptom changes in cognitive processing therapy. Journal of Anxiety Disorders. 2023;93.
109 Hahn HA, Blosnich JR. Adverse Childhood Experiences Among Lesbian, Gay, Bisexual, and Queer Veterans. American Journal of Preventive Medicine. 2023;65(4):704–709.37037327
110 Gregg LP, Richardson PA, Herrera MA, . Documented Adverse Drug Reactions and Discontinuation of Angiotensin-Converting Enzyme Inhibitors and Angiotensin Receptor Blockers in Chronic Kidney Disease. American Journal of Nephrology. 2023;54(3–4):126–135.37231800
111 Goulet J, Cheng Y, Becker W, . Opioid use and opioid use disorder in mono and dual-system users of veteran affairs medical centers. Frontiers in public health. 2023;11:1148189.37124766
112 Gonugunta AS, Von Itzstein MS, Hsiehchen D, . Antibiotic Prescriptions in Lung Cancer and Melanoma Populations: Differences With Potential Clinical Implications in the Immunotherapy Era. Clinical Lung Cancer. 2023;24(1):11–17.36253271
113 Goldstein KM, Bosworth HB, Gierisch JM. Can Right-Sizing the Use of Virtual Care Improve Access to Equitable, Patient-Centered Care for Women Veterans? JGIM: Journal of General Internal Medicine. 2023;38:868–870.36920681
114 Goldman SM, Weaver FM, Stroupe KT, . Risk of Parkinson Disease Among Service Members at Marine Corps Base Camp Lejeune. JAMA Neurology. 2023;80(7):673–681.37184848
115 Gelernter J, Levey D, Galimberti M, . Genomewide association study of epiretinal membrane: discovery of significant risk loci in each of three American populations. 2023.
116 Gaffey AE, Rosman L, Lampert R, . Insomnia and Early Incident Atrial Fibrillation: A 16-Year Cohort Study of Younger Men and Women Veterans. Journal of the American Heart Association. 2023:e030331.
117 Fox AB, Baier AL, Alpert E, . Psychosocial and Economic Impacts of the COVID-19 Pandemic on the Mental Health of Veteran Men and Women. Journal of Women’s Health (15409996). 2023;32(10):1041–1051.
118 Fischer IC, Schnurr PP, Pietrzak RH. Employment status among US military veterans with a history of posttraumatic stress disorder: Results from the National Health and Resilience in Veterans Study. J Trauma Stress. 2023;11:11.
119 Evans K, Barton R, Hendrickson R, LaPlante LM. Creating Safe Spaces for Those Who Have Lived through Intimate Partner Violence. Journal of Aggression, Maltreatment & Trauma. 2023;32(7/8):1108–1123.
120 Elsea SH, Razjouyan J, Lee KM, . Association of Glucose-6-Phosphate Dehydrogenase Deficiency With Outcomes in US Veterans With COVID-19. JAMA Network Open. 2023;6(3):e235626–e235626.36988953
121 Ellis L, Siff L. Comparing female veterans’ access to minimally invasive surgery in gender-neutral (appendectomy) vs. gender-specific operations (hysterectomy). American Journal of Obstetrics & Gynecology. 2023;228(3):S813–S815.
122 Ebrahimi R, Dennis P, Alvarez CA, . ASSOCIATION OF POSTTRAUMATIC STRESS DISORDER WITH INCIDENT VENOUS THROMBOEMBOLISM IN WOMEN VETERANS. Journal of the American College of Cardiology (JACC). 2023;81:2077–2077.
123 Duffy FF, Sudom K, Jones M, . Calibrating the Alcohol Use Disorders Identification Test-Consumption (AUDIT-C) for detecting alcohol-related problems among Canadian, UK and US soldiers: cross-sectional pre-deployment and post-deployment survey results. BMJ Open. 2023;13(5).
124 Deo SV, Motairek I, Nasir K, . Association Between Historical Neighborhood Redlining and Cardiovascular Outcomes Among US Veterans With Atherosclerotic Cardiovascular Diseases. JAMA Network Open. 2023;6(7):e2322727–e2322727.37432687
125 Cunningham AR, Gu L, Dubinskaya A, . Quality-of-life impact of interstitial cystitis and other pelvic pain syndromes. Front. 2023;4:1149783.
126 Copeland LA, Finley EP, Rubin ML, . Emergence of Probable PTSD Among U.S. Veterans Over the Military-to-Civilian Transition. Psychological Trauma: Theory, Research, Practice & Policy. 2023;15(4):697–704.35925701
127 Clark KD, Zaugg T, Defrancesco S, . Rehabilitation Service Needs and Preferences among Veterans with Tinnitus: A Qualitative Study. Seminars in Hearing. 2023.
128 Chu GM, Almklov E, Wang C, . Relationships among race, ethnicity, and gender and whole health among U.S. veterans. Psychol Serv. 2023;12:12.
129 Chidambaram S, Chang SH, Sandulache VC, . Human Papillomavirus Vaccination Prevalence and Disproportionate Cancer Burden Among US Veterans. JAMA Oncol. 2023;9(5):712–714.36862390
130 Chang CY, Park H, Hincapie-Castillo JM, . Trends, characteristics, race, and ethnicity associated with nonadherence to antidepressants among breast cancer survivors with depression. J Manag Care Spec Pharm. 2023;29(4):431–445.36989452
131 Chang CJ, Fischer IC, Depp CA, . A disproportionate burden: Prevalence of trauma and mental health difficulties among sexual minority versus heterosexual U.S. military veterans. Journal of Psychiatric Research. 2023;161:477–482.37086703
132 Carlson GC, Sharifian N, Jacobson IG, . Contribution of post-trauma insomnia to depression and posttraumatic stress disorder in women service members: findings from the Millennium Cohort Study. Sleep. 2023;46(3).
133 C Coleman B, Finch D, Wang R, . Extracting Pain Care Quality Indicators from U.S. Veterans Health Administration Chiropractic Care Using Natural Language Processing. Applied clinical informatics. 2023;14(3):600–608.37164327
134 Bail J, Kommalapati A, Dell’Italia J, Das DG. National lung cancer screening rates among women veterans within the Veterans’ Health Administration. Journal of Clinical Oncology. 2023;41:1543–1543.
135 Buckholdt KE, Taylor LD, Forbes RN, Caplan JR. Intimate Partner Violence and the COVID-19 Pandemic: The Veterans Health Administration Intimate Partner Violence Assistance Program Response. Journal of Aggression, Maltreatment & Trauma. 2023;32(7/8):1152–1169.
136 Brault ME, Laudermith A, Kroll-Desrosiers A. Telemedicine During COVID-19 Response: A Welcome Shift for Younger Female Healthcare Workers. Journal of General Internal Medicine. 2023;38(3):627–632.36127541
137 Bovin MJ, Resnik J, Linsky AM, . Does screening for PTSD lead to VA mental health care? Identifying the spectrum of initial VA screening actions. Psychological services. 2023;20(3):525–532.35446094
138 Blais RK, Tannahill HS, Cue Davis K. Sexual Risk Taking among Survivors of U.S. Military Sexual Assault: Associations with PTSD Symptom Severity and Alcohol Use. Journal of sex research. 2023:1–8.
139 Blais RK, Livingston WS, Barrett TS, Tannahill HS. Sexual Violence in Military Service Members/Veterans Individual and Interpersonal Outcomes Associated with Single and Multiple Exposures to Civilian and Military Sexual Violence. Journal of Interpersonal Violence. 2023;38(3/4):2585–2613.35658608
140 Beagley MC, Mann AJ, Patel TA, . Traditional Masculine Gender Role Norms and Nonsuicidal Self-Injury in Veterans. Psychology of Men & Masculinities. 2023;24(2):94–102.
141 Bajema KL, Rowneki M, Berry K, . Rates of and Factors Associated With Primary and Booster COVID-19 Vaccine Receipt by US Veterans, December 2020 to June 2022. JAMA Network Open. 2023;6(1):e2254387–e2254387.36729454
142 Aunon FM, Azrael D, Simonetti JA, Miller M. Beliefs Among Veteran Firearm Owners Regarding Whether Clinicians Should Discuss Firearm Safety With Patients. JAMA Network Open. 2023;6(6):e2321219–e2321219.37382951
143 Anderson TS, Herzig SJ, Jing B, . Clinical Outcomes of Intensive Inpatient Blood Pressure Management in Hospitalized Older Adults. JAMA Internal Medicine. 2023;183(7):715–723.37252732
144 Alpert E, Baier AL, Galovski TE. Psychiatric Issues in Women Veterans. Psychiatric Clinics of North America. 2023;46(3):621–633.37500255
145 Alemi F, Avramovic S, Schwartz M. Predicting 6-month mortality of patients from their medical history: Comparison of multimorbidity index to Deyo-Charlson index. Medicine (Spain). 2023;102(5):E32687.
146 Yarmolinsky J, Bouras E, Constantinescu A, . Genetically-proxied anti-diabetic drug target perturbation and risk of cancer: a Mendelian randomization analysis. 2022.
147 Wooldridge JS, Blanco BH, Dochat C, . Relationships Between Dietary Intake and Weight-Related Experiential Avoidance Following Behavioral Weight-Loss Treatment. International Journal of Behavioral Medicine. 2022;29(1):104–109.33864234
148 West MT, Tamba GP, Thawani R, . Gender and Patient Satisfaction in a Veterans Health Administration Outpatient Chemotherapy Unit. Fed. 2022;39(Suppl 3):e0292.
149 West MT, Tamba G, Thawani R, . Improving patient satisfaction and care delivery for female veteran patients with cancer receiving outpatient infusion therapies. Journal of Clinical Oncology. 2022;40:279–279.
150 Wang DD, Li Y, Nguyen XT, . Degree of Adherence to Based Diet and Total and Cause-Specific Mortality: Prospective Cohort Study in the Million Veteran Program. Public Health Nutr. 2022:1–38.
151 Vitzthum LK, Nalawade V, Riviere P, . Impacts of an Opioid Safety Initiative on US Veterans Undergoing Cancer Treatment. JNCI: Journal of the National Cancer Institute. 2022;114(5):753–760.35078240
152 Velagaleti RS, Vetter J, Parker R, . Change in Left Ventricular Ejection Fraction with Coronary Artery Revascularization and Subsequent Risk for Adverse Cardiovascular Outcomes. Circulation: Cardiovascular Interventions. 2022;15(4):E011284.35411780
153 Tisdale RL, Ferguson J, Van Campen J, . Disparities in virtual cardiology visits among Veterans Health Administration patients during the COVID-19 pandemic. JAMIA Open. 2022;5(4).
154 Therkorn JH, Hu S, Sotolongo AM, . Relationship between clinician documented blast exposure and pulmonary function: a retrospective chart review from a national specialty clinic. Respiratory Research. 2022;23(1):1–10.34983515
155 Szymkowiak D, Montgomery AE, Tsai J, O’Toole TP. Frequent Episodic Utilizers of Veterans Health Administration Homeless Programs Use: Background Characteristics and Health Services Use. Journal of Public Health Management & Practice. 2022;28(1):E211–E218.33208718
156 Strewler A, Bellamy K. Caring for Veteran Women: Collaborative Nursing Approaches to Improve Care. Nursing Clinics of North America. 2022;57(3):359–373.35985725
157 Stacy M, Kremer M, Schulkin J. Suicide Among Women and the Role of Women’s Health Care Providers. Obstetrical & Gynecological Survey. 2022;77(5):293–301.35522431
158 Spinella S, McCune N, McCarthy R, . WVSUD-PACT: a Primary-Care-Based Substance Use Disorder Team for Women Veterans. JGIM: Journal of General Internal Medicine. 2022;37:837–841.36042085
159 Southwell K, Topp D, McCall C, . Focus Forward Fellowship: Evaluation of a program for women student service members and veterans. Evaluation and program planning. 2022;95:102156.36081233
160 Sou WK, Perng CK, Ma H, . The Effect of Biological Scaffold (Biodesign) in Postmastectomy Direct-to-Implant Breast Reconstruction: A 5-Year Single-Institution Experience. Annals of plastic surgery. 2022;88(1s Suppl 1):S92–S98.35225854
161 Soohoo M, Hashemi L, Hsiung JT, . Association of Serum Triglycerides and Renal Outcomes among 1.6 Million US Veterans. Nephron. 2022;146(5):457–468.35354153
162 Song S, Thomas IC, Ganesan C, . Twenty-four-hour Urine Testing and Urinary Stone Disease Recurrence in Veterans. Urology. 2022;159:33–40.34688771
163 Shah A, Cieremans D, Slover J, . Trends in Complications and Outcomes in Patients Aged 65 Years and Younger Undergoing Total Knee Arthroplasty: Data From the American Joint Replacement Registry. Journal of the American Academy of Orthopaedic Surgeons. Global research & reviews. 2022;6(6).
164 Scoglio AAJ, Molnar BE, Lincoln AK, . Sexual and physical revictimization in U.S. military veterans. Journal of traumatic stress. 2022;35(4):1129–1141.35233826
165 Schnurr PP, Chard KM, Ruzek JI, . Comparison of Prolonged Exposure vs Cognitive Processing Therapy for Treatment of Posttraumatic Stress Disorder among US Veterans: A Randomized Clinical Trial. JAMA Network Open. 2022;5(1).
166 Schliep KC, Barbeau WA, Lynch KE, . Overall and sex-specific risk factors for subjective cognitive decline: findings from the 2015-2018 Behavioral Risk Factor Surveillance System Survey. Biology of sex differences. 2022;13(1):16.35414037
167 Scherrer J, Salas J, Jacobs C, Wiemken T. Lower dementia risk in patients vaccinated against herpes zoster. Annals of family medicine. 2022(20).
168 Rufa AK, Carroll KK, Lofgreen A, . “You’re going to look at me differently”: A qualitative study of disclosure experiences among survivors of military sexual assault. Journal of traumatic stress. 2022;35(3):901–913.35218235
169 Ross CS, Gradus JL, Siegel MB, . Distinct groups of firearm owners with differential risk for suicide in the United States: A latent class analysis. Preventive Medicine. 2022;164:N.PAG-N.PAG.
170 Romano CJ, Hall C, Bukowinski AT, . Pregnancy-associated and pregnancy-related deaths in the United States military, 2003-2014. American Journal of Obstetrics & Gynecology. 2022;227(3):508.e1–508.e9.
171 Rockett IRH, Jia H, Ali B, . Association of State Social and Environmental Factors with Rates of Self-injury Mortality and Suicide in the United States. JAMA Network Open. 2022;5(2).
172 Randles R, Finnegan A. Veteran help-seeking behaviour for mental health issues: a systematic review. BMJ military health. 2022;168(1):99–104.34253643
173 Radomski TR, Zhao X, Lovelace EZ, . Use and Cost of Low-Value Health Services Delivered or Paid for by the Veterans Health Administration. JAMA Internal Medicine. 2022;182(8):832–839.35788786
174 Prasad NK, Lake R, Englum BR, . Increased complications in patients who test COVID-19 positive after elective surgery and implications for pre and postoperative screening. American Journal of Surgery. 2022;223(2):380–387.33894979
175 Pittaras A, Faselis C, Doumas M, . EXERCISE CAPACITY AND MORTALITY RISK IN A WIDE AGE SPECTRUM COHORT OF 750,302 VETERANS. Journal of Hypertension. 2022;40:e50–e50.
176 Pierce ME, Fortier C, Fonda JR, . Intimate Partner Violence Predicts Posttraumatic Stress Disorder Severity Independent of Early Life and Deployment-Related Trauma in Deployed Men and Women Veterans. Journal of Interpersonal Violence. 2022;37(5/6):2659–2680.32659158
177 Pewowaruk RJ, Hein AJ, Carlsson CM, . Effects of nitroglycerin-induced vasodilation on elastic and muscular artery stiffness in older Veterans. Hypertension Research. 2022;45(12):1997–2007.35840750
178 Petersen JM, Jhala DN. Hospital and Laboratory Practice in an Integrated Medical System for HIV Infection Prevention Interventions at a Veteran Affairs Medical Center. Laboratory Medicine. 2022;53(5):e113–e116.34939111
179 Perino AC, Fan J, Pundi K, . Atrial fibrillation bleeding risk and prediction while treated with direct oral anticoagulants in warfarin-naïve or warfarin-experienced patients. Clinical Cardiology. 2022;45(9):960–969.35946047
180 Patel MR, Jacob KC, Parsons AW, . Impact of Gender on Postsurgical Outcomes in Patients Undergoing Anterior Cervical Discectomy and Fusion. International Journal of Spine Surgery. 2022;16(6):991–1000.36418177
181 Oslin DW, Lynch KG, Shih MC, . Effect of Pharmacogenomic Testing for Drug-Gene Interactions on Medication Selection and Remission of Symptoms in Major Depressive Disorder: The PRIME Care Randomized Clinical Trial. JAMA. 2022;328(2):151–161.35819423
182 Oberlin S, Nkiliza A, Parks M, . Sex-specific differences in plasma lipid profiles are associated with Gulf War Illness. Journal of Translational Medicine. 2022;20(1):1–12.34980160
183 O’Reilly OC, Day MA, Seiffert K, . Male Gender and Competitive Athlete Status Are Associated With Better Outcomes Following Hip Arthroscopy In Patients With Global Acetabular Retroversion. Arthroscopy, Sports Medicine, and Rehabilitation. 2022;4(5):e1721–e1729.36312706
184 Nolte MT, Parrish JM, Jenkins NW, . Validation of Veterans RAND 12-Item Physical Function Survey in Minimally Invasive Transforaminal Lumbar Interbody Fusion. International Journal of Spine Surgery. 2022;16(4):605–611.35728833
185 Nichter B, Na PJ, Stanley IH, . Identifying factors associated with elevated suicidal intent among U.S. military veterans. Journal of Psychiatric Research. 2022;155:68–74.35988305
186 Myers JL, Xia H, Caballero MY, . A Military Community Cohort Study Reveals Single Nucleotide Polymorphisms in Inflammation Mediator Genes That Associate With Type 2 Diabetes. Military medicine. 2022.
187 Mukherjee S, Kshirsagar M, Becker N, . Identifying long-term effects of SARS-CoV-2 and their association with social determinants of health in a cohort of over one million COVID-19 survivors. BMC public health. 2022;22(1):2394.36539760
188 Mukand NH, Ko NY, Nabulsi NA, . The association between physical health-related quality of life, physical functioning, and risk of contralateral breast cancer among older women. Breast Cancer. 2022;29(2):287–295.34797467
189 Monteith LL, Holliday R, Dichter ME, Hoffmire CA. Preventing Suicide Among Women Veterans: Gender-Sensitive, Trauma-Informed Conceptualization. Curr Treat Options Psychiatry. 2022;9(3):186–201.35730002
190 Mitzel LD, Possemato K, Smith AR, . Understanding Who Uses Whole Health Services: A Program Evaluation. Global Advances In Health and Medicine. 2022;11.
191 Miller LJ, Rowlands S, Esposito L, . The Veterans Health Administration Reproductive Mental Health Consultation Program: an Innovation to Improve Access to Specialty Care. JGIM: Journal of General Internal Medicine. 2022;37:833–836.36042089
192 Michailidou D, Zhang T, Stamatis P, Ng B. Risk of venous and arterial thromboembolism in patients with giant cell arteritis and/or polymyalgia rheumatica: A Veterans Health Administration population-based study in the United States. Journal of Internal Medicine. 2022;291(5):665–675.34982490
193 Meyer AND, Singh H, Zimolzak AJ, . Cancer Evaluations During the COVID-19 Pandemic: An Observational Study Using National Veterans Affairs Data. American Journal of Preventive Medicine. 2022;63(6):1026–1030.36055880
194 Mehta P, Raymond J, Punjani R, . Prevalence of amyotrophic lateral sclerosis (ALS), United States, 2016. Amyotrophic Lateral Sclerosis and Frontotemporal Degeneration. 2022;23(3–4):220–225.34423697
195 Megan L, Cosentino D, Kyriakides TC, . Clinical and virologic factors associated with outcomes of COVID-19 before and after vaccination among Veterans: Retrospective analysis from six New England states. Journal of Hospital Medicine. 2022;17(7):534–538.35661577
196 McLean CP, Wachsman T, Morland L, . The mental health impact of COVID-19-related stressors among treatment-seeking trauma-exposed veterans. Journal of traumatic stress. 2022;35(6):1792–1800.36065487
197 McLean CP, Levy HC, Miller ML, Tolin DF. Exposure therapy for PTSD in military populations: A systematic review and meta-analysis of randomized clinical trials. Journal of Anxiety Disorders. 2022;90.
198 McLean CL, Turchik JA, Kimerling R. Mental Health Beliefs, Access, and Engagement with Military Sexual Trauma-Related Mental Health Care. JGIM: Journal of General Internal Medicine. 2022;37:742–750.36042075
199 McGinnis KA, Justice AC, Moore RD, . Discrimination and Calibration of the Veterans Aging Cohort Study Index 2.0 for Predicting Mortality Among People With Human Immunodeficiency Virus in North America. Clinical Infectious Diseases. 2022;75(2):297–304.34609485
200 McDonald J, Liang SY, Li P, . DoD-VA Trauma Infection Research Collaboration. Military Medicine. 2022;187:17–24.
201 Mayor JM, Preventza O, McGinigle K, . Persistent under-representation of female patients in United States trials of common vascular diseases from 2008 to 2020. Journal of Vascular Surgery. 2022;75(1):30–36.34438003
202 Mahtta D, Lee MT, Ramsey DJ, . Significant Facility-Level Variation in Utilization of and Adherence with Secondary Prevention Therapies Among Patients with Premature Atherosclerotic Cardiovascular Disease: Insights from the VITAL (Veterans wIth premaTure AtheroscLerosis) Registry7. Cardiovascular Drugs and Therapy. 2022;36(1):93–102.33400053
203 Lundeen AL, Raduan FC, Stone McGaver R, . Takedown of Ankle Fusions and Conversion to Total Ankle Replacements. Foot & Ankle International. 2022;43(11):1402–1409.35942917
204 Livecchi R, Coe AB, Reyes-Gastelum D, . Concurrent Use of Thyroid Hormone Therapy and Interfering Medications in Older US Veterans. Journal of Clinical Endocrinology and Metabolism. 2022;107(7):E2738–E2742.35396840
205 Liu Q, Zhu J, Zhang W. The efficacy of mindfulness-based stress reduction intervention 3 for post-traumatic stress disorder (PTSD) symptoms in patients with PTSD: A meta-analysis of four randomized controlled trials. Stress and Health. 2022;38(4):626–636.35253353
206 Liang X, Sinha R, Justice AC, . A new monocyte epigenetic clock reveals nonlinear effects of alcohol consumption on biological aging in three independent cohorts (N = 2242). Alcoholism: Clinical & Experimental Research. 2022;46(5):736–748.35257385
207 Lee AK, Jing B, Jeon SY, . Predicting Life Expectancy to Target Cancer Screening Using Electronic Health Record Clinical Data. Journal of General Internal Medicine. 2022;37(3):499–506.34327653
208 Lamprea-Montealegre JA, Madden E, Tummalapalli SL, . Prescription Patterns of Cardiovascular- and Kidney-Protective Therapies Among Patients With Type 2 Diabetes and Chronic Kidney Disease. Diabetes Care. 2022;45(12):2900–2906.36156061
209 Kornblith E, Bahorik A, Boscardin WJ, . Association of Race and Ethnicity with Incidence of Dementia among Older Adults. JAMA. 2022;327(15):1488–1495.35438728
210 Knopp K, Wrape ER, McInnis R, . Posttraumatic stress disorder and relationship functioning: Examining gender differences in treatment-seeking veteran couples. Journal of Traumatic Stress. 2022;35(2):484–495.34800061
211 Kinney RL, Haskell S, Relyea MR, . Coordinating women’s preventive health care for rural veterans. Journal of Rural Health. 2022;38(3):630–638.
212 Kimbrel NA, Ashley-Koch AE, Qin XJ, . A genome-wide association study of suicide attempts in the million veterans program identifies evidence of pan-ancestry and ancestry-specific risk loci. Molecular Psychiatry. 2022;27(4):2264–2272.35347246
213 Kidwai N. Routine cancer screening delays due to pandemic at veteran affairs. Journal of the National Medical Association. 2022;114(1):12–15.34507828
214 Khalifian CE, Bosch J, Knopp K, . Adverse childhood experiences, mental health, and relationship satisfaction in military couples. Journal of family psychology : JFP : journal of the Division of Family Psychology of the American Psychological Association (Division 43). 2022;36(4):630–635.35084882
215 Kelton K, Young JR, Evans MK, . Complementary/integrative healthcare utilization in US Gulf-War era veterans: Descriptive analyses based on deployment history, combat exposure, and Gulf War Illness. Complementary Therapies in Clinical Practice. 2022;49:N.PAG-N.PAG.
216 Kelton K, Van Voorhees EE, Elbogen EB, Dillon KH. Correlates of Incarceration History Among Military Veterans. Mil Psychol. 2022;21:21.
217 Kelly J, Jones CC, Jomeen J, Martin C. Perinatal mental health and well-being of serving women and women veterans: A study protocol. BMJ Military Health. 2022;168(1):1–4.33789979
218 Keller MJ, Conard PL, Armstrong ML. Homelessness: Women Veterans without Billets. MEDSURG Nursing. 2022;31(4):233–238.
219 Kaul B, Lee JS, Zhang N, . Epidemiology of Idiopathic Pulmonary Fibrosis among U.S. Veterans, 2010-2019. Annals of the American Thoracic Society. 2022;19(2):196–203.34314645
220 Kasović M, Štefan L, Kalčik Z. Acute Responses to Resistance Training on Body Composition, Muscular Fitness and Flexibility by Sex and Age in Healthy War Veterans Aged 50–80 Years. Nutrients. 2022;14(16):3436–3436.36014943
221 Kasović M, Štefan L, Kalčik Z. The associations between health-related physical fitness and fasting blood glucose in war veterans: a population-based study. Scientific reports. 2022;12(1):6997.35487937
222 Kachadourian LK, Nichter B, Herzog S, . Non-suicidal self-injury in US military veterans: Results from the National Health and Resilience in Veterans Study. Clinical Psychology & Psychotherapy. 2022;29(3):941–949.34599541
223 Jalal SI, Guo A, Ahmed S, Kelley MJ. Analysis of actionable genetic alterations in lung carcinoma from the VA National Precision Oncology Program. Seminars in Oncology. 2022;49(3–4):265–274.35902275
224 Jackson CE, Currao A, Fonda JR, . Research utility of a CAPS-IV and CAPS-5 hybrid interview: Posttraumatic stress symptom and diagnostic concordance in recent-era U.S. veterans. Journal of traumatic stress. 2022;35(2):570–580.34973042
225 Iverson KM, Danitz SB, Low SK, . Recovering from Intimate Partner Violence through Strengths and Empowerment (RISE): Initial Evaluation of the Clinical Effects of RISE Administered in Routine Care in the US Veterans Health Administration. International Journal of Environmental Research and Public Health. 2022;19(14).
226 Iverson KM, Danitz SB, Driscoll M, . Recovering from intimate partner violence through Strengths and Empowerment (RISE): Development, pilot testing, and refinement of a patient-centered brief counseling intervention for women. Psychological services. 2022;19:102–112.34110870
227 Holzhauer CG, Epstein EE, Bickar L, . Pilot examination of stress, heart rate variability, and alcohol craving and use among female veterans. Frontiers in Psychiatry. 2022;13.
228 Haun JN, Paykel J, Fowler CA, . Preliminary Evidence on the Association of Complementary and Integrative Health Care Program Participation and Medical Cost in Veterans. Military medicine. 2022.
229 Hashemi L, Hsiung JT, Arif Y, . Serum Low-Density Lipoprotein Cholesterol and Cardiovascular Disease Risk Across Chronic Kidney Disease Stages (Data from 1.9 Million United States Veterans). American Journal of Cardiology. 2022;170:47–55.35300833
230 Harris AHS, Bowe T, Kamal RN, . Frequency and costs of low-value preoperative tests for patients undergoing low-risk procedures in the veterans health administration. Perioperative Medicine. 2022;11(1).
231 Harper KL, Thompson-Hollands J, Keane TM, Marx BP. Family-Involved Mental Health Care Among OEF/OIF Veterans With and Without PTSD Using VHA Administrative Records. Behavior Therapy. 2022;53(5):819–827.35987541
232 Hadlandsmyth K, Bernardy NC, Lund BC. Central nervous system polytherapy among veterans with posttraumatic stress disorder: changes across a decade. General Hospital Psychiatry. 2022;74:46–50.34906798
233 Guillot J, Rentsch CT, Gordon KS, . Potentially inappropriate medication use by level of polypharmacy among US Veterans 49–64 and 65–70 years old. Pharmacoepidemiology and Drug Safety. 2022;31(10):1056–1074.35780391
234 Gross GM, Kaczynski R, Resnick S. The effect of military sexual trauma on competitive employment status following veterans health administration supported employment services. Psychological services. 2022.
235 Gromisch ES, Turner AP, Leipertz SL, . Demographic and Clinical Factors Are Associated With Frequent Short-Notice Cancellations in Veterans With Multiple Sclerosis on Disease Modifying Therapies. Archives of Physical Medicine & Rehabilitation. 2022;103(5):915–915.34695387
236 Grigoryan L, Naik AD, Lichtenberger P, . Analysis of an Antibiotic Stewardship Program for Asymptomatic Bacteriuria in the Veterans Affairs Health Care System. JAMA Network Open. 2022;5(7):e2222530–e2222530.35877123
237 Grau PP, Valentine LM, Vuper TC, . Military sexual trauma in context: Ethnoracial differences in ecological resources among treatment-seeking veterans. Journal of Traumatic Stress. 2022;35(5):1535–1545.35819929
238 Grau PP, Bohnert KM, Ganoczy D, Sripada RK. Who improves in trauma-focused treatment: A cluster analysis of treatment response in VA patients undergoing PE and CPT. Journal of Affective Disorders. 2022;318:159–166.36070830
239 Graham LA, Schoemaker L, Rose L, . Expansion of the Veterans Health Administration Network and Surgical Outcomes. JAMA Surgery. 2022;157(12):1115–1123.36223115
240 Golla V, Kaye DR. The Impact of Health Delivery Integration on Cancer Outcomes. Surgical Oncology Clinics of North America. 2022;31(1):91–108.34776068
241 Goger P, Szpunar MJ, Baca SA, . Predictors of Early Postpartum Maternal Functioning Among Women Veterans. Maternal & Child Health Journal. 2022;26(1):149–155.34626289
242 Gardner J, Brown G, Vargas-Correa J, . An assessment of Veterans attitudes and willingness to receiving the COVID-19 vaccine: a mixed methods study. BMC Infectious Diseases. 2022;22(1):1–10.34983406
243 Galovski TE, Street AE, Creech S, . State of the Knowledge of VA Military Sexual Trauma Research. JGIM: Journal of General Internal Medicine. 2022;37:825–832.36042078
244 Funk LM, Alagoz E, Jolles SA, . A Qualitative Study of the System-level Barriers to Bariatric Surgery within the Veterans Health Administration. Annals of Surgery. 2022;275(1):E181–E188.32886462
245 Fried TR, Yang M, Martino S, . Effect of Computer-Tailored Print Feedback, Motivational Interviewing, and Motivational Enhancement Therapy on Engagement in Advance Care Planning: A Randomized Clinical Trial. JAMA Internal Medicine. 2022;182(12):1298–1305.36342678
246 Forkus SR, Weiss NH, Goncharenko S, . Elucidating the Association Between Military Sexual Trauma Types and Different Types of Risky Behaviors. Journal of Trauma & Dissociation. 2022;23(3):324–338.34641771
247 Fletcher TL, Amspoker AB, Wassef M, . Increasing access to care for trauma-exposed rural veterans: A mixed methods outcome evaluation of a web-based skills training program with telehealth-delivered coaching. Journal of Rural Health. 2022;38(4):740–747.
248 Etuk R, Shirk SD, Klein KM, . Examining the Clinical Correlates of Overeating and Binge-Eating Behaviors Among U. S. Veterans. Military Medicine. 2022;187(3/4):297–303.
249 Elbogen EB, Zeber JE, Vogt D, . Financial Status and Well-being in Recently Separated Military Veterans. Military medicine. 2022.
250 Dodlapati J, Hall JA, Kulkarni P, . Agent Orange Exposure, Transformation From MGUS to Multiple Myeloma, and Outcomes in Veterans. Fed. 2022;39(Suppl 3):S23–S29a.
251 Der-Martirosian C, Chu K, Steers WN, . Examining telehealth use among primary care patients, providers, and clinics during the COVID-19 pandemic. BMC Primary Care. 2022;23(1):1–10.
252 Dennis EL, Taylor BA, Newsome MR, . Advanced brain age in deployment-related traumatic brain injury: A LIMBIC-CENC neuroimaging study. Brain Injury. 2022;36(5):662–672.35125044
253 Deitelzweig S, Sah J, Kang A, . Effectiveness and Safety of Apixaban Versus Warfarin in Obese Patients with Nonvalvular Atrial Fibrillation Enrolled in Medicare and Veteran Affairs. American Journal of Cardiology. 2022;163:43–49.34930532
254 Davis JP, Lee DS, Saba S, . Applying Polyvictimization Theory to Veterans: Associations With Substance Use and Mental Health. Psychology of Addictive Behaviors. 2022;36(2):144–156.34582247
255 Cucciare MA, Mengeling MA, Han X, . Experiencing Sexual Assault and/or Stalking-Related Behavior is Associated with Binge Drinking and Substance Use Consequences in Deployed U.S. Servicewomen. Women’s Health Issues. 2022;32(4):402–410.34991954
256 Crasta D, Crane CA, Trabold N, . Relationship Health and Intimate Partner Violence in Integrated Primary Care: Individual Characteristics and Preferences for Relationship Support across Risk Levels. International Journal of Environmental Research and Public Health. 2022;19(21).
257 Cowlishaw S, Freijah I, Kartal D, . Intimate Partner Violence (IPV) in Military and Veteran Populations: A Systematic Review of Population-Based Surveys and Population Screening Studies. International Journal of Environmental Research and Public Health. 2022;19(14).
258 Corey RM, Rabe J, Yalcin S, . Factors Associated With Pain and Function Before Medial Patellofemoral Ligament Reconstruction. Orthopaedic Journal of Sports Medicine. 2022;10(8):1–8.
259 Coleman C, Yan CH, Ko NY, . Physical functioning, frailty and risks of locally-advanced breast cancer among older women. Breast. 2022;64:19–28.35468476
260 Chen JI, Hickok A, O’Neill AC, . Psychiatric disorders newly diagnosed among veterans subsequent to hospitalization for COVID-19. Psychiatry Research. 2022;312.
261 Chandra R, Meier J, Khoury MK, . Homelessness and Race are Mortality Predictors in US Veterans Undergoing CABG. Seminars in Thoracic and Cardiovascular Surgery. 2022.
262 Ceroni TL, Ennis CR, Shapiro MO, . Examining the unique and interactive associations of gender and race on PTSD symptom severity among military sexual trauma survivors. Psychological trauma : theory, research, practice and policy. 2022.
263 Carr MM, Serowik KL, Na PJ, . Co-occurring alcohol use disorder and obesity in U.S. military veterans: Prevalence, risk factors, and clinical features. Journal of Psychiatric Research. 2022;150:64–70.35358833
264 Carey FR, LeardMann CA, Lehavot K, . Health Disparities Among Lesbian, Gay, and Bisexual Service Members and Veterans. American Journal of Preventive Medicine. 2022;63(4):521–531.35794031
265 Carey FR, Jacobson IG, Lehavot K, . Military service experiences and reasons for service separation among lesbian, gay, and bisexual individuals in a large military cohort. BMC Public Health. 2022;22(1):1–13.34983455
266 Callegari LS, Borrero S. Abortion Care for Veterans-A Historic Step Forward. JAMA Health Forum. 2022;3(11):e224621.36318458
267 Buchanan CH, Brown EA, Bishu KG, . The Magnitude and Potential Causes of Sex Disparities in Statin Therapy in Veterans with Type 2 Diabetes: A 10-year Nationwide Longitudinal Cohort Study. Women’s Health Issues. 2022;32(3):274–283.34949527
268 Bond GR, Al-Abdulmunem M, Drake RE, . Transition from Military Service: Mental Health and Well-being Among Service Members and Veterans with Service-connected Disabilities. The journal of behavioral health services & research. 2022;49(3):282–298.35083657
269 Boice Jr JD, Quinn B, Al-Nabulsi I, . A million persons, a million dreams: a vision for a national center of radiation epidemiology and biology. International Journal of Radiation Biology. 2022;98(4):795–821.34669549
270 Boice JD, Cohen SS, Mumma MT, Ellis ED. The Million Person Study, whence it came and why. International Journal of Radiation Biology. 2022;98(4):537–550.30831042
271 Betancourt CA, Kitsantas P, Goldberg DG, Hawks BA. Substance Use Relapse Among Veterans at Termination of Treatment for Substance Use Disorders. Military Medicine. 2022;187(11/12):e1422–e1431.34272857
272 Bernardy NC, Friedman MJ, Lund BC. Deimplementation of Benzodiazepine Prescribing in Posttraumatic Stress Disorder in the Veterans Health Administration. Journal of Clinical Psychiatry. 2022;83(3).
273 Bennett JL, Craig P, Aytur S, . Community-Based Recreational Therapy for Veterans with Behavioral Health Disorders: Impacts on Quality of Life, Participation, and Happiness. Community Mental Health Journal. 2022;58(8):1477–1486.35312929
274 Belizaire S, Dickinson A, Webb M. Identifying Suicide Risk Factors in Lesbian, Gay, Bisexual, Transgender, and Queer Veterans. Nursing Clinics of North America. 2022;57(3):347–358.35985724
275 Beagley MC, Mann AJ, Patel TA, . Traditional Masculine Gender Role Norms and Nonsuicidal Self-Injury in Veterans. Psychol. 2022;1:08.
276 Apaydin EA, Mohr DC, Hamilton AB, . Differences in Burnout and Intent to Leave Between Women’s Health and General Primary Care Providers in the Veterans Health Administration. JGIM: Journal of General Internal Medicine. 2022;37(10):2382–2389.34618305
277 Ali A, Wolfert S, Lam ciyu I, . Treating the Effects of Military Sexual Trauma through a Theater-Based Program for U.S. Veterans. Women & Therapy. 2022;45(1):25–40.
278 Young-Xu Y, Korves C, Roberts J, . Coverage and Estimated Effectiveness of mRNA COVID-19 Vaccines Among US Veterans. JAMA Network Open. 2021;4(10):e2128391–e2128391.34613401
279 Ye W, Rodriguez JM. Highly vulnerable communities and the Affordable Care Act: Health insurance coverage effects, 2010–2018. Social Science & Medicine. 2021;270:N.PAG-N.PAG.
280 Xie Y, Bowe B, Gibson AK, . Comparative Effectiveness of Sodium-Glucose Cotransporter 2 Inhibitors vs Sulfonylureas in Patients With Type 2 Diabetes. JAMA Internal Medicine. 2021;181(8):1043–1053.34180939
281 Wilson TB, Caporale-Berkowitz NA, Parent MC, Brownson CB. Grit is associated with decreased mental health help-seeking among student veterans. Journal of American college health : J of ACH. 2021:1–6.
282 Williams SB, Howard LE, Foster ML, . Estimated Costs and Long-term Outcomes of Patients With High-Risk Non–Muscle-Invasive Bladder Cancer Treated With Bacillus Calmette-Guérin in the Veterans Affairs Health System. JAMA Network Open. 2021;4(4):e213800–e213800.33787908
283 Wilkinson LA, Carter MT, Wattengel BA, . Societal factors contributing to infections caused by Chlamydia trachomatis and Neisseria gonorrhoeae in a veteran population. International Journal of STD and AIDS. 2021;32(9):845–851.33949249
284 Wiemken TL, Salas J, Hoft DF, . Dementia risk following influenza vaccination in a large veteran cohort. Vaccine. 2021;39(39):5524–5531.34420785
285 Weygandt J, Robling K, Whitaker LA, . Cancer Screening Among Current and Former U.S. Military Personnel Compared to Civilians: A Cross-Sectional Analysis of the Behavioral Risk Factor Surveillance System. Military medicine. 2021.
286 Wayne MT, Seelye S, Molling D, . Temporal Trends and Hospital Variation in Time-to-Antibiotics Among Veterans Hospitalized With Sepsis. JAMA Network Open. 2021;4(9):e2123950–e2123950.34491351
287 Ward S, Boger M, Fleishman A, . Attitudes Toward Organ, Tissue, and Vascularized Composite Allograft (VCA) Donation and Transplantation: A Survey of United States Military Veterans. Transplantation. 2021;105(5):1116–1124.32639399
288 Wang A, Bossick A, Callegari L, . Presence of Pelvic Pain Does Not Influence Route of Benign Hysterectomy in Women Veterans. Journal of Minimally Invasive Gynecology. 2021;28(11):S132–S133.
289 Vashi AA, Urech T, Wu S, . Community Urgent Care Use Following Implementation of the Veterans Affairs Maintaining Internal Systems and Strengthening Integrated Outside Networks Act. Medical Care. 2021;59:S314–S321.33976082
290 Van Voorhees EE, Dillon KH, Wilson SM, . A Comparison of Group Anger Management Treatments for Combat Veterans With PTSD: Results From a Quasi-Experimental Trial. Journal of Interpersonal Violence. 2021;36(19/20):NP10276–NP10300.34523367
291 Valera EM, Joseph ALC, Snedaker K, . Understanding Traumatic Brain Injury in Females: A State-of-the-Art Summary and Future Directions. Journal of Head Trauma Rehabilitation. 2021;36(1):E1–E17.33369993
292 Torre GM, Montelongo-Mercado EA, Noyola-Villalobos HF, . Epidemiology of hospitalized patients with COVID-19 in a tertiary care hospital. Gac Med Mex. 2021;157(3):237–244.34667312
293 Tirone V, Smith D, Steigerwald VL, . Examining the Impact of Sexual Revictimization in a Sample of Veterans Undergoing Intensive PTSD Treatment. Journal of Interpersonal Violence. 2021;36(23/24):10989–11008.31898925
294 Tcheung LS, Cordasco KM, Danz M, . Quality of Care for Women with Urinary Incontinence in the Veterans Health Administration. J Gen Intern Med. 2021;36(9):2900–2902.32935317
295 Tantisattamo E, Murray V, Obi Y, . Association of Pre-ESRD Serum Bicarbonate with Post-ESRD Mortality in Patients with Incident ESRD. American Journal of Nephrology. 2021;52(4):304–317.33895727
296 Sumida K, Dashputre AA, Potukuchi PK, . Laxative Use and Change in Estimated Glomerular Filtration Rate in Patients With Advanced Chronic Kidney Disease. Journal of Renal Nutrition. 2021:361–369.
297 Sugarman EP, Birns ME, Fishman M, . Does Capsular Closure Affect Clinical Outcomes in Hip Arthroscopy? A Prospective Randomized Controlled Trial. Orthopaedic Journal of Sports Medicine. 2021;9(5):1–9.
298 Stirman SW, Cohen ZD, Lunney CA, . A personalized index to inform selection of a trauma-focused or non-trauma-focused treatment for PTSD. Behaviour Research and Therapy. 2021;142.
299 Steers MN, Macia KS, Young CM, . Self in the Service: Self-Identification Moderates the Association between Perceived Drinking Norms and Own Drinking among Veterans. Subst Use Misuse. 2021;56(10):1428–1438.34039252
300 Soohoo M, Hashemi L, Jui-Ting H, . Risk of Atherosclerotic Cardiovascular Disease and Nonatherosclerotic Cardiovascular Disease Hospitalizations for Triglycerides Across Chronic Kidney Disease Stages Among 2.9 Million US Veterans. Journal of the American Heart Association. 2021;10(23):1–11.
301 Simonov M, Abel EA, Skanderson M, . Use of Proton Pump Inhibitors Increases Risk of Incident Kidney Stones. Clinical Gastroenterology and Hepatology. 2021;19(1):72–79.e21.32147588
302 Shaine MJD, Cor DN, Campbell AJ, McAlister AL. Mental Health Care Experiences of Trans Service Members and Veterans: A Mixed-Methods Study. Journal of Counseling & Development. 2021;99(3):273–288.
303 Shahait AD, Mesquita-Neto JWB, Girten K, . Iatrogenic Ureteral Injury and Prophylactic Stent Use in Veterans Undergoing Colorectal. Journal of Surgical Research. 2021;265:272–277.33964637
304 Seligman B, Ferranna M, Bloom DE. Social determinants of mortality from COVID-19: A simulation study using NHANES. PLoS Medicine. 2021;18(1):1–13.
305 Seidenfeld J, Stechuchak KM, Coffman CJ, . Exploring differential response to an emergency department-based care transition intervention. American Journal of Emergency Medicine. 2021;50:640–645.34879480
306 Schirmer P, Lucero-Obusan C, Sharma A, . Respiratory co-infections with COVID-19 in the Veterans Health Administration, 2020. Diagnostic Microbiology and Infectious Disease. 2021;100(1).
307 Scherrer JF, Salas J, Wiemken TL, . Lower Risk for Dementia Following Adult Tetanus, Diphtheria, and Pertussis (Tdap) Vaccination. Journals of Gerontology Series A: Biological Sciences & Medical Sciences. 2021;76(8):1436–1443.33856020
308 Salloum RG, LeLaurin JH, Dallery J, . Cost evaluation of tobacco control interventions in clinical settings: A systematic review. Preventive Medicine. 2021;146:N.PAG-N.PAG.
309 Sadler AG, Mengeling MA, Cook BL, Torner JC. Factors Associated with U.S. Military Women Keeping Guns or Weapons Nearby for Personal Security Following Deployment. Journal of Women’s Health (15409996). 2021;30(1):103–112.
310 Ryan GL, Mengeling MA, Torner JC, . SEXUAL ASSAULT AND LIFETIME INFERTILITY DIAGNOSIS IN MALE AND FEMALE U.S. MILITARY VETERANS. Fertility & Sterility. 2021;116(3):e46–e46.
311 Qiao EM, Voora RS, Nalawade V, . Evaluating the clinical trends and benefits of low-dose computed tomography in lung cancer patients. Cancer Medicine. 2021;10(20):7289–7297.34528761
312 Pundi KN, Perino AC, Jun F, . Direct Oral Anticoagulant Adherence of Patients With Atrial Fibrillation Transitioned from Warfarin. Journal of the American Heart Association. 2021;10(23):1–10.
313 Pulverman CS, Creech SK. The Impact of Sexual Trauma on the Sexual Health of Women Veterans: A Comprehensive Review. Trauma, Violence & Abuse. 2021;22(4):656–671.
314 Pierce BS, Perrin PB, Tyler CM, . The COVID-19 telepsychology revolution: A national study of pandemic-based changes in U.S. mental health care delivery. The American psychologist. 2021;76(1):14–25.32816503
315 Perino AC, Kaiser DW, Lee RJ, . Incidence and outcomes of patients with atrial fibrillation and major bleeding complications: from the TREAT-AF study. Journal of Interventional Cardiac Electrophysiology. 2021;62(1):133–142.32986177
316 Perino AC, Fan J, Schmitt S, . Anticoagulation Treatment and Outcomes of Venous Thromboembolism by Weight and Body Mass Index: Insights From the Veterans Health Administration. Circulation: Cardiovascular Quality and Outcomes. 2021;14(11):E008005.34724801
317 Pedersen ER, Davis JP, Prindle J, . Mental health symptoms among American veterans during the COVID-19 Pandemic. Psychiatry Research. 2021;306.
318 Parrish JM, Jenkins NW, Massel DH, . The perioperative symptom severity of higher patient health questionnaire-9 scores between genders in single-level lumbar fusion. International Journal of Spine Surgery. 2021;15(1):62–73.33900958
319 Modiano YA, Karakas C, Haneef Z. Social determinants do not affect access to specialized epilepsy care in veterans. Epilepsy and Behavior. 2021;121.
320 Miller DR, Jasuja G, Davila HW, . Care processes related to clinical detection of Alzheimer’s disease in the U.S. Veterans Affairs Health Care System. Alzheimer’s & dementia : the journal of the Alzheimer’s Association. 2021;17:e054149.
321 Miao C, Yan X, Bowe B, . Temporal Trends in Incidence Rates of Lower Extremity Amputation and Associated Risk Factors Among Patients Using Veterans Health Administration Services From 2008 to 2018. JAMA Network Open. 2021;4(1):1–13.
322 McDaniel JT, McDermott RJ, Schneider T. A Fay-Herriot Model for Estimating Subjective Cognitive Decline among Military Veterans. Journal of Prevention of Alzheimer’s Disease. 2021;8(4):457–461.
323 Martinez RN, Smith BM, Etingen B, . Health-Related Goal Setting and Achievement Among Veterans with High Technology Adoption. Journal of General Internal Medicine. 2021;36(11):3337–3345.33963510
324 Marchand WR, Sandoval K, Lackner R, . Mindfulness-based interventions for military veterans: A systematic review and analysis of the literature. Complementary Therapies in Clinical Practice. 2021;42:N.PAG-N.PAG.
325 Mancuso AC, Mengeling MA, Holcombe A, Ryan GL. REPRODUCTIVE CONCERN AMONG FEMALE AND MALE UNITED STATES VETERANS EXPOSED TO ENVIRONMENTAL, CHEMICAL, AND HAZARDOUS MATERIALS. Fertility & Sterility. 2021;116(3):e90–e91.
326 Lynch TS, Oak SR, Cossell C, . Effect of Baseline Mental Health on 1-Year Outcomes After Hip Arthroscopy: A Prospective Cohort Study. Orthopaedic Journal of Sports Medicine. 2021;9(8):1–8.
327 Livingston NA, Farmer SL, Mahoney CT, . The role of PTSD symptom clusters and criterion in predicting future high-risk drug and alcohol use among returning veteran men and women. Psychological services. 2021.
328 Kumar S, Metz DC, Kaplan DE, Goldberg DS. Low Rates of Retesting for Eradication of Helicobacter pylori Infection After Treatment in the Veterans Health Administration. Clinical Gastroenterology and Hepatology. 2021;19(2):305–313.e1.32272245
329 Kosturakis AK, Mengeling MA, Holcombe A, . REPRODUCTIVE HEALTH MEASURES IN A LARGE POPULATION OF U.S. WOMEN MILITARY VETERANS. Fertility & Sterility. 2021;116(3):e321–e321.
330 Kolaja CA, Schuyler AC, Armenta RF, . Sexual health difficulties among service women: the influence of posttraumatic stress disorder. Journal of Affective Disorders. 2021;292:678–686.34157663
331 Koffel E, Branson M, Amundson E, Wisdom JP. “Sign Me Up, I’m Ready!”: Helping Patients Prescribed Sleeping Medication Engage with Cognitive Behavioral Therapy for Insomnia (CBT-I). Behavioral sleep medicine. 2021;19(5):629–639.33063548
332 Kasović M, Štefan L, Kalčik Z. The importance of cardiorespiratory vs. Muscular fitness in reducing the odds of hypertension in war veterans: A population-based study. International Journal of Environmental Research and Public Health. 2021;18(21).
333 Jones AL, Gordon AJ, Gabrielian SE, . Perceptions of care coordination among homeless veterans receiving medical care in the veterans health administration and community care settings results from a national survey. Medical Care. 2021;59(6):504–512.33827108
334 Jia X, Lee MT, Ramsey DJ, . Association of patient, provider and facility related characteristics with statin associated side effects and statin use: Insight from the Veteran’s Affairs healthcare system. Journal of Clinical Lipidology. 2021;15(6):832–839.34666951
335 Jasuja GK, Meterko M, Bradshaw LD, . Attitudes and Intentions of US Veterans Regarding COVID-19 Vaccination. JAMA Network Open. 2021;4(11):e2132548–e2132548.34730819
336 Ioannou GN, Green P, Locke ER, Berry K. Factors associated with early receipt of COVID-19 vaccination and adherence to second dose in the Veterans Affairs healthcare system. PLoS ONE. 2021;16(12 December).
337 Huang Y, Xu J, Zheng S, . The risk factors for insomnia and sleep-disordered breathing in military communities: A meta-analysis. PLoS ONE. 2021;16(5 May).
338 Hsiung J-T, Soohoo M, Marroquin M, . Short-Term Risk of ASCVD and non-ASCVD Hospitalization associated with LDL across CKD Stages among nearly two Million US Veterans. Journal of Clinical Lipidology. 2021;15(5):e20–e21.
339 Horseman TS, Crecelius EM, Miller MA, . Prevalence and Epidemiology of Mycoplasma genitalium in a Pacific-Region Military Population. Sexually Transmitted Diseases. 2021;48(8):578–582.34110757
340 Holens PL, Buhler JN, Yacucha S, . Effects of a modified DBT Skills Group for military personnel and Veterans with OSIs and borderline personality disorder or traits. Journal of Military, Veteran & Family Health. 2021;7(3):76–85.
341 Harvey PD, Bigdeli TB, Fanous AH, . Cooperative studies Program (CSP) #572: A study of serious mental illness in veterans as a pathway to personalized medicine in schizophrenia and bipolar illness. Personalized Medicine in Psychiatry. 2021;27–28.
342 Hahn CK, Turchik J, Kimerling R. A Latent Class Analysis of Mental Health Beliefs Related to Military Sexual Trauma. Journal of traumatic stress. 2021;34(2):394–404.32969098
343 Grillo AR, Danitz SB, Dichter ME, . Strides Toward Recovery From Intimate Partner Violence: Elucidating Patient-Centered Outcomes to Optimize a Brief Counseling Intervention for Women. Journal of Interpersonal Violence. 2021;36(15/16):NP8431–NP8453.30994401
344 Greiner B, Ottwell R, Corcoran A, Hartwell M. Smoking and Physical Activity Patterns of U.S. Military Veterans With Chronic Obstructive Pulmonary Disease: An Analysis of 2017 Behavioral Risk Factor Surveillance System. Military medicine. 2021;186(1–2):e1–e5.33007087
345 Greenhalgh M, Rigot S, Eckstein S, . A consumer assessment of women who use wheelchairs. Journal of Military, Veteran & Family Health. 2021;7(2):40–49.
346 Gomez F, Middlemass KM, Kilpela LS, Becker CB. Sexual Trauma Uniquely Associated With Eating Disorders: A Replication Study. Psychological Trauma: Theory, Research, Practice & Policy. 2021;13(2):202–205.32940521
347 Glynn H, Möller SP, Wilding H, . Prevalence and Impact of Post-traumatic Stress Disorder in Gastrointestinal Conditions: A Systematic Review. Digestive Diseases and Sciences. 2021;66(12):4109–4119.33433790
348 George EL, Hall DE, Youk A, . Association Between Patient Frailty and Postoperative Mortality Across Multiple Noncardiac Surgical Specialties. JAMA Surgery. 2021;156(1):e205152–e205152.33206156
349 Gawron LM, Simonsen S, Millar MM, . Pregnancy Risk Screening and Counseling for Women Veterans: Piloting the One Key Question in the Veterans Healthcare Administration. Southern Medical Journal. 2021;114(3):150–155.33655308
350 Gaffey AE, Rosman L, Burg MM, . Posttraumatic Stress Disorder, Antidepressant Use, and Hemorrhagic Stroke in Young Men and Women: A 13-Year Cohort Study. Stroke (00392499). 2021;52(1):121–129.
351 Fortney JC, Bauer AM, Cerimele JM, . Comparison of Teleintegrated Care and Telereferral Care for Treating Complex Psychiatric Disorders in Primary Care: A Pragmatic Randomized Comparative Effectiveness Trial. JAMA Psychiatry. 2021;78(11):1189–1199.34431972
352 Flores BE, Riley-Baker JK, Flores RA, Young-McCaughan S. Integrating Veteran Healthcare into Nursing Curricula: In the students’ Words. Clinical Simulation in Nursing. 2021;59:32–38.
353 Flatt RE, Norman E, Thornton LM, . Eating disorder behaviors and treatment seeking in self-identified military personnel and veterans: Results of the National Eating Disorders Association online screening. Eating Behaviors. 2021;43:N.PAG-N.PAG.
354 Finlay AK, Harris AHS, Timko C, . Disparities in Access to Medications for Opioid Use Disorder in the Veterans Health Administration. Journal of Addiction Medicine. 2021;15(2):143–149.32826617
355 Ferguson JM, Abdel Magid HS, Purnell AL, . Differences in COVID-19 Testing and Test Positivity Among Veterans, United States, 2020. Public Health Reports. 2021;136(4):483–492.33826875
356 Fenwick KM, Luger TM, Dyer KE, . Challenges to Addressing Patient-Perpetrated Sexual Harassment in Veterans Affairs Healthcare Settings. Journal of General Internal Medicine. 2021;36(8):2332–2338.33634380
357 Eichler M, Smith-Evans K, Spanner L, Tam-Seto L. Mind the gap: Sex, gender, and intersectionality in military-to-civilian transitions. Journal of Military, Veteran & Family Health. 2021;7:19–36.
358 Ebrahimi R, Lynch K, Viernes B, . POSTTRAUMATIC STRESS DISORDER AND CARDIOVASCULAR MORTALITY- IMPACT ON AGE AT DEATH FOR WOMEN VETERANS. Journal of the American College of Cardiology (JACC). 2021;77(18):1514–1514.
359 Denneson LM, Hoffmire CA, Blosnich JR, . Advancing Knowledge of Suicide Risk and Prevention Among Women: Introduction to the Supplement. Medical Care. 2021;59(2):S1–S3.33438873
360 Decker SE, Hoff R, Martino S, . Is Emotion Dysregulation Associated With Suicidal Ideation in Post 9/11 Veterans? Archives of Suicide Research. 2021;25(1):126–140.31556798
361 Davis JP, Prindle J, Castro CC, . Changes in alcohol use during the COVID-19 pandemic among American veterans. Addictive Behaviors. 2021;122:N.PAG-N.PAG.
362 Daphna-Tekoah S, Harel-Shalev A, Harpaz-Rotem I. Thank You for Hearing My Voice - Listening to Women Combat Veterans in the United States and Israeli Militaries. Front Psychol. 2021;12:769123.34938240
363 Dallocchio M. Women Veterans: Examining identity through an intersectional lens. Journal of Military, Veteran & Family Health. 2021;7:111–121.
364 Cunningham KC, Aunon FM, Patel TA, . Nonsuicidal Self-Injury Disorder, Borderline Personality Disorder, and Lifetime History of Suicide Attempts among Male and Female Veterans with Mental Health Disorders. Journal of Affective Disorders. 2021;287:276–281.33799048
365 Cucciare MA, Combs AS, Joshi G, . Computer-delivered brief alcohol intervention for patients with liver disease: a randomized controlled trial. Addiction. 2021;116(5):1076–1087.32924207
366 Creech SK, Pulverman CS, Shin ME, . An Open Trial to Test Participant Satisfaction With and Feasibility of a Computerized Intervention for Women Veterans With Sexual Trauma Histories Seeking Primary Care Treatment. Violence Against Women. 2021;27(3/4):597–614.31896315
367 Conard PL, Keller MJ, Armstrong ML. The Risks, Invisibility, and Health Issues Facing Women Veterans Who Are Homeless. Nursing for Women’s Health. 2021;25(6):471–481.
368 Cohen BE. Exploring Posttraumatic Stress Disorder as a Cardiovascular Risk Factor in Women Veterans: The Heart of the Matter. JAMA Cardiology. 2021;6(6):651–652.33729434
369 Byrne SP, Fogle BM, Asch R, . The hidden burden of social anxiety disorder in U.S. military veterans: Results from the National Health and Resilience in Veterans Study. Journal of Affective Disorders. 2021;291:9–14.34022553
370 Butt AA, Yan P, Kapadia S, . Social vulnerability in persons with chronic hepatitis C virus infection is associated with a higher risk of prescription opioid use. Scientific reports. 2021;11(1):5883.33723313
371 Brodhead F. Veterans’ Needs After Suicide Attempts. AJN American Journal of Nursing. 2021;121(5):1–18.
372 Braun TD, Uebelacker LA, Ward M, . “We really need this”: Trauma-informed yoga for Veteran women with a history of military sexual trauma. Complementary Therapies in Medicine. 2021;59:N.PAG-N.PAG.
373 Bountress KE, Vladimirov V, McMichael G, . Gene Expression Differences Between Young Adults Based on Trauma History and Post-traumatic Stress Disorder. Frontiers in Psychiatry. 2021;12.
374 Boersma P, Cohen RA, Zelaya CE, Moy E. Multiple Chronic Conditions Among Veterans and Nonveterans: United States, 2015-2018. National health statistics reports. 2021(153):1–13.
375 Blais RK, Hess RA, Serang S. The buffering role of higher romantic relationship satisfaction on the association of hazardous drinking with PTSD and depression symptoms among female military service members/veterans. Addictive Behaviors. 2021;123:N.PAG-N.PAG.
376 Bhanegaonkar A, Pandya S, Zheng Y, . Real-World Outcomes Among US Veterans Health Administration Patients Newly Diagnosed with Metastatic Renal Cell Carcinoma and Treated with First-Line Monotherapy. Advances in Therapy. 2021;38(5):2644–2661.33866526
377 Balut MD, Chu K, Gin JL, . Predictors of covid-19 vaccination among veterans experiencing homelessness. Vaccines. 2021;9(11).
378 Baca SA, Crawford JN, Allard CB. PTSD, depression, and suicidality among survivors of childhood sexual trauma (CST), military sexual trauma (MST), and sexual revictimization (CST + MST). Psychological trauma : theory, research, practice and policy. 2021.
379 Avoundjian T, Troszak L, Cave S, . Correlates of personal health record registration and utilization among veterans with HIV. JAMIA Open. 2021;4(2).
380 Appaneal HJ, Shireman TI, Lopes VV, . Poor clinical outcomes associated with suboptimal antibiotic treatment among older long-term care facility residents with urinary tract infection: a retrospective cohort study. BMC Geriatrics. 2021;21(1):1–13.33388045
381 Appaneal HJ, Caffrey AR, Lopes VV, . Predictors of potentially suboptimal treatment of urinary tract infections in long-term care facilities. Journal of Hospital Infection. 2021;110:114–121.33549769
382 Alqam B, Habash F, Gheith Z, . LONG TERM OUTCOMES OF TAKOTSUBO CARDIOMYOPATHY IN MEN COMPARED TO WOMEN IN THE US VETERAN AFFAIRS HEALTHCARE SYSTEM. Journal of the American College of Cardiology (JACC). 2021;77(18):867–867.
383 Allen KD, Woolson S, Hoenig HM, . Stepped Exercise Program for Patients With Knee Osteoarthritis : A Randomized Controlled Trial. Annals of Internal Medicine. 2021;174(3):298–307.33370174
384 Alcántara C, Giorgio Cosenzo L, McCullough E, . Cultural adaptations of psychological interventions for prevalent sleep disorders and sleep disturbances: A systematic review of randomized controlled trials in the United States. Sleep Medicine Reviews. 2021;56:N.PAG-N.PAG.
385 Akwo EA, Robinson-Cohen C, Chung CP, . Association of Apparent Treatment-Resistant Hypertension with Differential Risk of End-Stage Kidney Disease Across Racial Groups in the Million Veteran Program. Hypertension. 2021;78(2):376–386.34148359
386 Agarwal AK, Waddell KJ, Small DS, . Effect of Gamification With and Without Financial Incentives to Increase Physical Activity Among Veterans Classified as Having Obesity or Overweight: A Randomized Clinical Trial. JAMA Network Open. 2021;4(7):e2116256–e2116256.34241628
387 Abou-Donia MB, Krengel MH, Lapadula ES, . Sex-based differences in plasma autoantibodies to central nervous system proteins in gulf war veterans versus healthy and symptomatic controls. Brain Sciences. 2021;11(2):1–16.
388 Yoon J, Leung LB, Rubenstein LV, . Use of the Veterans’ Choice Program and Attrition From Veterans Health Administration Primary Care. Medical Care. 2020;58(12):1091–1097.32925455
389 Xie Y, Bowe B, Gibson AK, . Comparative Effectiveness of SGLT2 Inhibitors, GLP-1 Receptor Agonists, DPP-4 Inhibitors, and Sulfonylureas on Risk of Kidney Outcomes: Emulation of a Target Trial Using Health Care Databases. Diabetes Care. 2020;43(11):2859–2869.32938746
390 Womack JA, Murphy TE, Bathulapalli H, . Serious Falls in Middle-Aged Veterans: Development and Validation of a Predictive Risk Model. Journal of the American Geriatrics Society. 2020;68(12):2847–2854.32860222
391 Wilson LC, Newins AR, Wilson SM, . Self- and Other-Directed Violence as Outcomes of Deployment-Based Military Sexual Assault. Journal of Aggression, Maltreatment and Trauma. 2020;29(6):714–724.
392 Werum R, Steidl C, Harcey S, Absalon J. Military service and STEM employment: Do veterans have an advantage? Social science research. 2020;92:102478.33172566
393 Vogt DS, Tyrell FA, Bramande EA, . U.S. Military Veterans’ Health and Well-Being in the First Year After Service. American Journal of Preventive Medicine. 2020;58(3):352–360.31902684
394 Vassy JL, Michael Gaziano J, Green RC, . Effect of pharmacogenetic testing for statin myopathy risk vs usual care on blood cholesterol a randomized clinical trial. JAMA Network Open. 2020;3(12).
395 Turner AP, Harding KA, Brier MJ, . Military Sexual Trauma and Chronic Pain in Veterans. American Journal of Physical Medicine & Rehabilitation. 2020;99(11):1020–1025.32427603
396 Timko C, Nash A, Owens MD, . Systematic Review of Criminal and Legal Involvement After Substance Use and Mental Health Treatment Among Veterans: Building Toward Needed Research. Substance Abuse: Research & Treatment. 2020;14:1–13.
397 Thakur H, Oni O, Singh V, . Demographic Profile and Service-Connection Trends of Posttraumatic Stress Disorder and Traumatic Brain Injury in US Veterans Pre- and Post-9/11. Fed. 2020;37(3):128–137.
398 Tan EH, Sena AG, Prats-Uribe A, . Characteristics, outcomes, and mortality amongst 133,589 patients with prevalent autoimmune diseases diagnosed with, and 48,418 hospitalised for COVID-19: a multinational distributed network cohort analysis. medRxiv. 2020;27:27.
399 Taetzsch A, Roberts SB, Gilhooly CH, . Food cravings: Associations with dietary intake and metabolic health. Appetite. 2020;152:N.PAG-N.PAG.
400 Stefanovics EA, Gavriel-Fried B, Potenza MN, Pietrzak RH. Current drinking patterns in US veterans with a lifetime history of alcohol use disorder: Results from the National Health and Resilience in Veterans Study. American Journal of Drug and Alcohol Abuse. 2020;46(6):784–794.32975444
401 Skalitzky MK, Mengeling MA, Holcombe A, . ASSOCIATIONS BETWEEN QUALITY OF LIFE, SOCIODEMOGRAPHICS AND MILITARY CHARACTERISTICS IN A US VETERAN POPULATION WITH INFERTILITY. Fertility & Sterility. 2020;114:e448–e448.
402 Siddiqi A, Higuera-Rueda CA, Krebs VE, . Patient-Reported Outcome Measures (Pain, Function, and Quality of Life) After Aseptic Revision Total Knee Arthroplasty. Journal of Bone & Joint Surgery, American Volume. 2020;102(20):1–14.
403 Seymour JW, Fix L, Grossman D, Grindlay K. Pregnancy and Abortion: Experiences and Attitudes of Deployed U.S. Servicewomen. Military Medicine. 2020;185(9/10):e1390–e1390.32779707
404 Serper M, Vujkovic M, Kaplan DE, . Validating a non-invasive, ALT-based nonalcoholic fatty liver phenotype in the million veteran program. PLoS ONE. 2020;15(8 August 2020).
405 Selby LD, Park-Egan BAM, Winges KM. Temporal Artery Biopsy in the Workup of Giant Cell Arteritis: Diagnostic Considerations in a Veterans Administration Cohort. Journal of Neuro-Ophthalmology. 2020;40(4):450–456.32868573
406 Sanchez R, Zhou Y, Sarrazin MSV, . Lung Cancer Staging at Diagnosis in the Veterans Health Administration: Is Rurality an Influencing Factor? A Cross-Sectional Study. Journal of Rural Health. 2020;36(4):484–495.
407 Ryan GL, Thoma ME, Holcombe A, . ASSOCIATIONS BETWEEN INFERTILITY AND SEXUAL HEALTH IN U.S. FEMALE AND MALE VETERANS. Fertility & Sterility. 2020;114:e218–e218.
408 Ryan GL, Thoma ME, Holcombe A, . MILITARY SERVICE AND MEDICAL ASSOCIATIONS WITH INFERTILITY IN U.S. VETERANS. Fertility & Sterility. 2020;114:e25–e25.
409 Rubin ML, Copeland LA, Kroll-Desrosiers AR, Knittel AG. Demographic Variation in the Use of Prazosin for Treatment of Sleep Disturbance in Combat Veterans with PTSD. Psychopharmacology bulletin. 2020;50(2):26–35.32508364
410 Rossi FS, Shankar M, Buckholdt K, . Trying Times and Trying Out Solutions: Intimate Partner Violence Screening and Support for Women Veterans During COVID-19. JGIM: Journal of General Internal Medicine. 2020;35(9):2728–2731.32607932
411 Robbins AS, Pathak SR, Webber BJ, . Malignancy in U.S. Air Force fighter pilots and other officers, 1986–2017: A retrospective cohort study. PLoS ONE. 2020;15(9 September).
412 Richardson NM, Lamson AL, Smith M, . Defining Moral Injury Among Military Populations: A Systematic Review. Journal of Traumatic Stress. 2020;33(4):575–586.32567119
413 Resnik LJ, Borgia ML, Clark MA. A National Survey of Prosthesis Use in Veterans with Major Upper Limb Amputation: Comparisons by Gender. PM & R: Journal of Injury, Function & Rehabilitation. 2020;12(11):1086–1098.
414 Rentsch CT, Kidwai-Khan F, Tate JP, . Patterns of COVID-19 testing and mortality by race and ethnicity among United States veterans: A nationwide cohort study. PLoS Medicine. 2020;17(9).
415 Relyea MR, Portnoy GA, Klap R, . Evaluating Bystander Intervention Training to Address Patient Harassment at the Veterans Health Administration. Women’s Health Issues. 2020;30(5):320–329.32830008
416 Redd AM, Gundlapalli AV, Suo Y, . Exploring Disparities in Awarding VA Service-Connected Disability for Post-Traumatic Stress Disorder for Active Duty Military Service Members from Recent Conflicts in Iraq and Afghanistan. Military Medicine. 2020;185:296–302.32074380
417 Ravindran C, Morley SW, Stephens BM, . Association of Suicide Risk With Transition to Civilian Life Among US Military Service Members. JAMA Network Open. 2020;3(9):e2016261–e2016261.32915235
418 Raad JH, Tulsky DS, Lange RT, . Establishing the Factor Structure of a Health-Related Quality of Life Measurement System for Caregivers of Persons Living With Traumatic Brain Injury. Archives of Physical Medicine & Rehabilitation. 2020;101(7):1220–1232.32315649
419 Protsiv M, Ley C, Lankester J, . Decreasing human body temperature in the United States since the industrial revolution. eLife. 2020;9.
420 Portnoy GA, Colon R, Gross GM, . Patient and provider barriers, facilitators, and implementation preferences of intimate partner violence perpetration screening. BMC Health Services Research. 2020;20(1):1–12.
421 Porter B, Rodriguez LM, Woodall KA, . Alcohol misuse and separation from military service: A dyadic perspective. Addictive Behaviors. 2020;110:N.PAG-N.PAG.
422 Podlogar MC, Joiner TE. Allowing for Nondisclosure in High Suicide Risk Groups. Assessment. 2020;27(3):547–559.31053035
423 Park S, Je NK. Factors That Affect Time to Switch From Warfarin to a Direct Oral Anticoagulant After Change in the Reimbursement Criteria in Patients With Atrial Fibrillation. Journal of Cardiovascular Pharmacology & Therapeutics. 2020;25(1):57–64.31405298
424 Pak LM, Banaag A, Koehlmoos TP, . Non-clinical Drivers of Variation in Preoperative MRI Utilization for Breast Cancer. Annals of Surgical Oncology. 2020;27(9):3414–3423.32215756
425 Norman KP, Govindjee A, Norman SR, . Natural Language Processing Tools for Assessing Progress and Outcome of Two Veteran Populations: Cohort Study From a Novel Online Intervention for Posttraumatic Growth. JMIR Form Res. 2020;4(9):e17424.32769074
426 Nelson HD, Cantor A, Wagner J, . Effectiveness of Patient Navigation to Increase Cancer Screening in Populations Adversely Affected by Health Disparities: a Meta-analysis. Journal of General Internal Medicine. 2020;35(10):3026–3035.32700218
427 Montgomery AE, Tsai J, Blosnich JR. Demographic Correlates of Veterans’ Adverse Social Determinants of Health. American Journal of Preventive Medicine. 2020;59(6):828–836.33220754
428 Molloy JM, Pendergrass TL, Lee IE, . Musculoskeletal Injuries and United States Army Readiness Part I: Overview of Injuries and their Strategic Impact. Military medicine. 2020;185(9–10):e1461–e1471.32175566
429 McGlade E, Rogowska J, DiMuzio J, . Neurobiological evidence of sexual dimorphism in limbic circuitry of US Veterans. Journal of Affective Disorders. 2020;274:1091–1101.32663937
430 Mazzei KA, Trippett AN, Hedrick TD, Wen S. Analysis of patient-specific factors contributing to effectiveness of glucagon-like peptide-1 receptor agonists. Journal of the American Pharmacists Association: JAPhA. 2020;60(6):937–942.32778515
431 Maynard C, Mikuls TR, Cannon GW, . Sex Differences in the Achievement of Remission and Low Disease Activity in Rheumatoid Arthritis. Arthritis Care & Research. 2020;72(3):326–333.30875461
432 Mancuso AC, Holcombe A, Mengeling MA, Ryan GL. INFERTILITY AND ENVIRONMENTAL, CHEMICAL, AND HAZARDOUS EXPOSURES AMONG UNITED STATES VETERANS. Fertility & Sterility. 2020;114:e17–e17.
433 Mahtta D, Gupta A, Ramsey DJ, . Autoimmune Rheumatic Diseases and Premature Atherosclerotic Cardiovascular Disease: An Analysis From the VITAL Registry. American Journal of Medicine. 2020;133(12):1424–1424.32598903
434 Maguen S, Holder N, Li Y, . Factors associated with PTSD symptom improvement among Iraq and Afghanistan veterans receiving evidenced-based psychotherapy. Journal of Affective Disorders. 2020;268:1–7.32157998
435 Lord KA, Suvak MK, Holmes S, . Bidirectional Relationships Between Posttraumatic Stress Disorder and Social Functioning During Cognitive Processing Therapy. Behavior Therapy. 2020;51(3):447–460.32402260
436 Livingston WS, Fargo JD, Gundlapalli AV, . Comorbid PTSD and Depression Diagnoses Mediate the Association of Military Sexual Trauma and Suicide and Intentional Self-Inflicted Injury in VHA-Enrolled Iraq/Afghanistan Veterans, 2004-2014. Journal of Affective Disorders. 2020;274:1184–1190.32663949
437 Lee DJ, Lee LO, Bovin MJ, . The 20-year course of posttraumatic stress disorder symptoms among veterans. Journal of Abnormal Psychology. 2020;129(6):658–669.32478530
438 Lamba AH, Muralidhar K, Jain A, . Characteristics of Women Enrolled in a Patient Portal Intervention for Menopause. Womens Health Rep (New Rochelle). 2020;1(1):500–510.33786517
439 LaFrance WC, Vo P, Baird G, . Moral injury in Veterans with nonepileptic seizures. Epilepsy and Behavior. 2020;102.
440 Lacefield K, Samph SP, Orbon S, Otis J. Integrated Intervention for Comorbid Posttraumatic Stress Disorder and Fibromyalgia: A Pilot Study of Women Veterans. Psychological Trauma: Theory, Research, Practice & Policy. 2020;12(7):725–729.32757579
441 Kwan J, Sparrow K, Facer-Irwin E, . Prevalence of intimate partner violence perpetration among military populations: A systematic review and meta-analysis. Aggression & Violent Behavior. 2020;53:N.PAG-N.PAG.
442 Kumar S, Metz DC, Ellenberg S, . Risk Factors and Incidence of Gastric Cancer After Detection of Helicobacter pylori Infection: A Large Cohort Study. Gastroenterology. 2020;158(3):527–536.e7.31654635
443 Kobe EA, Edelman D, Tarkington PE, . Practical telehealth to improve control and engagement for patients with clinic-refractory diabetes mellitus (PRACTICE-DM): Protocol and baseline data for a randomized trial. Contemporary Clinical Trials. 2020;98.
444 Klapheke AK, Keegan THM, Ruskin R, Cress RD. Pre-diagnosis health-related quality of life and survival in older women with endometrial cancer. Supportive Care in Cancer. 2020;28(2):N.PAG-N.PAG.
445 Kinzel P, Marx CE, Sollmann N, . Serum Neurosteroid Levels Are Associated With Cortical Thickness in Individuals Diagnosed With Posttraumatic Stress Disorder and History of Mild Traumatic Brain Injury. Clinical EEG and Neuroscience. 2020;51(4):285–299.32186207
446 Khalifian CE, Knopp K, Wilks CR, . The Association Between Sexual Functioning and Suicide Risk in U.S. Military Veteran Couples Seeking Treatment for Post-Traumatic Stress Disorder. Archives of Sexual Behavior. 2020;49(5):1601–1613.31915971
447 Keach JW, Stanislawski MA, Barón AE, . Variation in contrast-associated acute kidney injury prophylaxis for percutaneous coronary intervention: insights from the Veterans Affairs Clinical Assessment, Reporting, and Tracking (CART) program. BMC Nephrology. 2020;21(1):1–11.
448 Katon JG, Gerber MR, Nillni YI, Patton EW. Consequences of Military Sexual Trauma for Perinatal Mental Health: How Do We Improve Care for Pregnant Veterans with a History of Sexual Trauma? Journal of Women’s Health. 2020;29(1):5–6.
449 Jenkins NW, Parrish JM, Nolte MT, . Validating the VR-12 Physical Function Instrument After Anterior Cervical Discectomy and Fusion with SF-12, PROMIS, and NDI. Hss J. 2020;16(Suppl 2):443–451.33380979
450 Iverson KM, Dichter ME, Stolzmann K, . Assessing the Veterans Health Administration’s response to intimate partner violence among women: protocol for a randomized hybrid type 2 implementation-effectiveness trial. Implementation Science. 2020;15(1):1–10.31900167
451 Holliday R, Smith NB, Holder N, . Comparing the effectiveness of VA residential PTSD treatment for veterans who do and do not report a history of MST: A national investigation. Journal of Psychiatric Research. 2020;122:42–47.31923834
452 Henderson J, Bouck Z, Holleman R, . Comparison of Payment Changes and Choosing Wisely Recommendations for Use of Low-Value Laboratory Tests in the United States and Canada. JAMA Internal Medicine. 2020;180(4):524–531.32040158
453 Hausmann LRM, Jones AL, McInnes SE, Zickmund SL. Identifying healthcare experiences associated with perceptions of racial/ethnic discrimination among veterans with pain: A cross-sectional mixed methods survey. PLoS ONE. 2020;15(9 September 2020).
454 Haun JN, Paykel J, Alman AC, . A complementary and integrative health group-based program pilot demonstrates positive health outcomes with female Veterans. Explore: The Journal of Science & Healing. 2020;16(2):85–89.31477475
455 Haun JN, Alman AC, Melillo C, . Using Electronic Data Collection Platforms to Assess Complementary and Integrative Health Patient-Reported Outcomes: Feasibility Project. JMIR Med Inform. 2020;8(6):e15609.32589163
456 Hamilton AB, Olmos-Ochoa TT, Canelo I, . Dynamic waitlisted design for evaluating a randomized trial of evidence-based quality improvement of comprehensive women’s health care implementation in low-performing VA facilities. Implement. 2020;1:59.
457 Gundlapalli AV, Redd AM, Suo Y, . Predicting and Planning for Musculoskeletal Service-Connected Disabilities in VA Using Disability for Active Duty OEF/OIF Military Service Members. Military Medicine. 2020;185:413–419.32074349
458 Gromisch ES, Kulas JF, Altalib H, . Neuropsychological assessments and psychotherapeutic services in Veterans with multiple sclerosis: Rates of utilization and their associations with socio-demographics and clinical characteristics using Veterans Health Administration-based data. Multiple Sclerosis and Related Disorders. 2020;43.
459 Griffiths HK, Hawkins BL, Crowe BM. Identifying contextual factors that impact community reintegration in injured female Veterans. Journal of Military, Veteran & Family Health. 2020;6(1):38–47.
460 Graham LA, Malone EB, Richman JS, . Association of Food Access, Recreational Opportunities, and Natural Amenities with Engagement in the Veterans MOVE! Weight Management Program. Obesity (19307381). 2020;28(1):55–64.
461 Gosmanova EO, Molnar MZ, Naseer A, . Longer Predialysis ACEi/ARB Utilization Is Associated With Reduced Postdialysis Mortality. American Journal of Medicine. 2020;133(9):1065–1065.32330490
462 Goode PS, Markland AD, Echt KV, . A mobile telehealth program for behavioral treatment of urinary incontinence in women veterans: Development and pilot evaluation of MyHealtheBladder. Neurourology and Urodynamics. 2020;39(1):432–439.31774200
463 Gnall KE, Cole HE, Creech SK, Taft CT. Client Experiences of the Strength at Home Intimate Partner Violence Program: A Qualitative Analysis. Partner Abuse. 2020;11(4):466–484.
464 Drake T, Gravely A, Westanmo A, Billington C. Prevalence of Thyroid Incidentalomas from 1995 to 2016: A Single-Center, Retrospective Cohort Study. Journal of the Endocrine Society. 2020;4(1):N.PAG-N.PAG.
465 Do MH, Lipner SR. Contribution of gender on compensation of Veterans Affairs-affiliated dermatologists: A cross-sectional study. International Journal of Women’s Dermatology. 2020;6(5):414–418.
466 Djousse L, Ho YL, Nguyen XT, . Egg consumption and risk of coronary artery disease in the Million Veteran Program. Clin Nutr. 2020;39(9):2842–2847.31902601
467 Dionne-Odom JN, Ejem DB, Wells R, . Effects of a Telehealth Early Palliative Care Intervention for Family Caregivers of Persons With Advanced Heart Failure: The ENABLE CHF-PC Randomized Clinical Trial. JAMA Network Open. 2020:e202583–e202583.
468 Dent KR, Griffin CA, McCarthy JF, Katz IR. Hypertension Treatment Modality and Suicide Risk Among Veterans in Veterans Health Administration Care From 2015 to 2017. JAMA Network Open. 2020;3(10):e2020330–e2020330.33044550
469 Damschroder LJ, Buis LR, McCant FA, . Effect of Adding Telephone-Based Brief Coaching to an mHealth App (Stay Strong) for Promoting Physical Activity Among Veterans: Randomized Controlled Trial. Journal of Medical Internet Research. 2020;22(8):N.PAG-N.PAG.
470 Cypel YS, Katon JG, Schure MB, Smith S. Food Insecurity in US Military Veterans. Food & Nutrition Bulletin. 2020;41(4):399–423.33356537
471 Cucciare MA, Mengeling MA, Han X, . Associations between Augmentee Status, Deployment Stress Preparedness and Depression, Post-Traumatic Stress Disorder, and Binge Drinking in U.S. Servicewomen. Women’s Health Issues. 2020;30(3):207–213.32081595
472 Chu PY, Hackstadt AJ, Chipman J, . Hospitalization for lactic acidosis among patients with reduced kidney function treated with metformin or sulfonylureas. Diabetes Care. 2020;43(7):1462–1470.32327421
473 Christiansen DM, Berke ET. Gender- and Sex-Based Contributors to Sex Differences in PTSD. Current Psychiatry Reports. 2020;22(4).
474 Chang ET, Zulman DM, Nelson KM, . Use of General Primary Care, Specialized Primary Care, and Other Veterans Affairs Services among High-Risk Veterans. JAMA Network Open. 2020.
475 Carbone LD, Gonzalez B, Miskevics S, . Association of Bisphosphonate Therapy With Incident of Lower Extremity Fractures in Persons With Spinal Cord Injuries or Disorders. Archives of Physical Medicine & Rehabilitation. 2020;101(4):633–641.31958428
476 Blais RK, Livingston WS, Fargo JD. Higher depression severity mediates the association of assault military sexual trauma and sexual function in partnered female service members/veterans. Journal of Affective Disorders. 2020;261:238–244.31655379
477 Blais RK. Lower Sexual Satisfaction and Function Mediate the Association of Assault Military Sexual Trauma and Relationship Satisfaction in Partnered Female Service Members/Veterans. Family Process. 2020;59(2):586–596.31041829
478 Blais RK. Lower intimate relationship satisfaction among partnered female service members/veterans is associated with the presence of suicidal ideation. Journal of clinical psychology. 2020;76(7):1353–1361.32040217
479 Blais RK. Higher anhedonia and dysphoric arousal relate to lower relationship satisfaction among trauma-exposed female service members/veterans. Journal of clinical psychology. 2020;76(7):1327–1338.32020632
480 Beach S, Ebrahimi R, Han JK. NO (WO)MAN LEFT BEHIND: FIFTY YEARS OF UNDERREPRESENTATION OF WOMEN VETERANS IN ATRIAL FIBRILLATION RESEARCH. Journal of the American College of Cardiology (JACC). 2020;75:356–356.
481 Baldassarri SR, Kachadourian LK, Esterlis I, Pietrzak RH. Nicotine dependence in US military veterans: results from the National Health and Resilience in Veterans Study. Addiction Research & Theory. 2020;28(2):160–164.32952489
482 Bade BC, DeRycke EC, Skanderson M, . Underutilization of Pulmonary Function Testing in Veterans Hospitalized for Chronic Obstructive Pulmonary Disease Exacerbation: Who are We Missing? COPD: Journal of Chronic Obstructive Pulmonary Disease. 2020;17(1):15–21.31948267
483 Arya S, Varley P, Youk A, . Recalibration and External Validation of the Risk Analysis Index: A Surgical Frailty Assessment Tool. Annals of Surgery. 2020;272(6):996–1005.30907757
484 Aronson KR, Perkins DF, Morgan NR, . Use of Health Services Among Post-9/11 Veterans With Mental Health Conditions Within 90 Days of Separation From the Military. Psychiatric Services. 2020;71(7):670–677.32393157
485 Anonymous. Quality of life among women veterans. J Am Assoc Nurse Pract. 2020;32(11):756–757.33177335
486 Alemi F, Avramovic S, Renshaw KD, . Relative accuracy of social and medical determinants of suicide in electronic health records. Health Services Research. 2020;55(S2):833–840.32880954
487 Zundel CG, Krengel MH, Heeren T, . Rates of chronic medical conditions in 1991 Gulf war veterans compared to the general population. International Journal of Environmental Research and Public Health. 2019;16(6).
488 Yoon J, Vanneman ME, Dally SK, . Veterans’ Reliance on VA Care by Type of Service and Distance to VA for Nonelderly VA-Medicaid Dual Enrollees. Medical Care. 2019;57(3):225–229.30676354
489 Yecies EB, Judge-Golden CP, Callegari L, Borrero S. Contraceptive Care in the Veterans Health Administration. Seminars in Reproductive Medicine. 2019;37(1):24–31.31185515
490 Wooldridge JS, Herbert MS, Hernandez J, . Improvement in 6-min Walk Test Distance Following Treatment for Behavioral Weight Loss and Disinhibited Eating: an Exploratory Secondary Analysis. International Journal of Behavioral Medicine. 2019;26(4):443–448.31236874
491 Williams EC, Bensley KM, Fortney J, . Patterns of Alcohol Use Among Patients Living With HIV in Urban, Large Rural, and Small Rural Areas. Journal of Rural Health. 2019;35(3):330–340.
492 Wells SY, Morland LA, Torres EM, . The Development of a Brief Version of the Posttraumatic Cognitions Inventory (PTCI-9). Assessment. 2019;26(2):193–208.28092974
493 Wells SY, Glassman LH, Talkovsky AM, . Examining Changes in Sexual Functioning after Cognitive Processing Therapy in a Sample of Women Trauma Survivors. Women’s Health Issues. 2019;29(1):72–79.30455090
494 Weissman JD, Russell D, Harris R, . Sociodemographic Risk Factors for Serious Psychological Distress among U.S. Veterans: Findings from the 2016 National Health Interview Survey. Psychiatric Quarterly. 2019;90(3):637–650.31240597
495 Weber JJ. A systematic review of nurse-led interventions with populations experiencing homelessness. Public Health Nursing. 2019;36(1):96–106.30353565
496 Weaver FM, Le B, Ray C, . Predicting osteoporosis medication receipt in Veterans with a spinal cord injury: A retrospective cohort study. Journal of Spinal Cord Medicine. 2019;42(6):760–767.30888309
497 Tsai J, Byrne TH. National Utilization Patterns of Veterans Affairs Homelessness Programs in the Era of Housing First. Psychiatric Services. 2019;70(4):309–315.30651057
498 Tsai J, Blue-Howells J, Nakashima J. Needs of homeless veterans: 5 years of the CHALENG Survey 2012–16. Journal of Public Health. 2019;41(1):e16–e24.29727001
499 Trbovich M, Mack D, Bruder JM. Osteoporosis in Veterans with Spinal Cord Injury: an Overview of Pathophysiology, Diagnosis, and Treatments. Clinical Reviews in Bone and Mineral Metabolism. 2019;17(2):94–108.
500 Thomas KH, McDaniel JT, Grohowski M, . Depression prevalence and geographic distribution in United States military women: results from the 2017 Service Women’s Action Network needs assessment. Journal of Military, Veteran & Family Health. 2019;5(2):6–15.
501 Thomas DD, Waring ME, Ameli O, . Patient Characteristics Associated with Receipt of Prescription Weight-Management Medications Among Veterans Participating in MOVE! Obesity (19307381). 2019;27(7):1168–1176.
502 Taylor SL, Herman PM, Marshall NJ, . Use of Complementary and Integrated Health: A Retrospective Analysis of U.S. Veterans with Chronic Musculoskeletal Pain Nationally. Journal of Alternative & Complementary Medicine. 2019;25(1):32–39.30312109
503 Tam-Seto L, English A. Need for cultural competency in the mentorship of female Veterans during civilian transitions. Journal of Military, Veteran & Family Health. 2019;5(1):115–118.
504 Sutton SS, Magagnoli J, Cummings TH, . Chronic kidney disease, cardiovascular disease, and osteoporotic fractures in patients with and without HIV in the US Veteran’s Affairs Administration System. Current Medical Research & Opinion. 2019;35(1):117–125.30378450
505 Stroupe KT, Martinez R, Hogan TP, . Experiences with the Veterans’ Choice Program. JGIM: Journal of General Internal Medicine. 2019;34(10):2141–2149.31388916
506 Sripada RK, Blow FC, Rauch SAM, . Examining the nonresponse phenomenon: Factors associated with treatment response in a national sample of veterans undergoing residential PTSD treatment. Journal of Anxiety Disorders. 2019;63:18–25.30785007
507 Soohoo M, Moradi H, Obi Y, . Serum triglycerides and mortality risk across stages of chronic kidney disease in 2 million U.S. veterans. Journal of Clinical Lipidology. 2019;13(5):744–744.31562050
508 Shuster BZ, Depireux DA, Mong JA, Hertzano R. Sex differences in hearing: Probing the role of estrogen signaling. The Journal of the Acoustical Society of America. 2019;145(6):3656.31255106
509 Shue SA, McGuire AB, Matthias MS. Facilitators and Barriers to Implementation of a Peer Support Intervention for Patients with Chronic Pain: A Qualitative Study. Pain Medicine. 2019;20(7):1311–1320.30481295
510 Shiner B, Gui J, Leonard Westgate C, . Using patient-reported outcomes to understand the effectiveness of guideline-concordant care for post-traumatic stress disorder in clinical practice. Journal of Evaluation in Clinical Practice. 2019;25(4):689–699.31115137
511 Segars JH. Reproductive Health Needs of the Military and Veterans, Part 2. Semin Reprod Med. 2019;37(1):1–2.31585467
512 Segars JH. Reproductive Health Needs of the Military and Veterans, Part 3. Semin Reprod Med. 2019;37(5–06):207–208.32645742
513 Scoglio AAJ, Shirk SD, Mazure C, . It all adds up: Addressing the roles of cumulative traumatic experiences on military veterans. Child Abuse and Neglect. 2019;98.
514 Schmidt EM, Barnes J, Chen C, . Patient and Health Care Factors Associated With Long-term Diabetes Complications Among Adults With and Without Mental Health and Substance Use Disorders. JAMA Network Open. 2019;2(9):e1912060–e1912060.31553472
515 Schifman RB, Luevano DR. Value and Use of Urinalysis for Myoglobinuria. Archives of Pathology & Laboratory Medicine. 2019;143(11):1378–1381.31116043
516 Ronzitti S, Kraus SW, Decker SE, Ashrafioun L. Clinical characteristics of veterans with gambling disorders seeking pain treatment. Addictive Behaviors. 2019;95:160–165.30925440
517 Rogal SS, Beste LA, Youk A, . Characteristics of Opioid Prescriptions to Veterans With Cirrhosis. Clinical Gastroenterology and Hepatology. 2019;17(6):1165–1174.e3.30342261
518 Riordan JKDNPFNPBCLTC, Alexander SDNPANPBCADMBC, Montgomery ISDNPFNPBCLTC. Use of technology to increase physical activity in female veterans and soldiers aged 19-64 years. Journal of the American Association of Nurse Practitioners. 2019;31(10):575–582.31567835
519 Piuzzi NS, Strnad GJ, Ali Sakr Esa W, . The Main Predictors of Length of Stay after Total Knee Arthroplasty: Patient-Related or Procedure-Related Risk Factors. Journal of Bone and Joint Surgery - American Volume. 2019;101(12):1093–1101.31220026
520 Peacock KS, Stoerkel E, Libretto S, . A randomized trial comparing the Tennant Biomodulator to transcutaneous electrical nerve stimulation and traditional Chinese acupuncture for the treatment of chronic pain in military service members. Military Medical Research. 2019;6(1).
521 Park S, Je NK. Factors That Affect Time to Switch From Warfarin to a Direct Oral Anticoagulant After Change in the Reimbursement Criteria in Patients With Atrial Fibrillation. Journal of Cardiovascular Pharmacology and Therapeutics. 2019.
522 Papaleontiou M, Banerjee M, Reyes-Gastelum D, . Risk of Osteoporosis and Fractures in Patients with Thyroid Cancer: A Case-Control Study in U.S. Veterans. Oncologist. 2019;24(9):1166–1173.31164453
523 Pan LF, Wang PH, Lin LT, . Factors that influence infertile couples’ selection of reproductive medicine centers—A cross-sectional questionnaire study. Taiwanese Journal of Obstetrics and Gynecology. 2019;58(5):633–639.31542084
524 Ozieh MN, Gebregziabher M, Ward RC, . Creating a 13-year National Longitudinal Cohort of veterans with chronic kidney disease. BMC Nephrology. 2019;20(1):N.PAG-N.PAG.
525 Nouri SS, Barnes DE, Volow AM, . Health Literacy Matters More Than Experience for Advance Care Planning Knowledge Among Older Adults. Journal of the American Geriatrics Society. 2019;67(10):2151–2156.31424575
526 Nenova Z, Hotchkiss J. Appointment utilization as a trigger for palliative care introduction: A retrospective cohort study. Palliative Medicine. 2019;33(4):457–461.30747040
527 Mull HJ, Rosen AK, Charns MR, . Emergency Department Use After Outpatient Surgery Among Dually Enrolled VA and Medicare Patients. Quality Management in Health Care. 2019;28(4):191–199.31567842
528 Morland LA, Wells SY, Glassman LH, . What Do Veterans Want? Understanding Veterans’ Preferences for PTSD Treatment Delivery. Military medicine. 2019;184(11–12):686–692.30839067
529 Monteith LL, Holliday R, Schneider AL, . Identifying factors associated with suicidal ideation and suicide attempts following military sexual trauma. Journal of Affective Disorders. 2019;252:300–309.30991258
530 Mikolić A, Polinder S, Retel Helmrich IRA, . Treatment for posttraumatic stress disorder in patients with a history of traumatic brain injury: A systematic review. Clinical Psychology Review. 2019;73.
531 Meffert BN, Morabito DM, Sawicki DA, . US Veterans Who Do and Do Not Utilize Veterans Affairs Health Care Services: Demographic, Military, Medical, and Psychosocial Characteristics. The primary care companion for CNS disorders. 2019;21(1).
532 McCulley CB, Barton JL, Cannon GW, . Body mass index and persistence of conventional DMARDs and TNF inhibitors in rheumatoid arthritis. Clinical and experimental rheumatology. 2019;37(3):422–428.30418120
533 McCarthy MS, Hoffmire C, Brenner LA, Nazem S. Sleep and timing of death by suicide among U.S. Veterans 2006-2015: Analysis of the American Time Use Survey and the National Violent Death Reporting System. Sleep. 2019;42(8):1–8.
534 Maskin RM, Iverson KM, Vogt D, Smith BN. Associations Between Intimate Partner Violence Victimization and Employment Outcomes Among Male and Female Post-9/11 Veterans. Psychological Trauma: Theory, Research, Practice & Policy. 2019;11(4):406–414.30372099
535 Maguen S, Li Y, Madden E, . Factors associated with completing evidence-based psychotherapy for PTSD among veterans in a national healthcare system. Psychiatry Research. 2019;274:112–128.30784780
536 Luciano MT, McDevitt-Murphy ME, Acuff SF, . Posttraumatic Stress Disorder Symptoms Improve After an Integrated Brief Alcohol Intervention for OEF/OIF/OND Veterans. Psychological Trauma: Theory, Research, Practice & Policy. 2019;11(4):459–465.29939060
537 Lifshitz J, Crabtree-Nelson S, Kozlowski DA. Traumatic Brain Injury in Victims of Domestic Violence. Journal of Aggression, Maltreatment & Trauma. 2019;28(6):655–659.
538 Liang SY, Jackson B, Kuhn J, . Urinary Tract Infections after Combat-Related Genitourinary Trauma. Surgical Infections. 2019;20(8):611–618.31112074
539 Lerman BJ, Popat RA, Assimes TL, . Association of Left Ventricular Ejection Fraction and Symptoms With Mortality After Elective Noncardiac Surgery Among Patients With Heart Failure. JAMA: Journal of the American Medical Association. 2019;321(6):572–579.30747965
540 Lentscher JA, Combs JC, Walker K, . Postdeployment Fertility Challenges and Treatment in the Modern Era. Seminars in Reproductive Medicine. 2019;37(5–6):239–245.32588419
541 Lee LO, James P, Zevon ES, . Optimism is associated with exceptional longevity in 2 epidemiologic cohorts of men and women. Proc Natl Acad Sci U S A. 2019;116(37):18357–18362.31451635
542 LaPosta GMP, Creech SK, Macdonald A, Taft CT. Predictors of Session Attendance in Intimate Partner Violence Treatment for Trauma-Exposed Veterans. Partner Abuse. 2019;10(3):283–297.
543 Korinek K, Teerawichitchainan B, Zimmer Z, . Design and measurement in a study of war exposure, health, and aging: protocol for the Vietnam health and aging study. BMC Public Health. 2019;19(1):N.PAG-N.PAG.
544 Kim JC, Matto M, Kristen E. Safer Housing for Homeless Women Veterans. The journal of the American Academy of Psychiatry and the Law. 2019;47(3):299–306.31186363
545 Kheirbek RE, Alemi Y, Wojtusiak J, . Impact of Hospice and Palliative Care Service Utilization on All-Cause 30-Day Readmission Rate for Older Adults Hospitalized with Heart Failure. American Journal of Hospice & Palliative Medicine. 2019;36(7):623–629.30773029
546 Kenny DJ, Yoder LH. A picture of the older homeless female veteran: A qualitative, case study analysis. Archives of Psychiatric Nursing. 2019;33(4):400–406.31280786
547 Kelley ML, Braitman AL, White TD, Ehlke SJ. Sex differences in mental health symptoms and substance use and their association with moral injury in veterans. Psychological Trauma: Theory, Research, Practice & Policy. 2019;11(3):337–344.30234322
548 Kauth MR, Barrera TL, Latini DM. Lesbian, gay, and transgender veterans’ experiences in the Veterans Health Administration: Positive signs and room for improvement. Psychological services. 2019;16(2):346–351.29369658
549 Juraschek SP, Simpson LM, Davis BR, . Effects of Antihypertensive Class on Falls, Syncope, and Orthostatic Hypotension in Older Adults: The ALLHAT Trial. Hypertension (0194911X). 2019;74(4):1033–1040.
550 Jackson C, Weiss BJ, Cloitre M. STAIR Group Treatment for Veterans with PTSD: Efficacy and Impact of Gender on Outcome. Military Medicine. 2019;184(1/2):e143–e147.
551 Iverson KM, Dardis CM, Grillo AR, . Associations between traumatic brain injury from intimate partner violence and future psychosocial health risks in women. Comprehensive Psychiatry. 2019;92:13–21.31203176
552 Hung YC, Lee CC, Guo WY, . Gamma knife radiosurgery for the treatment of cavernous sinus meningiomas: post-treatment long-term clinical outcomes, complications, and volume changes. Journal of Neuro-Oncology. 2019;143(2):261–270.31020456
553 Hugin M, Shaw JG. Obstetric Outcomes in US. Veterans: Emerging Knowledge, Considerations, and Gaps. Seminars in Reproductive Medicine. 2019;37(1):17–23.31185514
554 Huang GD, Ramoni RB. Evidence-Based Care for Women Veterans: A Burgeoning Effort in the Department of Veterans Affairs Healthcare System. Womens Health Issues. 2019;29 Suppl 1:S6–S8.31253244
555 Hsiung J-T, Kleine C-E, Naderi N, . Association of Pre-End-Stage Renal Disease Serum Albumin With Post-End-Stage Renal Disease Outcomes Among Patients Transitioning to Dialysis. Journal of Renal Nutrition. 2019:N.PAG-N.PAG.
556 Holder N, Holliday R, Wiblin J, Suris A. A Preliminary Examination of the Effect of Cognitive Processing Therapy on Sleep Disturbance Among Veterans with Military Sexual Trauma-Related Posttraumatic Stress Disorder. Traumatology. 2019;25(4):316–323.31275080
557 Himmelstein DU, Woolhandler S, Fauke C. Health Care Crisis by the Numbers. International Journal of Health Services. 2019;49(4):697–711.31422753
558 Harrison-Brown M, Scholes C, Ebrahimi M, . Predicting changes in the status of patient-reported outcome measures after Birmingham Hip Resurfacing: An observational cohort study with a median follow-up of ten years. Bone and Joint Journal. 2019;101-B(11):1431–1437.31674251
559 Harris AHS, Meerwijk EL, Kamal RN, . Variability and Costs of Low-Value Preoperative Testing for Carpal Tunnel Release Surgery. Anesthesia and Analgesia. 2019;129(3):804–811.31425223
560 Harb GC, Cook JM, Phelps AJ, . Randomized controlled trial of imagery rehearsal for posttraumatic nightmares in combat veterans. Journal of Clinical Sleep Medicine. 2019;15(5):757–767.31053215
561 Han DS, Lynch KE, Chang Jw, . Overuse of Cystoscopic Surveillance Among Patients With Low-risk Non-Muscle-invasive Bladder Cancer - A National Study of Patient, Provider, and Facility Factors. Urology. 2019;131:112–119.31145947
562 Gyamlani G, Potukuchi Praveen K, Thomas F, . Vancomycin-Associated Acute Kidney Injury in a Large Veteran Population. American Journal of Nephrology. 2019;49(2):133–142.30677750
563 Goldstein KM, Bastian LA, Duan-Porter W, . Accelerating the Growth of Evidence-Based Care for Women and Men Veterans. Womens Health Issues. 2019;29 Suppl 1:S2–S5.31253238
564 Gallegos Salazar J, O’Brien W, Strymish JM, . Association of Screening and Treatment for Preoperative Asymptomatic Bacteriuria With Postoperative Outcomes Among US Veterans. JAMA Surgery. 2019;154(3):241–248.30540346
565 Fredman SJ, Marshall AD, Yunying L, . Interpersonal Relationship Quality Mediates the Association Between Military-Related Posttraumatic Stress and Academic Dysfunction Among Student Veterans. Psychological Trauma: Theory, Research, Practice & Policy. 2019;11(4):415–423.29723031
566 Etingen B, Hogan TP, Martinez RN, . How Do Patients with Mental Health Diagnoses Use Online Patient Portals? An Observational Analysis from the Veterans Health Administration. Administration and policy in mental health. 2019;46(5):596–608.31065908
567 Edmonds SW, Zephyrin LC, Christy A, Ryan GL. Infertility Services for Veterans: Policies, Challenges, and Opportunities. Seminars in Reproductive Medicine. 2019;37(1):12–16.31185513
568 Demb J, Earles A, Martínez ME, . Risk factors for colorectal cancer significantly vary by anatomic site. BMJ Open Gastroenterology. 2019;6(1).
569 Davis LL, Whetsell C, Hamner MB, . A multisite randomized controlled trial of mindfulness-based stress reduction in the treatment of posttraumatic stress disorder. Psychiatric Research and Clinical Practice. 2019;1(2):39–48.34113802
570 Coughlin SS, Heboyan V, Sullivan K, . Cardiovascular Disease among Female Veterans of the 1991 Gulf War Era. J. 2019;5(1):24–25.
571 Cooper M, Yaqub M, Hinds JT, Perry CL. A longitudinal analysis of tobacco use in younger and older U.S. veterans. Preventive Medicine Reports. 2019;16.
572 Christy AY, Mottla GL. Reproductive Health Needs of the Military and Veterans: Part 3. Semin Reprod Med. 2019;37(5–06):209–210.32693430
573 Christy AY. Reproductive Health Needs of the Military and Veterans. Semin Reprod Med. 2019;37(1):3–4.31556092
574 Chermack ST, Bonar EE, Goldstick JE, . A randomized controlled trial for aggression and substance use involvement among Veterans: Impact of combining Motivational Interviewing, Cognitive Behavioral Treatment and telephone-based Continuing Care. Journal of Substance Abuse Treatment. 2019;98:78–88.30665608
575 Brunner J, Cain CL, Yano EM, Hamilton AB. Local Leaders’ Perspectives on Women Veterans’ Health Care: What Would Ideal Look Like? Women’s Health Issues. 2019;29(1):64–71.30455089
576 Brickell TA, Reid MW, French LM, . Factor analysis of the caregiver appraisal scale in military TBI. Rehabilitation Psychology. 2019;64(3):366–376.30896246
577 Brickell TA, French LM, Gartner RL, . Factors Related to Perceived Burden Among Caregivers of Service Members/Veterans Following TBI. Rehabilitation Psychology. 2019;64(3):307–319.30896245
578 Branch-Elliman W, Pizer SD, Dasinger EA, . Facility type and surgical specialty are associated with suboptimal surgical antimicrobial prophylaxis practice patterns: A multi-center, retrospective cohort study. Antimicrobial Resistance and Infection Control. 2019;8(1).
579 Branch-Elliman W, O’Brien W, Strymish J, . Association of Duration and Type of Surgical Prophylaxis With Antimicrobial-Associated Adverse Events. JAMA Surgery. 2019;154(7):590–598.31017647
580 Boehler J. The Efficacy of Cognitive Processing Therapy for PTSD Related to Military Sexual Trauma in Veterans: A Review. Journal of evidence-based social work (2019). 2019;16(6):595–614.32459157
581 Blais RK, Monteith LL. Suicide Ideation in Female Survivors of Military Sexual Trauma: The Trauma Source Matters. Suicide & Life-Threatening Behavior. 2019;49(3):643–652.29676496
582 Blais RK, Geiser C. Depression and PTSD-related anhedonia mediate the association of military sexual trauma and suicidal ideation in female service members/veterans. Psychiatry Research. 2019;279:148–154.31128854
583 Bevans M, Clayton JA. Integrating the Influence of Sex and Gender in Research: Keeping Women Veterans in Focus. Womens Health Issues. 2019;29 Suppl 1:S9–S11.31253248
584 Bennett DC, Thomas EJ, Porter KE, . Context Matters: Posttraumatic Stress Disorder Symptom Associations With Military Sexual Trauma Event Characteristics and Dual Histories of Interpersonal Trauma. Violence & Victims. 2019;34(1):69–84.30808794
585 Beckman JA, Duncan MS, Damrauer SM, . Microvascular Disease, Peripheral Artery Disease, and Amputation. Circulation. 2019;140(6):449–458.31280589
586 Bauer MS, Miller CJ, Kim B, . Effectiveness of Implementing a Collaborative Chronic Care Model for Clinician Teams on Patient Outcomes and Health Status in Mental Health: A Randomized Clinical Trial. JAMA Network Open. 2019;2(3):e190230–e190230.30821830
587 Andresen FJ, Blais RK. Higher Self-Stigma is Related to Lower Likelihood of Disclosing Military Sexual Trauma During Screening in Female Veterans. Psychological Trauma: Theory, Research, Practice & Policy. 2019;11(4):372–378.30284856
588 Alore EA, Suliburk JW, Ramsey DJ, . Diagnosis and Management of Primary Hyperparathyroidism Across the Veterans Affairs Health Care System. JAMA Internal Medicine. 2019;179(9):1220–1227.31305864
589 Wu AM, Wu CM, Tseng VL, . Characteristics Associated With Receiving Cataract Surgery in the US Medicare and Veterans Health Administration Populations. JAMA Ophthalmology. 2018;136(7):738–745.29800973
590 Won CHJ, Qin L, Selim B, Yaggi HK. Varying hypopnea definitions affect obstructive sleep apnea severity classification and association with cardiovascular disease. Journal of Clinical Sleep Medicine. 2018;14(12):1987–1994.30518445
591 Williams JB, Weiner H, Tyser AR. Long-Term Outcome and Secondary Operations after Proximal Row Carpectomy or Four-Corner Arthrodesis. Journal of Wrist Surgery. 2018;7(1):51–56.29383276
592 Westover AN, Nakonezny PA, Halm EA, Adinoff B. Risk of amphetamine use disorder and mortality among incident users of prescribed stimulant medications in the Veterans Administration. Addiction. 2018;113(5):857–867.29215762
593 Weisbord SD, Gallagher M, Jneid H, . Outcomes after Angiography with Sodium Bicarbonate and Acetylcysteine. New England Journal of Medicine. 2018;378(7):603–614.29130810
594 Wahl TS, Graham LA, Morris MS, . Association Between Preoperative Proteinuria and Postoperative Acute Kidney Injury and Readmission. JAMA Surgery. 2018;153(9):e182009–e182009.29971429
595 Vest BM, Homish DL, Fillo J, Homish GG. Military status and alcohol problems: Former soldiers may be at greater risk. Addictive Behaviors. 2018;84:139–143.29679924
596 Vassy JL, Brunette CA, Majahalme N, . The Integrating Pharmacogenetics in Clinical Care (I-PICC) Study: Protocol for a point-of-care randomized controlled trial of statin pharmacogenetics in primary care. Contemporary Clinical Trials. 2018;75:40–50.30367991
597 Strigo IA, Spadoni AD, Inslicht SS, Simmons AN. Repeated Exposure to Experimental Pain Differentiates Combat Traumatic Brain Injury with and without Post-Traumatic Stress Disorder. Journal of Neurotrauma. 2018;35(2):297–307.28931334
598 Stoerkel E, Bellanti D, Paat C, . Effectiveness of A Self-Care. Journal of Alternative and Complementary Medicine. 2018;24(9–10):916–925.30247967
599 Starr J, Rozet I, Ben-Ari A. A Risk Calculator Using Preoperative Opioids for Prediction of Total Knee Revision Arthroplasty. Clinical Journal of Pain. 2018;34(4):328–331.28915156
600 Srivastava P, Butler J, Shroyer AL, . Impact of Depressive Disorder on Access and Quality of Care in Veterans With Prevalent Cardiovascular Disease. American Journal of Cardiology. 2018;121(12):1629–1633.29606323
601 Spece LJ, Epler EM, Donovan LM, . Role of Comorbidities in Treatment and Outcomes after Chronic Obstructive Pulmonary Disease Exacerbations. Annals of the American Thoracic Society. 2018;15(9):1033–1038.30079748
602 Sloan DM, Marx BP, Lee DJ, Resick PA. A Brief Exposure-Based Treatment vs Cognitive Processing Therapy for Posttraumatic Stress Disorder: A Randomized Noninferiority Clinical Trial. JAMA Psychiatry. 2018;75(3):233–239.29344631
603 Singh M, Raghavan D, Williams JS, . Prevalence of Chronic Kidney Disease, Thrombotic Cardiovascular Events, and Use of Oral P2Y12 Inhibitors among Veterans. American Journal of Nephrology. 2018;47(2):67–71.29393120
604 Shea MT, Lambert J, Reddy MK, . Treatment of trauma related anger in operation enduring freedom, operation Iraqi freedom, and operation New Dawn veterans: Rationale and study protocol. Contemporary Clinical Trials Communications. 2018;12:26–31.30225391
605 Shayegani R, Song K, Amuan ME, . Patterns of zolpidem use among Iraq and Afghanistan veterans: A retrospective cohort analysis. PLoS ONE. 2018;13(1).
606 Ross J, Waterhouse-Bradley B, Contractor AA, Armour C. Typologies of adverse childhood experiences and their relationship to incarceration in U.S. military veterans. Child Abuse Negl. 2018;79:74–84.29426037
607 Rodriguez F, Knowles JW, Maron DJ, . Frequency of Statin Use in Patients With Low-Density Lipoprotein Cholesterol ≥190 mg/dl from the Veterans Affairs Health System. American Journal of Cardiology. 2018;122(5):756–761.30055758
608 Rhee CM, Kovesdy CP, Ravel VA, . Glycemic Status and Mortality in Chronic Kidney Disease According to Transition Versus Nontransition to Dialysis. Journal of Renal Nutrition. 2018:N.PAG-N.PAG.
609 Raskind MA, Peskind ER, Chow B, . Trial of Prazosin for Post-Traumatic Stress Disorder in Military Veterans. New England Journal of Medicine. 2018;378(6):507–217.29414272
610 Pourafkari L, Arora P, Porhomayon J, . Acute kidney injury after non-cardiovascular surgery: risk factors and impact on development of chronic kidney disease and long-term mortality. Current Medical Research & Opinion. 2018;34(10):1829–1837.29613817
611 Patros C, Sabol M, Paniagua A, Lans D. Implementation and evaluation of an algorithm-based order set for the outpatient treatment of urinary tract infections in the spinal cord injury population in a VA Medical Center. Journal of Spinal Cord Medicine. 2018;41(2):192–198.28571529
612 Park LS, Tate JP, Sigel K, . Association of viral suppression with lower aids-defining and non–AIDS-defining cancer incidence in HIV-infected veterans: A prospective cohort study. Annals of Internal Medicine. 2018;169(2):87–96.29893768
613 Obi Y, Nguyen DV, Zhou H, . Development and Validation of Prediction Scores for Early Mortality at Transition to Dialysis. Mayo Clinic Proceedings. 2018;93(9):1224–1235.30104041
614 Niznik JD, Zhang S, Mor MK, . Adaptation and Initial Validation of Minimum Data Set (MDS) Mortality Risk Index to MDS Version 3.0. Journal of the American Geriatrics Society. 2018;66(12):2353–2359.30335184
615 Najavits LM, Krinsley K, Waring ME, . A Randomized Controlled Trial for Veterans with PTSD and Substance Use Disorder: Creating Change versus Seeking Safety. Substance Use & Misuse. 2018;53(11):1788–1800.29461920
616 Nadpara PA, Joyce AR, Murrelle EL, . Risk Factors for Serious Prescription Opioid-Induced Respiratory Depression or Overdose: Comparison of Commercially Insured and Veterans Health Affairs Populations. Pain Medicine. 2018;19(1):79–96.28419384
617 Murff HJ, Roumie CL, Greevy RA, . Metformin use and incidence cancer risk: evidence for a selective protective effect against liver cancer. Cancer Causes & Control. 2018;29(9):823–832.30022336
618 Mosher CA, Brown GR, Weideman RA, . Incidence of Colorectal Cancer and Extracolonic Cancers in Veteran Patients With Inflammatory Bowel Disease. Inflammatory Bowel Diseases. 2018;24(3):617–623.29390104
619 Morris DH, Davis AK, Lauritsen KJ, . Substance use consequences, mental health problems, and readiness to change among Veterans seeking substance use treatment. Journal of Substance Abuse Treatment. 2018;94:113–121.30243411
620 Moreau JL, Cordasco KM, Young AS, . The Use of Telemental Health to Meet the Mental Health Needs of Women Using Department of Veterans Affairs Services. Women’s Health Issues. 2018;28(2):181–187.29339013
621 Metrik J, Gunn RL, Jackson KM, . Daily Patterns of Marijuana and Alcohol Co-Use Among Individuals with Alcohol and Cannabis Use Disorders. Alcoholism: Clinical & Experimental Research. 2018;42(6):1096–1104.29656401
622 McManus ES, Cuccurullo LJ, Uddo M, Franklin CL. MMPI-2-RF characteristics of veterans seeking treatment for military sexual trauma. Psychol Assess. 2018;30(4):561–566.29672106
623 McCabe JE, Katon JG, Ma E, . Preconception Health Risk Factors in Women with and without a History of Military Service. Women’s Health Issues. 2018;28(6):539–545.30314907
624 Maule AL, Janulewicz PA, Sullivan KA, . Meta-analysis of self-reported health symptoms in 1990-1991 Gulf War and Gulf War-era veterans. BMJ Open. 2018;8(2).
625 Markossian TW, Suda KJ, Abderhalden L, . Characteristics and medication use of veterans in medicare advantage plans. American Journal of Managed Care. 2018;24(5):247–255.29851441
626 Marcum ZA, Forsberg CW, Moore KP, . Mortality Associated with Metformin Versus Sulfonylurea Initiation: A Cohort Study of Veterans with Diabetes and Chronic Kidney Disease. JGIM: Journal of General Internal Medicine. 2018;33(2):155–165.29181788
627 Lucas CL, Goldbach JT, Mamey MR, . Military Sexual Assault as a Mediator of the Association Between Posttraumatic Stress Disorder and Depression Among Lesbian, Gay, and Bisexual Veterans. Journal of Traumatic Stress. 2018;31(4):613–619.30088291
628 Lippa SM, Brickell TA, Bailie JM, . Postconcussion Symptom Reporting After Mild Traumatic Brain Injury in Female Service Members: Impact of Gender, Posttraumatic Stress Disorder, Severity of Injury, and Associated Bodily Injuries. Journal of Head Trauma Rehabilitation. 2018;33(2):101–112.29084103
629 Lerner F. The Smith College Program in Psychiatric Social Work: A Pioneering Contribution to Veteran Mental Health. Smith College Studies in Social Work (Taylor & Francis Ltd). 2018;88(3):185–210.
630 Lee DJ, Kearns JC, Wisco BE, . A longitudinal study of risk factors for suicide attempts among Operation Enduring Freedom and Operation Iraqi Freedom veterans. Depression & Anxiety (1091-4269). 2018;35(7):609–618.29637667
631 Leapman MS, Derycke E, Skanderson M, . Variation in national opioid prescribing patterns following surgery for kidney stones. Pain Medicine (United States). 2018;19:S12–S18.
632 LaVaccare S, Diamant AL, Friedman J, . Healthcare Experiences of Underrepresented Lesbian and Bisexual Women: A Focus Group Qualitative Study. Health Equity. 2018;2(1):131–138.30283859
633 Kravitz RL, Schmid CH, Marois M, . Effect of Mobile Device-Supported Single-Patient Multi-crossover Trials on Treatment of Chronic Musculoskeletal Pain: A Randomized Clinical Trial. JAMA Internal Medicine. 2018;178(10):1368–1377.30193253
634 Kleine CE, Soohoo M, Ranasinghe ON, . Association of Pre-End-Stage Renal Disease Hemoglobin with Early Dialysis Outcomes. American Journal of Nephrology. 2018;47(5):333–342.29779027
635 Jones AL, Thomas R, Hedayati DO, . Patient predictors and utilization of health services within a medical home for homeless persons. Substance Abuse. 2018;39(3):354–360.29412071
636 Hudson TJ, Painter JT, Gressler LE, . Factors Associated with Opioid Initiation in OEF/OIF/OND Veterans with Traumatic Brain Injury. Pain Medicine. 2018;19(4):774–787.29036680
637 Hostetter TA, Schneider AL, Bahraini NH, . A Rasch analysis of the Neurobehavioral Symptom Inventory in a national cohort of Operation Enduring and Iraqi Freedom veterans with mild traumatic brain injury. Psychological Assessment. 2018;30(8):1013–1027.29878819
638 Holliday R, Smith NB, Monteith LL. An initial investigation of nonsuicidal self-injury among male and female survivors of military sexual trauma. Psychiatry Research. 2018;268:335–339.30096662
639 Holder N, Holliday R, Williams R, . A preliminary examination of the role of psychotherapist fidelity on outcomes of cognitive processing therapy during an RCT for military sexual trauma-related PTSD. Cognitive behaviour therapy. 2018;47(1):76–89.28793834
640 Hartz SM, Oehlert M, Horton AC, . Daily Drinking Is Associated with Increased Mortality. Alcoholism: Clinical & Experimental Research. 2018;42(11):2246–2255.30281161
641 Hallett LD, Gerber MR. Human Papillomavirus Testing by Veterans Administration Women’s Health Providers: Are They Adhering to Guidelines? Journal of Women’s Health (15409996). 2018;27(2):179–182.
642 Ha LD, Elbadawi A, Froelicher VF. Limited Relationship of Voltage Criteria for Electrocardiogram Left Ventricular Hypertrophy to Cardiovascular Mortality. American Journal of Medicine. 2018;131(1):101.e1–101.e8.
643 Gupta S, Liu L, Patterson OV, . A Framework for Leveraging “Big Data” to Advance Epidemiology and Improve Quality: Design of the VA Colonoscopy Collaborative. EGEMS (Wash DC). 2018;6(1):4.29881762
644 Grubbs KM, Fortney JC, Pyne J, . A comparison of collaborative care outcomes in two health care systems: VA clinics and federally qualified health centers. Psychiatric Services. 2018;69(4):431–437.29334874
645 Goodman P. Keeping the Promise to Women Veterans. Journal for Nurse Practitioners. 2018;14(10):763–764.
646 Gobin RL, Mackintosh MA, Willis E, . Predictors of differential PTSD treatment outcomes between veteran and civilian women after cognitive processing therapy. Psychological trauma : theory, research, practice and policy. 2018;10(2):173–182.28414493
647 Gerber MR, Bogdan KM, Haskell SG, Scioli ER. Experience of Childhood Abuse and Military Sexual Trauma Among Women Veterans with Fibromyalgia. Journal of General Internal Medicine. 2018;33(12):2030–2031.30076571
648 Gawron LM, Mohanty AF, Kaiser JE, Gundlapalli AV. Impact of Deployment on Reproductive Health in US. Active-Duty Servicewomen and Veterans. Seminars in Reproductive Medicine. 2018;36(6):361–370.31003251
649 Garner W, Wilson BM, Beste L, . Gaps in Preexposure Prophylaxis Uptake for HIV Prevention in the Veterans Health Administration. American Journal of Public Health. 2018;108:S305–S310.30383417
650 Eyawo O, McGinnis KA, Justice AC, . Alcohol and Mortality: Combining Self-Reported (AUDIT-C) and Biomarker Detected (PEth) Alcohol Measures among HIV Infected and Uninfected. Journal of Acquired Immune Deficiency Syndromes. 2018;77(2):135–143.29112041
651 Elbogen EB, Wagner HR, Kimbrel NA, . Risk factors for concurrent suicidal ideation and violent impulses in military veterans. Psychological Assessment. 2018;30(4):425–435.28627921
652 Edmond SN, Becker WC, Driscoll MA, . Use of Non-Pharmacological Pain Treatment Modalities Among Veterans with Chronic Pain: Results from a Cross-Sectional Survey. JGIM: Journal of General Internal Medicine. 2018;33:54–60.29633141
653 Davis LL, Kyriakides TC, Suris A, . Veterans Individual Placement and Support Towards Advancing Recovery: Methods and Baseline Clinical Characteristics of a Multisite Study. Psychiatric Rehabilitation Journal. 2018;41(1):55–66.28358525
654 Davis AK, Lin LA, Ilgen MA, Bohnert KM. Recent cannabis use among Veterans in the United States: Results from a national sample. Addictive Behaviors. 2018;76:223–228.28858694
655 Coughlin SS, Young L. A review of dual health care system use by veterans with cardiometabolic disease. J Hosp Manag Health Policy. 2018;2.
656 Connolly SL, Stoop TB, Logue MW, . Posttraumatic Stress Disorder Symptoms, Temperament, and the Pathway to Cellular Senescence. Journal of Traumatic Stress. 2018;31(5):676–686.30338579
657 Conard PL, Armstrong ML. Nursing Care of Women Veterans of the Iraq and Afghanistan Wars. Nursing for Women’s Health. 2018;22(2):158–173.
658 Burney R, Christy AY. Reproductive Health Needs of the Military and Veterans: Part 1. Semin Reprod Med. 2018;36(6):313–314.31003245
659 Bui E, Blackburn AM, Brenner LH, . Military and Veteran Caregivers’ Perspectives of Stressors and a Mind-Body Program. Issues in Mental Health Nursing. 2018;39(10):850–857.30212258
660 Brickell TA, French LM, Lippa SM, Lange RT. Characteristics and Health Outcomes of Post-9/11 Caregivers of US Service Members and Veterans Following Traumatic Brain Injury. Journal of Head Trauma Rehabilitation. 2018;33(2):133–145.29517593
661 Blais RK, Monteith LL, Kugler J. Sexual dysfunction is associated with suicidal ideation in female service members and veterans. Journal of Affective Disorders. 2018;226:52–57.28961442
662 Blais RK, Geiser C, Cruz RA. Specific PTSD symptom clusters mediate the association of military sexual trauma severity and sexual function and satisfaction in female service members/veterans. Journal of Affective Disorders. 2018;238:680–688.30029163
663 Bekelman DB, Allen LA, McBryde CF, . Effect of a Collaborative Care Intervention vs Usual Care on Health Status of Patients With Chronic Heart Failure: The CASA Randomized Clinical Trial. JAMA Internal Medicine. 2018;178(4):511–519.29482218
664 Barnes DE, Byers AL, Gardner RC, . Association of mild traumatic brain injury with and without loss of consciousness with dementia in US military veterans. JAMA Neurology. 2018;75(9):1055–1061.29801145
665 Bannister JA, Lopez FG, Menefee DS, . Military and Premilitary Trauma, Attachment Orientations, and Posttraumatic Stress Disorder Severity Among Male and Female Veterans. Journal of Traumatic Stress. 2018;31(4):558–567.30091801
666 Arya S, Binney Z, Khakharia A, . Race and Socioeconomic Status Independently Affect Risk of Major Amputation in Peripheral Artery Disease. Journal of the American Heart Association. 2018:1–12.
667 Armenta RF, Rush T, LeardMann CA, . Factors associated with persistent posttraumatic stress disorder among U.S. military service members and veterans. BMC Psychiatry. 2018;18(1).
668 Ahlin EM, Douds AS. Many Shades of Green: Assessing Awareness of Differences in Mental Health Care Needs Among Subpopulations of Military Veterans. International Journal of Offender Therapy & Comparative Criminology. 2018;62(10):3168–3184.28770637
669 Abel EA, Shimada SL, Wang K, . Dual Use of a Patient Portal and Clinical Video Telehealth by Veterans with Mental Health Diagnoses: Retrospective, Cross-Sectional Analysis. Journal of Medical Internet Research. 2018;20(11):1–1.
670 Aase DM, Babione JM, Proescher E, . Impact of PTSD on post-concussive symptoms, neuropsychological functioning, and pain in post-9/11 veterans with mild traumatic brain injury. Psychiatry Research. 2018;268:460–466.30138858
671 Anonymous. 2018 Congress on Cardiovascular Disease Prevention. Clinical Cardiology. 2018;41.
672 Yano EM, Hamilton AB. Accelerating delivery of trauma-sensitive care: Using multilevel stakeholder engagement to improve care for women veterans. Families, Systems & Health: The Journal of Collaborative Family HealthCare. 2017;35(3):373–375.
673 Wallace D, Heffernan K. The changing face of posttraumatic stress disorder in modern warfare. Australasian Psychiatry. 2017;25(4):336–338.28747109
674 Wahl TS, Graham LA, Hawn MT, . Association of the Modified Frailty Index With 30-Day Surgical Readmission. JAMA Surgery. 2017;152(8):749–757.28467535
675 Vora AN, Stanislawski M, Grunwald GK, . Association Between Chronic Kidney Disease and Rates of Transfusion and Progression to End-Stage Renal Disease in Patients Undergoing Transradial Versus Transfemoral Cardiac Catheterization-An Analysis From the Veterans Affairs Clinical Assessment Reporti. Journal of the American Heart Association. 2017;6(4):1-N.PAG.
676 Turban JL, Potenza MN, Hoff RA, . Psychiatric disorders, suicidal ideation, and sexually transmitted infections among post-deployment veterans who utilize digital social media for sexual partner seeking. Addictive Behaviors. 2017;66:96–100.27902944
677 Tarlov E, Zenk SN, Matthews SA, . Neighborhood Resources to Support Healthy Diets and Physical Activity Among US Military Veterans. Preventing Chronic Disease. 2017;14:1–14.
678 Sumida K, Molnar MZ, Potukuchi PK, . Blood Pressure Before Initiation of Maintenance Dialysis and Subsequent Mortality. American Journal of Kidney Diseases. 2017;70(2):207–217.28291617
679 Stroupe KT, Bailey L, Gellad WF, . Veterans’ Pharmacy and Health Care Utilization Following Implementation of the Medicare Part D Pharmacy Benefit. Medical Care Research & Review. 2017;74(3):328–344.27091212
680 Stahlman S, Garges EC, Ying S, Clark LL. Rates of Chlamydia trachomatis infections across the deployment cycle, active component, U.S. Armed Forces, 2008-2015. Msmr. 2017;24(1):12–18.
681 Shivakumar G, Anderson EH, Surís AM, North CS. Exercise for PTSD in Women Veterans: A Proof-of-Concept Study. Military Medicine. 2017;182(11):e1809–e1814.29087845
682 Shirazipour CH, Evans MB, Caddick N, . Quality participation experiences in the physical activity domain: Perspectives of veterans with a physical disability. Psychology of Sport & Exercise. 2017;29:40–50.
683 Sexton MB, Raggio GA, McSweeney LB, . Contrasting Gender and Combat Versus Military Sexual Traumas: Psychiatric Symptom Severity and Morbidities in Treatment-Seeking Veterans. Journal of Women’s Health (15409996). 2017;26(9):933–940.
684 Schroeck FR, Sirovich B, Seigne JD, . Assembling and validating data from multiple sources to study care for Veterans with bladder cancer. BMC Urology. 2017;17(1):78–78.28877694
685 Savitz ST, Stearns SC, Zhou L, . A Comparison of Self-reported Medication Adherence to Concordance between Part D Claims and Medication Possession. Medical Care. 2017;55(5):500–505.28221276
686 Ryan G, Thoma M, Stern JE, . Reproductive health risk due to sexual and combat-related trauma in US veterans. Fertility & Sterility. 2017;108:e2–e3.
687 Rubenstein JH, Pohl H, Adams MA, . Overuse of Repeat Upper Endoscopy in the Veterans Health Administration: A Retrospective Analysis. American Journal of Gastroenterology. 2017;112(11):1678–1685.28695907
688 Ruben MA, Blosnich JR, Dichter ME, . Will Veterans Answer Sexual Orientation and Gender Identity Questions? Med Care. 2017;55 Suppl 9 Suppl 2:S85–S89.28806370
689 Roumie CL, Min JY, D’Agostino McGowan L, . Comparative Safety of Sulfonylurea and Metformin Monotherapy on the Risk of Heart Failure: A Cohort Study. Journal of the American Heart Association. 2017;6(4):1-N.PAG.
690 Rodriguez F, Maron DJ, Knowles JW, . Association between intensity of statin therapy and mortality in patients with atherosclerotic cardiovascular disease. JAMA Cardiology. 2017;2(1):47–54.27829091
691 Radell ML, Beck KD, Gilbertson MW, Myers CE. Post-traumatic stress disorder symptom burden and gender each affect generalization in a reward- and punishment-learning task. PLoS ONE. 2017;12(2).
692 Puttnam R, Davis BR, Pressel SL, . Association of 3 different antihypertensive medications with hip and pelvic fracture risk in older adults secondary analysis of a randomized clinical trial. JAMA Internal Medicine. 2017;177(1):67–76.27893045
693 Puttnam R, Davis BR, Pressel SL, . Association of 3 Different Antihypertensive Medications With Hip and Pelvic Fracture Risk in Older Adults: Secondary Analysis of a Randomized Clinical Trial. JAMA Internal Medicine. 2017;177(1):67–76.27893045
694 Pogach L, Chin-Lin T, Orysya S, . A Proposal for an Out-of-Range Glycemic Population Health Safety Measure for Older Adults With Diabetes. Diabetes Care. 2017;40(4):518–525.28325799
695 Perino AC, Fan J, Schmitt SK, . Treating Specialty and Outcomes in Newly Diagnosed Atrial Fibrillation: From the TREAT-AF Study. Journal of the American College of Cardiology (JACC). 2017;70(1):78–86.28662810
696 Park LG, Schopfer DW, Zhang N, . Participation in Cardiac Rehabilitation Among Patients With Heart Failure. Journal of Cardiac Failure. 2017;23(5):427–431.28232047
697 Odden MC, Peralta CA, Berlowitz DR, . Effect of Intensive Blood Pressure Control on Gait Speed and Mobility Limitation in Adults 75 Years or Older: A Randomized Clinical Trial. JAMA Internal Medicine. 2017;177(4):500–507.28166324
698 McCabe C, McCann M, Brady AM. Computer and mobile technology interventions for self-management in chronic obstructive pulmonary disease. Cochrane Database Syst Rev. 2017;5:CD011425.28535331
699 Marshall BDL, Tate JP, McGinnis KA, . Long-term alcohol use patterns and HIV disease severity. AIDS (02699370). 2017;31(9):1313–1321.
700 Markland AD, Burgio KL, Beasley TM, . Psychometric evaluation of an online and paper accidental bowel leakage questionnaire: The ICIQ-B questionnaire. Neurourology and Urodynamics. 2017;36(1):166–170.26473313
701 MacGregor AJ, Clouser MC, Mayo JA, Galarneau MR. Gender Differences in Posttraumatic Stress Disorder Among U.S. Navy Healthcare Personnel. Journal of Women’s Health (15409996). 2017;26(4):338–344.
702 London MJ, Schwartz GG, Kwan H, . Association of Perioperative Statin Use With Mortality and Morbidity After Major Noncardiac Surgery. JAMA Internal Medicine. 2017;177(2):231–242.27992624
703 Leppert JT, Mittakanti HR, Thomas IC, . Contemporary Use of Partial Nephrectomy: Are Older Patients With Impaired Kidney Function Being Left Behind? Urology. 2017;100(1):65–71.27634733
704 LeBlanc MR, Clifford CP, Lathrop SL. Evaluation of Non-Natural Deaths among Veterans: New Mexico Medical Examiner-Investigated Deaths, 2002-2011. Journal of forensic sciences. 2017;62(3):668–673.28000209
705 Kwon JY, Sawatzky R. Examining gender-related differential item functioning of the Veterans Rand 12-item Health Survey. Quality of Life Research. 2017;26(10):2877–2883.28674768
706 Koo K, Schroeck FR, Zubkoff L, . The Burden of Cystoscopic Bladder Cancer Surveillance: Anxiety, Discomfort, and Patient Preferences for Decision Making. Urology. 2017;108(1):122–128.28739405
707 Koenig AF, Zhao X, Callegari LS, . Long-acting reversible contraceptive use among women veterans. Contraception. 2017;96(4):267–267.
708 Kleiber Balderrama C, Rosenthal AK, Lans D, . Calcium Pyrophosphate Deposition Disease and Associated Medical Comorbidities: A National Cross-Sectional Study of US Veterans. Arthritis Care & Research. 2017;69(9):1400–1406.27898996
709 Kinsinger LS, Anderson C, Kim J, . Implementation of lung cancer screening in the Veterans Health Administration. JAMA Internal Medicine. 2017;177(3):399–406.28135352
710 Kim-Dopp M, Gow-Lee V, Ferry L, . QUALITY AND ACCESS TO CARE FOR CARDIOVASCULAR DISEASE PREVALENCE IN WOMEN VETERANS: POPULATION ESTIMATE USING ELECTRONIC HEALTH RECORDS. Journal of the American College of Cardiology (JACC). 2017;69:1865–1865.
711 Keiichi S, Molnar MZ, Potukuchi PK, . Pre-end-stage renal disease visit-to-visit systolic blood pressure variability and post-end-stage renal disease mortality in incident dialysis patients. Journal of Hypertension. 2017;35(9):1816–1824.28399042
712 Jones CE, Graham LA, Morris MS, . Association Between Preoperative Hemoglobin A1c Levels, Postoperative Hyperglycemia, and Readmissions Following Gastrointestinal Surgery. JAMA Surgery. 2017;152(11):1031–1038.28746706
713 Jeon-Slaughter H, Tsai S, Kamath P, . Comparison of Lower Extremity Endovascular Intervention Outcomes in Women Versus Men. American Journal of Cardiology. 2017;119(3):490–496.27887687
714 Hoopsick RA, Homish DL, Homish GG, . Substance use and dependence among current reserve and former military members: Cross-sectional findings from the National Survey on Drug Use and Health, 2010–2014. Journal of Addictive Diseases. 2017;36(4):243–251.28813208
715 Holliday RP, Holder ND, Williamson MLC, Surís A. Therapeutic response to Cognitive Processing Therapy in White and Black female veterans with military sexual trauma-related PTSD. Cognitive behaviour therapy. 2017;46(5):432–446.28485687
716 Hauser P, Fuller B, Ho SB, . The safety and efficacy of baclofen to reduce alcohol use in veterans with chronic hepatitis C: a randomized controlled trial. Addiction. 2017;112(7):1173–1183.28192622
717 Haun JN, Chavez M, Nazi K, . Veterans’ Preferences for Exchanging Information Using Veterans Affairs Health Information Technologies: Focus Group Results and Modeling Simulations. Journal of Medical Internet Research. 2017;19(10):1–1.
718 Harrison JM, Davis MA, Barton DL, . Functional status and quality of life among breast cancer survivors with heart failure: results of the Medicare Health Outcomes Survey. Supportive Care in Cancer. 2017;25(8):2463–2473.28275898
719 Hamilton AB, Farmer MM, Moin T, . Enhancing Mental and Physical Health of Women through Engagement and Retention (EMPOWER): a protocol for a program of research. Implementation Science. 2017;12(1):1–12.28057027
720 Gustafson DR, Shi Q, Holman S, . Predicting death over 8 years in a prospective cohort of HIV-infected women: The Women’s Interagency HIV Study. BMJ Open. 2017;7(6).
721 George MD, Giles JT, Katz PP, . Impact of Obesity and Adiposity on Inflammatory Markers in Patients With Rheumatoid Arthritis. Arthritis Care & Research. 2017;69(12):1789–1798.28393498
722 Fox DS, McGinnis JJ, Tonnu-Mihara IQ, McCombs JS. Comparative treatment effectiveness of direct acting antiviral regimens for hepatitis C: Data from the Veterans administration. Journal of Gastroenterology and Hepatology (Australia). 2017;32(6):1136–1142.
723 Falkenstein MJ, C’De Baca J, Belon K, Castillo DT. Predictors of PTSD Improvement with Cognitive/Exposure Group Interventions in Operation Enduring Freedom/Operation Iraqi Freedom Female Veterans. Journal of Loss & Trauma. 2017;22(4):297–306.
724 Erickson ZD, Kwan CL, Gelberg HA, . A Randomized, Controlled Multisite Study of Behavioral Interventions for Veterans with Mental Illness and Antipsychotic Medication-Associated Obesity. Journal of General Internal Medicine. 2017;32:32–39.28271424
725 Doran JM, Pietrzak RH, Hoff R, Harpaz-Rotem I. Psychotherapy Utilization and Retention in a National Sample of Veterans With PTSD. Journal of clinical psychology. 2017;73(10):1259–1279.28186638
726 Dixon BE, Ofner S, Perkins SM, . Which veterans enroll in a VA health information exchange program? Journal of the American Medical Informatics Association. 2017;24(1):96–105.27274014
727 DiNapoli EA, Bramoweth AD, Whiteman KL, . Mood Disorders in Middle-Aged and Older Veterans With Multimorbidity. Journal of Aging & Health. 2017;29(4):657–668.27020938
728 D’Aoust RF, Rossiter AG, Elliott A, . Women Veterans, a Population at Risk for Fibromyalgia: The Associations Between Fibromyalgia, Symptoms, and Quality of Life. Military Medicine. 2017;182(7):e1828–e1835.28810979
729 Coughlin SS, Carbone LD, Heboyan V, . Use of My HealtheVet patient web portal among veterans seen for diabetes mellitus at a medical center in the southeastern United States. Mhealth. 2017;3:50.29354642
730 Conard PL, Armstrong ML. Deployed Women Veterans: Important Culturally Sensitive Care. Nursing Forum. 2017;52(4):225–231.26061771
731 Cleveland EC, Azrael D, Simonetti JA, Miller M. Firearm ownership among American veterans: findings from the 2015 National Firearm Survey. Injury Epidemiology. 2017;4(1).
732 Chun DS, Berse B, Venne VL, . BRCA testing within the Department of Veterans Affairs: concordance with clinical practice guidelines. Familial Cancer. 2017;16(1):41–49.27589855
733 Christie J, Shroff S, Shahnavaz N, . A Randomized, Double-Blind, Placebo-Controlled Trial to Examine the Effectiveness of Lubiprostone on Constipation Symptoms and Colon Transit Time in Diabetic Patients. American Journal of Gastroenterology. 2017;112(2):356–364.27922028
734 Ceylony M, Porhomayon J, Pourafkari L, Nader ND. Development of a curriculum and training program in Woman Veterans Health for Internal Medical Residents. Romanian journal of internal medicine = Revue roumaine de medecine interne. 2017;55(3):167–173.28365679
735 Callegari LS, Szarka J, Tartaglione E, . “Oh my God, my doctor is going to think I’m a whore”: how experiences of gender-based stigma in health care shape women veterans’ reproductive counseling needs. Contraception. 2017;96(4):287–287.
736 Callegari LS, Rosenfeld E, Zhao X, . Relationships between contraceptive preferences, knowledge and use among women veterans. Contraception. 2017;96(4):286–287.
737 Buchholz KR, Bohnert KM, Sripada RK, . Associations between PTSD and intimate partner and non-partner aggression among substance using veterans in specialty mental health. Addictive Behaviors. 2017;64:194–199.27636157
738 Branch-Elliman W, Ripollone JE, O’Brien WJ, . Risk of surgical site infection, acute kidney injury, and Clostridium difficile infection following antibiotic prophylaxis with vancomycin plus a beta-lactam versus either drug alone: A national propensity-score-adjusted retrospective cohort study. PLoS Medicine. 2017;14(7):1–17.
739 Bomyea J, Lang AJ, Schnurr PP. TBI and Treatment Response in a Randomized Trial of Acceptance and Commitment Therapy. Journal of Head Trauma Rehabilitation. 2017;32(5):E35–E43.
740 Bastian LA, Driscoll MA, Heapy AA, . Cigarette Smoking Status and Receipt of an Opioid Prescription Among Veterans of Recent Wars. Pain Medicine. 2017;18(6):1089–1097.27659441
741 Barry RG, Amiri FA, Gress TW, . Laparoscopic vertical sleeve gastrectomy: A 5-year veterans affairs review. Medicine. 2017;96(35):1–5.
742 Anderson RE, Bonar EE, Walton MA, . A Latent Profile Analysis of Aggression and Victimization Across Relationship Types Among Veterans Who Use Substances. Journal of Studies on Alcohol & Drugs. 2017;78(4):597–607.28728642
743 Altalib HH, Fenton BT, Sico J, . Increase in migraine diagnoses and guideline-concordant treatment in veterans, 2004-2012. Cephalalgia. 2017;37(1):3–10.
744 Abraham TH, Wright P, White P, . Feasibility and acceptability of shared decision-making to promote alcohol behavior change among women Veterans: Results from focus groups. Journal of Addictive Diseases. 2017;36(4):252–263.28863271
745 Zephyrin LC. Reproductive Health Management for the Care of Women Veterans. Obstetrics & Gynecology. 2016;127(2):383–392.26942369
746 Yeomans PD, Ross RJ. Removing Barriers in the Assessment of Combat-Related Post-traumatic Stress Disorder. Military Medicine. 2016;181(7):625–626.27391614
747 Xie Y, Bowe B, Li T, . Proton Pump Inhibitors and Risk of Incident CKD and Progression to ESRD. Journal of the American Society of Nephrology (JASN). 2016;27(10):3153–3163.27080976
748 Wright B, O’Shea AMJ, Glasgow JM, . Outcomes associated with observation versus short-stay admission among chest pain patients in the Veterans Health Administration. BMC Emergency Medicine. 2016;16(1).
749 Wright B, O’Shea AMJ, Glasgow JM, . Chest Pain Patients at Veterans Hospitals Are Increasingly More Likely to Be Observed Than Admitted for Short Stays. Inquiry (00469580). 2016;53:1–6.
750 Whiting SW, Potenza MN, Park CL, . Investigating Veterans’ Pre-, Peri-, and Post-Deployment Experiences as Potential Risk Factors for Problem Gambling. Journal of Behavioral Addictions. 2016;5(2):213–220.27156377
751 Wang FT, Chang Y, Chien WC, Li HH. Injury and medical expenditure in emergency department visits of older veterans. Geriatrics & Gerontology International. 2016;16(12):1254–1262.26458490
752 Waltz PK, Zuckerbraun BS, Li X, . Analysis of Morbidity and Mortality Outcomes in Postoperative Clostridium difficile Infection in the Veterans Health Administration. JAMA Surgery. 2016;151(4):322–322.26606279
753 Walser RD, Oser ML, Tran CT, Cook JA. Frequency and impact of trauma in older women: A military and nonmilitary sample. Journal of Loss & Trauma. 2016;21(1):62–73.
754 Wagner AC, Torbit L, Jenzer T, . The Role of Posttraumatic Growth in a Randomized Controlled Trial of Cognitive-Behavioral Conjoint Therapy for PTSD. Journal of Traumatic Stress. 2016;29(4):379–383.27434598
755 Wachterman MW, Pilver C, Smith D, . Quality of End-of-Life Care Provided to Patients With Different Serious Illnesses. JAMA Internal Medicine. 2016;176(8):1095–1102.27367547
756 Tsui JI, Williams EC, Green PK, . Alcohol use and hepatitis C virus treatment outcomes among patients receiving direct antiviral agents. Drug and Alcohol Dependence. 2016;169:101–109.27810652
757 Thomson M, Konerman MA, Choxi H, Lok ASF. Primary Care Physician Perspectives on Hepatitis C Management in the Era of Direct-Acting Antiviral Therapy. Digestive Diseases and Sciences. 2016;61(12):3460–3468.26957497
758 Taber DJ, Hunt KJ, Fominaya CE, . Impact of Cardiovascular Risk Factors on Graft Outcome Disparities in Black Kidney Transplant Recipients. Hypertension (0194911X). 2016;68(3):715–725.
759 Sumida K, Molnar MZ, Potukuchi PK, . Association of Slopes of Estimated Glomerular Filtration Rate With Post-End-Stage Renal Disease Mortality in Patients With Advanced Chronic Kidney Disease Transitioning to Dialysis. Mayo Clinic Proceedings. 2016;91(2):196–207.26848002
760 Sternke EA, Abrahamson K, Bair MJ. Comorbid Chronic Pain and Depression: Patient Perspectives on Empathy. Pain Management Nursing. 2016;17(6):363–371.27769812
761 Smith SM, Goldstein RB, Grant BF. The association between post-traumatic stress disorder and lifetime DSM-5 psychiatric disorders among veterans: Data from the National Epidemiologic Survey on Alcohol and Related Conditions-III (NESARC-III). Journal of Psychiatric Research. 2016;82:16–22.27455424
762 Shimada SL, Allison JJ, Rosen AK, . Sustained Use of Patient Portal Features and Improvements in Diabetes Physiological Measures. Journal of Medical Internet Research. 2016;18(7):24–24.
763 Rossiter AG, D’Aoust R, Shafer MR. Military Serving at What Cost? The Effects of Parental Service on the Well-Being Our Youngest Military Members. Annual review of nursing research. 2016;34:109–117.
764 Rogal SS, Yan P, Rimland D, . Incidence and Progression of Chronic Kidney Disease After Hepatitis C Seroconversion: Results from ERCHIVES. Digestive Diseases and Sciences. 2016;61(3):930–936.26526451
765 Rodriguez F, Lin S, Maron DJ, . Use of high-intensity statins for patients with atherosclerotic cardiovascular disease in the Veterans Affairs Health System: Practice impact of the new cholesterol guidelines. American Heart Journal. 2016;182:97–102.27914506
766 Robbins C, Carpenter JE, Bedi A, . Factors Related to Improved Quality of Life in Operative and Non-operative RCT Patients. Orthopaedic Journal of Sports Medicine. 2016:1–1.
767 Ramchand R, Ayer L, Kotzias V, . Suicide Risk among Women Veterans in Distress: Perspectives of Responders on the Veterans Crisis Line. Women’s Health Issues. 2016;26(6):667–673.27576006
768 Pugh MJ, Finley EP, Wang CP, . A retrospective cohort study of comorbidity trajectories associated with traumatic brain injury in veterans of the Iraq and Afghanistan wars. Brain Injury. 2016;30(12):1481–1490.27834535
769 Prentice JC, Pizer SD, Conlin PR. Identifying the independent effect of HbA1c variability on adverse health outcomes in patients with Type 2 diabetes. Diabetic Medicine. 2016;33(12):1640–1648.27279250
770 Pierce ME, Pritchard LM. Lower stress-reactive cortisol in female veterans associated with military status but not PTSD. Stress. 2016;19(5):486–491.27460501
771 Perez HR, Nick MW, Mateo KF, . Adapting a weight management tool for Latina women: a usability study of the Veteran Health Administration’s MOVE!23 tool. BMC Medical Informatics & Decision Making. 2016;16:128–128.27716279
772 Park LS, Tate JP, Sigel K, . Time trends in cancer incidence in persons living with HIV/AIDS in the antiretroviral therapy era: 1997-2012. AIDS. 2016;30(11):1795–1806.27064994
773 Park CL, Finkelstein-Fox L, Barnes DM, . CAM use in recently-returned OEF/OIF/OND US veterans: Demographic and psychosocial predictors. Complementary Therapies in Medicine. 2016;28:50–56.27670870
774 Naylor J, Kilts J, Strauss J, . (419) Neurosteroid levels are inversely associated with low back pain in female Iraq/Afghanistan-era veterans. Journal of Pain. 2016;17:S79–S79.
775 Mouilso ER, Tuerk PW, Schnurr PP, Rauch SAM. Addressing the gender gap: Prolonged exposure for PTSD in veterans. Psychol Serv. 2016;13(3):308–316.26121077
776 Moore CL, Wang N. A national benchmark investigation of return-to-work outcome rates between African American, Native American or Alaskan Native, Latino, Asian American or Pacific Islander, and Non-Latino White veterans served by state vocational rehabilitation agencies: A. Journal of Vocational Rehabilitation. 2016;45(2):133–147.
777 Montgomery AE, Szymkowiak D, Marcus J, . Homelessness, Unsheltered Status, and Risk Factors for Mortality: Findings From the 100 000 Homes Campaign. Public Health Reports. 2016;131(6):765–772.28123222
778 Monteith LL, Menefee DS, Forster JE, Bahraini NH. A Closer Examination of Sexual Trauma During Deployment: Not all Sexual Traumas are Associated with Suicidal Ideation. Suicide & Life-Threatening Behavior. 2016;46(1):46–54.26096625
779 Mehta P, Kaye W, Bryan L, . Prevalence of Amyotrophic Lateral Sclerosis - United States, 2012-2013. Morbidity and mortality weekly report. Surveillance summaries (Washington, D.C. : 2002). 2016;65(8):1–12.
780 McGinnis KA, Tate JP, Williams EC, . Comparison of AUDIT-C collected via electronic medical record and self-administered research survey in HIV infected and uninfected patients. Drug & Alcohol Dependence. 2016;168:196–202.27694059
781 Mankowski M, Everett JE. Women service members, veterans, and their families: What we know now. Nurse Education Today. 2016;47:23–28.26833173
782 Malaty HM, Sansgiry S, Artinyan A, Hou JK. Time Trends, Clinical Characteristics, and Risk Factors of Chronic Anal Fissure Among a National Cohort of Patients with Inflammatory Bowel Disease. Digestive Diseases and Sciences. 2016;61(3):861–864.26514675
783 Maguen S, Hoerster KD, Littman AJ, . Iraq and Afghanistan veterans with PTSD participate less in VA’s weight loss program than those without PTSD. Journal of Affective Disorders. 2016;193:289–294.26774516
784 Lonberger C, McSheffrey S, Allsup K, . (517) Potential barriers for achieving exercise maintenance among trauma exposed female veterans with Fibromyalgia. Journal of Pain. 2016;17:S104–S104.
785 Lindsay JA, Keo-Meier C, Hudson S, . Mental Health of Transgender Veterans of the Iraq and Afghanistan Conflicts Who Experienced Military Sexual Trauma. Journal of Traumatic Stress. 2016;29(6):563–567.27868261
786 Lederer S, Fischer MJ, Gordon HS, . A question prompt sheet for adult patients with chronic kidney disease. BMC Nephrology. 2016;17:155–155.27760524
787 Le KT, Sawicki MP, Wang MB, . High prevalence of agent orange exposure among thyroid cancer patients in the national VA healthcare system. Endocrine Practice. 2016;22(6):699–702.27176142
788 Lawrence-Wood E, Kumar S, Crompvoets S, . A Systematic Review of the Impacts of Active Military Service on Sexual and Reproductive Health Outcomes Among Servicewomen and Female Veterans of Armed Forces. Journal of Military & Veterans’ Health. 2016;24(3):34–55.
789 Latta R, Elwy A, Ngo T, Kelly M. Intimate Partner Violence Screening in a Women Veterans’ Health Clinic: Assessing Feasibility. Journal of Family Violence. 2016;31(5):595–606.
790 Langdon KJ, Fox AB, King LA, . Examination of the dynamic interplay between posttraumatic stress symptoms and alcohol misuse among combat-exposed Operation Enduring Freedom (OEF)/Operation Iraqi Freedom (OIF) Veterans. Journal of Affective Disorders. 2016;196:234–242.26938966
791 Kopacz MS, Kane CP, Stephens B, Pigeon WR. Use of ICD-9-CM diagnosis code V62.89 (other psychological or physical stress, not elsewhere classified) following a suicide attempt. Psychiatric Services. 2016;67(7):807–810.26876664
792 Kip KE, D’Aoust RF, Hernandez DF, . Evaluation of brief treatment of symptoms of psychological trauma among veterans residing in a homeless shelter by use of Accelerated Resolution Therapy. Nursing Outlook. 2016;64(5):411–423.27601310
793 Kazerooni R, Lim J. Topiramate-Associated Weight Loss in a Veteran Population. Military Medicine. 2016;181(3):283–286.26926755
794 Inacio MCS, Hansen C, Pratt NL, . Risk factors for persistent and new chronic opioid use in patients undergoing total hip arthroplasty: A retrospective cohort study. BMJ Open. 2016;6(4).
795 Heung M, Steffick DE, Zivin K, . Acute Kidney Injury Recovery Pattern and Subsequent Risk of CKD: An Analysis of Veterans Health Administration Data. American Journal of Kidney Diseases. 2016;67(5):742–752.26690912
796 Halvorson MA, Finlay AK, Cronkite RC, . Ten-Year Publication Trajectories of Health Services Research Career Development Award Recipients: Collaboration, Awardee Characteristics, and Productivity Correlates. Evaluation & the Health Professions. 2016;39(1):49–64.25015081
797 Haaland KY, Sadek JR, Keller JE, Castillo DT. Neurocognitive Correlates of Successful Treatment of PTSD in Female Veterans. Journal of the International Neuropsychological Society : JINS. 2016;22(6):643–651.27264618
798 Grams ME, Sang Y, Coresh J, . Candidate Surrogate End Points for ESRD after AKI. Journal of the American Society of Nephrology (JASN). 2016;27(9):2851–2859.26857682
799 Gosmanova EO, Mikkelsen MK, Molnar MZ, . Association of Systolic Blood Pressure Variability With Mortality, Coronary Heart Disease, Stroke, and Renal Disease. Journal of the American College of Cardiology (JACC). 2016;68(13):1375–1386.27659458
800 Gosmanov AR, Lub JL, Keiichi S, . Synergistic association of combined glycemic and blood pressure level with risk of complications in US veterans with diabetes. Journal of Hypertension. 2016;34(5):907–913.26928222
801 Gorman LA, Sripada RK, Ganoczy D, . Determinants of National Guard Mental Health Service Utilization in VA versus Non-VA Settings. Health Services Research. 2016;51(5):1814–1837.26840993
802 Ganzer CA. Veteran Women: Mental Health-Related Consequences of Military Service. AJN American Journal of Nursing. 2016;116(11):32–40.
803 Funderburk JS, Arigo D, Kenneson A. Initial engagement and attrition in a national weight management program: demographic and health predictors. Translational Behavioral Medicine. 2016;6(3):358–368.27528525
804 Finlay AK, Smelson D, Sawh L, . U.S. Department of Veterans Affairs Veterans Justice Outreach Program: Connecting Justice-Involved Veterans with Mental Health and Substance Use Disorder Treatment. Crim. 2016;27(2).
805 Echevarria Baez M, Miller S, Banou E. (523) Psychological and personality differences between male and female veterans in an inpatient interdisciplinary chronic pain program. Journal of Pain. 2016;17:S105–S105.
806 Copeland LA, Finley EP, Bollinger MJ, . Comorbidity Correlates of Death Among New Veterans of Iraq and Afghanistan Deployment. Medical Care. 2016;54(12):1078–1081.27367868
807 Connor RR, Boivin MR, Packnett ER, . The Relationship Between Deployment Frequency and Cumulative Duration, and Discharge for Disability Retirement Among Enlisted Active Duty Soldiers and Marines. Military Medicine. 2016;181(11):e1532–e1539.27849486
808 Callegari L, Schwarz EB, Zhao X, . Women veterans’ perceptions of contraceptive counseling quality in the Examining Contraceptive Use and Unmet Need among women veterans (ECUUN) study. Contraception. 2016;94(4):410–410.
809 Boos EM, Bittner MJ, Kramer MR. A Profile of Patients Who Fail to Keep Appointments in a Veterans Affairs Primary Care Clinic. WMJ : official publication of the State Medical Society of Wisconsin. 2016;115(4):185–190.29099155
810 Bethel M, Bailey L, Weaver F, . A historical study of appendicular fractures in veterans with traumatic chronic spinal cord injury: 2002-2007. Journal of Spinal Cord Medicine. 2016;39(6):686–692.26899918
811 Ashrafioun L, Kane C, Stephens B, . Suicide attempts among alcohol-dependent pain patients before and after an inpatient hospitalization. Drug & Alcohol Dependence. 2016;163:209–215.27141842
812 Anker N, Peralta C, Banjeree T, . Racial Disparities in Creatinine-based Kidney Function Estimates Among HIV-infected Adults. Ethnicity & Disease. 2016;26(2):213–220.27103772
813 Anonymous. 2016 North American Forum on Family Planning Scientific Abstracts. Contraception. 2016;94(4).
814 Xue C, Ge Y, Tang B, . A meta-analysis of risk factors for combat-related PTSD among military personnel and veterans. PLoS ONE. 2015;10(3):e0120270.25793582
815 Simonetti JA, Lapham GT, Williams EC. Association Between Receipt of Brief Alcohol Intervention and Quality of Care among Veteran Outpatients with Unhealthy Alcohol Use. J Gen Intern Med. 2015;30(8):1097–104.25691238
816 Mosher HJ, Krebs EE, Carrel M, . Trends in prevalent and incident opioid receipt: an observational study in Veterans Health Administration 2004-2012. J Gen Intern Med. 2015;30(5):597–604.25519224
817 McCauley HL, Blosnich JR, Dichter ME. Adverse Childhood Experiences and Adult Health Outcomes Among Veteran and Non-Veteran Women. J Womens Health (Larchmt). 2015;24(9):723–9.26390379
818 Kimerling R, Pavao J, Greene L, . Access to mental health care among women veterans: Is VA meeting women’s needs? Medical Care. 2015;53(4):S97–S104.25767985
819 Fischer EP, Sherman MD, McSweeney JC, . Perspectives of family and veterans on family programs to support reintegration of returning veterans with posttraumatic stress disorder. Psychological services. 2015;12(3):187–198.26213788
820 Fang SC, Schnurr PP, Kulish AL, . Psychosocial Functioning and Health-Related Quality of Life Associated with Posttraumatic Stress Disorder in Male and Female Iraq and Afghanistan War Veterans: The VALOR Registry. J Womens Health (Larchmt). 2015;24(12):1038–46.26204466
821 Bullman T, Hoffmire C, Schneiderman A, Bossarte R. Time dependent gender differences in suicide risk among Operation Enduring Freedom and Operation Iraqi Freedom veterans. Annals of Epidemiology. 2015;25(12):964–965.26493115
822 Zullig LL, Pathman J, Melnyk SD, . A protocol to evaluate the efficacy, perceptions, and cost of a cholesterol packaging approach to improve medication adherence. Contemporary Clinical Trials. 2014;39(1):106–112.25117806
823 Blosnich JR, Brown GR, Wojcio S, . Mortality Among Veterans with Transgender-Related Diagnoses in the Veterans Health Administration, FY2000-2009. LGBT health. 2014;1(4):269–76.26789855
824 Sternke LM. Measurement of Military Combat Exposure Among Women: Analysis and Implications. Women’s Health Issues. 2011;21(4):S160–S168.21724136
825 Oishi SM, Rose DE, Washington DL, . National Variations in VA Mental Health Care for Women Veterans. Women’s Health Issues. 2011;21(4):S130–S137.21724132
826 MacGregor C, Hamilton AB, Oishi S, Yano EM. Description, Development, and Philosophies of Mental Health Service Delivery for Female Veterans in the VA: A Qualitative Study. Women’s Health Issues. 2011;21(4):S138–S144.21724133
827 Iverson KM, Hendricks AM, Kimerling R, . Psychiatric Diagnoses and Neurobehavioral Symptom Severity Among OEF/OIF VA Patients with Deployment-Related Traumatic Brain Injury: A Gender Comparison. Women’s Health Issues. 2011;21(4):S210–S217.21724143
828 Cone C, Murata G, Myers O. Demographic determinants of response to statin medications. American Journal of Health-System Pharmacy. 2011;68(6):511–517.21378299
829 Curran GM, Stecker T, Han X, Booth BM. Individual and program predictors of attrition from VA substance use treatment. The journal of behavioral health services & research. 2009;36(1):25–34.18188705

## SUMMARY OF INCLUDED STUDIES

| Systematic Reviews; k = 17 | Other; (Methods Development, Protocols, Program Eval/QI); k = 71 | Qualitative; k = 106 | Observational; k = 685 | Mixed Methods; k = 21 | Experimental
| Systematic Reviews; k = 17 | Other; (Methods Development, Protocols, Program Eval/QI); k = 71 | Qualitative; k = 106 | Observational; k = 685 | Mixed Methods; k = 21 | Efficacy/Effectiveness; k = 22 | Implementation; k = 10
Preventative health | 0 studies | 7 studies | 6 studies; Median participants: 27.5; 4 studies of women only | 29 studies; Median participants: 6578; 8 studies of women only | 1 study; Median participants: 5; 0 studies of women only | 1 study; Median participants: 883; 1 studies of women only | 1 study; Median participants: 58,159; 0 studies of women only
Access to care/utilization | 1 study | 0 studies | 7 studies; Median participants: 51; 4 studies of women only | 20 studies; Median participants: 6,728; 11 studies of women only | 1 study; Median participants: 68; 0 studies of women only | 0 studies | 1 study; Median participants: 11,337; 0 studies of women only
Health care delivery | 1 study | 13 studies | 15 studies; Median participants: 35; 7 studies of women only | 19 studies; Median participants: 1,395; 6 studies of women only | 2 studies; Median participants: 22; 1 studies of women only | 0 studies | 0 studies
Reproductive health | 1 study | 7 studies | 6 studies; Median participants: 28.5; 5 studies of women only | 69 studies; Median participants: 1,341; 59 studies of women only | 3 studies; Median participants: 979; 2 studies of women only | 0 studies | 2 studies; Median participants: 12,206; 2 studies of women only
Chronic medical conditions | 1 study | 8 studies | 5 studies; Median participants: 24; 2 studies of women only | 120 studies; Median participants: 58,525; 27 studies of women only | 1 study; Median participants: 119; 1 studies of women only | 1 studies; Median participants: 481; 0 studies of women only | 1 study; Median participants: 14,792; 0 studies of women only
Cancer care | 0 studies | 1 study | 1 study; Median participants: 23; 0 studies of women only | 10 studies; Median participants:10,550.5; 3 studies of women only | 0 studies | 0 studies | 0 studies
Chronic pain & opioids | 0 studies | 1 study | 3 studies; Median participants: 16; 2 studies of women only | 25 studies; Median participants: 46,320; 7 studies of women only | 0 studies | 0 studies | 1 study; Median participants: 764; 0 studies of women only
Suicide & NSSI | 0 studies | 4 studies | 5 studies; Median participants: 50; 1 studies of women only | 45 studies; Median participants: 4,285; 13 studies of women only | 1 study; Median participants: 76,927; 0 studies of women only | 0 studies | 0 studies
Reproductive Mental Health | 0 studies | 2 studies | 3 studies; Median participants: 33; 2 studies of women only | 14 studies; Median participants: 560.5; 12 studies of women only | 2 studies; Median participants: 126.5; 2 studies of women only | 0 studies | 0 studies
General mental health | 4 studies | 12 studies | 16 studies; Median participants: 30; 12 studies of women only | 153 studies; Median participants: 1,162; 48 studies of women only | 6 studies; Median participants: 559; 2 studies of women only | 12 studies; Median participants: 142; 9 studies of women only | 0 studies
Interpersonal violence | 3 studies | 9 studies | 23 studies; Median participants: 27; 15 studies of women only | 77 studies; Median participants: 840; 40 studies of women only | 2 studies; Median participants: 170; 1 study of women only | 3 studies; Median participants: 136; 2 studies of women only | 4 studies; Median participants: 7,421; 4 studies of women only
Long-term care & aging | 2 studies | 0 studies | 0 studies | 19 studies; Median participants: 109,140; 7 studies of women only | 0 studies | 0 studies | 0 studies
Toxic Exposures | 0 studies | 0 studies | 0 studies | 3 studies; Median participants: 2,189; 1 studies of women only | 0 studies | 0 studies | 0 studies
Social determinants of health | 2 studies | 1 study | 4 studies; Median participants: 13.5; 4 studies of women only | 22 studies; Median participants: 22,850; 7 studies of women only | 1 study; Median participants: 833; 0 studies of women only | 0 studies | 0 studies
Harassment/discrimination | 0 studies | 0 studies | 4 studies; Median participants: 87.5; 1 study of women only | 4 studies; Median participants: 1,840.5; 3 studies of women only | 0 studies; Median participants: 0; 0 studies of women only | 1 study; Median participants: 3,011; 1 study of women only | 0 studies
Other Violence | 0 studies | 0 studies | 1 study; Median participants: 16; 1 study of women only | 4 study; Median participants: 25,358; 1 study of women only | 1 study; Median participants: 501; 1 study of women only | 0 studies | 0 studies
Substance Use | 2 study | 6 studies | 7 studies; Median participants: 17; 5 studies of women only | 52 studies; Median participants: 42,627; 10 studies of women only | 0 studies | 4 studies; Median participants: 425; 2 studies of women only | 0 studies

## CHARACTERISTICS OF INCLUDED SYSTEMATIC REVIEWS

Author, Year,; N Articles | Title | Objective | Secondary Focus Area(s) | Prioritized Populations; Funding
Mental Health Not Otherwise Categorized (General Mental Health)
Creech, 2021^17^; 21 | Clinical Complexity in Women Veterans: A Systematic Review of the Recent Evidence on Mental Health and Physical Health Comorbidities | The aim of this systematic review was to evaluate and synthesize research published between 2008 and 2015 and identified in the WVs Health Research Evidence Map as related to mental and physical health comorbidities among WVs. | Chronic medical conditions | N/A; VA
Godier-McBard, 2023^21^; 24 | Barriers and Facilitators to Mental Healthcare for Women Veterans: A Scoping Review | This paper aimed to provide a comprehensive up-to-date scoping review of current knowledge regarding the barriers and facilitators experienced by WVs when accessing mental health services. | Access to care/utilization; Health care organization/delivery of care for WV | N/A; University
Jones, 2017^24^; 8 | The Psychological Health and Well-being Experiences of Female Military Veterans: A Systematic Review of the Qualitative Literature | To determine what is known about the psychological health and well-being experiences of female military Veterans. | N/A | OEF/OIF/OND; Not reported
Orshak, 2022^20^; 8 | Interventions for Women Veterans with Mental Health Care Needs: Findings from a Scoping Review | The purpose of this study was to conduct a scoping review of the literature to summarize interventions for WVs with mental health care needs designed in the VA. | Access to care/utilization; Health care organization/delivery of care for WV | Justice involved; University
Interpersonal Violence
Pulverman, 2019^236^; 6 | Military Sexual Trauma and Sexual Health in Women Veterans: A Systematic Review | This paper aimed to systematically review the existing research on the impact of MST on sexual health in WVs. | Reproductive health | History of trauma; VA
Sparrow, 2017^240^; 13 | Systematic Review of Mental Health Disorders and Intimate Partner Violence Victimisation Among Military Populations | This study systematically reviewed extant studies to summarize the literature exploring IPV victimization and specific mental health problems among male and female military personnel (serving and ex-serving). | General mental health | N/A; Not reported
Wilson, 2018^235^; 69 | The Prevalence of Military Sexual Trauma: A Meta-Analysis | This meta-analysis aimed to obtain a single estimate of the prevalence of MST across methodologies and participant characteristics. | N/A | N/A; Unfunded
Substance Use
Simpson, 2022^39^; 44 | Seeking Care Where They Can: A Systematic Review of Global Trends in Online Alcohol Treatment Utilization Among Non-Veteran and Veteran Women | This systematic review examined associations between gender-tailored recruitment/inclusion criteria and proportions of women enrolled in online alcohol intervention trials, evaluated whether community samples have greater proportions of women than clinical samples, and compared country-specific average proportions of women in trials to country-specific proportions of women with AUD. | Access to care/utilization | N/A; Not reported
Weinberger, 2016^40^ | A Review of Research on Smoking Behavior in Three Demographic Groups of Veterans: Women, Racial/Ethnic Minorities, and Sexual Orientation Minorities | This study reviewed published studies of smoking behavior in three demographic subgroups of veterans: women, racial and ethnic minorities, and sexual orientation minorities to synthesize current knowledge and identify areas in need of more research. | Preventative health | Sexual minoritized populations; Racial and ethnic minoritized populations; VA
Chronic Medical Conditions
Coughlin, 2017^107^; 21 | A Review of Epidemiologic Studies of the Health of Gulf War Women Veterans | This study reviewed epidemiologic studies of the health of women who served in the 1990-1991 Gulf War. | General mental health; Reproductive health | Gulf War I Veterans; NIH/other government
Reproductive Health
Katon, 2018^166^; 52 | Reproductive Health of Women Veterans: A Systematic Review of the Literature from 2008 to 2017 | This systematic review aimed to (1) review the literature pertaining to reproductive health of WVs and (2) synthesize findings. | N/A | N/A; VA; NIH/other government
Long-Term Care/Aging
Varilek, 2021^223^; 19 | Female Veteran Use of Palliative and Hospice Care: A Scoping Review | This scoping review explored the palliative and hospice care literature specific to WVs to: (1) learn what evidence was available regarding WVs use of palliative and hospice care, and (2) identify the existing gaps specific to WVs use of palliative and hospice care, to meet the needs of this growing population. | Access to care/utilization; Health care organization/delivery of care for WV | N/A; Not reported
Weitlauf, 2023^214^; 6 | Mortality of Women Vietnam War Era Veterans | The objectives of this study were to 1) understand the scope of the current mortality literature on US Vietnam War era WVs and 2) identify major themes and knowledge gaps that might guide future research. | Preventative health; Chronic medical conditions | Vietnam era; VA; DOD
Health Care Organization/Delivery of Care for WVs
Danan, 2019^282^; 45 | Evidence Map: Reporting of Results by Sex or Gender in Randomized, Controlled Trials with Women Veteran Participants (2008 to 2018) | The main purpose of this study was to compare characteristics of RCTs that included WVs and did or did not report results by sex or gender. | NA | NA; VA
Access to Care/Utilization
Flike, 2023^288^; 35 | Systematic Review of Access to Healthcare and Social Services Among US Women Veterans Experiencing Homelessness | This systematic review examined the barriers and facilitators for access to health care and social care among WVs experiencing homelessness. | SDOH | People with experiences of homelessness; Unfunded
Social Determinants of Health
Kondo, 2017^305^; 109 | Health Disparities in Veterans: A Map of the Evidence | This study aimed to characterize the research on health care disparities in the Veterans Health Administration via an evidence map. | Access to care/utilization; Health care organization/delivery of care for WV | N/A; VA
Short, 2023^302^; 15 | Female Veterans’ Risk Factors for Homelessness: A Scoping Review | This scoping review aimed to identify published peer-reviewed academic and grey literature about the lived experiences of homeless WVs and risk factors for homelessness among WVs. | N/A | People with experiences of homelessness; Veterans Affairs Canada

## CHARACTERISTICS OF INCLUDED RCTS

Author; Year; N (% women) | Title | Objective | Secondary Focus Areas | Target Populations; Funding
General Mental Health
Acierno, 2021^342^; 136 (100%) | A Randomized Clinical Trial of In-person vs. Home-based Telemedicine Delivery of Prolonged Exposure for PTSD in Military Sexual Trauma Survivors | This study used a randomized controlled design to examine PTSD and depression symptom outcomes, overall number of sessions completed. | Access to care/utilization | History of trauma; DOD
Amsalem, 2021^14^; 172 (31.39%) | Increasing Treatment-Seeking Intentions of US Veterans in the Covid-19 era: A Randomized Controlled Trial | This study screened for clinical symptoms and evaluated the efficacy of a brief, online social contact based video intervention in increasing treatment seeking intentions among Veterans. | Access to care/utilization | N/A; Not reported
Castillo, 2016^343^; 86 (100%) | Group-Delivered Cognitive/Exposure Therapy for PTSD in Women Veterans: A Randomized Controlled Trial | The primary aim of this RCT was to examine the overall efficacy of the 16-week, three-module group protocol on PTSD severity compared to a minimal attention waitlist control in a sample of Afghanistan (OEF) and Iraq (OIF) WVs. | N/A | History of trauma; OEF/OIF/OND; DOD
Creech, 2022^344^; 153 (100%) | Computerized Intervention in Primary Care for Women Veterans with Sexual Assault Histories and Psychosocial Health Risks: a Randomized Clinical Trial | This study aimed to test the impact of a brief computerized intervention delivered in primary care to reduce health risks and increase mental health treatment utilization among women with histories of sexual assault and current health risks. | Substance use; General mental health | History of trauma; NIH/other government
Gobin, 2019^345^; 160 (20%) | Gender Differences in Response to Acceptance and Commitment Therapy Among Operation Enduring Freedom/Operation Iraqi Freedom/Operation New Dawn Veterans | The purpose of this investigation was to examine gender differences in response to acceptance and commitment therapy, an empirically supported transdiagnostic psychotherapy. | N/A | OEF/OIF/OND; DOD
Kelly, 2021^346^; 104 (100%) | Trauma-Sensitive Yoga for Post-Traumatic Stress Disorder in Women Veterans who Experienced Military Sexual Trauma: Interim Results from a Randomized Controlled Trial | This study aimed to assess the effectiveness of Trauma Center Trauma-Sensitive Yoga for PTSD among WVs with PTSD related to MST. | Interpersonal violence | History of trauma; VA
Lehavot, 2021^347^; 102 (100%) | A Randomized Trial of an Online, Coach-Assisted Self-Management PTSD Intervention Tailored for Women Veterans | This RCT aimed to evaluate the feasibility, acceptability, and efficacy of DElivery of Self TRaining and Education for Stressful Situations (DESTRESS)-WVs compared to an active control (phone monitoring) on PTSD symptoms at post-treatment and at three- and six-months post-treatment. | N/A | N/A; Not reported
Lopez, 2022^348^; 151 (100%) | Effects of Emotion Dysregulation on Post-treatment Post-traumatic Stress Disorder and Depressive Symptoms Among Women Veterans With Military Sexual Trauma | This study aimed to present secondary data analyses from a randomized clinical trial comparing the efficacy of in-person versus telemedicine delivery of prolonged exposure therapy for WVs with MST-related PTSD. | Interpersonal violence | History of trauma; NIH/other government; DOD
Martin, 2023^349^; 149 (100%) | Novel Treatment Based on Acceptance and Commitment Therapy Versus Cognitive Behavioral Therapy for Insomnia: A Randomized Comparative Effectiveness Trial in Women Veterans | The primary objectives of this study were to determine whether acceptance and commitment therapy for insomnia (ABC-I) was noninferior to cognitive behavioral therapy for insomnia (CBT-I) in improving sleep and to test whether ABC-I resulted in higher treatment completion and adherence versus CBT-I. | N/A | NA; VA; NIH/other government
Murdoch, 2022^350^; 383 (50.30%) | Impact of Different Cover Letter Information and Incentives on Veterans’ Emotional Responses to an Unsolicited Mailed Survey About Military Traumas: A Randomized, 3x2x2 Factorial Trial | This postal survey study aimed to test whether altering cover letter information would induce or reduce non-response bias in a sample of US Veterans applying for PTSD disability benefits, and examined whether those cover letter alterations impacted participant emotional reactions. | N/A | OEF/OIF/OND; VA
Saban, 2022^25^; 136 (100%) | Impact of a Mindfulness-Based Stress Reduction Program on Psychological Well-Being, Cortisol, and Inflammation in Women Veterans | This study determined the effectiveness of the Mindfulness-Based Stress Reduction Program for improving psychological well-being, cortisol, and inflammation associated with CVD in WVs. | Preventative health; Chronic medical conditions | N/A; VA
Thompson-Hollands, 2023^351^; 284 (100%) | Treatment Length and Symptom Improvement in Prolonged Exposure and Present-Centered Therapy for Posttraumatic Stress Disorder: Comparing Dose-Response and Good-Enough Level Models in Two Manualized Interventions | To compare two theories (the dose-response model and the good-enough level model) across two manualized treatments for PTSD. | Access to care/utilization | History of trauma; DOD
Zaccari, 2022^352^; 152 (100%) | Synchronous Telehealth Yoga and Cognitive Processing Group Therapies for Women Veterans with Posttraumatic Stress Disorder: A Multisite Randomized Controlled Trial Adapted for COVID-19 | This study aimed to present modifications made to pivot a multisite RCT at a Southeastern and Pacific Northwestern VA Health Care Systems from in-person to virtual study implementation.. | Health care organization/delivery of care for WV; Interpersonal violence | History of trauma; VA
Substance Use
Danan, 2019^44^; 2654 (5.22%) | Smoking Cessation among Female and Male Veterans before and after a Randomized Trial of Proactive Outreach | This study compared baseline experiences with VA smoking cessation care for men and women and assessed differing gender responses to a proactive intervention. | N/A | N/A; VA
Holzhauer, 2021^48^; 50 (100%) | Targeting Women Veteran’s Stress-Induced Drinking with Cognitive Reappraisal: Mechanisms and Moderators of Change | This study examined the effects of cognitive reappraisal, an adaptive emotion regulation strategy, on mechanisms that contribute to drinking among 50 WVs. | General mental health | N/A; VA
Najavits, 2018^353^; 66 (100%) | A Randomized Controlled Trial of a Gender-Focused Addiction Model Versus 12-Step Facilitation for Women Veterans | This study compared 12 individual sessions of a gender-focused substance use disorder (SUD) recovery model, ‘A Womans Path to Recovery’ to an evidence-based, non-gender-focused SUD model, 12-Step Facilitation, in WVs with severe SUD. | Health care organization/delivery of care for WV | Justice-involved; VA
Pedersen, 2017^45^; 784 (17%) | A Randomized Controlled Trial of a Web-Based, Personalized Normative Feedback Alcohol Intervention for Young-Adult Veterans | This RCT tested a very brief alcohol intervention delivered over the Internet to reach the population of young adult veterans to help reduce their drinking. | Preventative health | N/A; NIH/other government
Interpersonal Violence
Gilmore, 2016^238^; 100 (100%) | “Do You Expect Me to Receive PTSD Care in a Setting Where Most of the Other Patients Remind Me of the Perpetrator?”: Home-Based Telemedicine to Address Barriers to Care Unique to Military Sexual Trauma and Veterans Affairs Hospitals | This manuscript described an ongoing federally funded RCT comparing PE delivered in-person to PE delivered via home-based telemedicine. | Health care organization/delivery of care for WV; General mental health | History of trauma; NIH/other government
Gilmore, 2020^239^; 136 (100%) | Emotion Dysregulation Predicts Dropout from Prolonged Exposure Treatment among Women Veterans with Military Sexual Trauma-Related Posttraumatic Stress Disorder | This study examined factors associated with treatment dropout among WVs with MST-related PTSD enrolled in PE both in person or via telemedicine as part of an ongoing randomized clinical trial. | Access to care/utilization; General mental health | History of trauma; NIH/other government; DOD
Iverson, 2021^241^; 60 (100%) | Recovering From Intimate Partner Violence Through Strengths and Empowerment: Findings From a Randomized Clinical Trial | This study examined the effectiveness of RISE compared to an advocacy-based enhanced care as usual condition consisting of education, safety planning, resources, and referrals in a sample of women VHA patients. | N/A | History of trauma; VA
Iverson, 2023^234^; 7421 (100%) | Integrating Intimate Partner Violence Screening Programs in Primary Care: Results from a Hybrid-II Implementation-Effectiveness RCT | This stepped-wedge, hybrid-II, implementation-effectiveness, cluster randomized trial investigated implementation and clinical effectiveness outcomes associated with VHA leadership’s use of implementation facilitation to roll out IPV screening programs in mixed-sex/gender and shared-space primary care clinics. | Health care organization/delivery of care for WV | N/A; VA
Preventive Health
Hamilton, 2023^195^; 40 (100%) | Enhancing Mental and Physical Health of Women Through Engagement and Retention (EMPOWER) 2.0 QUERI: Study Protocol for a Cluster-Randomized Hybrid Type 3 Effectiveness-Implementation Trial | This study aimed to compare the effectiveness of Replicating Effective Practices and Evidence-Based QI on improved access to and rates of engagement in telehealth preventive lifestyle and mental health services. | General mental health | N/A; VA
Marcotte, 2023^169^; 883 (100%) | Automated Opt-Out vs Opt-In Patient Outreach Strategies for Breast Cancer Screening: A Randomized Clinical Trial | This study evaluated the effect of an opt-out automatic mammography referral strategy compared with an opt-in automated telephone message strategy, on breast cancer screening. | Health care organization/delivery of care for WV; Cancer care | N/A; VA; NIH/other government
Chronic Medical Conditions
Markland, 2023^114^; 286 (100%) | Optimizing Remote Access to Urinary Incontinence Treatments for Women Veterans (PRACTICAL): Study Protocol for a Pragmatic Clinical Trial Comparing Two Virtual Care Options | This pragmatic clinical trial aimed to increase access to behavioral treatment of urinary incontinence for WVs by comparing the effectiveness of two virtual care delivery modalities. | N/A | NA; VA
Vimalananda, 2016^90^; 481 (15%) | Weight Loss Among Women and Men in the ASPIRE-VA Behavioral Weight Loss Intervention Trial | This study examined weight loss among WVs and Veteran men in the Aspiring for Lifelong Health (ASPIRE) trial, a small changes weight loss program. | Preventative health | General population/not specified; VA
Health Care Organization/Delivery of Care for WVs
Yano, 2016^261^; N/A | Cluster Randomized Trial of a Multilevel Evidence-Based Quality Improvement Approach to Tailoring VA Patient Aligned Care Teams to the Needs of Women Veterans | This study tested an evidence-based QI approach to tailoring PACT to meet WVs needs, incorporating comprehensive primary care services and gender-specific care in gender-sensitive environments, accelerating achievement of PACT tenets for women (Womens Health [WH]-PACT). | Access to care/utilization | N/A; VA

## CHARACTERISTICS OF INCLUDED PROGRAM EVALUATIONS AND QI STUDIES

Author, Year,; N (% Women) | Title | Objective | Secondary Focus Areas | Target Populations; Funding
General Mental Health
Bauer, 2021^354^; 80 (66%) | A Resource Building Virtual Care Programme: improving symptoms and social functioning among female and male rural Veterans | This project aimed to (1) identify whether webSTAIR would effectively improve PTSD and depression, (2) identify whether the programme would improve functioning, particularly social functioning and the related outcomes of emotion regulation and interpersonal skills, and (3) assess programme feasibility and satisfaction. | Health care organization/delivery of care for WV | History of trauma; VA
Galovski, 2022^36^; 699 (100%) | WoVeN, the Women Veterans Network: an Innovative Peer Support Program for Women Veterans | This program aimed to (1) foster connections and build relationships among WVs in local communities and nationwide and (2) develop a collaborative network of stakeholders, agencies, and organizations that share the goal of improving the quality of life of WVs. | N/A | N/A; Foundation
Green, 2017^355^; 1347 (51%) | Examining the Diagnostic Utility of the DSM-5 PTSD Symptoms Among Male and Female Returning Veterans | This study aimed to examine the diagnostic utility of the DSM-5 PTSD symptoms among Veterans. | Substance use | OEF/OIF/OND; VA; NIH/other government; DOD
Katz, 2016^38^; 62 (100%) | Improved Attachment Style for Female Veterans Who Graduated Warrior Renew Sexual Trauma Treatment | This study examined Relationships Scales Questionnaire and Brief Symptom Inventory scores pre- and post-treatment in WVs who graduated the program. | Interpersonal violence | History of trauma; VA
Lawrence, 2019^27^; 346 (30.1%) | Civic Service as an Intervention to Promote Psychosocial Health and Implications for Mental Health in Post-9/11/01 Era Women Veterans | This study characterized the physical and mental health and psychosocial functioning of WVs and evaluated changes in these domains following completion of an intensive civic service program. | N/A | OEF/OIF/OND; VA
Laws, 2018^356^; 6107 (8.6%) | Posttraumatic Stress Symptom Change after Family Involvement in Veterans’ Mental Health Care | This study assessed PTSD symptoms before and after Veterans first family session to test whether symptoms changed after family inclusion. | N/A | N/A; VA
Menefee, 2016^357^; 559 (49.55%) | Inpatient Trauma-Focused Treatment for Veterans: Implementation and Evaluation of Patient Perceptions and Outcomes of an Integrated Evidence-Based Treatment Approach | This article aimed to describe and evaluate the integration of evidence-based treatments for PTSD implemented in two gender-specific, VA inpatient programs. | Health care organization/delivery of care for WV | N/A; VA
Mengeling, 2022^358^; 414 (51.69%) | Online Screening and Personalized Education to Identify Post-Deployment Mental Health Need and Facilitate Access to Care | This article examined an online intervention (Web-Ed) with regard to participation, screening results, satisfaction, and intent to seek follow-up mental health care, with comparisons by gender and post-deployment mental health care receipt. | Access to care/utilization | OEF/OIF/OND; VA
Pebole, 2021^359^; 107 (100%) | Patient-Centered Behavioral Services for Women Veterans with Mental Health Conditions | This study explored wellness priorities and program preferences among WVs utilizing VHA mental health services. | Access to care/utilization; Health care organization/delivery of care for WV | N/A; VA
Stefanovics, 2020^360^; 3370 (14.7%) | Gender Differences in Outcomes Following Specialized Intensive PTSD Treatment in the Veterans Health Administration | This program evaluated specialized intensive VHA PTSD treatment program data to compare sociodemographic and clinical characteristics as well as differences in military and traumatic experiences of men and WVs at the time of program entry. | Health care organization/delivery of care for WV; Substance use | N/A; Not reported
Substance Use
Berg, 2016^361^; 759 (100%) | Identifying Opportunities to Improve Smoking Cessation Among Women Veterans at a Veterans Hospital | This study described the demographics, smoking characteristics, and medical and psychiatric comorbidities of WVs at a Midwestern VA, and examined tobacco cessation service referral and enrollment. | Access to care/utilization | N/A; Unfunded
Livingston, 2021^42^; 222 (22.5%) | Differential Alcohol Treatment Response by Gender Following use of VetChange | This study examined differences among returning Veteran men and WVs who used VetChange, a web-based intervention for hazardous drinking and posttraumatic stress symptoms. | General mental health | OEF/OIF/OND; VA; Foundation
Stefanovics, 2020^43^; 7047 (2.9%) | Gender Difference in Substance Use and Psychiatric Outcomes Among Dually Diagnosed Veterans Treated in Specialized Intensive PTSD Programs | This study focused on Veteran men and WVs with a clinical diagnoses of PTSD and SUD and who reported active use of alcohol or illicit drugs in the 30 days prior to admission. | Access to care/utilization; General mental health | N/A; Unfunded
Timko, 2017^362^; 140 (NA) | Substance Use Disorder Treatment Services for Women in the Veterans Health Administration | This study used national VHA facility-level data to examine the extent of womens specialty SUD treatment programming in the VHA. | Health care organization/delivery of care for WV | N/A; VA
Interpersonal Violence
Dichter, 2023^363^; 208 (100%) | Clinical Response to Positive Screens for Intimate Partner Violence in the Veterans Health Administration: Findings from Review of Medical Records | This study examined the clinical responses to the positive screen in two early-adopting VA medical centers that had implemented both routine IPV screening for women patients and an on-site IPV coordinator. | Preventative health | N/A
Katz, 2023^237^; 27 (100%) | Delivering Brief Warrior Renew Over Video Teleconferencing to Women Veterans with Military Sexual Trauma: A Pragmatic Trial | This study examined effectiveness and acceptability of an 8-session brief warrior renew treatment protocol, modified and delivered over video teleconferencing to WVs who experienced MST. | Health care organization/delivery of care for WV | History of trauma; Not reported
Portnoy, 2021^364^; 62 (N/A) | A Multisite Quality Improvement Initiative to Enhance the Adoption of Screening Practices for Intimate Partner Violence Into Routine Primary Care for Women Veterans | This study evaluated the helpfulness of VHA Office of Women’s Health Services QI program for comprehensive women’s health clinics and reported lessons for implementation of similar screening programs in the VHA and other settings. | Preventative health; Health care organization/delivery of care for WV | Justice involved; Unfunded
Suicide/NSSI
Kumpula, 2019^365^; 1780 (20.4%) | An Evaluation of the Effectiveness of Evidence-Based Psychotherapies for Depression to Reduce Suicidal Ideation among Male and Female Veterans | This study aimed to examine the impact of evidence-based psychotherapies for depression on suicidal ideation and the role of gender and treatment type in patients responses to treatment. | General mental health | N/A; VA
Reproductive Mental Health
Gisseman, 2021^366^; 4402 (2.49%) | Depression Screening During Pregnancy: Compliance and Effectiveness in a Military Population | This study was designed to assess the rate and effectiveness of screening in a major military medical center. | Preventative health; Reproductive health | N/A; Not reported
Solness, 2021^77^; 326 (100%) | Treating Postpartum Depression in Rural Veterans using Internet Delivered CBT: Program Evaluation of MomMoodBooster | This program evaluation paper compared urban and rural-dwelling WVs using pre-post measures of depression, behavioral activation, and automatic thoughts. | Access to care/utilization; SDOH | Rural dwelling; VA
Chronic Medical Conditions
Batch, 2018^367^; 62882 (14.6%) | Outcome by Gender in the Veterans Health Administration Motivating Overweight/Obese Veterans Everywhere Weight Management Program | This study aimed to determine patterns of change in weight over six months in women and men enrolled in the MOVE! Program. | Chronic medical conditions; General mental health | N/A; VA; NIH/other government
Dyer, 2020^92^; 119 (100%) | Tailoring an Evidence-Based Lifestyle Intervention to Meet the Needs of Women Veterans with Prediabetes | This study aimed to assess the impact of gender-tailoring and modality choice on diabetes prevention program engagement among WVs with prediabetes. | Preventative health | N/A; VA
Reproductive Health
Combellick, 2020^368^; 66 (100%) | Severe Maternal Morbidity Among a Cohort of Post-9/11 Women Veterans | This study aimed to evaluate a surveillance methodology at the VA and describe the characteristics of WVs who experienced severe maternal morbidity events. | N/A | OEF/OIF/OND; VA
Cordasco, 2019^153^; 266 (100%) | Veterans Health Administration Primary Care Provider Adherence to Prescribing Guidelines for Systemic Hormone Therapy in Menopausal Women | This study assessed primary care guideline adherence in prescribing systemic hormone therapy, and associations between adherence and provider characteristics, in four VHA facilities. | Health care organization/delivery of care for WV | N/A; VA
Cordasco, 2018^134^; 1199 (100%) | Care Coordination for Pregnant Veterans: VA’s Maternity Care Coordinator Telephone Care Program | This study aimed to develop and assess the feasibility of the VA Maternity Care Coordinator Telephone Care Program, as well as facilitators and barriers encountered in its implementation. | Access to care/utilization | N/A; VA
Cordasco, 2019^152^; 305 episodes | Guideline Adherence of Veterans Health Administration Primary Care for Abnormal Uterine Bleeding | This study assessed the extent to which VA primary care patients with AUB receive guideline-adherent primary care. | Health care organization/delivery of care for WV | N/A; VA
Shroff, 2017^135^; N/A | An Innovative Framework to Improve Teratogenic Medication Risk Counseling | This study described the development and implementation of the TARCC framework in a quality improvement initiative. | Health care organization/delivery of care for WV; Chronic medical conditions | N/A; Not reported
Preventive Health
Avery, 2021^369^; 953 (27%) | Clinical Yoga Program Utilization in a Large Health Care System | This study described referral patterns and patient adoption rates in a clinical yoga program. | Access to care/utilization; General mental health | N/A; VA
Bean-Mayberry, 2022^179^; 52 (37%) | Cardiovascular Risk Screening among Women Veterans: Identifying Provider and Patient Barriers and Facilitators to Develop a Clinical Toolkit | This study identified barriers/facilitators to CV risk identification and reduction among VA providers and their women patients to develop a clinical toolkit to improve CV risk factor screening and lifestyle changes. | Health care organization/delivery of care for WV; Chronic medical conditions | N/A; VA
Zenk, 2018^187^; 3,261,115 (6.92%) | Weight and Veterans’ Environments Study (WAVES) I and II: Rationale, Methods, and Cohort Characteristics | This study presented the rationale, methods, and cohort characteristics for two complementary big-data studies of residential environment contributions to body weight, metabolic risk, and weight management program participation and effectiveness. | Chronic medical conditions | N/A; VA; NIH/other government
Chronic Pain/Opioids
Okvat, 2022^370^; 36 (100%) | Mindfulness-Based Training for Women Veterans with Chronic Pain: A Retrospective Study | This retrospective study evaluated (1) if women who engaged in treatment showed pre-to-post treatment improvement in psychosocial/physical functioning and (2) whether demographic/clincal data differed among those referred to the program who engaged versus did not engage in treatment. | Health care organization/delivery of care for WV; General mental health | N/A; Unfunded
Health Care Organization/Delivery of Care for WVs
Farkas, 2022^276^; 2664 (NA) | Retaining Providers with Women’s Health Expertise: Decreased Provider Loss Among VHA Women’s Health Faculty Development Program Attendees | The objective of this program evaluation was to determine the impact of Women’s Health-Mini Residency participation on WH-Primary Care Provider (PCPs) retention. | N/A | N/A; VA
Gawron, 2023^263^; 15 (86.67%) | Women’s Health Provider Perspectives on Reproductive Services Provision in the Veterans Health Administration | This study explored barriers and facilitators to VHA reproductive service provision across a catchment area from womens health providers perspectives. | Reproductive health | N/A; VA; NIH/other government; Private company
Manwell, 2022^371^; 234 N/A) | Mini-Residencies to Improve Care for Women Veterans: A Decade of Re-Educating Veterans Health Administration Primary Care Providers | This study aimed to design, implement, and evaluate a training program to increase participant comfort with and provision of care to WVs, and foster practice changes in womens health care at local institutions. | Preventative health | N/A; VA
Moreau, 2020^372^; 1303 (100%) | Women Veterans’ Perspectives on How to Make Veterans Affairs Healthcare Settings More Welcoming to Women | This study analyzed patient suggestions on how to make the VA more welcoming to women. | Access to care/utilization | N/A; VA
Rose, 2022^373^; 4254 (100%) | Association Between Availability of Women’s Health Services and Women Veterans’ Care Experiences | This study assessed associations between availability of womens health services and WVs ratings of care experiences. | Access to care/utilization | N/A; VA
Sanders, 2022^274^; 501 (NA%) | Implementation Experience and Initial Assessment of a Rural Women’s Health Training Program in Support of the U.S. Department of Veterans Affairs as a Learning Health System | This study reported the implementation of a women’s health rural workforce training program, demonstrated initial evidence of its effectiveness within VHA as a Learning Health System, and presented lessons learned and implications for other workforce training programs. | Reproductive health | Rural dwelling; VA
Shipherd, 2016^273^; 111 providers | Interdisciplinary Transgender Veteran Care: Development of a Core Curriculum for VHA Providers | This article aimed to: (1) describe the Transgender SCAN-ECHO program curriculum as a minimum of core content for learners who treat transgender Veterans and (2) report the performance of Transgender SCAN-ECHO from the first three cohorts of learners. | SDOH | N/A; Not reported
Vincent, 2023^272^; 29 (100%) | Mind Full or Mindful? A Cohort Study of Equine-Facilitated Therapy for Women Veterans | This study aimed to explore the assets and challenges of partnering with equines for WVs seeking to increase aspects of mind-fulness that can be applied daily. | N/A | N/A; Unfunded
Yano, 2016^261^; N/A | Cluster Randomized Trial of a Multilevel Evidence-Based Quality Improvement Approach to Tailoring VA Patient Aligned Care Teams to the Needs of Women Veterans | This study aimed to test an evidence-based QI approach to tailoring PACT to meet the WVs needs, incorporating comprehensive primary care services and gender-specific care in gender-sensitive environments, thereby accelerating achievement of WH-PACT. | Access to care/utilization | N/A; VA
Access to Care/Utilization
Blosnich, 2019^289^; 15 (provider interviews), 53 (provider surveys) (NA%) | Utilization of the Veterans Affairs’ Transgender E-consultation Program by Health Care Providers: Mixed-Methods Study | This mixed-methods project aimed to describe providers program experiences, reasons for non-use of the VA Transgender E-consultation program, and ways to improve program use. | Health care organization/delivery of care for WV | N/A; VA
Social Determinants of Health
Liu, 2023^304^; 577 (10.9%) | Intimate Partner Violence Screening for Veterans Accessing Homelessness Services | This three-month screening pilot aimed to explore IPV screening for participants of VA homeless Veteran programs at 5 VA medical centers throughout Tennessee and Kentucky. | Health care organization/delivery of care for WV; Interpersonal violence | People with experiences of homelessness; Not reported

## INCLUDED STUDIES

Author, Year | Title | Target Population | Secondary Focus Area | Sub-Focus Area
General Mental Health
Liu, 2019^374^ | The prevalence and trend of depression among Veterans in the United States | General population/not specified | N/a | Depression
Davis, 2016^22^ | Women Veterans with Depression in Veterans Health Administration Primary Care: An Assessment of Needs and Preferences | General population/not specified | N/a | Depression
Sairsingh, 2018^375^ | Depression in Female Veterans Returning from Deployment: The Role of Social Factors | OEF/OIF/OND | SDOH; combat exposure | Depression
Anderson, 2023^376^ | Baseline platelet serotonin in a multi-site treatment study of depression in Veterans administration patients: Distribution and effects of demographic variables and serotonin reuptake inhibitors | General population/not specified | N/a | Depression
Lam, 2017^23^ | Differences in Depression Care for Men and Women among Veterans with and without Psychiatric Comorbidities | General population/not specified | N/a | Depression
Thomas, 2016^377^ | Predictors of Depression Diagnoses and Symptoms in United States Female Veterans: Results from a National Survey and Implications for Programming | General population/not specified | Health care organization/delivery of care for WVs; SDOH | Depression
Borowski, 2021^378^ | Work-family conflict and subsequent depressive symptoms among war-exposed post-9/11 U.S. military Veterans | OEF/OIF/OND | work-family conflict | Depression
Curry, 2021^379^ | Sex differences in predictors of recurrent major depression among current-era military Veterans | OEF/OIF/OND | traumatic experiences | Depression
King, 2023^18^ | Qualitative Exploration of Factors Influencing Women Veterans’ Disordered Eating Symptoms and Treatment Preferences in VHA Primary Care | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WVs | Disordered eating
Breland, 2017^380^ | Military experience can influence Women’s eating habits | General population/not specified | N/a | Disordered eating
Breland, 2016^19^ | Women Veterans’ Treatment Preferences for Disordered Eating | General population/not specified | Health care organization/delivery of care for WVs | Disordered eating
Vaught, 2021^381^ | Prevalence of eating disorders and comorbid psychopathology in a US sample of treatment-seeking Veterans | General population/not specified | N/a | Disordered eating
Buchholz, 2018^382^ | Rates and correlates of disordered eating among women Veterans in primary care | General population/not specified | N/a | Disordered eating
Rosenbaum, 2016^383^ | Binge Eating among Women Veterans in Primary Care: Comorbidities and Treatment Priorities | General population/not specified | Health care organization/delivery of care for WVs; Chronic medical conditions | Disordered eating
Zhao, 2023^249^ | Gender similarities and differences in associations between weight discrimination, shape/weight concerns, and eating disorder symptoms among post-9/11 Veterans | OEF/OIF/OND | Chronic medical conditions; Harassment/discrimination | Disordered eating
Masheb, 2021^384^ | Atypical Anorexia Nervosa, not so atypical after all: Prevalence, correlates, and clinical severity among United States military Veterans | OEF/OIF/OND | N/a | Disordered eating
Masheb, 2021^385^ | DSM-5 eating disorder prevalence, gender differences, and mental health associations in United States military Veterans | OEF/OIF/OND | N/a | Disordered eating
Slane, 2016^386^ | Eating Behaviors: Prevalence, Psychiatric Comorbidity, and Associations With Body Mass Index Among Male and Female Iraq and Afghanistan Veterans | OEF/OIF/OND | Chronic medical conditions | Disordered eating
Krupp, 2023^387^ | Health service utilization among women Veterans who report eating disorder symptoms | General population/not specified | Access to care/utilization; General mental health | Disordered eating
Sienkiewicz, 2021^388^ | Associations between eating disorder symptoms, employment status, and occupational functioning among female Veterans | General population/not specified | SDOH | Disordered eating
Huston, 2018^389^ | Associations between health care use and disordered eating among female Veterans | General population/not specified | Preventative health; Access to care/utilization | Disordered eating
Breland, 2018^390^ | Military sexual trauma is associated with eating disorders, while combat exposure is not | General population/not specified | Preventative health; Interpersonal Violence | Disordered eating
Zelkowitz, 2022^391^ | Gender differences in direct and indirect associations of trauma types with disordered eating in a national U.S. Veteran sample | History of trauma | Suicide/Non-suicidal self-injury; Harassment/discrimination | Disordered eating
Arditte Hall, 2018^392^ | Eating disorder symptoms in female Veterans: The role of childhood, adult, and military trauma exposure | History of trauma | Interpersonal Violence; Other Violence | Disordered eating
Mitchell, 2022^393^ | Associations between probable eating disorders and health care use among post-9/11 Veteran men and women | OEF/OIF/OND | Access to care/utilization | Disordered eating
Serier, 2022^394^ | Disordered eating in sexual minority post-9/11 United States Veterans | Sexual minoritized populations; OEF/OIF/OND | Harassment/discrimination; SDOH | Disordered eating
Creech, 2021^17^ | Clinical Complexity in Women Veterans: A Systematic Review of the Recent Evidence on Mental Health and Physical Health Comorbidities | General population/not specified | Chronic medical conditions | Multiple mental health symptoms and diagnosis
Ziobrowski, 2017^395^ | Gender differences in mental and physical health conditions in U.S. Veterans: Results from the National Health and Resilience in Veterans Study | General population/not specified | Chronic medical conditions; Interpersonal Violence | Multiple mental health symptoms and diagnosis
Brown, 2016^396^ | Mental Health and Medical Health Disparities in 5135 Transgender Veterans Receiving Health care in the Veterans Health Administration: A Case-Control Study | Transgender or gender nonbinary | Chronic medical conditions | Multiple mental health symptoms and diagnosis
Serier, 2022^16^ | Analysis of the bidirectional relationships between posttraumatic stress and depression symptoms with physical health functioning in post-9/11 Veteran men and women deployed to a war zone | OEF/OIF/OND | N/a | Multiple mental health symptoms and diagnosis
Fenton, 2018^15^ | Relationships Between Temporomandibular Disorders, MSD Conditions, and Mental Health Comorbidities: Findings from the Veterans Musculoskeletal Disorders Cohort | General population/not specified | Chronic Pain/Opioids; Chronic medical conditions | Multiple mental health symptoms and diagnosis
Fitzke, 2023^397^ | Barriers and Facilitators to Behavioral Health care for Women Veterans: a Mixed-Methods Analysis of the Current Landscape | General population/not specified | N/a | Mental health care
Ingelse, 2016^398^ | Rural Women Veterans’ Use and Perception of Mental Health Services | Rural dwelling | Access to care/utilization | Mental health care
Creech, 2022^344^ | Computerized Intervention in Primary Care for Women Veterans with Sexual Assault Histories and Psychosocial Health Risks: a Randomized Clinical Trial | History of trauma | Substance Use; General mental health | Mental health care
Mengeling, 2022^358^ | Online Screening and Personalized Education to Identify Post-Deployment Mental Health Need and Facilitate Access to Care | OEF/OIF/OND | Access to care/utilization | Mental health care
Rossi, 2021^399^ | An Examination of the Association Between Patient Experience and Quality of Mental Health Care Among Women Veterans | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WV | Mental health care
Pebole, 2021^359^ | Patient-centered behavioral services for women Veterans with mental health conditions | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WV | Mental health care
Brunner, 2019^400^ | Timely access to mental health care among women Veterans | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WV | Mental health care
Lindsay, 2022^401^ | Getting Connected: a Retrospective Cohort Investigation of Video-to-Home Telehealth for Mental Health Care Utilization Among Women Veterans | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WV | Mental health care
Williston, 2020^402^ | An Examination of the Roles of Mental Health Literacy, Treatment-Seeking Stigma, and Perceived Need for Care in Female Veterans’ Service Use | General population/not specified | Access to care/utilization | Mental health care
Lilienthal, 2017^403^ | Mental health measurement among women Veterans receiving co-located, collaborative care services | General population/not specified | Health care organization/delivery of care for WVs; General mental health | Mental health care
Kimerling, 2016^404^ | Patient Activation and Mental Health Care Experiences Among Women Veterans | General population/not specified | Health care organization/delivery of care for WVs; SDOH | Mental health care
Tsai, 2017^405^ | One-year incidence and predictors of homelessness among 300,000 U.S. Veterans seen in specialty mental health care | People with experiences of homelessness | SDOH | Mental health care
Fischer, 2021^406^ | Impact of Attitudes and Rurality on Veterans’ Use of Veterans Health Administration Mental Health Services | Rural dwelling; General population/not specified | Access to care/utilization | Mental health care
Harper, 2022^407^ | Mental health treatment utilization and relationship functioning among male and female OEF/OIF Veterans | OEF/OIF/OND | Access to care/utilization | Mental health care
Kotzias, 2019^408^ | Mental Health Service Preferences and Utilization Among Women Veterans in Crisis: Perspectives of Veterans Crisis Line Responders | General population/not specified | Health care organization/delivery of care for WVs; Veterans crisis line | Mental health care
Godier-McBard, 2023^21^ | Barriers and facilitators to mental health care for women Veterans: a scoping review | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WVs | Mental health care
Orshak, 2022^20^ | Interventions for Women Veterans with Mental Health Care Needs: Findings from a Scoping Review | Justice-involved ; General population/not specified | Access to care/utilization; Health care organization/delivery of care for WVs | Mental health care
Sayer, 2021^409^ | What the public should know about Veterans returning from combat deployment to support reintegration: A qualitative analysis | OEF/OIF/OND | SDOH | Multiple mental health symptoms and diagnosis
Amsalem, 2021^14^ | Increasing treatment-seeking intentions of US Veterans in the Covid-19 era: A randomized controlled trial | General population/not specified | Access to care/utilization; COVID-19 | Multiple mental health symptoms and diagnosis
Breland, 2020^410^ | Mental Health and Obesity Among Veterans: A Possible Need for Integrated Care | General population/not specified | Chronic medical conditions | Multiple mental health symptoms and diagnosis
Wilson, 2018^411^ | The Association Between Alcohol Consumption, Lifetime Alcohol Use Disorder, and Psychiatric Distress Among Male and Female Veterans | OEF/OIF/OND | Suicide/Non-suicidal self-injury; Substance Use | Multiple mental health symptoms and diagnosis
Desai, 2023^412^ | Racial, ethnic, and sex differences in psychiatric diagnosis, mental health sequelae, and VHA service utilization among justice-involved Veterans | Justice-involved ; Racial/ethnic minoritized | Access to care/utilization; SDOH | Multiple mental health symptoms and diagnosis
Ramsey, 2017^413^ | Incidence of Mental Health Diagnoses in Veterans of Operations Iraqi Freedom, Enduring Freedom, and New Dawn, 2001-2014 | OEF/OIF/OND | N/a | Multiple mental health symptoms and diagnosis
Merians, 2023^414^ | Racial and ethnic mental health disparities in U.S. Military Veterans: Results from the National Health and Resilience in Veterans Study | Racial/ethnic minoritized | Suicide/Non-suicidal self-injury; Substance Use | Multiple mental health symptoms and diagnosis
Blosnich, 2016^415^ | Mental Health of Transgender Veterans in US States With and Without Discrimination and Hate Crime Legal Protection | Transgender or gender nonbinary | SDOH | Multiple mental health symptoms and diagnosis
Smith, 2020^416^ | Impact of Wartime Stress Exposures and Mental Health on Later-Life Functioning and Disability in Vietnam-Era Women Veterans: Findings From the Health of Vietnam-Era Women’s Study | Vietnam | Long-term care/aging | Multiple mental health symptoms and diagnosis
Maiocco, 2016^417^ | The Experience of Women Veterans Coming Back from War | OEF/OIF/OND | N/a | Multiple mental health symptoms and diagnosis
Pless Kaiser, 2017^418^ | Stressful and positive experiences of women who served in Vietnam | Vietnam | Interpersonal Violence; Other Violence | Multiple mental health symptoms and diagnosis
Quinn, 2023^419^ | Recent and Frequent Mental Distress Among Women with a History of Military Service, 2003-2019 | General population/not specified | N/a | Multiple mental health symptoms and diagnosis
Albright, 2019^420^ | When women Veterans return: The role of postsecondary education in transition in their civilian lives | General population/not specified | Preventative health; Access to care/utilization | Multiple mental health symptoms and diagnosis
Aronson, 2020^313^ | The Impact of Adverse Childhood Experiences (ACEs) and Combat Exposure on Mental Health Conditions Among New Post-9/11 Veterans | OEF/OIF/OND | Preventative health; Substance Use | Multiple mental health symptoms and diagnosis
Vanneman, 2017^421^ | Postdeployment Behavioral Health Screens and Linkage to the Veterans Health Administration for Army Reserve Component Members | OEF/OIF/OND | Access to care/utilization; Substance Use | Multiple mental health symptoms and diagnosis
Scoglio, 2021^422^ | Gender-Specific Risk Factors for Psychopathology and Reduced Functioning in a Post-9/11 Veteran Sample | OEF/OIF/OND | Interpersonal Violence | Multiple mental health symptoms and diagnosis
Muralidharan, 2016^423^ | Deployment Experiences, Social Support, and Mental Health: Comparison of Black, White, and Hispanic U.S. Veterans Deployed to Afghanistan and Iraq | OEF/OIF/OND | Harassment/discrimination; family stressors and social support | Multiple mental health symptoms and diagnosis
Lawrence, 2021^424^ | Mental health and psychosocial functioning in recently separated U.S. women Veterans: Trajectories and bi-directional relationships | OEF/OIF/OND | N/a | Multiple mental health symptoms and diagnosis
Adams, 2021^425^ | Risk and protective factors associated with mental health among female military Veterans: results from the Veterans’ health study | General population/not specified | N/a | Multiple mental health symptoms and diagnosis
Creech, 2016^426^ | Combat exposure, mental health, and relationship functioning among women Veterans of the Afghanistan and Iraq wars | OEF/OIF/OND | Substance Use; Family and relationship functioning Intimate relationship satisfaction, ) parenting confidence and satisfaction | Multiple mental health symptoms and diagnosis
Lehavot, 2019^427^ | Race/Ethnicity and Sexual Orientation Disparities in Mental Health, Sexism, and Social Support among Women Veterans | Sexual minoritized populations; General population/not specified | Harassment/discrimination; SDOH | Multiple mental health symptoms and diagnosis
Lehavot, 2022^428^ | Disparities in Mental Health and Health Risk Behaviors for LGBT Veteran Subgroups in a National U.S. Survey | Transgender or gender nonbinary; Sexual minoritized populations | Suicide/Non-suicidal self-injury; Substance Use | Multiple mental health symptoms and diagnosis
Hamrick, 2022^429^ | Moral Injury as a Mediator of the Associations Between Sexual Harassment and Mental Health Symptoms and Substance Use Among Women Veterans | History of trauma | Substance Use; Interpersonal Violence | Moral injury
Ranney, 2022^430^ | Moral injury and chronic pain in Veterans | OEF/OIF/OND | Chronic Pain/Opioids | Moral injury
Maguen, 2020^431^ | Gender differences in prevalence and outcomes of exposure to potentially morally injurious events among post-9/11 Veterans | OEF/OIF/OND | N/a | Moral injury
Masheb, 2021^311^ | Associations between adverse childhood experiences and weight, weight control behaviors and quality of life in Veterans seeking weight management services | General population/not specified | Preventative health; N/a | Additional mental health
Groër 2016^30^ | Allostatic Perspectives in Women Veterans With a History of Childhood Sexual Assault | History of trauma; General population/not specified | Interpersonal Violence | Additional mental health
Beckie, 2016^31^ | The Relationship between Allostatic Load and Psychosocial Characteristics among Women Veterans | General population/not specified | Interpersonal Violence | Additional mental health
Lwi, 2019^33^ | Ten-Year Prevalence of Cognitive Impairment Diagnoses and Associated Medical and Psychiatric Conditions in a National Cohort of Older Female Veterans | General population/not specified | Long-term care/aging | Additional mental health
Fox, 2016^34^ | Understanding how deployment experiences change over time: Comparison of female and male OEF/OIF and Gulf War Veterans | OEF/OIF/OND ; Gulf War I | N/a | Additional mental health
Sullivan-Baca, 2020^35^ | Gender Differences in Veterans Referred for Neuropsychological Evaluation in an Outpatient Neuropsychology Consultation Service | General population/not specified | Long-term care/aging | Additional mental health
Galovski, 2022^36^ | WoVeN, the Women Veterans Network: an Innovative Peer Support Program for Women Veterans | General population/not specified | N/a | Additional mental health
Leslie, 2017^37^ | Returning to civilian life: Family reintegration challenges and resilience of women Veterans of the Iraq and Afghanistan wars | OEF/OIF/OND | SDOH | Additional mental health
Katz, 2016^38^ | Improved Attachment Style for Female Veterans Who Graduated Warrior Renew Sexual Trauma Treatment | History of trauma | Interpersonal Violence | Additional mental health
Wang, 2016^32^ | Stress-related biobehavioral responses, symptoms, and physical activity among female Veterans in the community: An exploratory study | History of trauma | Substance Use; General mental health | Additional mental health
Saban, 2022^25^ | Impact of a Mindfulness-Based Stress Reduction Program on Psychological Well-Being, Cortisol, and Inflammation in Women Veterans | General population/not specified | Preventative health; Chronic medical conditions | Well-being
Lawrence, 2019^27^ | Civic Service as an Intervention to Promote Psychosocial Health and Implications for Mental Health in Post-9/11/01 Era Women Veterans | OEF/OIF/OND | civic service and engagement | Well-being
Vogt, 2022^26^ | Changes in the health and broader well-being of U.S. Veterans in the first three years after leaving military service: Overall trends and group differences | OEF/OIF/OND | long-term health outcomes | Well-being
Vogt, 2022^28^ | Strengths and vulnerabilities: Comparing post-9/11 U.S. Veterans’ and non-Veterans’ perceptions of health and broader well-being | OEF/OIF/OND | Substance Use; SDOH | Well-being
Jones, 2017^24^ | The psychological health and well-being experiences of female military Veterans: a systematic review of the qualitative literature | OEF/OIF/OND | N/a | Well-being
Kehle-Forbes, 2022^432^ | “It leaves me very skeptical” messaging in marketing prolonged exposure and cognitive processing therapy to Veterans with PTSD | General population/not specified | Access to care/utilization | PTSD
Wilson, 2021^433^ | Female U.S. Military Veterans’ (Non)Disclosure of Mental Health Issues with Family and Friends: Privacy Rules and Boundary Management | History of trauma | Health care organization/delivery of care for WVs | PTSD
Kehle-Forbes, 2017^434^ | Experiences with VHA care: a qualitative study of U.S. women Veterans with self-reported trauma histories | History of trauma | Health care organization/delivery of care for WVs; Interpersonal Violence | PTSD
Haun, 2016^435^ | Qualitative Inquiry Explores Health-Related Quality of Life of Female Veterans With Post-Traumatic Stress Disorder | History of trauma | Health-related quality of life | PTSD
Krupnick, 2017^436^ | Gender Differences in Trauma Types and Themes in Veterans with Posttraumatic Stress Disorder | History of trauma | Interpersonal Violence | PTSD
Lehavot, 2021^347^ | A randomized trial of an online, coach-assisted self-management PTSD intervention tailored for women Veterans | General population/not specified | N/a | PTSD
Thompson-Hollands, 2023^351^ | Treatment length and symptom improvement in prolonged exposure and present-centered therapy for posttraumatic stress disorder: Comparing dose-response and good-enough level models in two manualized interventions | History of trauma | Access to care/utilization | PTSD
Lopez, 2022^348^ | Effects of Emotion Dysregulation on Post-treatment Post-traumatic Stress Disorder and Depressive Symptoms Among Women Veterans With Military Sexual Trauma | History of trauma | Interpersonal Violence | PTSD
Kelly, 2021^346^ | Trauma-Sensitive Yoga for Post-Traumatic Stress Disorder in Women Veterans who Experienced Military Sexual Trauma: Interim Results from a Randomized Controlled Trial | History of trauma | Interpersonal Violence | PTSD
Gobin, 2019^345^ | Gender Differences in Response to Acceptance and Commitment Therapy Among Operation Enduring Freedom/Operation Iraqi Freedom/Operation New Dawn Veterans | OEF/OIF/OND | N/a | PTSD
Laws, 2018^356^ | Posttraumatic stress symptom change after family involvement in Veterans’ mental health care | General population/not specified | N/a | PTSD
Valenstein-Mah, 2019^437^ | Gender Differences in Rates and Predictors of Individual Psychotherapy Initiation and Completion Among Veterans Health Administration Users Recently Diagnosed With PTSD | History of trauma | Preventative health; Access to care/utilization | PTSD
Farmer, 2020^438^ | Psychotherapy Utilization, Preferences, and Retention among Women Veterans with Post-traumatic Stress Disorder | History of trauma | Preventative health; Access to care/utilization | PTSD
Lehavot, 2017^439^ | Study adaptation, design, and methods of a web-based PTSD intervention for women Veterans | History of trauma; General population/not specified | Access to care/utilization | PTSD
Menefee, 2016^357^ | Inpatient Trauma-Focused Treatment for Veterans: Implementation and Evaluation of Patient Perceptions and Outcomes of an Integrated Evidence-Based Treatment Approach | General population/not specified | Health care organization/delivery of care for WVs | PTSD
Stefanovics, 2020^360^ | Gender Differences in Outcomes Following Specialized Intensive PTSD Treatment in the Veterans Health Administration | General population/not specified | Health care organization/delivery of care for WVs; Substance Use | PTSD
Murdoch, 2019^440^ | Changes in Post-traumatic Stress Disorder Service Connection Among Veterans Under Age 55: An 18-Year Ecological Cohort Study | History of trauma | SDOH; Service Connection Outcomes | PTSD
Hadlandsmyth, 2022^441^ | Gender differences in medication prescribing patterns for Veterans with posttraumatic stress disorder: A 10-year follow-up study | General population/not specified | Access to care/utilization | PTSD
Wisco, 2016^442^ | Probable posttraumatic stress disorder in the US Veteran population according to DSM-5: Results from the national health and resilience in Veterans study | General population/not specified | Suicide/Non-suicidal self-injury; Substance Use | PTSD
Davin, 2022^443^ | Prospective mental health effects of intimate partner stalking among women Veterans | General population/not specified | Interpersonal Violence; Intimate partner stalking | PTSD
Webermann, 2023^444^ | Military sexual trauma-related posttraumatic stress disorder service-connection award denial across gender and race | History of trauma | Interpersonal Violence | PTSD
Moye, 2022^445^ | Post-traumatic Stress Disorder in Older U.S. Military Veterans: Prevalence, Characteristics, and Psychiatric and Functional Burden | History of trauma | Interpersonal Violence; Other Violence | PTSD
Schnurr, 2019^446^ | Residual symptoms following prolonged exposure and present-centered therapy for PTSD in female Veterans and soldiers | History of trauma | Health care organization/delivery of care for WVs; General mental health | PTSD
Andresen, 2019^447^ | Institutional betrayal following military sexual trauma is associated with more severe depression and specific posttraumatic stress disorder symptom clusters | History of trauma | Interpersonal Violence | PTSD
Stainbrook, 2016^448^ | Female Veterans in Jail Diversion Programs: Differences From and Similarities to Their Male Peers | Justice-involved | Substance Use; jail diversion programs | PTSD
Tsai, 2016^449^ | Accuracy of screening for posttraumatic stress disorder in specialty mental health clinics in the U.S. Veterans Affairs Health care System | OEF/OIF/OND ; General population/not specified | Preventative health | PTSD
Murdoch, 2017^450^ | Persistent Serious Mental Illness Among Former Applicants for VA PTSD Disability Benefits and Long-Term Outcomes: Symptoms, Functioning, and Employment | Other: Veterans who applied for PTSD disability benefits (severe mental illness, PTSD and other mental conditions) | N/a | PTSD
McClendon, 2019^451^ | Patterns and correlates of racial/ethnic disparities in posttraumatic stress disorder screening among recently separated Veterans | Racial/ethnic minoritized | Preventative health; Access to care/utilization | PTSD
Shipherd, 2021^452^ | Estimating Prevalence of PTSD Among Veterans With Minoritized Sexual Orientations Using Electronic Health Record Data | Sexual minoritized populations | N/a | PTSD
Green, 2017^355^ | Examining the diagnostic utility of the DSM-5 PTSD symptoms among male and female returning Veterans | OEF/OIF/OND ; General population/not specified | Substance Use; Functional impairment (not necessarily related to long-term care/aging) | PTSD
Shastry, 2022^453^ | The impact of post-traumatic stress on quality of life and fatigue in women with Gulf War Illness | Gulf War I | Chronic medical conditions | PTSD
James, 2022^454^ | Immunogenetics of posttraumatic stress disorder (PTSD) in women Veterans | General population/not specified | N/a | PTSD
Kimbrel, 2018^455^ | Wall/Object Punching: An Important but Under-Recognized Form of Nonsuicidal Self-Injury | History of trauma | N/a | PTSD
Schnurr, 2016^456^ | Symptom Benchmarks Of Improved Quality Of Life In Ptsd | History of trauma | quality of life | PTSD
Maguen, 2020^457^ | Factors associated with PTSD symptom improvement among Iraq and Afghanistan Veterans receiving evidenced-based psychotherapy | OEF/OIF/OND | Access to care/utilization | PTSD
Vogt, 2021^458^ | Identifying factors that contribute to military Veterans’ post-military well-being | General population/not specified | Suicide/Non-suicidal self-injury; Substance Use | PTSD
Shiner, 2017^459^ | Effect of Patient-Therapist Gender Match on Psychotherapy Retention Among United States Veterans with Posttraumatic Stress Disorder | General population/not specified | Health care organization/delivery of care for WVs | PTSD
Lehavot, 2018^460^ | Do trauma type, stressful life events, and social support explain women Veterans’ high prevalence of PTSD? | General population/not specified | SDOH | PTSD
Lehavot, 2018^461^ | Post-traumatic Stress Disorder by Gender and Veteran Status | General population/not specified | N/a | PTSD
James, 2022^462^ | Classification of posttraumatic stress disorder and related outcomes in women Veterans using magnetoencephalography | General population/not specified | N/a | PTSD
Wooldridge, 2020^312^ | Relationships among adverse childhood experiences, posttraumatic stress disorder symptom clusters, and health in women Veterans | General population/not specified | N/a | PTSD
Stefanovics, 2019^463^ | Comparing Outcomes of Women-Only and Mixed-Gender Intensive Posttraumatic Stress Disorder Treatment for Female Veterans | General population/not specified | Health care organization/delivery of care for WVs; Harassment/discrimination | PTSD
Harper, 2023^464^ | The Role of PTSD Symptom Severity and Relationship Functioning in Male and Female Veterans’ Mental Health Service Use | History of trauma | N/a | PTSD
Christ, 2022^465^ | Comparing Veterans with Posttraumatic Stress Disorder Related to Military Sexual Trauma or Other Trauma Types: Baseline Characteristics and Residential Cognitive Processing Therapy Outcomes | History of trauma | Interpersonal Violence | PTSD
Rosen, 2019^466^ | Which patients initiate cognitive processing therapy and prolonged exposure in department of Veterans affairs PTSD clinics? | History of trauma | Access to care/utilization; Health care organization/delivery of care for WVs | PTSD
Shapiro, 2022^467^ | Pain and posttraumatic stress: Associations among women Veterans with a history of military sexual trauma | History of trauma | Chronic Pain/Opioids; Interpersonal Violence | PTSD
Wolf, 2016^468^ | The Influence of the Dissociative Subtype of Posttraumatic Stress Disorder on Treatment Efficacy in Female Veterans and Active Duty Service Members | History of trauma | N/a | PTSD
Miles, 2016^469^ | The Relationship Between Emotion Dysregulation and Impulsive Aggression in Veterans With Posttraumatic Stress Disorder Symptoms | History of trauma; OEF/OIF/OND ; Vietnam | Access to care/utilization | PTSD
Buta, 2018^470^ | Posttraumatic stress disorder diagnosis and gender are associated with accelerated weight gain trajectories in Veterans during the post-deployment period | OEF/OIF/OND | obesity/accelerated weight gain | PTSD
Smith, 2017^471^ | The role of postdeployment social factors in linking deployment experiences and current posttraumatic stress disorder symptomatology among male and female Veterans | OEF/OIF/OND | Other Violence; SDOH | PTSD
Zelkowitz, 2023^472^ | Postdeployment Mental Health Concerns and Family Functioning in Veteran Men and Women | OEF/OIF/OND | Substance Use; Relationship quality/Parenting self-efficacy | PTSD
Webermann, 2023^334^ | The Role of Unit and Interpersonal Support in Military Sexual Trauma and Posttraumatic Stress Disorder Symptoms | OEF/OIF/OND | Interpersonal Violence | PTSD
Meyer, 2018^473^ | Gender differences in associations between DSM-5 posttraumatic stress disorder symptom clusters and functional impairment in war Veterans | OEF/OIF/OND | Chronic medical conditions | PTSD
Vogt, 2017^474^ | Consequences of PTSD for the work and family quality of life of female and male U.S. Afghanistan and Iraq War Veterans | OEF/OIF/OND | Relationship and work quality of life | PTSD
Burg, 2017^475^ | Risk for Incident Hypertension Associated With Posttraumatic Stress Disorder in Military Veterans and the Effect of Posttraumatic Stress Disorder Treatment | OEF/OIF/OND | Chronic medical conditions | PTSD
Janke-Stedronsky, 2016^476^ | Association of parental status and diagnosis of posttraumatic stress disorder among Veterans of Operations Iraqi and Enduring Freedom | OEF/OIF/OND | Parental Status | PTSD
McClendon, 2021^477^ | The Impact of Discriminatory Stress on Changes in Posttraumatic Stress Severity at the Intersection of Race/Ethnicity and Gender | Racial/ethnic minoritized; General population/not specified | SDOH | PTSD
Ceja, 2022^478^ | Posttraumatic stress disorder symptom expression in racially and ethnically diverse women Veterans | Racial/ethnic minoritized; General population/not specified | SDOH | PTSD
Koo, 2016^479^ | PTSD detection and symptom presentation: Racial/ethnic differences by gender among Veterans with PTSD returning from Iraq and Afghanistan | Racial/ethnic minoritized; OEF/OIF/OND | SDOH | PTSD
Caska-Wallace, 2016^480^ | Posttraumatic Stress Disorder Symptom Severity and Relationship Functioning Among Partnered Heterosexual and Lesbian Women Veterans | Sexual minoritized populations; General population/not specified | N/a | PTSD
Murdoch, 2022^350^ | Impact of different cover letter information and incentives on Veterans’ emotional responses to an unsolicited mailed survey about military traumas: a randomized, 3x2x2 factorial trial | OEF/OIF/OND | Research methods | PTSD
Sripada, 2018^481^ | Mental Health Service Utilization before and after Receipt of a Service-Connected Disability Award for PTSD: Findings from a National Sample | History of trauma | Access to care/utilization; Health care organization/delivery of care for WV | PTSD
Acierno, 2021^342^ | A randomized clinical trial of in-person vs. home-based telemedicine delivery of Prolonged Exposure for PTSD in military sexual trauma survivors | History of trauma | Access to care/utilization | PTSD
Castillo, 2016^343^ | Group-Delivered Cognitive/Exposure Therapy for PTSD in Women Veterans: A Randomized Controlled Trial | History of trauma; OEF/OIF/OND | N/a | PTSD
Benfer, 2023^482^ | An examination of the criterion-related validity of varying methods of indexing clinically significant change in posttraumatic stress disorder treatment | History of trauma | N/a | PTSD
Reuman, 2022^483^ | Women Veterans’ attitudes toward family involvement in PTSD treatment: A mixed-methods examination | History of trauma | Health care organization/delivery of care for WVs; Interpersonal Violence | PTSD
Gros, 2023^484^ | Influence of comorbid social anxiety disorder in PTSD treatment outcomes for Prolonged Exposure in female military sexual trauma survivors with PTSD | History of trauma | Interpersonal Violence | PTSD
Banducci, 2019^485^ | The associations between deployment experiences, PTSD, and alcohol use among male and female Veterans | OEF/OIF/OND | Substance Use | PTSD
Olmos-Ochoa, 2023^486^ | Supporting Equitable Engagement and Retention of Women Patients in a Trauma-Informed Virtual Mental Health Intervention: Acceptability and Needed Adaptations | History of trauma | N/a | PTSD
Bauer, 2021^354^ | A Resource Building Virtual Care Programme: improving symptoms and social functioning among female and male rural Veterans | History of trauma | Health care organization/delivery of care for WVs; N/a | PTSD
Goldstein, 2017^487^ | Impact of military trauma exposures on posttraumatic stress and depression in female Veterans | History of trauma | Interpersonal Violence | PTSD
Lucas, 2021^488^ | An Examination of Stalking Experiences During Military Service Among Female and Male Veterans and Associations With PTSD and Depression | General population/not specified | Preventative health; Interpersonal Violence | PTSD
Gross, 2023^489^ | Clinical outcomes of Veterans affairs residential PTSD treatment for PTSD and depressive symptoms: 1-year follow-up outcomes and gender differences | History of trauma | N/a | PTSD
ArditteHall, 2019^490^ | Associations Between Trauma-Related Rumination and Symptoms of Posttraumatic Stress and Depression in Treatment-Seeking Female Veterans | History of trauma | Interpersonal Violence; Other Violence | PTSD
Holliday, 2021^491^ | Associations between justice involvement and PTSD and depressive symptoms, suicidal ideation, and suicide attempt among post-9/11 Veterans | Justice-involved ; OEF/OIF/OND | Suicide/Non-suicidal self-injury; SDOH | PTSD
Welsh, 2019^492^ | Gender Differences in Post-deployment Adjustment of Air Force Personnel: The Role of Wartime Experiences, Unit Cohesion, and Self-efficacy | OEF/OIF/OND | Interpersonal Violence; Other Violence | PTSD
Smith, 2017^493^ | The Role of PTSD, Depression, and Alcohol Misuse Symptom Severity in Linking Deployment Stressor Exposure and Post-Military Work and Family Outcomes in Male and Female Veterans | OEF/OIF/OND | Interpersonal Violence; Harassment/discrimination | PTSD
Vogt, 2019^494^ | Do functional impairments promote or hinder mental health treatment seeking: Differential results for women and men | OEF/OIF/OND | Access to care/utilization; Relationship and work impairment | PTSD
Gorman, 2022^495^ | The impact of deployment-related stressors on the development of PTSD and depression among sexual minority and heterosexual female Veterans | OEF/OIF/OND | Interpersonal Violence; Harassment/discrimination | PTSD
Finkelstein-Fox, 2021^496^ | Meaningful military engagement among male and female post-9/11 Veterans: An examination of correlates and implications for resilience | OEF/OIF/OND | N/a | PTSD
Gutner, 2018^497^ | Going direct to the consumer: Examining treatment preferences for Veterans with insomnia, PTSD, and depression | General population/not specified | Access to care/utilization | PTSD
Sandhu, 2023^498^ | PTSD symptoms as a potential mediator of associations between military sexual assault and disordered eating | History of trauma; General population/not specified | Interpersonal Violence | PTSD
Stojek, 2021^499^ | Investigating sex differences in rates and correlates of food addiction status in women and men with ptsd | OEF/OIF/OND | N/a | PTSD
Webermann, 2022^500^ | The role of general self-efficacy in intimate partner violence and symptoms of posttraumatic stress disorder among women Veterans | History of trauma | Interpersonal Violence; PTSD symptoms | PTSD
C’De Baca, 2016^501^ | Examining Relationships Among Ethnicity, PTSD, Life Functioning, and Comorbidity in Female OEF/OIF Veterans | Racial/ethnic minoritized; OEF/OIF/OND | SDOH | PTSD
Williams, 2017^502^ | Borderline Personality Disorder and Military Sexual Trauma: Analysis of Previous Traumatization and Current Psychiatric Presentation | History of trauma | Interpersonal Violence | PTSD
Creech, 2019^503^ | Longitudinal associations in the direction and prediction of PTSD symptoms and romantic relationship impairment over one year in post 9/11 Veterans: A comparison of theories and exploration of potential gender differences | OEF/OIF/OND | N/a | PTSD
James, 2022^504^ | MEG neural signature of sexual trauma in women Veterans with PTSD | History of trauma | Interpersonal Violence | PTSD
Saba, 2021^505^ | Associations between symptoms of posttraumatic stress disorder, pain, and alcohol use disorder among OEF/OIF/OND Veterans | OEF/OIF/OND | Substance Use; Chronic Pain/Opioids | PTSD
Epstein, 2019^506^ | Posttraumatic stress disorder and traumatic brain Injury: Sex differences in Veterans | OEF/OIF/OND | Chronic Pain/Opioids; Chronic medical conditions | PTSD
Jackson, 2016^507^ | Mild Traumatic Brain Injury, PTSD, and Psychosocial Functioning Among Male and Female U.S. OEF/OIF Veterans | OEF/OIF/OND | Chronic medical conditions | PTSD
Portnoy, 2018^508^ | Understanding Gender Differences in Resilience Among Veterans: Trauma History and Social Ecology | OEF/OIF/OND | Interpersonal Violence | PTSD
Sexton, 2018^509^ | A psychometric evaluation of the Posttraumatic Cognitions Inventory with Veterans seeking treatment following military trauma exposure | History of trauma | Health care organization/delivery of care for WVs | PTSD
Zaccari, 2022^352^ | Synchronous Telehealth Yoga and Cognitive Processing Group Therapies for Women Veterans with Posttraumatic Stress Disorder: A Multisite Randomized Controlled Trial Adapted for COVID-19 | History of trauma | Health care organization/delivery of care for WVs; Interpersonal Violence | PTSD
Schuman, 2019^510^ | A systematic review of the psychosocial impact of emotional numbing in US combat Veterans | General population/not specified | Suicide/Non-suicidal self-injury; Substance Use | PTSD
0^511^ | Mortality Among Veterans with Major Mental Illnesses Seen in Primary Care: Results of a National Study of Veteran Deaths | General population/not specified | Chronic medical conditions | Severe mental illness
Holliday, 2023^512^ | Personality Disorder Diagnosis among Justice-Involved Veterans: An Investigation of VA Using Veterans | Justice-involved | N/a | Severe mental illness
Goodsmith, 2023^513^ | Predictors of Functioning and Recovery Among Men and Women Veterans with Schizophrenia | General population/not specified | social support, mental health recovery | Severe mental illness
Saldana, 2023^514^ | Values Expressed by Women Veterans Receiving Treatment for Chronic Insomnia Disorder | General population/not specified | N/a | Sleep related
Martin, 2023^349^ | Novel treatment based on acceptance and commitment therapy versus cognitive behavioral therapy for insomnia: A randomized comparative effectiveness trial in women Veterans | General population/not specified | N/a | Sleep related
Carlson, 2022^515^ | Benefits of Cognitive Behavioral Therapy for Insomnia for Women Veterans with and without Probable Post-Traumatic Stress Disorder | History of trauma | Chronic medical conditions | Sleep related
Jasuja, 2019^516^ | Gender differences in prescribing of zolpidem in the Veterans Health Administration | General population/not specified | Access to care/utilization | Sleep related
Babson, 2018^517^ | Insomnia symptoms among female Veterans: Prevalence, risk factors, and the impact on psychosocial functioning and health care utilization | General population/not specified | Health care organization/delivery of care for WVs | Sleep related
Martin, 2017^518^ | Estimated Prevalence of Insomnia among Women Veterans: Results of a Postal Survey | General population/not specified | N/a | Sleep related
Culver, 2016^519^ | Acceptability of Medication and Nonmedication Treatment for Insomnia Among Female Veterans: Effects of Age, Insomnia Severity, and Psychiatric Symptoms | General population/not specified | Access to care/utilization; Chronic medical conditions | Sleep related
Taylor, 2023^520^ | Probable trauma associated sleep disorder in post-9/11 US Veterans | History of trauma; OEF/OIF/OND | N/a | Sleep related
Colvonen, 2020^521^ | Prevalence rates and correlates of insomnia disorder in post-9/11 Veterans enrolling in VA health care | OEF/OIF/OND | N/a | Sleep related
Carlson, 2019^522^ | Trauma as an insomnia precipitating event among women Veterans | History of trauma; General population/not specified | Chronic medical conditions; Interpersonal Violence | Sleep related
Kim, 2018^523^ | Responsiveness of Veterans affairs health care system to zolpidem safety warnings | General population/not specified | N/a | Sleep related
Rosen, 2019^524^ | Posttraumatic Stress Disorder Severity and Insomnia-Related Sleep Disturbances: Longitudinal Associations in a Large, Gender-Balanced Cohort of Combat-Exposed Veterans | OEF/OIF/OND | N/a | Sleep related
Kim, 2019^525^ | Predictors of long-term and high-dose use of zolpidem in Veterans | General population/not specified | N/a | Sleep related
Song, 2018^526^ | Caregiving-Related Sleep Problems and Their Relationship to Mental Health and Daytime Function in Female Veterans | General population/not specified | N/a | Sleep related
Carlson, 2021^527^ | Insomnia Precipitating Events among Women Veterans: The Impact of Traumatic and Nontraumatic Events on Sleep and Mental Health Symptoms | General population/not specified | Chronic medical conditions | Sleep related
Mahoney, 2022^528^ | Longing for sleep after violence: The impact of PTSD symptoms, avoidance, and pain on insomnia among female Veterans | History of trauma; General population/not specified | Chronic Pain/Opioids; Interpersonal Violence | Sleep related
Gaffey, 2020^529^ | The role of insomnia in the association between posttraumatic stress disorder and hypertension | OEF/OIF/OND | Chronic medical conditions | Sleep related
Interpersonal Violence
Webermann, 2023^530^ | A Two-Year Examination of Intimate Partner Violence and Associated Mental and Physical Health among Sexual Minority and Heterosexual Women Veterans | General population/not specified | General mental health; Physical pain related to IPV (eg, stomach pain, headaches, dizziness) | IPV
Tuepker, 2023^531^ | High-Risk Encounters: Primary Care Experiences of Women Living with Intimate Partner Violence, and Implications for the Patient Centered Medical Home | History of trauma | Health care organization/delivery of care for WVs | IPV
Miller, 2023^532^ | Intimate Partner Violence Screening for Women in the Veterans Health Administration: Temporal Trends from the Early Years of Implementation 2014-2020 | General population/not specified | Preventative health; Health care organization/delivery of care for WV | IPV
Kim, 2023^533^ | Experience of Intimate Partner Violence and Associated Psychiatric, Neurobehavioral, and Functional Burden in Male and Female Veterans: Implications for Treatment | OEF/OIF/OND | General mental health | IPV
Iverson, 2023^234^ | Integrating Intimate Partner Violence Screening Programs in Primary Care: Results from a Hybrid-II Implementation-Effectiveness RCT | General population/not specified | Health care organization/delivery of care for WVs | IPV
Goldstein, 2023^534^ | Lifetime history of interpersonal partner violence is associated with insomnia among midlife women Veterans | History of trauma | General mental health | IPV
Dichter, 2023^363^ | Clinical Response to Positive Screens for Intimate Partner Violence in the Veterans Health Administration: Findings from Review of Medical Records | General population/not specified | Preventative health | IPV
Shayani, 2022^535^ | Women Tell All: A Comparative Thematic Analysis of Women’s Perspectives on Two Brief Counseling Interventions for Intimate Partner Violence | History of trauma | Access to care/utilization; Health care organization/delivery of care for WVs | IPV
Iverson, 2022^536^ | PTSD and Depression Symptoms Increase Women’s Risk for Experiencing Future Intimate Partner Violence | History of trauma; General population/not specified | Substance Use; General mental health | IPV
Iverson, 2022^537^ | Effects of Intimate Partner Violence During COVID-19 and Pandemic-Related Stress on the Mental and Physical Health of Women Veterans | History of trauma | General mental health; Chronic medical conditions | IPV
Watkins, 2021^538^ | A Dyadic Analysis of PTSD and Psychological Partner Aggression Among U.S. Iraq and Afghanistan Veterans: The Impact of Gender and Dual-Veteran Couple Status | OEF/OIF/OND | General mental health | IPV
Sorrentino, 2021^539^ | Mental health care in the context of intimate partner violence: Survivor perspectives | History of trauma | Health care organization/delivery of care for WVs; General mental health | IPV
Portnoy, 2021^364^ | A Multisite Quality Improvement Initiative to Enhance the Adoption of Screening Practices for Intimate Partner Violence Into Routine Primary Care for Women Veterans | Justice-involved ; Other: providers | Preventative health; Health care organization/delivery of care for WV | IPV
Iverson, 2021^241^ | Recovering From Intimate Partner Violence Through Strengths and Empowerment: Findings From a Randomized Clinical Trial | History of trauma | N/a | IPV
Creech, 2021^540^ | Intimate Partner Violence Among Pregnant Veterans: Prevalence, Associated Mental Health Conditions, and Health Care Utilization | General population/not specified | Reproductive Mental Health; Reproductive health | IPV
Adjognon, 2021^541^ | Getting routine intimate partner violence screening right: Implementation strategies used in Veterans Health Administration (VHA) primary care | Other: provider/staff study | Health care organization/delivery of care for WVs | IPV
Portnoy, 2020^542^ | A Longitudinal Analysis of Women Veterans’ Partner Violence Perpetration: the Roles of Interpersonal Trauma and Posttraumatic Stress Symptoms | History of trauma | General mental health | IPV
Makaroun, 2020^543^ | Association of Health Conditions and Health Service Utilization with Intimate Partner Violence Identified via Routine Screening among Middle-Aged and Older Women | General population/not specified | Preventative health; Access to care/utilization | IPV
Iverson, 2020^544^ | Intimate Partner Violence Among Female OEF/OIF/OND Veterans Who Were Evaluated for Traumatic Brain Injury in the Veterans Health Administration: A Preliminary Investigation | History of trauma; OEF/OIF/OND | Chronic medical conditions | IPV
Dichter, 2020^545^ | Missed Opportunity for HIV Prevention Among a High-Risk Population of Women Experiencing Intimate Partner Violence | General population/not specified | Preventative health | IPV
Dichter, 2020^546^ | Middle-aged Women’s Experiences of Intimate Partner Violence Screening and Disclosure: “It’s a private matter. It’s an embarrassing situation” | History of trauma | Health care organization/delivery of care for WVs | IPV
Iverson, 2019^547^ | Intimate Partner Violence Screening Programs in the Veterans Health Administration: Informing Scale-up of Successful Practices | Other: administrators and clinicians | Health care organization/delivery of care for WVs | IPV
Iovine-Wong, 2019^548^ | Intimate Partner Violence, Suicide, and Their Overlapping Risk in Women Veterans: A Review of the Literature | General population/not specified | Suicide/Non-suicidal self-injury | IPV
Huston, 2019^549^ | Associations between disordered eating and intimate partner violence mediated by depression and posttraumatic stress disorder symptoms in a female Veteran sample | History of trauma | General mental health | IPV
Danitz, 2019^550^ | When user-centered design meets implementation science: integrating provider perspectives in the development of an intimate partner violence intervention for women treated in the United States’ largest integrated health care system | Other: VA providers involved in coordinating IPV related care | N/a | IPV
Rosenfeld, 2018^551^ | Male partner reproductive coercion among women Veterans | General population/not specified | Access to care/utilization; Reproductive health | IPV
Portnoy, 2018^552^ | Accuracy and Acceptability of a Screening Tool for Identifying Intimate Partner Violence Perpetration among Women Veterans: A Pre-Implementation Evaluation | General population/not specified | Preventative health; N/a | IPV
Iverson, 2018^553^ | Adoption, penetration, and effectiveness of a secondary risk screener for intimate partner violence: Evidence to inform screening practices in integrated care settings | General population/not specified | Access to care/utilization | IPV
Dichter, 2018^554^ | Women’s Health care Utilization Following Routine Screening for Past-Year Intimate Partner Violence in the Veterans Health Administration | General population/not specified | Preventative health; Access to care/utilization | IPV
Dardis, 2018^555^ | Empowerment, PTSD and revictimization among women who have experienced intimate partner violence | History of trauma | General mental health | IPV
Bartlett, 2018^556^ | Intimate partner violence and disordered eating among male and female Veterans | History of trauma | General mental health | IPV
Sparrow, 2017^240^ | Systematic review of mental health disorders and intimate partner violence victimisation among military populations | General population/not specified | General mental health | IPV
Meredith, 2017^557^ | Primary Care Providers with More Experience and Stronger Self-Efficacy Beliefs Regarding Women Veterans Screen More Frequently for Interpersonal Violence | Other: VA primary care providers | Preventative health; VA Women’s Health Workforce | IPV
Iverson, 2017^558^ | Intimate Partner Violence Victimization and Associated Implications for Health and Functioning Among Male and Female Post-9/11 Veterans | OEF/OIF/OND | N/a | IPV
Dichter, 2017^559^ | Disproportionate Mental Health Burden Associated With Past-Year Intimate Partner Violence Among Women Receiving Care in the Veterans Health Administration | History of trauma | Substance Use; General mental health | IPV
Dichter, 2017^560^ | Intimate Partner Violence Screening in the Veterans Health Administration: Demographic and Military Service Characteristics | General population/not specified | Preventative health | IPV
Dardis, 2017^561^ | Intimate partner violence among women Veterans by sexual orientation | Sexual minoritized populations | General mental health; SDOH | IPV
Dardis, 2017^562^ | Intimate partner stalking: Contributions to PTSD symptomatology among a national sample of women Veterans | History of trauma | General mental health | IPV
Creech, 2017^563^ | Use and Experience of Recent Intimate Partner Violence Among Women Veterans Who Deployed to Iraq and Afghanistan | OEF/OIF/OND | Substance Use; General mental health | IPV
Kimerling, 2016^564^ | Prevalence of Intimate Partner Violence among Women Veterans who Utilize Veterans Health Administration Primary Care | History of trauma; General population/not specified | N/a | IPV
Iverson, 2016^565^ | Female Veterans’ preferences for counseling related to intimate partner violence: Informing patient-centered interventions | History of trauma; General population/not specified | Health care organization/delivery of care for WVs | IPV
Rodriguez, 2023^566^ | Associations among military sexual trauma, positive alcohol expectancies, and coping behaviors in female Veterans | History of trauma | Substance Use; Coping behaviors | MST
Reinhardt, 2023^567^ | In Their Own Words: Women Veterans Identify the Personal Consequences of Military Sexual Trauma Victimization | History of trauma | General mental health; PTSD | MST
Monteith, 2023^568^ | Military Sexual Trauma Among Women Veterans Using Veterans Health Administration Reproductive Health Care: Screening Challenges and Associations with Post-Military Suicidal Ideation and Suicide Attempts | OEF/OIF/OND | Suicide/Non-suicidal self-injury; Reproductive health | MST
Katz, 2023^237^ | Delivering brief warrior renew over video teleconferencing to women Veterans with military sexual trauma: A pragmatic trial | History of trauma | Health care organization/delivery of care for WVs | MST
Kalvesmaki, 2023^569^ | The Impact of Resilience on Employment Among Post-9/11 Veterans With and Without Military Sexual Trauma Exposure | History of trauma; OEF/OIF/OND | SDOH | MST
Holliday, 2023^570^ | Military sexual trauma among Veterans using and not using VA justice-related programing: A national examination | Justice-involved ; General population/not specified | Access to care/utilization | MST
Hargrave, 2023^571^ | Factors Associated with Military Sexual Trauma (MST) Disclosure During VA Screening Among Women Veterans | General population/not specified | Preventative health; SDOH | MST
Galovski, 2023^572^ | The Relative Impact of Different Types of Military Sexual Trauma on Long-Term PTSD, Depression, and Suicidality | History of trauma; General population/not specified | Suicide/Non-suicidal self-injury; General mental health | MST
Doucette, 2023^310^ | The Effects of Adverse Childhood Experiences and Warfare Exposure on Military Sexual Trauma Among Veterans | OEF/OIF/OND | Other Violence | MST
Blais, 2022^573^ | Interpersonal Trauma and Sexual Function and Satisfaction: The Mediating Role of Negative Affect Among Survivors of Military Sexual Trauma | General population/not specified | Reproductive health | MST
Preston, 2022^574^ | Defeated No More: Meaning-Making After Military Sexual Trauma | History of trauma | N/a | MST
Paulson, 2022^575^ | Contrasting ecological contexts among treatment-seeking military sexual assault survivors: Consideration of relationships with sexual and gender minority identification | History of trauma | SDOH | MST
Patel, 2022^576^ | Correlates and clinical associations of military sexual assault in Gulf War era U.S. Veterans: Findings from a national sample | History of trauma | General mental health; Harassment/discrimination | MST
Nichter, 2022^577^ | Military sexual trauma in the United States: Results from a population-based study | General population/not specified | Access to care/utilization; General mental health | MST
Monteith, 2022^578^ | Institutional Betrayal and Closeness Among Women Veteran Survivors of Military Sexual Trauma: Associations with Self-Directed Violence and Mental Health Symptoms | History of trauma | Suicide/Non-suicidal self-injury | MST
McBain, 2022^579^ | The Relationship Between Provider Gender Preferences and Perceptions of Providers Among Veterans Who Experienced Military Sexual Trauma | History of trauma | Health care organization/delivery of care for WVs | MST
Hargrave, 2022^580^ | Veterans Health Administration Screening for Military Sexual Trauma May Not Capture Over Half of Cases Among Midlife Women Veterans | General population/not specified | Preventative health; Access to care/utilization | MST
Gaffey, 2022^581^ | Military sexual trauma and incident hypertension: a 16-year cohort study of young and middle-aged men and women | OEF/OIF/OND | Chronic medical conditions | MST
Wiblin, 2021^582^ | Predictors of Unbearability, Unlovability, and Unsolvability in Veterans With Military-Sexual-Trauma-Related Posttraumatic Stress Disorder | History of trauma | General mental health | MST
Wiblin, 2021^583^ | A Factor Analysis of the Suicide Cognitions Scale in Veterans with Military Sexual Trauma-Related Posttraumatic Stress Disorder | General population/not specified | N/a | MST
Tannahill, 2021^584^ | Gender as a moderator of the association of military sexual trauma and posttraumatic stress symptoms | General population/not specified | General mental health | MST
Sumner, 2021^585^ | Military Sexual Trauma and Adverse Mental and Physical Health and Clinical Comorbidity in Women Veterans | History of trauma; General population/not specified | Suicide/Non-suicidal self-injury; Substance Use | MST
Street, 2021^586^ | Veterans’ perspectives on military sexual trauma-related communication with VHA providers | General population/not specified | Preventative health; Health care organization/delivery of care for WV | MST
Newins, 2021^587^ | Psychological outcomes following sexual assault: Differences by sexual assault setting | OEF/OIF/OND | General mental health | MST
Monteith, 2021^588^ | Assessing Institutional Betrayal Among Female Veterans Who Experienced Military Sexual Trauma: A Rasch Analysis of the Institutional Betrayal Questionnaire.2 | History of trauma | Access to care/utilization | MST
Monteith, 2021^589^ | Institutional betrayal and help-seeking among women survivors of military sexual trauma | History of trauma | Access to care/utilization; General mental health | MST
Kelly, 2021^590^ | Barriers to PTSD treatment-seeking by women Veterans who experienced military sexual trauma decades ago: The role of institutional betrayal | History of trauma | Access to care/utilization; Other Violence | MST
Hannan, 2021^591^ | Posttraumatic Stress Symptom Severity Mediates the Relationship Between Military Sexual Trauma and Tension Reduction Behaviors in Male and Female Veterans | History of trauma | General mental health | MST
Felder, 2021^592^ | Life course perspective on the role of military sexual trauma as a pathway to homelessness for female Veterans | People with experiences of homelessness | SDOH | MST
Blais, 2021^593^ | The association of assault military sexual trauma and sexual function among partnered female service members and Veterans: the mediating roles of depression and sexual self-schemas | General population/not specified | General mental health; sexual function | MST
Monteith, 2020^594^ | Military sexual trauma survivors’ perceptions of Veterans health administration care: A qualitative examination | History of trauma | Access to care/utilization; Health care organization/delivery of care for WV | MST
Khan, 2020^595^ | How do gender and military sexual trauma impact PTSD symptoms in cognitive processing therapy and prolonged exposure? | OEF/OIF/OND | General mental health | MST
Gross, 2020^596^ | Sex Differences in Military Sexual Trauma and Severe Self-Directed Violence | OEF/OIF/OND | Suicide/Non-suicidal self-injury | MST
Gilmore, 2020^239^ | Emotion Dysregulation Predicts Dropout from Prolonged Exposure Treatment among Women Veterans with Military Sexual Trauma-Related Posttraumatic Stress Disorder | History of trauma | Access to care/utilization; General mental health | MST
Gibson, 2020^597^ | Military Sexual Trauma in Older Women Veterans: Prevalence and Comorbidities | General population/not specified | Long-term care/aging | MST
Garneau-Fournier, 2020^598^ | Factors Associated with Sexual Satisfaction among Veterans Who Have Experienced Military Sexual Trauma | History of trauma | General mental health; sexual satisfaction | MST
Pulverman, 2019^599^ | Sexual Assault in the Military and Increased Odds of Sexual Pain Among Female Veterans | History of trauma | General mental health; Reproductive health | MST
Pulverman, 2019^236^ | Military Sexual Trauma and Sexual Health in Women Veterans: A Systematic Review | History of trauma | Reproductive health | MST
Holder, 2019^600^ | Predictors of dropout from a randomized clinical trial of cognitive processing therapy for female Veterans with military sexual trauma-related PTSD | History of trauma | Access to care/utilization; General mental health | MST
Gundlapalli, 2019^601^ | Combining Natural Language Processing of Electronic Medical Notes With Administrative Data to Determine Racial/Ethnic Differences in the Disclosure and Documentation of Military Sexual Trauma in Veterans | Racial/ethnic minoritized; OEF/OIF/OND | SDOH | MST
Gross, 2019^602^ | Meaning in life following deployment sexual trauma: Prediction of posttraumatic stress symptoms, depressive symptoms, and suicidal ideation | OEF/OIF/OND | General mental health | MST
Dichter, 2019^603^ | Women’s Participation in Research on Intimate Partner Violence: Findings on Recruitment, Retention, and Participants’ Experiences | History of trauma | research participation | MST
Cichowski, 2019^604^ | Female Veterans’ Experiences With VHA Treatment for Military Sexual Trauma | History of trauma | Health care organization/delivery of care for WVs | MST
Bovin, 2019^605^ | The Impact of Assessment Modality and Demographic Characteristics on Endorsement of Military Sexual Trauma | Sexual minoritized populations; Racial/ethnic minoritized; History of trauma | Preventative health | MST
Bergman, 2019^606^ | Primary Care Providers’ Perspectives on Providing Care to Women Veterans with Histories of Sexual Trauma | Other: primary care providers with any number of women Veterans on their panels | VA Women’s Health Workforce | MST
Averill, 2019^607^ | Sex Differences in Correlates of Risk and Resilience Associated with Military Sexual Trauma | History of trauma | General mental health | MST
Wilson, 2018^235^ | The Prevalence of Military Sexual Trauma: A Meta-Analysis | General population/not specified | N/a | MST
Pandey, 2018^608^ | Military Sexual Trauma and Obesity Among Women Veterans | History of trauma | General mental health; obesity | MST
Gross, 2018^609^ | Does Deployment-Related Military Sexual Assault Interact with Combat Exposure to Predict Posttraumatic Stress Disorder in Female Veterans? | OEF/OIF/OND | General mental health | MST
Freysteinson, 2018^610^ | Body Image Perceptions of Women Veterans With Military Sexual Trauma | People with experiences of homelessness | SDOH | MST
Foynes, 2018^611^ | “Who Are You Going to Tell? Who’s Going to Believe You?” | History of trauma | General mental health | MST
Dardis, 2018^612^ | Labeling of deployment sexual harassment experiences among male and female Veterans | OEF/OIF/OND | General mental health | MST
Calhoun, 2018^613^ | The Association Between Military Sexual Trauma and Use of VA and Non-VA Health Care Services Among Female Veterans With Military Service in Iraq or Afghanistan | OEF/OIF/OND | Access to care/utilization; General mental health | MST
Brownstone, 2018^614^ | The Phenomenology of Military Sexual Trauma Among Women Veterans | History of trauma | N/a | MST
Blais, 2018^615^ | Assailant identity and self-reported nondisclosure of military sexual trauma in partnered women Veterans | General population/not specified | Access to care/utilization | MST
Beckman, 2018^616^ | Military Sexual Assault in Transgender Veterans: Results From a Nationwide Survey | Transgender or gender nonbinary | Substance Use; General mental health | MST
Story, 2017^617^ | Guided Imagery and Music with female military Veterans: An intervention development study | History of trauma | General mental health | MST
Katz, 2017^618^ | In Her Own Words: Semi-structured Interviews of Women Veterans Who Experienced Military Sexual Assault | History of trauma | Suicide/Non-suicidal self-injury; General mental health | MST
Gundlapalli, 2017^619^ | Using Structured and Unstructured Data to Refine Estimates of Military Sexual Trauma Status Among US Military Veterans | OEF/OIF/OND | N/a | MST
Brignone, 2017^620^ | Increased Health Care Utilization and Costs Among Veterans With a Positive Screen for Military Sexual Trauma | OEF/OIF/OND | Access to care/utilization | MST
Blais, 2017^621^ | Military sexual trauma is associated with post-deployment eating disorders among Afghanistan and Iraq Veterans | OEF/OIF/OND | General mental health | MST
Wolff, 2016^622^ | Reporting Military Sexual Trauma: A Mixed-Methods Study of Women Veterans’ Experiences Who Served From World War II to the War in Afghanistan | History of trauma; OEF/OIF/OND ; Gulf War I; Vietnam ; Other: World War II | Access to care/utilization | MST
Laws, 2016^623^ | Within-unit relationship quality mediates the association between military sexual trauma and posttraumatic stress symptoms in Veterans separating from military service | OEF/OIF/OND | General mental health | MST
Kimerling, 2016^624^ | Military Sexual Trauma and Suicide Mortality | History of trauma; General population/not specified | Suicide/Non-suicidal self-injury | MST
Gilmore, 2016^238^ | “Do you expect me to receive PTSD care in a setting where most of the other patients remind me of the perpetrator?”: Home-based telemedicine to address barriers to care unique to military sexual trauma and Veterans affairs hospitals | History of trauma | Health care organization/delivery of care for WVs; General mental health | MST
Gilmore, 2016^625^ | Military Sexual Trauma and Co-occurring Posttraumatic Stress Disorder, Depressive Disorders, and Substance Use Disorders among Returning Afghanistan and Iraq Veterans | History of trauma; OEF/OIF/OND | Substance Use; General mental health | MST
Gibson, 2016^626^ | Sexual Assault, Sexual Harassment, and Physical Victimization during Military Service across Age Cohorts of Women Veterans | General population/not specified | Long-term care/aging | MST
Gaher, 2016^627^ | Alexithymia, Coping Styles and Traumatic Stress Symptoms in a Sample of Veterans Who Experienced Military Sexual Trauma | History of trauma; General population/not specified | General mental health | MST
Barth, 2016^628^ | Military Sexual Trauma Among Recent Veterans: Correlates of Sexual Assault and Sexual Harassment | OEF/OIF/OND | N/a | MST
Rossi, 2023^629^ | The association between lifetime trauma exposure typologies and mental health outcomes among Veterans | General population/not specified | General mental health; Other Violence | Other interpersonal trauma
Esopenko, 2023^630^ | Characterizing the Influence of Exposure to Military Sexual Trauma and Intimate Partner Violence on Mental Health Outcomes among Female Veterans | History of trauma | General mental health | Other interpersonal trauma
Relyea, 2020^631^ | Military Sexual Trauma and Intimate Partner Violence: Subtypes, Associations, and Gender Differences | OEF/OIF/OND | N/a | Other interpersonal trauma
Combellick, 2019^632^ | Trauma and Sexual Risk: Do Men and Women Veterans Differ? | History of trauma | N/a | Other interpersonal trauma
Dichter, 2018^633^ | Women Veterans’ Experiences of Intimate Partner Violence and Non-Partner Sexual Assault in the Context of Military Service: Implications for Supporting Women’s Health and Well-Being | General population/not specified | General mental health; SDOH | Other interpersonal trauma
Bomyea, 2017^634^ | Trauma-Related Disgust in Veterans With Interpersonal Trauma | History of trauma | General mental health | Other interpersonal trauma
Danan, 2022^242^ | The Relationship Between Sexual Assault History and Cervical Cancer Screening Completion Among Women Veterans in the Veterans Health Administration | History of trauma | Preventative health | Sexual violence
Edmonds, 2021^244^ | Associations Between Sexual Assault and Reproductive and Family Planning Behaviors and Outcomes in Female Veterans | General population/not specified | Reproductive health | Sexual violence
VanderWeg, 2020^243^ | Lifetime History of Sexual Assault and Emergency Department Service Use among Women Veterans | General population/not specified | Access to care/utilization; General mental health | Sexual violence
Dognin, 2017^245^ | Group education sessions for women Veterans who experienced sexual violence: Qualitative findings | History of trauma | Access to care/utilization; General mental health | Sexual violence
Schry, 2016^635^ | Sexual revictimization among Iraq and Afghanistan war era Veterans | OEF/OIF/OND | N/a | Sexual violence
Other Violence
Morgan, 2022^247^ | The interaction of exposure to adverse childhood and combat experiences on the current mental health of new post-9/11 Veterans | OEF/OIF/OND | Suicide/Non-suicidal self-injury; General mental health | Exposure to violence
Murdoch, 2017^248^ | Changes in affect after completing a mailed survey about trauma: two pre- and post-test studies in former disability applicants for posttraumatic stress disorder | History of trauma; Gulf War I; Vietnam ; General population/not specified | General mental health; Interpersonal Violence | Exposure to violence
Monteith, 2023^636^ | “Feel the need to prepare for Armageddon even though I do not believe it will happen”: Women Veterans’ Firearm Beliefs and Behaviors during the COVID-19 Pandemic, Associations with Military Sexual Assault and Posttraumatic Stress Disorder Symptoms | OEF/OIF/OND | General mental health; Interpersonal Violence | Firearms
Monteith, 2023^637^ | Associations between deployment experiences, safety-related beliefs, and firearm ownership among women Veterans | OEF/OIF/OND | Safety beliefs & Deployment experiences | Firearms
Brandt, 2021^246^ | Documentation of Screening for Firearm Access by Health care Providers in the Veterans Health care System: A Retrospective Study | OEF/OIF/OND | Health care organization/delivery of care for WVs | Firearms
Monteith, 2020^638^ | Understanding female Veterans’ experiences and perspectives of firearms | General population/not specified | Suicide/Non-suicidal self-injury; N/a | Firearms
Substance Use
Fink, 2023^41^ | Trends in Cannabis-positive Urine Toxicology Test Results: US Veterans Health Administration Emergency Department Patients, 2008 to 2019 | General population/not specified | N/a | Prevalence, associations, and risk factors
Williams, 2022^639^ | Comparison of Substance Use Disorder Diagnosis Rates From Electronic Health Record Data With Substance Use Disorder Prevalence Rates Reported in Surveys Across Sociodemographic Groups in the Veterans Health Administration | General population/not specified | N/a | Prevalence, associations, and risk factors
Waddell, 2022^640^ | Age, sex, and race-varying rates of alcohol use, cannabis use, and alcohol and cannabis co-use in Veterans vs. non-Veterans | General population/not specified | N/a | Prevalence, associations, and risk factors
Stefanovics, 2022^641^ | Long-term impact of the U.S. Armed forces Zero-Tolerance drug policy on female Veterans | General population/not specified | N/a | Prevalence, associations, and risk factors
Hasin, 2022^642^ | Trends in Cannabis Use Disorder Diagnoses in the U.S. Veterans Health Administration, 2005-2019 | General population/not specified | N/a | Prevalence, associations, and risk factors
Begley, 2022^643^ | Veteran drug overdose mortality, 2010-2019 | General population/not specified | N/a | Prevalence, associations, and risk factors
Peltier, 2021^644^ | Sex Differences in Opioid Use Disorder Prevalence and Multimorbidity Nationally in the Veterans Health Administration | General population/not specified | Access to care/utilization; Chronic medical conditions | Prevalence, associations, and risk factors
Peltzman, 2020^645^ | Veteran drug overdose mortality, 2010-2019 | General population/not specified | N/a | Prevalence, associations, and risk factors
Agaku, 2020^646^ | U.S. Military Veteran Versus NonVeteran Use of Licit and Illicit Substances | General population/not specified | N/a | Prevalence, associations, and risk factors
Schweizer, 2019^47^ | Use of alcohol as a sleep aid, unhealthy drinking behaviors, and sleeping pill use among women Veterans | General population/not specified | General mental health; insomnia, PTSD symptoms | Prevalence, associations, and risk factors
Kalpakci, 2018^647^ | Gender differences among Veterans with alcohol use disorder nationally in the Veterans Health Administration | General population/not specified | N/a | Prevalence, associations, and risk factors
Hoggatt, 2017^648^ | Prevalence of substance misuse among US Veterans in the general population | General population/not specified | N/a | Prevalence, associations, and risk factors
Grossbard, 2017^649^ | Prevalence of Alcohol Misuse and Follow-Up Care in a National Sample of OEF/OIF VA Patients With and Without TBI | OEF/OIF/OND | Chronic medical conditions; traumatic brain injury | Prevalence, associations, and risk factors
Williams, 2016^650^ | Racial/Ethnic Differences in the Prevalence of Clinically Recognized Alcohol Use Disorders Among Patients from the U.S. Veterans Health Administration | Racial/ethnic minoritized; General population/not specified | SDOH | Prevalence, associations, and risk factors
Simpson, 2016^46^ | Alcohol Consumption Levels and All-Cause Mortality Among Women Veterans and Non-Veterans Enrolled in the Women’s Health Initiative | General population/not specified | Reproductive health; Long-term care/aging | Prevalence, associations, and risk factors
Shahoumian, 2016^651^ | Cigarette Smoking, Reduction and Quit Attempts: Prevalence Among Veterans With Coronary Heart Disease | General population/not specified | Chronic medical conditions | Prevalence, associations, and risk factors
Bastian, 2016^652^ | Differences in Active and Passive Smoking Exposures and Lung Cancer Incidence Between Veterans and Non-Veterans in the Women’s Health Initiative | General population/not specified | Preventative health; Cancer | Prevalence, associations, and risk factors
Than, 2023^50^ | Ask and Ask Again: Repeated Screening for Smoking Increases Likelihood of Prescription for Cessation Treatment Among Women Veterans | General population/not specified | Preventative health | Screening and detection
Giannitrapani, 2022^51^ | Provider perceptions of challenges to identifying women Veterans with hazardous substance use | Other: provider sample | N/a | Screening and detection
Hoggatt, 2018^54^ | Identifying women Veterans with unhealthy alcohol use using gender-tailored screening | General population/not specified | Preventative health; Health care organization/delivery of care for WV | Screening and detection
Bachrach, 2018^653^ | Alcohol screening and brief intervention in a representative sample of Veterans receiving primary care services | General population/not specified | Preventative health | Screening and detection
Williams, 2017^654^ | Influence of a targeted performance measure for brief intervention on gender differences in receipt of brief intervention among patients with unhealthy alcohol use in the Veterans Health Administration | General population/not specified | Preventative health | Screening and detection
Abraham, 2017^52^ | Providers’ perceptions of barriers and facilitators to disclosure of alcohol use by women Veterans | Other: Women’s Health Clinic Providers | Access to care/utilization; N/a | Screening and detection
Cucciare, 2016^53^ | Factors Affecting Women’s Disclosure of Alcohol Misuse in Primary Care: A Qualitative Study with U.S. Military Veterans | General population/not specified | Access to care/utilization | Stress and substance use
Buckheit, 2023^655^ | Rates and Correlates of Alcohol and Substance Use Among Women Veterans During the COVID-19 Pandemic: The Moderating Role of COVID-Specific Anxiety | General population/not specified | General mental health | Stress and substance use
Beckman, 2022^656^ | Associations Among Military Sexual Trauma, Opioid Use Disorder, and Gender | General population/not specified | Interpersonal Violence | Stress and substance use
Beckman, 2022^657^ | The impact of military sexual trauma and gender on receipt of evidence-based medication treatment among Veterans with opioid use disorder | History of trauma | Interpersonal Violence | Stress and substance use
Livingston, 2021^658^ | Longitudinal assessment of PTSD and illicit drug use among male and female OEF-OIF Veterans | OEF/OIF/OND | General mental health | Stress and substance use
Holzhauer, 2021^48^ | Targeting women Veteran’s stress-induced drinking with cognitive reappraisal: Mechanisms and moderators of change | General population/not specified | General mental health | Stress and substance use
Mahoney, 2020^659^ | Cross-lagged effects of posttraumatic stress disorder symptom severity and cigarette smoking among OEF/OIF/OND Veterans | OEF/OIF/OND | General mental health | Stress and substance use
Mahoney, 2020^660^ | The Roles of Alcohol Use Severity and Posttraumatic Stress Disorder Symptoms as Risk Factors for Women’s Intimate Partner Violence Experiences | History of trauma | General mental health; Interpersonal Violence | Stress and substance use
Gross, 2020^661^ | Sex Differences in Associations between Depression and Posttraumatic Stress Disorder Symptoms and Tobacco Use among Veterans of Recent Conflicts | OEF/OIF/OND | General mental health | Stress and substance use
Gross, 2020^662^ | Perceived Stress Mediates the Association between Deployment Sexual Trauma and Nicotine Dependence in Women Veterans | History of trauma; OEF/OIF/OND | Interpersonal Violence | Stress and substance use
Goldberg, 2019^663^ | A positive screen for military sexual trauma is associated with greater risk for substance use disorders in women Veterans | History of trauma | Interpersonal Violence | Stress and substance use
Yalch, 2018^664^ | Influence of military sexual assault and other military stressors on substance use disorder and PTS symptomology in female military Veterans | History of trauma | General mental health | Stress and substance use
Evans, 2018^665^ | Differences by Veteran/civilian status and gender in associations between childhood adversity and alcohol and drug use disorders | General population/not specified | N/a | Stress and substance use
Browne, 2018^666^ | Regular past year cannabis use in women Veterans and associations with sexual trauma | Sexual minoritized populations; History of trauma | Interpersonal Violence | Stress and substance use
Gradus, 2017^667^ | Gender differences in substance abuse, PTSD and intentional self-harm among Veterans health administration patients | History of trauma | Suicide/Non-suicidal self-injury; General mental health | Stress and substance use
Japuntich, 2016^668^ | Deployment stress, tobacco use, and postdeployment posttraumatic stress disorder: Gender differences | OEF/OIF/OND | General mental health | Stress and substance use
Ruiz, 2023^669^ | Cigarette Smoking Motives and Stages of Change in Smoking Cessation Among Veterans: Differences by Gender and Sexual Orientation | Sexual minoritized populations; General population/not specified | SDOH | Substance use in marginalized groups
Livingston, 2023^670^ | Causes of alcohol-attributable death and associated years of potential life lost among LGB and non-LGB Veteran men and women in Veterans Health Administration | Sexual minoritized populations | SDOH | Substance use in marginalized groups
Matson, 2022^49^ | Influence of a national transgender health care directive on receipt of alcohol-related care among transgender Veteran Health Administration patients with unhealthy alcohol use | Transgender or gender nonbinary | Preventative health; Health care organization/delivery of care for WV | Substance use in marginalized groups
Lynch, 2022^671^ | Alcohol-attributable deaths and years of potential life lost due to alcohol among Veterans: Overall and between persons with minoritized and non-minoritized sexual orientations | Sexual minoritized populations; General population/not specified | SDOH | Substance use in marginalized groups
Fletcher, 2022^672^ | Prevalence of social and economic stressors among transgender Veterans with alcohol and other drug use disorders | Transgender or gender nonbinary | SDOH | Substance use in marginalized groups
Williams, 2021^673^ | Patterns of Alcohol Use Among Transgender Patients Receiving Care at the Veterans Health Administration: Overall and Relative to Nontransgender Patients | Transgender or gender nonbinary; General population/not specified | N/a | Substance use in marginalized groups
Williams, 2021^674^ | Receipt of evidence-based alcohol-related care in a national sample of transgender patients with unhealthy alcohol use: Overall and relative to non-transgender patients | Transgender or gender nonbinary; General population/not specified | Access to care/utilization | Substance use in marginalized groups
Frost, 2021^675^ | Disparities in Documented Drug Use Disorders Between Transgender and Cisgender U.S. Veterans Health Administration Patients | Transgender or gender nonbinary | General mental health; SDOH | Substance use in marginalized groups
Dawson, 2021^676^ | Mental and Physical Health Correlates of Tobacco Use Among Transgender Veterans of the Iraq and Afghanistan Conflicts | Transgender or gender nonbinary; OEF/OIF/OND | N/a | Substance use in marginalized groups
Anderson-Carpenter, 2020^677^ | Prescription opioid misuse among heterosexual versus lesbian, gay, and bisexual military Veterans: Evidence from the 2015-2017 national survey of drug use and health | Sexual minoritized populations | N/a | Substance use in marginalized groups
Bukowski, 2017^678^ | Exploring Rural Disparities in Medical Diagnoses Among Veterans With Transgender-related Diagnoses Utilizing Veterans Health Administration Care | Transgender or gender nonbinary; Rural dwelling | General mental health | Substance use in marginalized groups
Weinberger, 2016^40^ | A review of research on smoking behavior in three demographic groups of Veterans: women, racial/ethnic minorities, and sexual orientation minorities | Sexual minoritized populations; Racial/ethnic minoritized | Preventative health | Substance use in marginalized groups
Lehavot, 2016^679^ | Association of Alcohol Misuse With Sexual Identity and Sexual Behavior in Women Veterans | Sexual minoritized populations; General population/not specified | SDOH | Substance use in marginalized groups
Bachrach, 2023^680^ | The role of gender and Veteran status in health care access among a national sample of U.S. adults with unhealthy alcohol use | General population/not specified | Access to care/utilization | Treatment access, utilization and outcomes
Simpson, 2022^39^ | Seeking care where they can: A systematic review of global trends in online alcohol treatment utilization among non-Veteran and Veteran women | General population/not specified | Access to care/utilization | Treatment access, utilization and outcomes
Pugatch, 2021^681^ | Rates and predictors of brief intervention for women Veterans returning from recent wars: Examining gaps in service delivery for unhealthy alcohol use | OEF/OIF/OND | N/a | Treatment access, utilization and outcomes
Meshberg-Cohen, 2021^682^ | Binge drinking following residential treatment for posttraumatic stress disorder among Veterans with and without alcohol use disorder | History of trauma | General mental health | Treatment access, utilization and outcomes
Livingston, 2021^42^ | Differential alcohol treatment response by gender following use of VetChange | OEF/OIF/OND | General mental health | Treatment access, utilization and outcomes
Stefanovics, 2020^43^ | Gender Difference in Substance Use and Psychiatric Outcomes Among Dually Diagnosed Veterans Treated in Specialized Intensive PTSD Programs | General population/not specified | Access to care/utilization; General mental health | Treatment access, utilization and outcomes
Chen, 2020^683^ | Racial/ethnic and gender differences in receipt of brief intervention among patients with unhealthy alcohol use in the U.S. Veterans Health Administration | Racial/ethnic minoritized | Health care organization/delivery of care for WVs | Treatment access, utilization and outcomes
Berg, 2020^684^ | Helping women Veterans quit smoking: a qualitative analysis of successful and unsuccessful attempts | General population/not specified | Preventative health | Treatment access, utilization and outcomes
Wilson, 2019^685^ | Lifetime Smoking Patterns and Preferences for Smoking Cessation Among Women Veterans Receiving Veterans Health Administration Care | General population/not specified | Health care organization/delivery of care for WVs | treatment access, utilization and outcomes
Taylor, 2019^686^ | Receipt of pharmacotherapy for alcohol use disorder by justice-involved women in the Veterans Health Administration | Justice-involved | N/a | Treatment access, utilization and outcomes
Danan, 2019^44^ | Smoking Cessation among Female and Male Veterans before and after a Randomized Trial of Proactive Outreach | General population/not specified | N/a | Treatment access, utilization and outcomes
Painter, 2018^687^ | Gender differences in service utilization among Operations Enduring Freedom, Iraqi Freedom, and New Dawn Veterans Affairs patients with severe mental illness and substance use disorders | OEF/OIF/OND | Access to care/utilization; General mental health | Treatment access, utilization and outcomes
Najavits, 2018^353^ | A randomized controlled trial of a gender-focused addiction model versus 12-step facilitation for women Veterans | Justice-involved ; General population/not specified | Health care organization/delivery of care for WVs | Treatment access, utilization and outcomes
Timko, 2017^362^ | Substance Use Disorder Treatment Services for Women in the Veterans Health Administration | Other: NA (VA facilities) | VA Women’s Health Workforce | Treatment access, utilization and outcomes
Pedersen, 2017^45^ | A randomized controlled trial of a web-based, personalized normative feedback alcohol intervention for young-adult Veterans | General population/not specified | Preventative health | Treatment access, utilization and outcomes
Abraham, 2017^688^ | Providers’ Perspectives on Barriers and Facilitators to Connecting Women Veterans to Alcohol-Related Care From Primary Care | Other: Providers from VA WH PC clinics | Access to care/utilization; Health care organization/delivery of care for WVs | Treatment access, utilization and outcomes
Myers, 2016^689^ | Factors Associated With Accepting Assistance for Smoking Cessation Among Military Veterans | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WV | Treatment access, utilization and outcomes
Lewis, 2016^690^ | Receptivity to alcohol-related care among U.S. women Veterans with alcohol misuse | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WV | Treatment access, utilization and outcomes
Berg, 2016^361^ | Identifying Opportunities to Improve Smoking Cessation Among Women Veterans at a Veterans Hospital | General population/not specified | Access to care/utilization | Treatment access, utilization and outcomes
Suicide/Non-Suicidal Self Injury
Smolenski, 2023^74^ | Informing measurement of gender differences in suicide risk and resilience: A national study of United States military Veterans | General population/not specified | General mental health | Research methods
Holliday, 2022^75^ | Factor Structure of the Suicide Cognitions Scale in a National Sample of Female Veterans | General population/not specified | Preventative health | Research methods
Gaeddert, 2020^76^ | Recruitment of women Veterans into suicide prevention research: Improving response rates with enhanced recruitment materials and multiple survey modalities | General population/not specified | Access to care/utilization | Research methods
Krishnamurti, 2023^72^ | Improving suicide prevention for women Veterans: Recommendations from VHA suicide prevention coordinators | General population/not specified | Access to care/utilization | VA practices and programs to address suicide
Chen, 2021^691^ | Assessment of Suicidal Intent in Self-directed Violence and Subsequent Care Received Among Military Veterans: A National Study of Gender Differences | General population/not specified | N/a | VA practices and programs to address suicide
Krishnamurti, 2023^692^ | Gender Differences in Connecting Veterans to Care Through the Veterans Crisis Line: A Mixed Methods Evaluation of Referrals to Suicide Prevention Coordinators | General population/not specified | Access to care/utilization; General mental health | VA practices and programs to address suicide
Chhatre, 2023^693^ | Relationship between Veterans Crisis Line risk rating and subsequent suicidal self-directed violence among Veteran callers: A gender comparison | General population/not specified | N/a | VA practices and programs to address suicide
Dichter, 2022^694^ | Gender differences in Veterans’ use of the Veterans Crisis Line (VCL): Findings from VCL call data | General population/not specified | N/a | VA practices and programs to address suicide
Dichter, 2022^695^ | Variation in call volume to the Veterans Crisis Line by women and men Veterans prior to and following onset of the COVID-19 pandemic | General population/not specified | Access to care/utilization; COVID-19 | VA practices and programs to address suicide
Carter, 2020^73^ | Examination of potential disparities in suicide risk identification and follow-up care within the Veterans Health Administration | General population/not specified | Substance Use | VA practices and programs to address suicide
Kumpula, 2019^365^ | An Evaluation of the Effectiveness of Evidence-Based Psychotherapies for Depression to Reduce Suicidal Ideation among Male and Female Veterans | General population/not specified | General mental health | VA practices and programs to address suicide
Denneson, 2021^67^ | Gender Differences in Recovery Needs After a Suicide Attempt: A National Qualitative Study of US Military Veterans | General population/not specified | Health care organization/delivery of care for WVs; General mental health | Prevalence studies, risk factor analyses, and formative evaluation
Denneson, 2020^66^ | Gender differences in the development of suicidal behavior among United States military Veterans: A national qualitative study | General population/not specified | Health care organization/delivery of care for WVs | Prevalence studies, risk factor analyses, and formative evaluation
Polzer, 2023^65^ | Women Veterans’ experiences discussing household firearms with their intimate partners: collaborative, devalued, and deferential relational types | General population/not specified | General mental health; household firearm access and storage with partners | Prevalence studies, risk factor analyses, and formative evaluation
Hoffmire, 2020^696^ | Reevaluating Suicide Mortality for Veterans With Data From the VA-DoD Mortality Data Repository, 2000-2010 | General population/not specified | N/a | Prevalence studies, risk factor analyses, and formative evaluation
Stefanovics, 2023^697^ | Sex-specific risk and resilience correlates of suicidal ideation in U.S. military Veterans | General population/not specified | General mental health; SDOH | Prevalence studies, risk factor analyses, and formative evaluation
Zelkowitz, 2021^698^ | Latent Class Analysis of Self-directed Violence and Indirect Self-harm Behaviors: Gender Differences and Associations With Mental Health Symptoms | General population/not specified | General mental health; Harassment/discrimination | Prevalence studies, risk factor analyses, and formative evaluation
Günak, 2021^70^ | Risk of Suicide Attempt in Patients With Recent Diagnosis of Mild Cognitive Impairment or Dementia | General population/not specified | General mental health; Long-term care/aging | Prevalence studies, risk factor analyses, and formative evaluation
Androulakis, 2021^699^ | Suicide attempts in us Veterans with chronic headache disorders: A 10-year retrospective cohort study | General population/not specified | Chronic Pain/Opioids; General mental health | Prevalence studies, risk factor analyses, and formative evaluation
Aslan, 2020^700^ | Suicidal ideation, behavior, and mortality in male and female US Veterans with severe mental illness | General population/not specified | General mental health | Prevalence studies, risk factor analyses, and formative evaluation
Bohnert, 2017^701^ | Substance use disorders and the risk of suicide mortality among men and women in the US Veterans Health Administration | General population/not specified | Substance Use | Prevalence studies, risk factor analyses, and formative evaluation
Blosnich, 2016^702^ | Population mental health among U.S. military Veterans: results of the Veterans Health Module of the Behavioral Risk Factor Surveillance System, 2011-2012 | General population/not specified | General mental health | Prevalence studies, risk factor analyses, and formative evaluation
Halverson, 2022^55^ | Nonsuicidal self-injury in Veterans: Prevalence, clinical characteristics, and gender differences from a national cohort | Gulf War I | N/a | Prevalence studies, risk factor analyses, and formative evaluation
Livingston, 2023^71^ | The Association of Military Sexual Harassment/Assault With Suicide Ideation, Plans, Attempts, and Mortality Among US Service Members/Veterans: A Meta-Analysis | History of trauma | Interpersonal Violence | Prevalence studies, risk factor analyses, and formative evaluation
Monteith, 2018^703^ | Psychiatric and Interpersonal Correlates of Suicide Ideation in Military Sexual Trauma Survivors: The National Health and Resilience in Veterans Study | History of trauma; General population/not specified | General mental health; Interpersonal Violence | Prevalence studies, risk factor analyses, and formative evaluation
Zelkowitz, 2023^704^ | Associations between DSM-5 posttraumatic stress disorder Criterion E2 endorsement and selected self-destructive behaviors in recent-era Veterans: A focus on disordered eating | History of trauma; OEF/OIF/OND | Preventative health; General mental health | Prevalence studies, risk factor analyses, and formative evaluation
Holliday, 2021^56^ | Association of lifetime homelessness and justice involvement with psychiatric symptoms, suicidal ideation, and suicide attempt among post-9/11 Veterans | Justice-involved; People with experiences of homelessness; OEF/OIF/OND | General mental health; SDOH | Prevalence studies, risk factor analyses, and formative evaluation
Maguen, 2023^68^ | Moral injury and peri- and post-military suicide attempts among post-9/11 Veterans | OEF/OIF/OND | moral injury | Prevalence studies, risk factor analyses, and formative evaluation
Lawrence, 2021^62^ | Temporal Sequencing of Mental Health Symptom Severity and Suicidal Ideation in Post-9/11 Men and Women Veterans Who Recently Separated from the Military | OEF/OIF/OND | General mental health | Prevalence studies, risk factor analyses, and formative evaluation
Hoffmire, 2021^64^ | A sex-stratified analysis of suicidal ideation correlates among deployed post-9/11 Veterans: Results from the survey of experiences of returning Veterans | OEF/OIF/OND | General mental health; SDOH | Prevalence studies, risk factor analyses, and formative evaluation
Decker, 2021^705^ | Military sexual trauma and suicidal ideation in VHA-care-seeking OEF/OIF/OND Veterans without mental health diagnosis or treatment | OEF/OIF/OND | Interpersonal Violence | Prevalence studies, risk factor analyses, and formative evaluation
Bullman, 2021^706^ | Risk of suicide among U.S. Veterans who deployed as part of Operation Enduring Freedom, Operation Iraqi Freedom, and Operation New Dawn | OEF/OIF/OND | N/a | Prevalence studies, risk factor analyses, and formative evaluation
Ronzitti, 2019^707^ | Gender Differences in Suicide and Self-Directed Violence Risk Among Veterans With Post-traumatic Stress and Substance Use Disorders | OEF/OIF/OND | Substance Use; General mental health | Prevalence studies, risk factor analyses, and formative evaluation
Monteith, 2018^708^ | Do unit and post-deployment social support influence the association between deployment sexual trauma and suicidal ideation? | OEF/OIF/OND | Interpersonal Violence; SDOH | Prevalence studies, risk factor analyses, and formative evaluation
Gradus, 2017^709^ | Gender Differences in Machine Learning Models of Trauma and Suicidal Ideation in Veterans of the Iraq and Afghanistan Wars | OEF/OIF/OND | Combat trauma | Prevalence studies, risk factor analyses, and formative evaluation
Montgomery, 2021^57^ | Gender Differences in the Predictors of Suicide-related Morbidity Among Veterans Reporting Current Housing Instability | People with experiences of homelessness | N/a | Prevalence studies, risk factor analyses, and formative evaluation
Boyer, 2021^60^ | Suicide, Homicide, and All-Cause Mortality Among Transgender and Cisgender Patients in the Veterans Health Administration | Transgender or gender nonbinary | Other Violence; mortality causes | Prevalence studies, risk factor analyses, and formative evaluation
Blosnich, 2021^59^ | Differences in Methods of Suicide Death Among Transgender and Nontransgender Patients in the Veterans Health Administration, 1999-2016 | Transgender or gender nonbinary | General mental health; SDOH | Prevalence studies, risk factor analyses, and formative evaluation
Blosnich, 2021^710^ | Differences in childhood adversity, suicidal ideation, and suicide attempt among Veterans and nonVeterans | General population/not specified | SDOH | Prevalence studies, risk factor analyses, and formative evaluation
Hoffmire, 2021^63^ | Gender Differences in Lifetime Prevalence and Onset Timing of Suicidal Ideation and Suicide Attempt Among Post-9/11 Veterans and NonVeterans | OEF/OIF/OND | N/a | Prevalence studies, risk factor analyses, and formative evaluation
Horwitz, 2019^711^ | Characteristics of Veteran and Civilian Suicide Decedents: A Sex-Stratified Analysis | General population/not specified | General mental health | Prevalence studies, risk factor analyses, and formative evaluation
Aboussouan, 2019^58^ | Non-suicidal self-injury, suicide ideation, and past suicide attempts: Comparison between transgender and gender diverse Veterans and non-Veterans | Transgender or gender nonbinary | SDOH | Prevalence studies, risk factor analyses, and formative evaluation
Monteith, 2020^712^ | Suicidal ideation, suicide attempt, and non-suicidal self-injury among female Veterans: Prevalence, timing, and onset | General population/not specified | SDOH | Prevalence studies, risk factor analyses, and formative evaluation
Gibson, 2022^61^ | Long-term Psychoactive Medications, Polypharmacy, and Risk of Suicide and Unintended Overdose Death Among Midlife and Older Women Veterans | General population/not specified | Substance Use; General mental health | Prevalence studies, risk factor analyses, and formative evaluation
Monteith, 2021^713^ | Female Veterans’ Willingness to Seek Veterans Health Administration and Non-Veterans Health Administration Services for Suicidal Thoughts and Mental Health Concerns | General population/not specified | Access to care/utilization | Prevalence studies, risk factor analyses, and formative evaluation
Holliday, 2021^69^ | Interpersonal Violence Throughout the Lifespan: Associations With Suicidal Ideation and Suicide Attempt Among a National Sample of Female Veterans | General population/not specified | Interpersonal Violence | Prevalence studies, risk factor analyses, and formative evaluation
Brignone, 2018^714^ | Suicidal ideation and behaviors among women Veterans with recent exposure to intimate partner violence | History of trauma | Interpersonal Violence | Prevalence studies, risk factor analyses, and formative evaluation
Monteith, 2017^715^ | Perceived Burdensomeness, Thwarted Belongingness, and Fearlessness about Death: Associations With Suicidal Ideation among Female Veterans Exposed to Military Sexual Trauma | History of trauma | General mental health; Interpersonal Violence | Prevalence studies, risk factor analyses, and formative evaluation
Khan, 2019^716^ | Examining the impact of different types of military trauma on suicidality in women Veterans | History of trauma; General population/not specified | Interpersonal Violence; Military stressors | Prevalence studies, risk factor analyses, and formative evaluation
Monteith, 2022^717^ | Prevalence and Correlates of Firearm Access Among Post-9/11 US Women Veterans Using Reproductive Health care: a Cross-Sectional Survey | OEF/OIF/OND | Interpersonal Violence; Other Violence | Prevalence studies, risk factor analyses, and formative evaluation
Lawrence, 2022^718^ | Psychosocial functioning deficits impact and are impacted by suicidal ideation in post-9/11 women Veterans | OEF/OIF/OND | General mental health | Prevalence studies, risk factor analyses, and formative evaluation
Tucker, 2019^719^ | Current and Military-Specific Gender Minority Stress Factors and Their Relationship with Suicide Ideation in Transgender Veterans | Transgender or gender nonbinary | SDOH | Prevalence studies, risk factor analyses, and formative evaluation
Carter, 2019^720^ | Discrimination and Suicidal Ideation Among Transgender Veterans: The Role of Social Support and Connection | Transgender or gender nonbinary | SDOH | Prevalence studies, risk factor analyses, and formative evaluation
Tucker, 2018^721^ | Hormone therapy, gender affirmation surgery, and their association with recent suicidal ideation and depression symptoms in transgender Veterans | Transgender or gender nonbinary | General mental health | Prevalence studies, risk factor analyses, and formative evaluation
Sayer, 2023^722^ | The Effects of Suicide Exposure on Mental Health Outcomes Among Post-9/11 Veterans: Protocol for an Explanatory, Sequential, Mixed Methods Study | OEF/OIF/OND | General mental health | Prevalence studies, risk factor analyses, and formative evaluation
Reproductive Mental Health
Solness, 2023^723^ | Relationship Factors in Internet-Delivered Psychological Interventions for Veterans Experiencing Postpartum Depression: Qualitative Analysis | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WVs | Peripartum Mental Health Care
Howard, 2023^724^ | Exploring the prevalence of antidepressant medication discontinuation among pregnant Veterans | General population/not specified | Health care organization/delivery of care for WVs | Peripartum Mental Health Care
Anderson, 2023^725^ | Perinatal Symptoms and Treatment Engagement in Female Veterans | General population/not specified | Access to care/utilization; Reproductive health | Peripartum Mental Health Care
Kroll-Desrosiers, 2022^336^ | Exploring the Acceptability of Expanded Perinatal Depression Care Practices Among Women Veterans | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WV | Peripartum Mental Health Care
Solness, 2021^77^ | Treating postpartum depression in rural Veterans using internet delivered CBT: program evaluation of MomMoodBooster | Rural dwelling | Access to care/utilization; SDOH | Peripartum Mental Health Care
Kroll-Desrosiers, 2021^726^ | Exploring the Extent of Perinatal Depression Screening in the Health Records of Veterans | General population/not specified | Preventative health; Health care organization/delivery of care for WV | Peripartum Mental Health Care
Gisseman, 2021^366^ | Depression Screening During Pregnancy: Compliance and Effectiveness in a Military Population | General population/not specified | Preventative health; Reproductive health | Peripartum Mental Health Care
Kroll-Desrosiers, 2020^727^ | Treatment and Management of Depression Symptoms in Pregnant Veterans: Varying Experiences of Mental Health Care in the Prenatal Period | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WV | Peripartum Mental Health Care
Kroll-Desrosiers, 2019^78^ | Bridging the Gap for Perinatal Veterans: Care by Mental Health Providers at the Veterans Health Administration | General population/not specified | Care Coordination; VA Women’s Health Workforce | Peripartum Mental Health Care
Pratt, 2023^728^ | Incidence and risk factors for postpartum mood and anxiety disorders among women Veterans | General population/not specified | Reproductive health | Prevalence and risk factors of peripartum mental health
Mattocks, 2022^729^ | Veterans’ Perinatal Care and Mental Health Experiences During the COVID-19 Pandemic: An Examination of the Role of Prior Trauma and Pandemic-Related Stressors | General population/not specified | Access to care/utilization; General mental health | Prevalence and risk factors of peripartum mental health
Creech, 2022^730^ | The impact of military sexual trauma on parent-infant bonding in a sample of perinatal women Veterans | General population/not specified | Interpersonal Violence | Prevalence and risk factors of peripartum mental health
Holzhauer, 2021^731^ | Prenatal Stress Exposure and Post-traumatic Stress Disorder Associated With Risk of Postpartum Alcohol Misuse Among Women Veterans | History of trauma; General population/not specified | Substance Use | Prevalence and risk factors of peripartum mental health
Coleman, 2021^80^ | Predictors of prenatal smoking among US women Veterans | OEF/OIF/OND | Substance Use | Prevalence and risk factors of peripartum mental health
Gross, 2020^79^ | A Longitudinal Investigation of Military Sexual Trauma and Perinatal Depression | General population/not specified | Interpersonal Violence | Prevalence and risk factors of peripartum mental health
Kroll-Desrosiers, 2019^732^ | Rates and Correlates of Depression Symptoms in a Sample of Pregnant Veterans Receiving Veterans Health Administration Care | General population/not specified | General mental health; Reproductive health | Prevalence and risk factors of peripartum mental health
Katon, 2020^82^ | Association of Depression and Post-Traumatic Stress Disorder with Receipt of Minimally Invasive Hysterectomy for Uterine Fibroids: Findings from the U.S. Department of Veterans Affairs | General population/not specified | Reproductive health | Reproductive lifecycle
Miller, 2018^81^ | Mental Health Across the Reproductive Cycle in Women Veterans | General population/not specified | Interpersonal Violence | Reproductive lifecycle
Caloudas, 2022^12^ | Prevalence of sexual desire and arousal difficulties among women Veterans: A retrospective cohort design | General population/not specified | General mental health | Sexual functioning
Blais, 2022^83^ | Mechanisms of the association between PTSD and sexual arousal and lubrication functioning among trauma-exposed female service members/Veterans | History of trauma | General mental health; N/a | Sexual functioning
Shepardson, 2021^733^ | Sexual dysfunction and preferences for discussing sexual health concerns among Veteran primary care patients | General population/not specified | Health care organization/delivery of care for WVs | Sexual functioning
Chronic Medical Conditions
Vassy, 2023^734^ | Cardiovascular Disease Risk Assessment Using Traditional Risk Factors and Polygenic Risk Scores in the Million Veteran Program | General population/not specified | Preventative health | Cardiovascular Disorders
Maskoun, 2023^735^ | Sex Differences in Stress-Induced (Takotsubo) Cardiomyopathy | General population/not specified | N/a | Cardiovascular Disorders
Zheutlin, 2022^736^ | Lipid-Lowering Therapy Use and Intensification among United States Veterans Following Myocardial Infarction or Coronary Revascularization between 2015 and 2019 | General population/not specified | N/a | Cardiovascular Disorders
Lu, 2022^737^ | Prediction of Cardiovascular and All-Cause Mortality After Myocardial Infarction in US Veterans | General population/not specified | Preventative health | Cardiovascular Disorders
Dhruva, 2022^738^ | Gender Differences in Guideline-Directed Medical Therapy for Cardiovascular Disease Among Young Veterans | OEF/OIF/OND | N/a | Cardiovascular Disorders
Mahtta, 2021^739^ | Recreational substance use among patients with premature atherosclerotic cardiovascular disease | General population/not specified | Substance Use | Cardiovascular Disorders
Lee, 2021^740^ | Sex-Related Disparities in Cardiovascular Health Care among Patients with Premature Atherosclerotic Cardiovascular Disease | General population/not specified | Access to care/utilization; SDOH | Cardiovascular Disorders
Jeon-Slaughter, 2021^85^ | Developing an Internally Validated Veterans Affairs Women Cardiovascular Disease Risk Score Using Veterans Affairs National Electronic Health Records | General population/not specified | N/a | Cardiovascular Disorders
Gaziano, 2021^741^ | Risk factors and prediction models for incident heart failure with reduced and preserved ejection fraction | General population/not specified | N/a | Cardiovascular Disorders
Gaffey, 2021^742^ | Post-9/11 Veterans’ heart disease knowledge, self-perceived risk, and prevention beliefs and behaviors | OEF/OIF/OND | Preventative health; Health care organization/delivery of care for WV | Cardiovascular Disorders
Ebrahimi, 2021^743^ | Association of Posttraumatic Stress Disorder and Incident Ischemic Heart Disease in Women Veterans | General population/not specified | General mental health; Long-term care/aging | Cardiovascular Disorders
Xiaofei, 2020^84^ | Differential Impact of Aging on Cardiovascular Risk in Women Military Service Members | General population/not specified | N/a | Cardiovascular Disorders
Weeda, 2020^744^ | Joint effect of race/ethnicity or location of residence and sex on low density lipoprotein-cholesterol among Veterans with type 2 diabetes: a 10-year retrospective cohort study | Racial/ethnic minoritized | SDOH | Cardiovascular Disorders
Vassy, 2020^745^ | Estimation of Atherosclerotic Cardiovascular Disease Risk among Patients in the Veterans Affairs Health Care System | General population/not specified | N/a | Cardiovascular Disorders
Mahtta, 2020^746^ | Statin Prescription Rates, Adherence, and Associated Clinical Outcomes Among Women with PAD and ICVD | General population/not specified | Preventative health; Chronic medical conditions | Cardiovascular Disorders
Cavanagh, 2020^88^ | Barriers to Cardiovascular Disease Preventive Behaviors Among OEF/OIF/OND Women and Men Veterans | OEF/OIF/OND | Preventative health | Cardiovascular Disorders
Ajam, 2020^747^ | Lower Post Myocardial Infarction Mortality Among Women Treated at Veterans Affairs Hospitals Compared to Men | General population/not specified | N/a | Cardiovascular Disorders
Vance, 2019^748^ | Increased Cardiovascular Disease Risk in Veterans With Mental Illness | General population/not specified | General mental health | Cardiovascular Disorders
Rodriguez, 2019^749^ | Association of Statin Adherence with Mortality in Patients with Atherosclerotic Cardiovascular Disease | General population/not specified | N/a | Cardiovascular Disorders
Mattingly, 2019^750^ | Association of Sex With Postoperative Mortality Among Patients With Heart Failure Who Underwent Elective Noncardiac Operations | General population/not specified | N/a | Cardiovascular Disorders
Hinojosa, 2019^751^ | Sex, Age, Race/Ethnicity, Veteran Status, and the Likelihood of Reporting Cardiovascular Conditions in the National Health Interview Survey | OEF/OIF/OND | SDOH | Cardiovascular Disorders
Gibson, 2018^752^ | Gender Differences in Cardiovascular Risk Related to Diabetes and Posttraumatic Stress Disorder | General population/not specified | General mental health; Long-term care/aging | Cardiovascular Disorders
Gerber, 2018^86^ | Association Between Mental Health Burden and Coronary Artery Disease in U.S. Women Veterans Over 45: A National Cross-Sectional Study | General population/not specified | Substance Use; General mental health | Cardiovascular Disorders
Ajam, 2018^753^ | Effect of carvedilol vs metoprolol succinate on mortality in heart failure with reduced ejection fraction | General population/not specified | N/a | Cardiovascular Disorders
Ventetuolo, 2017^754^ | Sex-based differences in Veterans with pulmonary hypertension: Results from the Veterans affairs-clinical assessment reporting and tracking database | General population/not specified | N/a | Cardiovascular Disorders
Sussman, 2017^755^ | The Veterans Affairs Cardiac Risk Score: Recalibrating the Atherosclerotic Cardiovascular Disease Score for Applied Use | General population/not specified | Preventative health | Cardiovascular Disorders
Haskell, 2017^756^ | Incident Cardiovascular Risk Factors Among Men and Women Veterans After Return From Deployment | OEF/OIF/OND | N/a | Cardiovascular Disorders
Goldstein, 2017^757^ | Impact of Gender on Satisfaction and Confidence in Cholesterol Control Among Veterans at Risk for Cardiovascular Disease | General population/not specified | N/a | Cardiovascular Disorders
Goldstein, 2017^758^ | Characteristics and Health Care Preferences Associated with Cardiovascular Disease Risk among Women Veterans | General population/not specified | Access to care/utilization; General mental health | Cardiovascular Disorders
Farmer, 2017^759^ | Sex Differences in 1-Year Outcomes After Percutaneous Coronary Intervention in the Veterans Health Administration | General population/not specified | Access to care/utilization | Cardiovascular Disorders
Aghazadehsanai, 2017^87^ | Prevalence of calcified carotid artery atheromas on digital panoramic images among perimenopausal and postmenopausal African American women | Racial/ethnic minoritized | Preventative health | Cardiovascular Disorders
Whitehead, 2019^760^ | Sex Differences in Veterans’ Cardiovascular Health | General population/not specified | N/a | Cardiovascular Disorders
Lee, 2023^761^ | Demographic, social and geographic factors associated with glycaemic control among US Veterans with new onset type 2 diabetes: a retrospective cohort study | General population/not specified | N/a | Endocrine disorders
Inoue, 2023^762^ | Iodine-Induced Hypothyroidism and Long-Term Risks of Incident Heart Failure | General population/not specified | Access to care/utilization | Endocrine disorders
Inoue, 2023^763^ | Iodinated Contrast Administration and Risks of Thyroid Dysfunction: A Retrospective Cohort Analysis of the U.S. Veterans Health Administration System | General population/not specified | Access to care/utilization | Endocrine disorders
Inoue, 2023^764^ | Iodine-Induced Hyperthyroidism and Long-term Risks of Incident Atrial Fibrillation and Flutter | General population/not specified | Access to care/utilization | Endocrine disorders
Gulanski, 2023^94^ | Metformin Prescription for U.S. Veterans with Prediabetes, 2010-2019 | General population/not specified | Preventative health | Endocrine disorders
Gray, 2023^91^ | Gender differences in social support for diabetes self-management: A qualitative study among Veterans | General population/not specified | SDOH | Endocrine disorders
Dawson, 2023^89^ | Weight Management Treatment Representations: A Novel Use of the Common Sense Model | General population/not specified | N/a | Endocrine disorders
Wander, 2022^765^ | The Incidence of Diabetes Among 2,777,768 Veterans With and Without Recent SARS-CoV-2 Infection | General population/not specified | COVID-19 infection | Endocrine disorders
Dyer, 2020^92^ | Tailoring an evidence-based lifestyle intervention to meet the needs of women Veterans with prediabetes | General population/not specified | Preventative health | Endocrine disorders
Breland, 2020^766^ | Differences in body mass index based on self-reported versus measured data from women Veterans | General population/not specified | Reproductive health | Endocrine disorders
Schmidt, 2019^767^ | Four Decades after War: Incident Diabetes among Women Vietnam-Era Veterans in the HealthViEWS Study | Vietnam | N/a | Endocrine disorders
Santhiveeran, 2019^768^ | The influence of obesity and sociodemographic factors on the health hardships among women Veterans | General population/not specified | N/a | Endocrine disorders
Breland, 2019^769^ | Obesity and Health Care Experiences among Women and Men Veterans | General population/not specified | Health care organization/delivery of care for WVs | Endocrine disorders
Gatwood, 2018^93^ | Differences in health outcomes associated with initial adherence to oral antidiabetes medications among Veterans with uncomplicated Type 2 diabetes: a 5-year survival analysis | General population/not specified | Preventative health; Chronic medical conditions | Endocrine disorders
Batch, 2018^367^ | Outcome by Gender in the Veterans Health Administration Motivating Overweight/Obese Veterans Everywhere Weight Management Program | General population/not specified | General mental health | Endocrine disorders
Breland, 2017^770^ | The Obesity Epidemic in the Veterans Health Administration: Prevalence Among Key Populations of Women and Men Veterans | General population/not specified | SDOH | Endocrine disorders
Vimalananda, 2016^90^ | Weight loss among women and men in the ASPIRE-VA behavioral weight loss intervention trial | General population/not specified | Preventative health | Endocrine disorders
LaFleur, 2016^771^ | Fracture Rates and Bone Density Among Postmenopausal Veteran and Non-Veteran Women From the Women’s Health Initiative | General population/not specified | Long-term care/aging | Endocrine disorders
Gray, 2016^95^ | Association Between Chronic Conditions and Physical Function Among Veteran and Non-Veteran Women With Diabetes | General population/not specified | Long-term care/aging; physical functioning | Endocrine disorders
Goodrich, 2016^772^ | Sex Differences in Weight Loss among Veterans with Serious Mental Illness: Observational Study of a National Weight Management Program | General population/not specified | General mental health | Endocrine disorders
Chang, 2016^96^ | Prevalence and risk of fracture diagnoses in women across the adult life span: a national cross-sectional study | General population/not specified | Access to care/utilization | Endocrine disorders
Bethel, 2016^97^ | Risk factors for osteoporotic fractures in persons with spinal cord injuries and disorders | General population/not specified | spinal cord injury | Endocrine disorders
Heredia, 2023^120^ | Association of Diet Quality with Metabolic (Dysfunction) Associated Fatty Liver Disease in Veterans in Primary Care | General population/not specified | Preventative health | Gastrointestinal Disorders
Pandey, 2016^121^ | Preventative care for patients with inflammatory bowel disease in the Veterans Health Administration | General population/not specified | Preventative health | Gastrointestinal Disorders
Lafferty, 2023^108^ | Women of the Gulf War: Understanding Their Military and Health Experiences Over 30 Years | Gulf War I | Health care organization/delivery of care for WVs; SDOH | Military Era associated chronic conditions
Dursa, 2023^773^ | Comparison of Health Outcomes Over Time Among Women 1990-1991 Gulf War Veterans, Women 1990-1991 Gulf Era Veterans, and Women in the U.S. General Population | Gulf War I | Long-term care/aging | Military Era associated chronic conditions
Cypel, 2023^774^ | Physical health of Post-9/11 U.S. Military Veterans in the context of Healthy People 2020 targeted topic areas: Results from the Comparative Health Assessment Interview Research Study | OEF/OIF/OND | N/a | Military Era associated chronic conditions
Gaffey, 2021^775^ | Baseline Characteristics from the Women Veterans Cohort Study: Gender Differences and Similarities in Health and Health care Utilization | OEF/OIF/OND | Access to care/utilization; Health care organization/delivery of care for WV | Military Era associated chronic conditions
Bullman, 2021^776^ | Cause-specific mortality risks among U.S. Veterans: 25 years after their service in the 1990-1991 gulf war | Gulf War I | N/a | Military Era associated chronic conditions
Sullivan, 2020^323^ | Prevalence and Patterns of Symptoms Among Female Veterans of the 1991 Gulf War Era: 25 Years Later | Gulf War I | Toxic Exposures | Military Era associated chronic conditions
Heboyan, 2019^777^ | Sex Differences in Gulf War Illness: A Reanalysis of Data From the CDC Air Force Study Using CDC and Modified Kansas Case Definitions | Gulf War I | N/a | Military Era associated chronic conditions
Dursa, 2019^325^ | Health Status of Female and Male Gulf War and Gulf Era Veterans: A Population-Based Study | Gulf War I | General mental health; Toxic Exposures | Military Era associated chronic conditions
Brown, 2019^778^ | Gender-based Differences among 1990-1991 Gulf War Era Veterans: Demographics, Lifestyle Behaviors, and Health Conditions | Gulf War I | N/a | Military Era associated chronic conditions
Coughlin, 2018^779^ | Study Protocol: Southern Women Veterans’ Health Study | General population/not specified | Access to care/utilization; Reproductive health | Military Era associated chronic conditions
Kilbourne, 2017^780^ | Physical Health Conditions Among a Population-Based Cohort of Vietnam-Era Women Veterans: Agreement Between Self-Report and Medical Records | Vietnam | Health care organization/delivery of care for WVs; SDOH | Military Era associated chronic conditions
Coughlin, 2017^107^ | A Review of Epidemiologic Studies of the Health of Gulf War Women Veterans | Gulf War I | General mental health; Reproductive health | Military Era associated chronic conditions
Harfouch, 2023^781^ | Impact of the COVID-19 Pandemic on the PrEP Cascade at Two Veterans Affairs Health care Systems | General population/not specified | Preventative health; Reproductive health | Infectious Diseases
Upchurch, 2022^112^ | COVID-19 Infection in the Veterans Health Administration: Gender-specific Racial and Ethnic Differences | Racial/ethnic minoritized; General population/not specified | Preventative health; SDOH | Infectious Diseases
Lynch, 2022^113^ | Sexual orientation-related disparities in health conditions that elevate COVID-19 severity | Sexual minoritized populations | Access to care/utilization | Infectious Diseases
Tsai, 2021^111^ | COVID-19 associated mortality and cardiovascular disease outcomes among US women Veterans | General population/not specified | N/a | Infectious Diseases
McGinnis, 2021^782^ | HIV care using differentiated service delivery during the COVID-19 pandemic: a nationwide cohort study in the US Department of Veterans Affairs | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WV | Infectious Diseases
Clark, 2021^109^ | Veteran Women Living With Human Immunodeficiency Virus Have Increased Risk of Human Papillomavirus (HPV)-Associated Genital Tract Cancers | General population/not specified | Cancer care | Infectious Diseases
Matson, 2018^783^ | Gender and alcohol use: Influences on HIV care continuum in a national cohort of patients with HIV | General population/not specified | Access to care/utilization; Substance Use | Infectious Diseases
Kramer, 2017^784^ | Hepatitis C virus-related complications are increasing in women Veterans: A national cohort study | General population/not specified | N/a | Infectious Diseases
Hotton, 2017^110^ | Prevalence and Predictors of Hospitalizations among HIV-Infected and At-Risk HIV-Uninfected Women | General population/not specified | SDOH | Infectious Diseases
Kanwal, 2016^785^ | Race and Gender Differences in the Use of Direct Acting Antiviral Agents for Hepatitis C Virus | General population/not specified | Access to care/utilization; SDOH | Infectious Diseases
Webster, 2023^786^ | Prosthesis nonuse and discontinuation in United States Veterans with major limb amputation: Results of a national survey | General population/not specified | Access to care/utilization | Musculoskeletal and Rheumatologic Disorders
RussellEsposito, 2023^102^ | Footwear limitations in women prosthesis users relate to more than preference | General population/not specified | N/a | Musculoskeletal and Rheumatologic Disorders
Norvell, 2023^787^ | The effect of depression on prosthesis prescription in men and women who have undergone a lower limb amputation | General population/not specified | Access to care/utilization; General mental health | Musculoskeletal and Rheumatologic Disorders
Littman, 2023^788^ | Differences in Prosthetic Prescription Between Men and Women Veterans After Transtibial or Transfemoral Lower-Extremity Amputation: A Longitudinal Cohort Study (2005-2018) | General population/not specified | Access to care/utilization | Musculoskeletal and Rheumatologic Disorders
Kuo, 2023^789^ | Gender differences in prosthesis-related outcomes among Veterans: Results of a national survey of U.S. Veterans | General population/not specified | Health care organization/delivery of care for WVs; prosthesis | Musculoskeletal and Rheumatologic Disorders
Meadows, 2022^790^ | Validity of Methods to Identify Individuals With Lower Extremity Amputation Using Department of Veterans Affairs Electronic Medical Records | General population/not specified | Health care organization/delivery of care for WVs | Musculoskeletal and Rheumatologic Disorders
Lehavot, 2022^103^ | Voices of Women Veterans with Lower Limb Prostheses: a Qualitative Study | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WV | Musculoskeletal and Rheumatologic Disorders
Aday, 2022^791^ | Association of Sex and Race With Incident Peripheral Artery Disease Among Veterans With Normal Ankle-Brachial Indices | General population/not specified | SDOH | Musculoskeletal and Rheumatologic Disorders
Vina, 2021^105^ | Use of Complementary and Alternative Therapy for Knee Osteoarthritis: Race and Gender Variations | Racial/ethnic minoritized; General population/not specified | SDOH; Complementary and alternative medicine | Musculoskeletal and Rheumatologic Disorders
Haskell, 2020^104^ | Incident Musculoskeletal Conditions Among Men and Women Veterans Returning From Deployment | OEF/OIF/OND | Chronic Pain/Opioids | Musculoskeletal and Rheumatologic Disorders
Higgins, 2017^792^ | Gender Differences in Demographic and Clinical Correlates among Veterans with Musculoskeletal Disorders | General population/not specified | General mental health; SDOH | Musculoskeletal and Rheumatologic Disorders
Goulet, 2016^793^ | The musculoskeletal diagnosis cohort: Examining pain and pain care among Veterans | General population/not specified | Chronic Pain/Opioids | Musculoskeletal and Rheumatologic Disorders
Quiñones, 2023^794^ | Hydroxychloroquine and Risk of Long QT Syndrome in Rheumatoid Arthritis: A Veterans Cohort Study With Nineteen-Year Follow-up | General population/not specified | N/a | Musculoskeletal and Rheumatologic Disorders
England, 2023^795^ | Identification of Multimorbidity Patterns in Rheumatoid Arthritis Through Machine Learning | General population/not specified | N/a | Musculoskeletal and Rheumatologic Disorders
Fadhil, 2022^106^ | Prevalence of neurological dysfunction and irregularities in people suffering from auto-immune conditions: An Iraqi perspective | OEF/OIF/OND | General mental health | Musculoskeletal and Rheumatologic Disorders
Sullivan-Baca, 2023^796^ | Psychiatric co-morbidity of drug-resistant epilepsy in Veterans | General population/not specified | Access to care/utilization; General mental health | Nervous System Disorders
Sullivan-Baca, 2023^797^ | Utilization of epilepsy care among Women Veterans: A population-based study | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WVs | Nervous System Disorders
Sofer, 2023^798^ | Genome-wide association study of obstructive sleep apnoea in the Million Veteran Program uncovers genetic heterogeneity by sex | General population/not specified | Health care organization/delivery of care for WVs; Chronic medical conditions | Nervous System Disorders
Moghtaderi, 2023^799^ | Identifying gaps in clinical evaluation and treatment of sleep-disordered breathing in women Veterans | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WVs | Nervous System Disorders
Merritt, 2023^99^ | Exploring Interactions Between Traumatic Brain Injury History and Gender on Medical Comorbidities in Military Veterans: An Epidemiological Analysis in the VA Million Veteran Program | General population/not specified | General mental health | Nervous System Disorders
Lopez, 2023^100^ | Prescribing Trends of Antiseizure Drugs in Women Veterans With Epilepsy | General population/not specified | Care Coordination; Reproductive health | Nervous System Disorders
Sullivan-Baca, 2022^800^ | Characterizing differences in psychiatric profiles between male and female Veterans with epilepsy and psychogenic non-epileptic seizures | General population/not specified | General mental health | Nervous System Disorders
Sullivan-Baca, 2022^801^ | Characterizing women Veterans receiving seizure care in the Veterans affairs health care system | General population/not specified | Access to care/utilization; General mental health | Nervous System Disorders
Sico, 2022^101^ | Characteristics and Gender Differences of Headache in the Veterans Health Administration: A National Cohort Study, Fiscal Year 2008-2019 | General population/not specified | Access to care/utilization | Nervous System Disorders
Seng, 2022^802^ | Frequency, Demographics, Comorbidities, and Health Care Utilization by Veterans With Migraine: A VA Nationwide Cohort Study | General population/not specified | Access to care/utilization | Nervous System Disorders
Merritt, 2022^803^ | Characterizing Sex Differences in Clinical and Functional Outcomes Among Military Veterans with a Comprehensive Traumatic Brain Injury Evaluation (CTBIE): A Million Veteran Program (MVP) Study | General population/not specified | N/a | Nervous System Disorders
Chung, 2022^98^ | In her own words: a phenomenological analysis of stories told by female service members and Veterans after traumatic brain injury | General population/not specified | N/a | Nervous System Disorders
Song, 2021^804^ | Sleep Disruption Due to Stress in Women Veterans: A Comparison between Caregivers and Noncaregivers | General population/not specified | General mental health | Nervous System Disorders
Martin, 2021^805^ | Sleep apnea in women Veterans: Results of a national survey of VA health care users | General population/not specified | Preventative health; Health care organization/delivery of care for WV | Nervous System Disorders
Cogan, 2020^806^ | Self-reported Participation Restrictions Among Male and Female Veterans With Traumatic Brain Injury in Veterans Health Administration Outpatient Polytrauma Programs | History of trauma; General population/not specified | Access to care/utilization | Nervous System Disorders
Rosman, 2019^807^ | Posttraumatic Stress Disorder and Risk for Stroke in Young and Middle-Aged Adults: A 13-Year Cohort Study | OEF/OIF/OND | General mental health | Nervous System Disorders
Amara, 2019^808^ | Predictors of Employment Status in Male and Female Post-9/11 Veterans Evaluated for Traumatic Brain Injury | OEF/OIF/OND | General mental health; SDOH | Nervous System Disorders
Nelson, 2018^809^ | Estimation of the Prevalence of Amyotrophic Lateral Sclerosis in the United States Using National Administrative Health care Data from 2002 to 2004 and Capture-Recapture Methodology | General population/not specified | N/a | Nervous System Disorders
Iverson, 2017^810^ | Traumatic brain injury and PTSD symptoms as a consequence of intimate partner violence | General population/not specified | General mental health; Interpersonal Violence | Nervous System Disorders
Rissling, 2016^811^ | Sleep Disturbance, Diabetes, and Cardiovascular Disease in Postmenopausal Veteran Women | General population/not specified | N/a | Nervous System Disorders
MacGregor, 2021^122^ | Health Profiles of Military Women and the Impact of Combat-Related Injury | OEF/OIF/OND | Combat-related injury | Other
Maynard, 2019^123^ | Characteristics of younger women Veterans with service connected disabilities | General population/not specified | Long-term care/aging | Other
Harrington, 2019^812^ | Gender Differences in Demographic and Health Characteristics of the Million Veteran Program Cohort | General population/not specified | N/a | Other
Maynard, 2018^813^ | Disability Rating, Age at Death, and Cause of Death in U.S. Veterans with Service-Connected Conditions | General population/not specified | General mental health; Long-term care/aging | Other
Clifford, 2022^124^ | The Interrelationship of Tinnitus and Hearing Loss Secondary to Age, Noise Exposure, and Traumatic Brain Injury | General population/not specified | N/a | Other
Kaul, 2023^119^ | Disparities in Antifibrotic Medication Utilization Among Veterans With Idiopathic Pulmonary Fibrosis | General population/not specified | N/a | Pulmonary Disorders
Bade, 2019^117^ | Sex Differences in Veterans Admitted to the Hospital for Chronic Obstructive Pulmonary Disease Exacerbation | General population/not specified | N/a | Pulmonary Disorders
Rinne, 2017^118^ | Implementation of guideline-based therapy for chronic obstructive pulmonary disease: Differences between men and women Veterans | General population/not specified | Health care organization/delivery of care for WVs | Pulmonary Disorders
Gregg, 2023^116^ | Predictors, Disparities, and Facility-Level Variation: SGLT2 Inhibitor Prescription Among US Veterans With CKD | Racial/ethnic minoritized | Preventative health | Renal Disorders
Hassan, 2022^814^ | Association of Uric Acid–Lowering Therapy With Incident Chronic Kidney Disease | General population/not specified | Preventative health | Renal Disorders
Akwo, 2022^815^ | Phenome-Wide Association Study of UMOD Gene Variants and Differential Associations With Clinical Outcomes Across Populations in the Million Veteran Program a Multiethnic Biobank | General population/not specified | UMOD gene variants | Renal Disorders
You, 2020^816^ | Mortality Risk in Chronic Kidney Disease Patients Transitioning to Dialysis: Impact of Opiate and Non-Opiate Use | General population/not specified | Chronic medical conditions; Post-ESRD mortality | Renal Disorders
Soohoo, 2019^817^ | Statin Therapy Before Transition to End-Stage Renal Disease With Posttransition Outcomes | General population/not specified | Preventative health | Renal Disorders
Kim, 2016^818^ | Tenofovir exposure alters associations of serum bicarbonate with chronic kidney disease risk in HIV-infected Veterans | General population/not specified | medication use | Renal Disorders
Markland, 2023^114^ | Optimizing remote access to urinary incontinence treatments for women Veterans (PRACTICAL): Study protocol for a pragmatic clinical trial comparing two virtual care options | General population/not specified | N/a | Urinary System Disorders
Tholemeier, 2022^115^ | Do medication prescription patterns follow guidelines in a cohort of women with interstitial cystitis/bladder pain syndrome? | General population/not specified | interstitial cystitis/bladder pain | Urinary System Disorders
Dubinskaya, 2022^819^ | Prevalence of Overactive Bladder Symptoms among Women with Interstitial Cystitis/Bladder Pain Syndrome | General population/not specified | N/a | Urinary System Disorders
Dallas, 2022^820^ | Demographic Differences and Disparities in the Misdiagnosis of Interstitial Cystitis/Bladder Pain Syndrome in a National Cohort of VA Patients | General population/not specified | N/a | Urinary System Disorders
Welch, 2021^821^ | Retrospective Review on the Safety and Efficacy of Nitrofurantoin for the Treatment of Cystitis in the Veteran Population with or without Renal Insufficiency | General population/not specified | N/a | Urinary System Disorders
Laden, 2021^822^ | Comorbidities in a Nationwide, Heterogenous Population of Veterans with Interstitial Cystitis/Bladder Pain Syndrome | General population/not specified | N/a | Urinary System Disorders
Volpe, 2020^823^ | Female Veterans with Diagnoses of Both Chronic Pelvic Pain and Overactive Bladder; How Do They Compare to Women Diagnosed with Interstitial Cystitis? | General population/not specified | General mental health; Reproductive health | Urinary System Disorders
Lynch, 2020^824^ | Sex and the Diagnostic Pathway to Bladder Cancer among Veterans: No Evidence of Disparity | General population/not specified | N/a | Urinary System Disorders
Ninivaggio, 2018^825^ | One and the Same? Nocturnal Enuresis and Overactive Bladder in the Female Veteran Population: Evaluation of a Large National Database | General population/not specified | General mental health; Interpersonal Violence | Urinary System Disorders
Bradley, 2017^826^ | Longitudinal associations between mental health conditions and overactive bladder in women Veterans | OEF/OIF/OND | General mental health; Interpersonal Violence | Urinary System Disorders
Reproductive Health
Schwarz, 2018^162^ | Induced abortion among women Veterans: data from the ECUUN study | General population/not specified | Abortions; Access to care/utilization | Other reproductive health services
Judge-Golden, 2022^163^ | Prior Abortions and Barriers to Abortion Access Reported by Pregnant Women Veterans | General population/not specified | Abortions; Access to care/utilization | Other reproductive health services
Friedman, 2022^126^ | Gynecologist Supply Deserts Across the VA and in the Community | General population/not specified | Access to reproductive health services; Access to care/utilization | Other reproductive health services
Vinekar, 2023^161^ | Using Primary Care Geographic Network Adequacy Metrics for VA Obstetric Referrals: a Foundation for Equitable, Timely, and Veteran-Centered Care | General population/not specified | Access to reproductive health services; Access to care/utilization | Other reproductive health services
Coady-Fariborzian, 2021^165^ | Twenty Years of Breast Reduction Surgery at a Veterans Affairs Medical Center | General population/not specified | Breast surgery; N/a | Other reproductive health services
Judge-Golden, 2020^145^ | Agreement between Self-Reported “Ideal” and Currently Used Contraceptive Methods among Women Veterans Using the Veterans Affairs Health care System | General population/not specified | Contraception; Access to care/utilization | Family planning
Judge-Golden, 2019^142^ | Financial Implications of 12-Month Dispensing of Oral Contraceptive Pills in the Veterans Affairs Health Care System | General population/not specified | Contraception; N/a | Family planning
Gawron, 2022^827^ | Oral Emergency Contraception Provision in the Veterans Health Administration: a Retrospective Cohort Study | General population/not specified | Contraception; Health care organization/delivery of care for WV | Family planning
Mahorter, 2023^828^ | Variations in Provision of Long-Acting Reversible Contraception Across Veterans Health Administration Facilities | General population/not specified | Contraception; Preventative health | Family planning
Arora, 2020^829^ | Factors Associated with Choice of Sterilization Among Women Veterans | General population/not specified | Contraception; N/a | Family planning
Callegari, 2019^143^ | Understanding Women Veterans’ Family Planning Counseling Experiences and Preferences to Inform Patient-Centered Care | General population/not specified | Contraception; Health care organization/delivery of care for WV | Family planning
Wolgemuth, 2020^144^ | Perceived Barriers and Facilitators to Contraceptive Use Among Women Veterans Accessing the Veterans Affairs Health care System | General population/not specified | Contraception; Access to care/utilization | Family planning
Judge, 2018^830^ | Medical contraindications to estrogen and contraceptive use among women Veterans | General population/not specified | Contraception; N/a | Family planning
Britton, 2019^831^ | Associations Between Perceived Susceptibility to Pregnancy and Contraceptive Use in a National Sample of Women Veterans | General population/not specified | Contraception; Preventative health | Family planning
Gawron, 2017^138^ | The “Safety Net” of Community Care: Leveraging GIS to Identify Geographic Access Barriers to Texas Family Planning Clinics for Homeless Women Veterans | People with experiences of homelessness | Contraception homeless; Access to care/utilization | Family planning
Borrero, 2017^129^ | Unintended Pregnancy and Contraceptive Use Among Women Veterans: The ECUUN Study | General population/not specified | Contraception, ECUUN study; Access to care/utilization | Family planning
Callegari, 2022^338^ | Perceived Contraceptive Counseling Quality Among Veterans Using VA Primary Care: Data from the ECUUN Study | General population/not specified | Contraception, ECUUN study; Health care organization/delivery of care for WV | Family planning
Wolgemuth, 2018^832^ | Associations between Pregnancy Intention, Attitudes, and Contraceptive Use among Women Veterans in the ECUUN Study | General population/not specified | Contraception, ECUUN study; Access to care/utilization | Family planning
Koenig, 2019^833^ | Factors associated with long-acting reversible contraception use among women Veterans in the ECUUN study | General population/not specified | Contraception, ECUUN study; Access to care/utilization | Family planning
Rosenfeld, 2017^139^ | Racial and ethnic disparities in contraceptive knowledge among women Veterans in the ECUUN study | Racial/ethnic minoritized; General population/not specified | Contraception, ECUUN study; Health care organization/delivery of care for WV | Family planning
Gawron, 2017^137^ | Long-acting Reversible Contraception Among Homeless Women Veterans With Chronic Health Conditions: A Retrospective Cohort Study | People with experiences of homelessness; OEF/OIF/OND | Contraception, homeless; Chronic medical conditions | Family planning
Gawron, 2019^136^ | Distance Matters: Geographic barriers to long acting reversible and permanent contraception for homeless women Veterans | People with experiences of homelessness; Rural dwelling | Contraception, homeless; Access to care/utilization | Family planning
Schexnayder, 2020^834^ | Documentation of contraceptive counseling in female Veterans of reproductive age | General population/not specified | Contraception, medications of teratogenic potential; Chronic medical conditions | Family planning
Callegari, 2017^140^ | Racial/ethnic differences in contraceptive preferences, beliefs, and self-efficacy among women Veterans | Racial/ethnic minoritized; General population/not specified | Contraception, Racial disparity; N/a | Family planning
MacDonald, 2017^141^ | Associations Between Perceived Race-based Discrimination and Contraceptive Use Among Women Veterans in the ECUUN Study | Racial/ethnic minoritized; General population/not specified | Contraception, Racial disparity; SDOH | Family planning
Mancuso, 2022^324^ | Lifetime infertility and environmental, chemical, and hazardous exposures among female and male US Veterans | OEF/OIF/OND | Infertility; Toxic Exposures | Family planning
Kroll-Desrosiers, 2023^835^ | Infertility Services for Veterans Enrolled in Veterans Health Administration Care | General population/not specified | Infertility; Access to care/utilization | Family planning
Goossen, 2019^146^ | Ethnic Minority Status and Experiences of Infertility in Female Veterans | Racial/ethnic minoritized; General population/not specified | Infertility; Access to care/utilization | Family planning
Mancuso, 2020^836^ | Infertility and Health-Related Quality of Life in United States Women Veterans | General population/not specified | Infertility; Chronic Pain/Opioids | Family planning
Judge-Golden, 2018^837^ | The Association between Mental Health Disorders and History of Unintended Pregnancy among Women Veterans | General population/not specified | Unintended pregnancy; General mental health | Family planning
Quinn, 2020^838^ | History of unintended pregnancy and patterns of contraceptive use among racial and ethnic minority women Veterans | Racial/ethnic minoritized; General population/not specified | Unintended pregnancy; Access to care/utilization | Family planning
Friedman, 2022^839^ | Preliminary Findings from the Gulf War Women’s Cohort: Reproductive and Children’s Health Outcomes among Women Veterans | Gulf War I | AND newborn/infant health; Children’s health outcomes | Maternal health
Shaw, 2018^840^ | Selection of Higher Risk Pregnancies into Veterans Health Administration Programs: Discoveries from Linked Department of Veterans Affairs and California Birth Data | General population/not specified | AND newborn/infant health; Health care organization/delivery of care for WV | Maternal health
Katon, 2023^841^ | Assessing Racial Disparities in Access, Use, and Outcomes for Pregnant and Postpartum Veterans and Their Infants in Veterans Health Administration | Racial/ethnic minoritized | AND newborn/infant health AND racial disparity; Access to care/utilization | Maternal health
Keddem, 2020^842^ | Disparities in Breastfeeding Among Military Veterans | General population/not specified | Breast feeding; SDOH | Maternal health
Sheahan, 2022^843^ | Sufficiency of Health Information During Pregnancy: What’s Missing and for Whom? A Cross-Sectional Analysis Among Veterans | General population/not specified | Counseling; Care Coordination | Maternal health
Mattocks, 2019^844^ | Factors Impacting Perceived Access to Early Prenatal Care among Pregnant Veterans Enrolled in the Department of Veterans Affairs | General population/not specified | Maternal health; Access to care/utilization | Maternal health
Katon, 2017^845^ | Deployment and Adverse Pregnancy Outcomes: Primary Findings and Methodological Considerations | OEF/OIF/OND | Maternal health; deployment | Maternal health
Grekin, 2020^846^ | Predictors of Veterans Affairs Health Service Utilization by Women Veterans during Pregnancy | General population/not specified | Maternal health; Access to care/utilization | Maternal health
Katon, 2018^130^ | Women Veterans’ Experiences with Department of Veterans Affairs Maternity Care: Current Successes and Targets for Improvement | General population/not specified | Maternal health; Health care organization/delivery of care for WV | Maternal health
Gopisetty, 2022^131^ | Veteran Postpartum Health: VA Care Team Perspectives on Care Coordination, Health Equity, and Trauma-Informed Care | General population/not specified | MCC program; Care Coordination | Maternal health
Mattocks, 2017^133^ | Implementing and Evaluating a Telephone-Based Centralized Maternity Care Coordination Program for Pregnant Veterans in the Department of Veterans Affairs | General population/not specified | MCC program; Health care organization/delivery of care for WV | Maternal health
Cordasco, 2018^134^ | Care coordination for pregnant Veterans: VA’s Maternity Care Coordinator Telephone Care Program | General population/not specified | MCC program; Access to care/utilization | Maternal health
Mattocks, 2019^132^ | Understanding Maternity Care Coordination for Women Veterans Using an Integrated Care Model Approach | General population/not specified | MCC program; Access to care/utilization | Maternal health
Copeland, 2022^847^ | Medications with Potential for Fetal Risk Prescribed to Veterans | General population/not specified | Medication with teratogenicity; Care Coordination | Maternal health
Shroff, 2017^135^ | An Innovative Framework to Improve Teratogenic Medication Risk Counseling | Other: n/a | Medications with teratogenic potential; Health care organization/delivery of care for WV | Maternal health
Nillni, 2022^848^ | The impact of military sexual trauma and warfare exposure on women Veterans’ perinatal outcomes | General population/not specified | Mental health; Reproductive Mental Health | Maternal health
Shaw, 2017^849^ | Post-traumatic Stress Disorder and Antepartum Complications: a Novel Risk Factor for Gestational Diabetes and Preeclampsia | General population/not specified | Mental health; Preventative health | Maternal health
Shivakumar, 2021^850^ | Patterns of Treatment Utilization Across the Perinatal Period in the Center for Maternal and Infant Outcomes and Research in Translation (COMFORT) Veterans Study | General population/not specified | Mental health; Health care organization/delivery of care for WV | Maternal health
Shapiro, 2023^851^ | Understanding the Mental Health Impact of Previous Pregnancy Loss Among Currently Pregnant Veterans | History of trauma | Mental health; Reproductive Mental Health | Maternal health
Nillni, 2020^852^ | The Impact of Posttraumatic Stress Disorder and Moral Injury on Women Veterans’ Perinatal Outcomes Following Separation From Military Service | General population/not specified | Mental health; General mental health | Maternal health
Kinney, 2023^853^ | Newborn Outcomes Among Veterans Utilizing VHA Maternity Benefits, 2016-2020 | General population/not specified | Newborn/infant health; Health care organization/delivery of care for WV | Maternal health
Panelli, 2023^854^ | An Exploratory Analysis of Factors Associated With Spontaneous Preterm Birth Among Pregnant Veterans With Post-Traumatic Stress Disorder | History of trauma | Newborn/infant health; Reproductive Mental Health | Maternal health
Katon, 2022^125^ | Timeliness and Adequacy of Prenatal Care Among Department of Veterans Affairs’ Enrolled Veterans: The First Step May Be the Biggest Hurdle | General population/not specified | Payer variation; Access to care/utilization | Maternal health
Shankar, 2021^855^ | Postpartum Transition of Care: Racial/Ethnic Gaps in Veterans’ Re-Engagement in VA Primary Care after Pregnancy | Racial/ethnic minoritized | Racial disparity; Access to care/utilization | Maternal health
Lumsden, 2022^856^ | Racial Differences in Nontraditional Risk Factors Associated with Cardiovascular Conditions in Pregnancy Among U.S. Women Veterans | Racial/ethnic minoritized | Racial disparity; Chronic medical conditions | Maternal health
Hansen, 2023^857^ | Disparate Risk Factors Among Pregnant Veterans Using Veterans Administration Health Benefits for Community-Based Obstetrical Care | General population/not specified | risk factors; Preventative health | Maternal health
Combellick, 2020^368^ | Severe Maternal Morbidity Among a Cohort of Post-9/11 Women Veterans | OEF/OIF/OND | risk factors; N/a | Maternal health
Albright, 2021^858^ | Pregnancy and Binge Drinking: An Intersectionality Theory Perspective Using Veteran Status and Racial/Ethnic Identity | Racial/ethnic minoritized; General population/not specified | Substance use in pregnancy; Substance Use | Maternal health
Kroll-Desrosiers, 2021^859^ | Factors Associated With Quitting Smoking During Pregnancy Among Women Veterans | General population/not specified | Substance use in pregnancy; Preventative health | Maternal health
Mattocks, 2021^860^ | Racial Differences in the Cesarean Section Rates Among Women Veterans Using Department of Veterans Affairs Community Care | Racial/ethnic minoritized; General population/not specified | Racial disparity; SDOH | Maternal health
Katon, 2016^861^ | Vasomotor Symptoms and Quality of Life Among Veteran and Non-Veteran Postmenopausal Women | General population/not specified | Menopause; Quality of Life | Menopause
Dang, 2019^127^ | A Patient Portal Intervention for Menopause Knowledge and Shared Decision-Making | General population/not specified | Menopause; Health care organization/delivery of care for WV | Menopause
Dietz, 2018^157^ | Women Veterans and menopause: Knowledge and preferences | General population/not specified | Menopause; Health care organization/delivery of care for WV | Menopause
Cordasco, 2019^153^ | Veterans Health Administration Primary Care Provider Adherence to Prescribing Guidelines for Systemic Hormone Therapy in Menopausal Women | General population/not specified | MHT; Health care organization/delivery of care for WV | Menopause
Blondon, 2021^154^ | Comparative venous thromboembolic safety of oral and transdermal postmenopausal hormone therapies among women Veterans | General population/not specified | MHT; N/a | Menopause
Gibson, 2021^155^ | Menopausal Hormone Therapy and Suicide in a National Sample of Midlife and Older Women Veterans | General population/not specified | MHT; Suicide/Non-suicidal self-injury | Menopause
Blanken, 2022^156^ | Racial/ethnic disparities in the diagnosis and management of menopause symptoms among midlife women Veterans | Racial/ethnic minoritized | MHT; Health care organization/delivery of care for WV | Menopause
Quinn, 2023^337^ | Reproductive health services: A missed opportunity in VA primary care? | General population/not specified | Access to reproductive health services; Access to care/utilization | Family planning
Quinn, 2021^862^ | Measuring Female Veterans’ Prepregnancy Wellness Using Department of Veterans Affairs’ Health Record Data | General population/not specified | Pre-pregnancy care; Preventative health | Family planning
Quinn, 2021^863^ | Veteran-Reported Receipt of Prepregnancy Care: Data from the Examining Contraceptive Use and Unmet Need (ECUUN) Study | General population/not specified | Pre-pregnancy care; General mental health | Family planning
Breyer, 2016^158^ | Sexual Health in Male and Female Iraq and Afghanistan U. S. War Veterans With and Without PTSD: Findings From the VALOR Cohort | History of trauma; OEF/OIF/OND | Sexual health; General mental health | Sexual health
Garneau-Fournier, 2018^159^ | Factors Associated with Sexual Dysfunction Symptoms among Veterans who Have Experienced Military Sexual Trauma | History of trauma | Sexual health; Interpersonal Violence | Sexual health
Blais, 2019^128^ | The association of disordered eating and sexual health with relationship satisfaction in female service members/Veterans | General population/not specified | Sexual health; General mental health | Sexual health
DiMauro, 2018^160^ | Sexual vs. Non-sexual trauma, sexual satisfaction and function, and mental health in female Veterans | History of trauma | Sexual health; General mental health | Sexual health
Goyal, 2017^164^ | Lifetime Sexual Assault and Sexually Transmitted Infections Among Women Veterans | General population/not specified | Sexually transmitted infection; Interpersonal Violence | Other reproductive health services
Katon, 2018^166^ | Reproductive Health of Women Veterans: A Systematic Review of the Literature from 2008 to 2017 | General population/not specified | Systematic review of reproductive health; N/a | Other reproductive health services
Washington, 2019^151^ | Development of Quality Indicators for the Care of Women with Abnormal Uterine Bleeding by Primary Care Providers in the Veterans Health Administration | General population/not specified | Abnormal uterine; bleeding Health care organization/delivery of care for WV | Unterine Diagnoses and Surgeries
Cordasco, 2019^152^ | Guideline Adherence of Veterans Health Administration Primary Care for Abnormal Uterine Bleeding | General population/not specified | Abnormal uterine bleeding; Health care organization/delivery of care for WV | Unterine Diagnoses and Surgeries
Katon, 2017^864^ | Trends in hysterectomy rates among women Veterans in the US Department of Veterans Affairs | General population/not specified | Hysterectomy; Health care organization/delivery of care for WV | Unterine Diagnoses and Surgeries
Katon, 2019^865^ | Contributors to Racial Disparities in Minimally Invasive Hysterectomy in the US Department of Veterans Affairs | General population/not specified | Hysterectomy; SDOH | Unterine Diagnoses and Surgeries
Callegari, 2019^866^ | Associations between Race/Ethnicity, Uterine Fibroids, and Minimally Invasive Hysterectomy in the VA Health care System | General population/not specified | Hysterectomy; SDOH | Unterine Diagnoses and Surgeries
Ryan, 2016^867^ | Hysterectomy risk in premenopausal-aged military Veterans: associations with sexual assault and gynecologic symptoms | General population/not specified | Hysterectomy; General mental health | Unterine Diagnoses and Surgeries
Carey, 2022^868^ | Uterine Weight as a Modifier of Black/White Racial Disparities in Minimally Invasive Hysterectomy Among Veterans with Fibroids in the Veterans Health Administration | Racial/ethnic minoritized | Hysterectomy; N/a | Unterine Diagnoses and Surgeries
Callegari, 2016^147^ | Hysterectomy and Bilateral Salpingo-Oophorectomy: Variations by History of Military Service and Birth Cohort | General population/not specified | Hysterectomy, bilateral salpingo-oophorectomy; Long-term care/aging | Unterine Diagnoses and Surgeries
Bossick, 2020^148^ | Concomitant Bilateral Salpingo-Oophorectomy at Hysterectomy: Differences by Race and Menopausal Status in the Veterans Affairs Health Care System, 2007-2014 | Racial/ethnic minoritized; General population/not specified | Hysterectomy, bilateral salpingo-oophorectomy; SDOH | Unterine Diagnoses and Surgeries
Carey, 2023^149^ | “I Wasn’t Presented With Options”: Perspectives of Black Veterans Receiving Care for Uterine Fibroids in the Veterans Health Administration | Racial/ethnic minoritized | Uterine fibroids; Health care organization/delivery of care for WV | Unterine Diagnoses and Surgeries
Katon, 2023^150^ | Racial Disparities in Uterine Fibroid Treatment Among Veterans Using VA Health Care | Racial/ethnic minoritized; General population/not specified | Uterine fibroids; Health care organization/delivery of care for WV | Unterine Diagnoses and Surgeries
Preventative Health
Blalock, 2023^869^ | BMI Trends for Veterans Up to 10 Years After VA Enrollment Following Military Discharge | OEF/OIF/OND | General mental health | Health behaviors
Whitbourne, 2022^190^ | Million Veteran Program’s response to COVID-19: Survey development and preliminary findings | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WV | Health behaviors
Cohen, 2022^870^ | Risk factors for Veteran food insecurity: findings from a National US Department of Veterans Affairs Food Insecurity Screener | General population/not specified | SDOH | Health behaviors
Stefanovics, 2021^871^ | Personality and Body Mass Index in U.S. Military Veterans: Results from the National Health and Resilience in Veterans Study | General population/not specified | General mental health | Health behaviors
Avery, 2021^369^ | Clinical yoga program utilization in a large health care system | General population/not specified | Access to care/utilization; General mental health | Health behaviors
Tarlov, 2020^188^ | Neighborhood Walkability and BMI Change: A National Study of Veterans in Large Urban Areas | General population/not specified | Chronic medical conditions | Health behaviors
Batch, 2020^184^ | Women Veterans Experience with the VA MOVE! Weight Management Program | General population/not specified | Access to care/utilization | Health behaviors
Zenk, 2019^185^ | Does the built environment influence the effectiveness of behavioral weight management interventions? | General population/not specified | SDOH | Health behaviors
Slater, 2019^872^ | Would increasing access to recreational places promote healthier weights and a healthier nation? | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WV | Health behaviors
Schult, 2019^873^ | The Health Status of Veteran Employees Compared to Civilian Employees in Veterans Health Administration | General population/not specified | Substance Use; Chronic medical conditions | Health behaviors
Powell, 2019^189^ | The price of ultra-processed foods and beverages and adult body weight: Evidence from U.S. Veterans | General population/not specified | SDOH | Health behaviors
Kreyenbuhl, 2019^193^ | Understanding Women Veterans’ Experiences With and Management of Weight Gain From Medications for Serious Mental Illness: A Qualitative Study | General population/not specified | General mental health | Health behaviors
Zenk, 2018^186^ | Long-term weight loss effects of a behavioral weight management program: Does the community food environment matter? | General population/not specified | Health care organization/delivery of care for WVs; SDOH | Health behaviors
Tarlov, 2018^874^ | Does Effectiveness of Weight Management Programs Depend on the Food Environment? | General population/not specified | SDOH; obesity | Health behaviors
Tamas, 2018^875^ | Weight Trends in Veterans With and Without Diabetes, 2000 to 2014 | General population/not specified | Chronic medical conditions | Health behaviors
Nguyen, 2018^191^ | Baseline Characterization and Annual Trends of Body Mass Index for a Mega-Biobank Cohort of US Veterans 2011-2017 | General population/not specified | N/a | Health behaviors
Washington, 2016^192^ | Trajectories in Physical Activity and Sedentary Time Among Women Veterans in the Women’s Health Initiative | General population/not specified | Reproductive health | Health behaviors
Jay, 2016^876^ | Military service and other socioecological factors influencing weight and health behavior change in overweight and obese Veterans: A qualitative study to inform intervention development within primary care at the United States Veterans Health Administrati | General population/not specified | Access to care/utilization; Chronic medical conditions | Health behaviors
Albright, 2019^171^ | Sexual Behaviors and Health Practices Among Student Service Members and Veterans | General population/not specified | Reproductive health | Health behaviors
Goldstein, 2018^194^ | Understanding women Veterans’ preferences for peer support interventions to promote heart healthy behaviors: A qualitative study | General population/not specified | Health care organization/delivery of care for WVs; Chronic medical conditions | Health behaviors
Zenk, 2018^187^ | Weight and Veterans’ Environments Study (WAVES) I and II: Rationale, Methods, and Cohort Characteristics | General population/not specified | Chronic medical conditions | Health behaviors
Hamilton, 2023^195^ | Enhancing Mental and Physical Health of Women through Engagement and Retention (EMPOWER) 2.0 QUERI: study protocol for a cluster-randomized hybrid type 3 effectiveness-implementation trial | General population/not specified | General mental health; Research methods | Health behaviors
Monty, 2023^178^ | “We Are Working Harder, Not Smarter”: A Qualitative Inquiry into Care Coordination for Department of Veterans Affairs Mammograms Referred to the Community | Other: VA staff | Care Coordination | Screening
Marcotte, 2023^169^ | Automated Opt-Out vs Opt-In Patient Outreach Strategies for Breast Cancer Screening: A Randomized Clinical Trial | General population/not specified | Health care organization/delivery of care for WVs; Cancer care | Screening
Syler, 2021^172^ | Cervical Cancer Screening in South Florida Veteran Population, 2014 to 2020: Cytology and High-Risk Human Papillomavirus Correlation and Epidemiology | General population/not specified | N/a | Screening
Schuttner, 2021^167^ | Factors Associated With Low-Value Cancer Screenings in the Veterans Health Administration | General population/not specified | Health care organization/delivery of care for WVs | Screening
Minnier, 2021^877^ | Polygenic breast cancer risk for women Veterans in the million Veteran program | General population/not specified | Cancer care | Screening
Imperiale, 2021^878^ | Prevalence of Advanced Colorectal Neoplasia in Veterans: Effects of Age, Sex, and Race/Ethnicity | General population/not specified | N/a | Screening
Bidassie, 2020^173^ | Breast Cancer Risk Assessment and Chemoprevention Use Among Veterans Affairs Primary Care Providers: A National Online Survey | Other: VA primary care providers | VA Women’s Health Workforce | Screening
Brunner, 2022^879^ | Implementing clinical decision support for reducing women Veterans’ cardiovascular risk in VA: A mixed-method, longitudinal study of context, adaptation, and uptake | General population/not specified | Health care organization/delivery of care for WVs | Screening
Bean-Mayberry, 2022^179^ | Cardiovascular Risk Screening among Women Veterans: Identifying Provider and Patient Barriers and Facilitators to Develop a Clinical Toolkit | General population/not specified | Health care organization/delivery of care for WVs; Chronic medical conditions | Screening
Jeon-Slaughter, 2021^181^ | Assessing performance of the Veterans affairs women cardiovascular risk model in predicting a short-term risk of cardiovascular disease incidence using united states Veterans affairs covid-19 shared data | General population/not specified | Chronic medical conditions | Screening
Sullivan-Baca, 2023^174^ | An Update on the Healthy Soldier Effect in U.S. Veterans | General population/not specified | Access to care/utilization | Screening
Sternke, 2017^182^ | Assessment of a Revised Wartime Experiences Scale for Vietnam-Era Women: The Health of Vietnam-Era Women’s Study (HealthViEWS) | Vietnam | N/a | Screening
Hoffmire, 2022^880^ | Women Veterans’ Perspectives on Suicide Prevention in Reproductive Health Care Settings: An Acceptable, Desired, Unmet Opportunity | General population/not specified | Health care organization/delivery of care for WVs; Suicide/Non-suicidal self-injury | Screening
Hardin, 2022^180^ | Male and Female Veterans’ Preferences for Eating Disorders Screening | General population/not specified | General mental health | Screening
Bovin, 2021^183^ | Diagnostic Accuracy and Acceptability of the Primary Care Posttraumatic Stress Disorder Screen for the Diagnostic and Statistical Manual of Mental Disorders (Fifth Edition) Among US Veterans | General population/not specified | General mental health | Screening
Reddy, 2019^170^ | Screening for Military Sexual Trauma Is Associated With Improved HIV Screening in Women Veterans | OEF/OIF/OND | Substance Use; General mental health | Screening
Trowbridge, 2016^175^ | Prevalence of positive screening test for cognitive impairment among elderly urogynecologic patients | General population/not specified | Long-term care/aging | Screening
Ferras, 2023^881^ | An Examination of Factors That Influence Receipt of Reproductive Health Screenings Among Female Veterans | General population/not specified | Reproductive health | Screening
Keddem, 2022^168^ | Gonorrhea and Chlamydia Testing and Case Rates Among Women Veterans in the Veterans Health Administration | General population/not specified | Health care organization/delivery of care for WVs; SDOH | Screening
Beste, 2022^176^ | Sexually Transmitted Infection Testing in the National Veterans Health Administration Patient Cohort During the Coronavirus Disease 2019 Pandemic | General population/not specified | Access to care/utilization | Screening
Beste, 2021^177^ | Testing Practices and Incidence of Chlamydial and Gonococcal Infection in the Veterans Health Administration, 2009-2019 | General population/not specified | Access to care/utilization | Screening
Bernstein, 2023^196^ | Racial, Ethnic, and Rural Disparities in US Veteran COVID-19 Vaccine Rates | Racial/ethnic minoritized; General population/not specified | SDOH | Vaccines
Mattocks, 2022^197^ | Examining Pregnant Veterans’ Acceptance and Beliefs Regarding the COVID-19 Vaccine | General population/not specified | Reproductive health | Vaccines
Chronic Pain/Opioids
Gibson, 2019^882^ | Menopausal Symptoms and Higher Risk Opioid Prescribing in a National Sample of Women Veterans with Chronic Pain | General population/not specified | Reproductive Mental Health; Long-term care/aging | Opioid use among VA users
Salas, 2018^883^ | Gender and the Association between Long-Term Prescription Opioid Use and New-Onset Depression | General population/not specified | General mental health | Opioid use among VA users
Cichowski, 2018^884^ | A 10-yr Analysis of Chronic Pelvic Pain and Chronic Opioid Therapy in the Women Veteran Population | General population/not specified | Interpersonal Violence | Opioid use among VA users
Kroll-Desrosiers, 2016^885^ | Receipt of Prescription Opioids in a National Sample of Pregnant Veterans Receiving Veterans Health Administration Care | General population/not specified | Health care organization/delivery of care for WVs; Reproductive Mental Health | Opioid use among VA users
Martinson, 2020^886^ | Factors associated with participation and nonparticipation in a VA Whole Health Primary Care Pain Education and Opioid Monitoring Program (PC-POP) | General population/not specified | N/a | Opioid use among VA users
Goldsmith, 2020^887^ | Complementary, Integrative, and Nondrug Therapy Use for Pain Among US Military Veterans on Long-term Opioids | General population/not specified | N/a | Opioid use among VA users
Driscoll, 2017^888^ | Examining Gender as a Correlate of Self-Reported Pain Treatment Use Among Recent Service Veterans with Deployment-Related Musculoskeletal Disorders | OEF/OIF/OND | N/a | Opioid use among VA users
Boyer, 2022^202^ | Comparing Outpatient Opioids, High-Risk Prescribing, and Opioid Poisoning Between Transgender and Cisgender Veterans: A Cross-sectional Analysis | Transgender or gender nonbinary | Access to care/utilization | Opioid use among VA users
Naylor, 2019^889^ | Pain Intensity and Pain Interference in Male and Female Iraq/Afghanistan-era Veterans | OEF/OIF/OND | N/a | Pain assessment and management
Vigil, 2017^203^ | How nurse gender influences patient priority assignments in US emergency departments | General population/not specified | Care Coordination; Vital signs (heart rate and respiratory rate) | Pain assessment and management
Okvat, 2022^370^ | Mindfulness-based training for women Veterans with chronic pain: A retrospective study | General population/not specified | Health care organization/delivery of care for WVs; General mental health | Pain assessment and management
Nicosia, 2021^890^ | Women Veterans’ Experiences with Integrated, Biopsychosocial Pain Care: A Qualitative Study | General population/not specified | Health care organization/delivery of care for WVs; VA Women’s Health Workforce | Pain assessment and management
Evans, 2018^891^ | Gender Differences in Use of Complementary and Integrative Health by U.S. Military Veterans with Chronic Musculoskeletal Pain | General population/not specified | Access to care/utilization | Pain assessment and management
Corcoran, 2017^892^ | Chiropractic Management for US Female Veterans With Low Back Pain: A Retrospective Study of Clinical Outcomes | General population/not specified | Chiropractic care | Pain assessment and management
Murphy, 2016^893^ | Sex differences between Veterans participating in interdisciplinary chronic pain rehabilitation | General population/not specified | Health care organization/delivery of care for WVs | Pain assessment and management
Gibson, 2019^894^ | Menopause symptoms and chronic pain in a national sample of midlife women Veterans | General population/not specified | Reproductive health | Risk factors for chronic pain
Arout, 2018^201^ | Gender Differences in the Prevalence of Fibromyalgia and in Concomitant Medical and Psychiatric Disorders: A National Veterans Health Administration Study | General population/not specified | N/a | Risk factors for chronic pain
Rogers, 2017^200^ | Military Sexual Trauma in Female Veterans is Associated With Chronic Pain Conditions | General population/not specified | Interpersonal Violence | Risk factors for chronic pain
Nahin, 2017^895^ | Severe Pain in Veterans: The Effect of Age and Sex, and Comparisons With the General Population | General population/not specified | Chronic medical conditions | Risk factors for chronic pain
Patel, 2016^896^ | Association of Pain With Physical Function, Depressive Symptoms, Fatigue, and Sleep Quality Among Veteran and non-Veteran Postmenopausal Women | General population/not specified | General mental health; Long-term care/aging | Risk factors for chronic pain
Higgins, 2016^897^ | Prevalence and correlates of painful conditions and multimorbidity in national sample of overweight/obese Veterans | General population/not specified | Preventative health; Chronic medical conditions | Risk factors for chronic pain
Naylor, 2017^898^ | Self-Reported Pain in Male and Female Iraq/Afghanistan-Era Veterans: Associations with Psychiatric Symptoms and Functioning | OEF/OIF/OND | Access to care/utilization; General mental health | Risk factors for chronic pain
Green, 2017^899^ | Cigarette Smoking and Musculoskeletal Pain Severity Among Male and Female Afghanistan/Iraq Era Veterans | OEF/OIF/OND | Substance Use | Risk factors for chronic pain
Buttner, 2017^199^ | Combat exposure and pain in male and female Afghanistan and Iraq Veterans: The role of mediators and moderators | OEF/OIF/OND | Other Violence | Risk factors for chronic pain
Mohanty, 2016^900^ | Fibromyalgia syndrome care of Iraq- and Afghanistan-deployed Veterans in Veterans Health Administration | OEF/OIF/OND | Access to care/utilization; Chronic Pain/Opioids | Risk factors for chronic pain
Higgins, 2022^335^ | Risk Factors Associated with Health care Utilization for Spine Pain | General population/not specified | Access to care/utilization | Utilization among patients with chronic pain
Kroll-Desrosiers, 2023^901^ | Musculoskeletal Pain During Pregnancy Among Veterans: Associations With Health and Health Care Utilization | General population/not specified | Reproductive health | Utilization among patients with chronic pain
Driscoll, 2018^204^ | Patient Experiences Navigating Chronic Pain Management in an Integrated Health Care System: A Qualitative Investigation of Women and Men | General population/not specified | Health care organization/delivery of care for WVs | Utilization among patients with chronic pain
Johnson, 2023^198^ | “It Made Me Not Want to See him…”: The Role of Patient-Provider Communication in Influencing Rural-Dwelling Women Veterans’ Motivation to Seek Health Care for Managing Chronic Pain | Rural dwelling | Access to care/utilization | Utilization among patients with chronic pain
Hadlandsmyth, 2023^205^ | Rurality impacts pain care for female Veterans similarly to male Veterans | Rural dwelling | Access to care/utilization; SDOH | Utilization among patients with chronic pain
Long-Term Care/Aging
Tabio, 2021^224^ | Association of Lifetime TBI and Military Employment with Late Life ADL Functioning: A Population-Based Prospective Cohort Study | General population/not specified | Chronic medical conditions; TBI | Functioning
LaCroix, 2016^225^ | Aging Well Among Women Veterans Compared With Non-Veterans in the Women’s Health Initiative | General population/not specified | N/a | Functioning
Cheng, 2023^219^ | Cardiorespiratory fitness and risk of Alzheimer’s disease and related dementias among American Veterans | General population/not specified | Preventative health | Cognitive function
Dinesh, 2023^215^ | The epidemiology of mild cognitive impairment, Alzheimer’s disease and related dementia in U.S. Veterans | General population/not specified | N/a | Cognitive function
Eastman, 2022^902^ | Sex Differences in the Risk of Dementia in Older Veterans | General population/not specified | N/a | Cognitive function
Padula, 2016^220^ | Longitudinal Cognitive Trajectories of Women Veterans from the Women’s Health Initiative Memory Study | General population/not specified | Reproductive health | Cognitive function
Yaffe, 2019^218^ | Military-related risk factors in female Veterans and risk of dementia | General population/not specified | General mental health | Cognitive function
Bahorik, 2021^216^ | Increased risk of dementia in older female US Veterans with alcohol use disorder | General population/not specified | Substance Use | Cognitive function
Kornblith, 2020^217^ | Sex, race, and risk of dementia diagnosis after traumatic brain injury among older Veterans | History of trauma | Chronic medical conditions | Cognitive function
Varilek, 2021^223^ | Female Veteran Use of Palliative and Hospice Care: A Scoping Review | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WV | End of life care
West, 2022^222^ | Advance Care Directive Preferences in Women Veterans: A Snapshot | General population/not specified | N/a | End of life care
Varilek, 2023^221^ | Analysis of Palliative Care Knowledge and Symptom Burden Among Female Veterans With Serious Illness: A Cross-Sectional Study | General population/not specified | Health care organization/delivery of care for WVs; Long-term care/aging | End of life care
Orkaby, 2019^209^ | The Burden of Frailty Among U.S. Veterans and Its Association With Mortality, 2002-2012 | General population/not specified | N/a | Morbidity and mortality
Bernstein, 2022^208^ | Estimating Median Survival Following Hip Fracture Among Geriatric Females: (100 - Patient Age) / 4 | General population/not specified | N/a | Morbidity and mortality
Cho, 2016^211^ | Protective and Risk Factors for 5-Year Survival in the Oldest Veterans: Data from the Veterans Health Administration | General population/not specified | Access to care/utilization; Chronic medical conditions | Morbidity and mortality
Howard, 2021^213^ | Telomere shortening and accelerated aging in US military Veterans | General population/not specified | N/a | Morbidity and mortality
Gonsoulin, 2017^212^ | A Health Profile of Senior-Aged Women Veterans: A Latent Class Analysis of Condition Clusters | General population/not specified | Chronic medical conditions | Morbidity and mortality
Washington, 2016^210^ | Military Generation and Its Relationship to Mortality in Women Veterans in the Women’s Health Initiative | General population/not specified | General mental health; Chronic medical conditions | Morbidity and mortality
Wong, 2019^207^ | Racial/Ethnic Disparities in Mortality Across the Veterans Health Administration | Racial/ethnic minoritized; General population/not specified | Access to care/utilization; Chronic medical conditions | Morbidity and mortality
Lehavot, 2016^206^ | Mortality in Postmenopausal Women by Sexual Orientation and Veteran Status | Sexual minoritized populations; General population/not specified | Preventative health; Chronic medical conditions | Morbidity and mortality
Weitlauf, 2023^214^ | Mortality of Women Vietnam War-Era Veterans | Vietnam | Preventative health; Chronic medical conditions | Morbidity and mortality
Cancer
Zullig, 2019^232^ | Cancer Among Women Treated in the Veterans Affairs Health care System | General population/not specified | N/a | Non–sex-specific cancers
Zullig, 2017^231^ | Cancer Incidence Among Patients of the U.S. Veterans Affairs Health Care System: 2010 Update | General population/not specified | N/a | Non–sex-specific cancers
Bihn, 2023^903^ | Brain Tumors in United States Military Veterans | General population/not specified | N/a | Non–sex-specific cancers
Demb, 2021^227^ | Young-onset colorectal cancer risk among individuals with iron-deficiency anaemia and haematochezia | General population/not specified | Chronic medical conditions | Non–sex-specific cancers
Oppegaard, 2020^233^ | Gender Differences in the Use of Engagement and Disengagement Coping Strategies in Patients With Cancer Receiving Chemotherapy | General population/not specified | General mental health | Non–sex-specific cancers
Jeon, 2022^226^ | Prediction of Pancreatic Cancer in Diabetes Patients with Worsening Glycemic Control | General population/not specified | Preventative health | Non–sex-specific cancers
Gaffey, 2023^228^ | Post-9/11 deployment history and the incidence of breast cancer among women Veterans | OEF/OIF/OND | Preventative health | Sex-specific cancers
Aggarwal, 2021^904^ | Gender Disparity in Breast Cancer: A Veteran Population-Based Comparison | General population/not specified | N/a | Sex-specific cancers
Johnson, 2020^230^ | The relationship between circulating lipids and breast cancer risk: A Mendelian randomization study | General population/not specified | Preventative health; Chronic medical conditions | Sex-specific cancers
Azad, 2020^905^ | Acute pain after breast surgery and reconstruction: A two-institution study of surgical factors influencing short-term pain outcomes | General population/not specified | Chronic Pain/Opioids | Sex-specific cancers
Hull, 2018^229^ | Clinical Impact of 21-Gene Recurrence Score Test Within the Veterans Health Administration: Utilization and Receipt of Guideline-Concordant Care | General population/not specified | Health care organization/delivery of care for WVs | Sex-specific cancers
Zuchowski, 2017^906^ | Coordinating Care Across Health Care Systems for Veterans With Gynecologic Malignancies: A Qualitative Analysis | General population/not specified | Reproductive health; Care Coordination | Sex-specific cancers
Health Care Organization/Delivery of Care
Fried, 2021^277^ | Total and Per-Patient Fiscal Year 2013 VA Disability Compensation and Medical Care Expenditures and Utilization for Vietnam Era Veterans with Service-Connected Disabilities | Vietnam | Access to care/utilization | Cost of Care
Capitulo, 2023^907^ | Voices of women Veterans: My Life, My Story | General population/not specified | Access to care/utilization | Population-specific care needs and preferences
Sheahan, 2022^908^ | Women Veterans’ Health care Needs, Utilization, and Preferences in Veterans Affairs Primary Care Settings | General population/not specified | Access to care/utilization; Care Coordination | Population-specific care needs and preferences
Holzhauer, 2019^909^ | Profiles of Clinical Need Among Homeless Individuals with Dual Diagnoses | People with experiences of homelessness | General mental health; SDOH | Population-specific care needs and preferences
Sedlander, 2018^910^ | Veterans’ Preferences for Remote Management of Chronic Conditions | General population/not specified | Chronic medical conditions; remote management/telehealth | Population-specific care needs and preferences
Evans, 2018^911^ | Psychosocial Factors that Shape Substance Abuse and Related Mental Health of Women Military Veterans who Use Community-Based Services | General population/not specified | Substance Use; General mental health | Population-specific care needs and preferences
Brooks, 2016^912^ | Listening to the Patient: Women Veterans’ Insights About Health Care Needs, Access, and Quality in Rural Areas | Rural dwelling | Access to care/utilization | Population-specific care needs and preferences
Whitbourne, 2023^286^ | Overview of Efforts to Increase Women Enrollment in the Veterans Affairs Million Veteran Program | General population/not specified | VA Women’s Health Workforce | Research methods
Nik-Ahd, 2023^279^ | Seeing the unseen: how can we best identify transgender women within the Veterans Affairs health care system’s electronic medical record? | Transgender or gender nonbinary | Preventative health; gender affirming therapy | Research methods
Fan, 2023^284^ | Recruiting Sexual and Gender Minority Veterans for Health Disparities Research: Recruitment Protocol of a Web-Based Prospective Cohort Study | Transgender or gender nonbinary; Sexual minoritized populations | N/a | Research methods
Chrystal, 2022^285^ | Increasing Engagement of Women Veterans in Health Research | General population/not specified | N/a | Research methods
Blosnich, 2022^281^ | Concordance of Data About Sex From Electronic Health Records and the National Death Index: Implications for Transgender Populations | Transgender or gender nonbinary | SDOH; all cause mortality | Research methods
Wolfe, 2021^280^ | Validating Data-Driven Methods for Identifying Transgender Individuals in the Veterans Health Administration of the US Department of Veterans Affairs | Transgender or gender nonbinary | SDOH | Research methods
Golden, 2021^287^ | Promoting learning health system feedback loops: Experience with a VA practice-based research network card study: VA Card Study Promotes Learning Health System | General population/not specified | N/a | Research methods
Goldstein, 2019^283^ | Enrollment and Retention of Men and Women in Health Services Research and Development Trials | General population/not specified | Research methods | Research methods
Danan, 2019^282^ | Evidence Map: Reporting of Results by Sex or Gender in Randomized, Controlled Trials with Women Veteran Participants (2008 to 2018) | General population/not specified | Research methods | Research methods
Blosnich, 2018^278^ | Using clinician text notes in electronic medical record data to validate transgender-related diagnosis codes | Transgender or gender nonbinary | N/a | Research methods
Vincent, 2023^272^ | Mind Full or Mindful? A Cohort Study of Equine-Facilitated Therapy for Women Veterans | General population/not specified | mindfulness | Service delivery
Tsui, 2023^913^ | Patient inequities in affording surgical resident operative autonomy at Veterans Affairs teaching hospitals, does it extend to female patients? | General population/not specified | N/a | Service delivery
Scheuner, 2022^914^ | Demographic Differences Among US Department of Veterans Affairs Patients Referred for Genetic Consultation to a Centralized VA Telehealth Program, VA Medical Centers, or the Community | General population/not specified | Preventative health; Health care organization/delivery of care for WV | Service delivery
Lynch, 2021^259^ | Variation in Sexual Orientation Documentation in a National Electronic Health Record System | Sexual minoritized populations; Racial/ethnic minoritized | SDOH | Service delivery
Moreau, 2020^372^ | Women Veterans’ Perspectives on How to Make Veterans Affairs Health care Settings More Welcoming to Women | General population/not specified | VA Women’s Health Workforce; Health care organization/delivery of care for WV | Service delivery
Gray, 2020^915^ | Understanding Variation in Availability and Provision of Minimally Invasive Hysterectomy: A Qualitative Study of Department of Veterans Affairs Gynecologists | General population/not specified | Access to care/utilization; Reproductive health | Service delivery
Zickmund, 2018^916^ | Racial, Ethnic, and Gender Equity in Veteran Satisfaction with Health Care in the Veterans Affairs Health Care System | General population/not specified | SDOH; Racial, Ethnic, and Gender Equity | Service delivery
Gawron, 2023^263^ | Women’s Health Provider Perspectives on Reproductive Services Provision in the Veterans Health Administration | Other: VA Staff | Reproductive health; VA Women’s Health Workforce | Service delivery
Than, 2022^917^ | Discontinuity of Women Veterans’ Care in Patient-Centered Medical Homes: Does Workforce Gender Sensitivity Matter? | General population/not specified | Access to care/utilization | Service delivery
Hamilton, 2017^262^ | Engaging multilevel stakeholders in an implementation trial of evidence-based quality improvement in VA women’s health primary care | Other: VA staff | VA Women’s Health Workforce | Service delivery
Yano, 2016^261^ | Cluster randomized trial of a multilevel evidence-based quality improvement approach to tailoring VA Patient Aligned Care Teams to the needs of women Veterans | General population/not specified | Access to care/utilization; Care Coordination | Service delivery
Reddy, 2016^918^ | The Role of Organizational Factors in the Provision of Comprehensive Women’s Health in the Veterans Health Administration | General population/not specified | Preventative health | Service delivery
Devine, 2020^919^ | Quality of life among women Veterans | General population/not specified | General mental health; Interpersonal Violence | Service delivery
Vance, 2023^920^ | Women Veterans’ Descriptions of Interactions With Civilian Health Care Providers: A Qualitative Inquiry | General population/not specified | N/a | Service delivery
Rose, 2022^373^ | Association Between Availability of Women’s Health Services and Women Veterans’ Care Experiences | General population/not specified | Access to care/utilization | Service delivery
Carlson, 2022^265^ | What Drives Women Veterans’ Trust in VA Health care Providers? | General population/not specified | Health care organization/delivery of care for WVs | Service delivery
Jones, 2021^266^ | National Media Coverage of the Veterans Affairs Waitlist Scandal: Effects on Veterans’ Distrust of the VA Health Care System | General population/not specified | N/a | Service delivery
Fleming, 2021^921^ | An Exploration into the Experiences of Female Veterans Who Attended Higher Ground Military Programming | General population/not specified | General mental health; Chronic medical conditions | Service delivery
Shamaskin-Garroway, 2018^267^ | “I Think It’s Pretty Much the Same, as It Should Be”: Perspectives of Inpatient Care Among Women Veterans | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WV | Service delivery
Mattocks, 2018^268^ | Examining Women Veteran’s Experiences, Perceptions, and Challenges With the Veterans Choice Program | General population/not specified | Access to care/utilization; Reproductive health | Service delivery
Chanfreau-Coffinier, 2018^264^ | Mental Health Screening Results Associated with Women Veterans’ Ratings of Provider Communication, Trust, and Care Quality | General population/not specified | N/a | Service delivery
Trentalange, 2016^260^ | Patient Perception of Enough Time Spent With Provider Is a Mechanism for Improving Women Veterans’ Experiences With VA Outpatient Health Care | General population/not specified | VA Women’s Health Workforce | Service delivery
Cannedy, 2023^269^ | Coping with disruptive patients: Perspectives of primary care employees | Other: VA primary care providers | N/a | Service delivery
Hamilton, 2020^922^ | Usual Care Among Providers Treating Women Veterans: Managing Complexity and Multimorbidity in the Era of Evidence-Based Practice | General population/not specified | Access to care/utilization | Service delivery
Meredith, 2017^271^ | Attitudes, Practices, and Experiences with Implementing a Patient-Centered Medical Home for Women Veterans | Other: PCP and primary care-affiliated staff in PCP or Women’s Health Clinic | N/a | Service delivery
Chuang, 2017^270^ | Challenges with Implementing a Patient-Centered Medical Home Model for Women Veterans | Other: VA providers/staff | VA Women’s Health Workforce | Service delivery
Farkas, 2022^276^ | Retaining Providers with Women’s Health Expertise: Decreased Provider Loss Among VHA Women’s Health Faculty Development Program Attendees | Other: VA Women’s Health Primary Care Providers | WH education | Staffing and training of VA women’s health care providers
Schwartz, 2021^275^ | Retaining VA Women’s Health Primary Care Providers: Work Setting Matters | Other: VA women’s health PCP’s | N/a | Staffing and training of VA women’s health care providers
Sanders, 2022^274^ | Implementation experience and initial assessment of a rural women’s health training program in support of the U.S. Department of Veterans Affairs as a learning health system | Rural dwelling; Other: Rural providers and nurses | Reproductive health | Staffing and training of VA women’s health care providers
Baier Manwell, 2022^371^ | Mini-Residencies to Improve Care for Women Veterans: A Decade of Re-Educating Veterans Health Administration Primary Care Providers | General population/not specified | Preventative health | Staffing and training of VA women’s health care providers
Than, 2020^923^ | Understanding Gender Sensitivity of the Health Care Workforce at the Veterans Health Administration | General population/not specified | N/a | Staffing and training of VA women’s health care providers
Zuchowski, 2017^924^ | Drivers of Continuing Education Learning Preferences for Veterans Affairs Women’s Health Primary Care Providers | General population/not specified | Health care organization/delivery of care for WVs | Staffing and training of VA women’s health care providers
Shipherd, 2016^273^ | Interdisciplinary Transgender Veteran Care: Development of a Core Curriculum for VHA Providers | Other: Provider sample | SDOH | Staffing and training of VA women’s health care providers
Access to Care/Utilization
Murdoch, 2021^299^ | Reversals in initially denied Department of Veterans Affairs’ PTSD disability claims after 17 years: a cohort study of gender differences | History of trauma | Health care organization/delivery of care for WVs; General mental health | Disability claims
Chrystal, 2022^290^ | Women Veterans’ Attrition from the VA Health Care System | General population/not specified | Health care organization/delivery of care for WVs | General access to care/utilization
Baldomero, 2022^292^ | Drive Time and Receipt of Guideline-Recommended Screening, Diagnosis, and Treatment | General population/not specified | Preventative health; Chronic medical conditions | General access to care/utilization
Marshall, 2021^925^ | The Focus They Deserve: Improving Women Veterans’ Health Care Access | General population/not specified | Care Coordination; VA Women’s Health Workforce | General access to care/utilization
Weitlauf, 2020^295^ | Characterization and Comparison of Physical and Mental Health Profiles and Department of Veterans Affairs Health Care Utilization Patterns among Operation Iraqi Freedom/Operation Enduring Freedom Women Veterans in Puerto Rico versus the United States | OEF/OIF/OND | Health care organization/delivery of care for WVs; SDOH | General access to care/utilization
Vance, 2020^926^ | Five-year trend in health care access and patient-reported health outcomes among women Veterans | General population/not specified | Chronic medical conditions | General access to care/utilization
Copeland, 2020^294^ | Gender Differences in Newly Separated Veterans’ Use of Health care | OEF/OIF/OND | N/a | General access to care/utilization
Brunner, 2020^927^ | The role of health care system hassles in delaying or forgoing care | General population/not specified | N/a | General access to care/utilization
Newins, 2019^928^ | Barriers to the use of Veterans Affairs health care services among female Veterans who served in Iraq and Afghanistan | OEF/OIF/OND | N/a | General access to care/utilization
Chanfreau-Coffinier, 2019^929^ | Exploring the association of care fragmentation and patient ratings of care quality: A mediation analysis of women Veterans’ experience with VA care | General population/not specified | N/a | General access to care/utilization
Narain, 2018^291^ | Access to Care and Health Outcomes Among Women Veterans Using Veterans Administration Health Care: Association With Food Insufficiency | General population/not specified | SDOH; Food Insufficiency | General access to care/utilization
Brunner, 2018^930^ | Patient-Rated Access to Needed Care: Patient-Centered Medical Home Principles Intertwined | General population/not specified | Health care organization/delivery of care for WVs | General access to care/utilization
Di Leone, 2016^931^ | Women’s Veteran identity and utilization of VA health services | OEF/OIF/OND | Health care organization/delivery of care for WVs; SDOH | General access to care/utilization
Davies, 2016^293^ | Large-Scale No-Show Patterns and Distributions for Clinic Operational Research | General population/not specified | N/a | General access to care/utilization
Flike, 2023^288^ | Systematic review of access to health care and social services among US women Veterans experiencing homelessness | People with experiences of homelessness | SDOH | Prioritized population specific utilization and access
Gawron, 2017^932^ | Distance to Veterans Administration Medical Centers as a Barrier to Specialty Care for Homeless Women Veterans | People with experiences of homelessness | SDOH | Prioritized population specific utilization and access
Wolfe, 2023^933^ | Barriers and Facilitators to Gender-affirming Hormone Therapy in the Veterans Health Administration | Transgender or gender nonbinary | Health care organization/delivery of care for WVs | Prioritized population specific utilization and access
Rose, 2023^934^ | Trends in Feminizing Hormone Therapy for Transgender Patients, 2006-2017 | Transgender or gender nonbinary | N/a | Prioritized population specific utilization and access
Hahn, 2023^935^ | Primary sources of health care among LGBTQ+ Veterans: Findings from the Behavioral Risk Factor Surveillance System | Transgender or gender nonbinary; Sexual minoritized populations | N/a | Prioritized population specific utilization and access
Boyer, 2023^936^ | Patient Experiences and Provider Perspectives on Accessing Gender-Affirming Surgical Services in the Veterans Health Administration | Transgender or gender nonbinary; Other: VA providers | N/a | Prioritized population specific utilization and access
Wolfe, 2022^937^ | Patient Characteristics Associated with Receiving Gender-Affirming Hormone Therapy in the Veterans Health Administration | Transgender or gender nonbinary | N/a | Prioritized population specific utilization and access
Blosnich, 2019^289^ | Utilization of the Veterans Affairs’ Transgender E-consultation Program by Health Care Providers: Mixed-Methods Study | Other: VA providers | Health care organization/delivery of care for WVs; transgender health | Prioritized population specific utilization and access
Shipherd, 2018^938^ | Experiences in the Veterans Health Administration and Impact on Health care Utilization: Comparisons Between LGBT and Non-LGBT Women Veterans | Sexual minoritized populations | Harassment/discrimination | Prioritized population specific utilization and access
Dietert, 2017^939^ | Addressing the Needs of Transgender Military Veterans: Better Access and More Comprehensive Care | Transgender or gender nonbinary | Health care organization/delivery of care for WVs | Prioritized population specific utilization and access
Rohs, 2023^940^ | Perspectives of VA health care from rural women Veterans not enrolled in or using VA health care | Rural dwelling | SDOH | Prioritized population specific utilization and access
Cordasco, 2016^941^ | Health and Health Care Access of Rural Women Veterans: Findings From the National Survey of Women Veterans | Rural dwelling | N/a | Prioritized population specific utilization and access
Graham, 2023^13^ | Evaluating rates of chiropractic use and utilization by patient sex within the United States Veterans Health Administration: a serial cross-sectional analysis | General population/not specified | N/a | Specific service access and utilization
Haskell, 2022^296^ | Sex Differences in Use of a Clinical Complexity Measure to Predict Primary Care Utilization | OEF/OIF/OND | Health care organization/delivery of care for WVs; Chronic medical conditions | Specific service access and utilization
Williams, 2018^298^ | Clearing Away Past Wreckage: A Constructivist Grounded Theory of Identity and Mental Health Access by Female Veterans | General population/not specified | Health care organization/delivery of care for WVs; General mental health | Specific service access and utilization
Moore, 2016^297^ | Return-to-Work Outcome Rates of African American Versus White Veterans Served by State Vocational Rehabilitation Agencies | Racial/ethnic minoritized; General population/not specified | SDOH | Specific service access and utilization
Social Determinates of Health
Nillni, 2023^306^ | The impact of perceived everyday discrimination and income on racial and ethnic disparities in PTSD, depression, and anxiety among Veterans | Racial/ethnic minoritized | General mental health; Harassment/discrimination | General or overlapping SDOH
Tynan, 2022^309^ | Latent Class Patterns of Adverse Childhood Experiences and Their Relationship to Veteran Status and Sex in the National Epidemiologic Survey of Alcohol and Related Conditions Wave III | History of trauma | N/a | General or overlapping SDOH
Ward, 2021^942^ | Racial and Ethnic Disparities in U.S. Veteran Health Characteristics | General population/not specified | Access to care/utilization; Care Coordination | General or overlapping SDOH
Blosnich, 2020^307^ | Adverse social factors and all-cause mortality among male and female patients receiving care in the Veterans Health Administration | General population/not specified | all-cause mortality | General or overlapping SDOH
Gaska, 2018^308^ | Patterns of Adverse Experiences and Health Outcomes Among Women Veterans | General population/not specified | Interpersonal Violence | General or overlapping SDOH
Kondo, 2017^305^ | Health Disparities in Veterans: A Map of the Evidence | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WV | General or overlapping SDOH
Tsai, 2023^943^ | Unmet needs of homeless U.S. Veterans by gender and race/ethnicity: Data from five annual surveys | People with experiences of homelessness | N/a | Housing instability
Short, 2023^302^ | Female Veterans’ risk factors for homelessness: A scoping review | People with experiences of homelessness | N/a | Housing instability
Liu, 2023^304^ | Intimate Partner Violence Screening for Veterans Accessing Homelessness Services | People with experiences of homelessness | Health care organization/delivery of care for WVs; Interpersonal Violence | Housing instability
Tsai, 2022^944^ | Psychopharmacoepidemiology of antidepressant medications among homeless and unstably housed service users in the Veterans Affairs health care system | People with experiences of homelessness | Access to care/utilization; General mental health | Housing instability
Tsai, 2021^300^ | The Problem of Veteran Homelessness: An Update for the New Decade | People with experiences of homelessness | Access to care/utilization | Housing instability
Spinola, 2021^945^ | A psychosocial mediational model of homelessness among U.S. male and female Veterans who served in Iraq and Afghanistan | People with experiences of homelessness; OEF/OIF/OND | N/a | Housing instability
Mulcahy, 2021^946^ | Psychosocial risk factors for transitions into housing instability among women Veterans | People with experiences of homelessness; General population/not specified | N/a | Housing instability
Yu, 2020^947^ | The Intersection of Interpersonal Violence and Housing Instability: Perspectives From Women Veterans | People with experiences of homelessness; Other: people with experiences of housing instability (including but not limited to homelessness) | Interpersonal Violence | Housing instability
Montgomery, 2020^948^ | Use of Veterans Health Administration Homeless Programs Among Transgender and Non-Transgender Veterans Experiencing Self-Reported Housing Instability | Transgender or gender nonbinary | Access to care/utilization; Chronic medical conditions | Housing instability
Felder, 2020^949^ | The life course of homeless female Veterans: Qualitative study findings | People with experiences of homelessness | N/a | Housing instability
Carter, 2019^950^ | Housing Instability Characteristics Among Transgender Veterans Cared for in the Veterans Health Administration, 2013-2016 | Transgender or gender nonbinary | N/a | Housing instability
Montgomery, 2018^951^ | Recent Intimate Partner Violence and Housing Instability Among Women Veterans | People with experiences of homelessness; History of trauma | Interpersonal Violence | Housing instability
Dichter, 2017^952^ | Intimate partner violence, unhealthy alcohol use, and housing instability among women Veterans in the Veterans Health Administration | General population/not specified | Substance Use; Interpersonal Violence | Housing instability
Montgomery, 2016^301^ | Services Receipt Following Veteran Outpatients’ Positive Screen for Homelessness | People with experiences of homelessness | Access to care/utilization | housing instability
Brignone, 2016^303^ | Differential Risk for Homelessness Among US Male and Female Veterans With a Positive Screen for Military Sexual Trauma | History of trauma; General population/not specified | Interpersonal Violence | Housing instability
Scoglio, 2023^314^ | Social support over time for men and women Veterans with and without complex trauma histories | OEF/OIF/OND | General mental health | Other SDOH
Campbell, 2021^953^ | Differences in functional and structural social support among female and male Veterans and civilians | General population/not specified | N/a | Other SDOH
Narain, 2018^316^ | The Association of Food Insufficiency with Patient Activation Among Women Veterans Using Veterans Administration Health care: a Cross-Sectional Analysis | General population/not specified | Preventative health; Access to care/utilization | Other SDOH
McCall, 2018^315^ | Characteristics and Health Needs of Veterans in Jails and Prisons: What We Know and Do Not Know about Incarcerated Women Veterans | Justice-involved | Access to care/utilization; Chronic medical conditions | Other SDOH
Hill, 2016^317^ | Fit to Serve? Exploring Mental and Physical Health and Well-Being among Transgender Active-Duty Service Members and Veterans in the U.S. Military | Transgender or gender nonbinary | General mental health; Chronic medical conditions | Other SDOH
Carter, 2016^318^ | Racial and Ethnic Health Care Disparities Among Women in the Veterans Affairs Health care System: A Systematic Review | Racial/ethnic minoritized | Access to care/utilization; N/a | Other SDOH
Boros, 2021^954^ | Women Veterans after Transition to Civilian Life: An Interpretative Phenomenological Analysis | OEF/OIF/OND | General mental health; Chronic medical conditions | Social outcomes
Sienkiewicz, 2020^955^ | Examining the association between trauma exposure and work-related outcomes in women Veterans | History of trauma | General mental health; Interpersonal Violence | Social outcomes
Hawkins, 2018^319^ | Contextual Facilitators and Barriers of Community Reintegration Among Injured Female Military Veterans: A Qualitative Study | History of trauma | Chronic medical conditions; Injury | Social outcomes
Harassment
Mattocks, 2020^251^ | Women Veterans’ Experiences with Perceived Gender Bias in U.S. Department of Veterans Affairs Specialty Care | OEF/OIF/OND | Health care organization/delivery of care for WVs; VA Women’s Health Workforce | Harassment in VA
MacDonald, 2020^253^ | Experiences of Perceived Gender-based Discrimination Among Women Veterans: Data From the ECUUN Study | General population/not specified | Health care organization/delivery of care for WVs; SDOH | Harassment in VA
Stanton, 2022^250^ | Combat exposure and mental health outcomes: The incremental impact of nonsexual harassment on women Veterans | History of trauma; OEF/OIF/OND | General mental health; combat exposure | Other harassment
Reddy, 2016^258^ | Does the Factor Structure of Military Sexual Stressors in Men Correspond to Women’s? A Confirmatory Factor Analysis Using the Sexual Harassment Inventory | General population/not specified | N/a | Other harassment
Cannedy, 2022^255^ | Managers’ and Leaders’ Perceptions of Sexual and Gender-Based Public Harassment in the Veterans Health Administration | Other: VA middle managers and facility leaders | Health care organization/delivery of care for WVs | Harassment in VA
Fenwick, 2021^256^ | Staff and Patient Perspectives on Bystander Intervention Training to Address Patient-Initiated Sexual Harassment in Veterans Affairs Health care Settings | General population/not specified | Health care organization/delivery of care for WVs; VA Women’s Health Workforce | sexual/gender-based harassment in VA
Fenwick, 2021^257^ | Women Veterans’ Experiences of Harassment and Perceptions of Veterans Affairs Health Care Settings During a National Anti-Harassment Campaign | General population/not specified | Health care organization/delivery of care for WVs | Harassment in VA
Klap, 2019^252^ | Prevalence of Stranger Harassment of Women Veterans at Veterans Affairs Medical Centers and Impacts on Delayed and Missed Care | General population/not specified | Access to care/utilization | Harassment in VA
Dyer, 2019^254^ | Gender Differences in Veterans’ Perceptions of Harassment on Veterans Health Administration Grounds | General population/not specified | Access to care/utilization; Health care organization/delivery of care for WV | Harassment in VA
Toxic Exposures
Krengel, 2021^320^ | Neurotoxicant exposures and rates of Chronic Multisymptom Illness and Kansas Gulf War Illness criteria in Gulf War deployed women Veterans | Gulf War I | Chronic medical conditions | Toxic Exposures
Shinawi, 2019^321^ | Birth Defects Among 788 Children Born to Gulf War Veterans Based on Physical Examination | Gulf War I | Reproductive health | Toxic Exposures
Barth, 2016^322^ | All-CauseMortality Among US Veterans of the Persian Gulf War: 13-Year Follow-up | Gulf War I | Chronic medical conditions; Long-term care/aging | Toxic Exposures

## PEER REVIEW COMMENTS AND RESPONSES

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 1 | Yes | Acknowledged
2 | 2 | Yes | Acknowledged
3 | 3 | Yes | Acknowledged
4 | 4 | Yes | Acknowledged
5 | 5 | Yes | Acknowledged
6 | 6 | Yes | Acknowledged
7 | 7 | Yes | Acknowledged
8 | 8 | Yes | Acknowledged
Is there any indication of bias in our synthesis of the evidence?
9 | 1 | No | Acknowledged
10 | 2 | No | Acknowledged
11 | 3 | No | Acknowledged
12 | 4 | No | Acknowledged
13 | 5 | No | Acknowledged
14 | 6 | No | Acknowledged
15 | 7 | No | Acknowledged
16 | 8 | No | Acknowledged
Are there any published or unpublished studies that we may have overlooked?
17 | 1 | No | Acknowledged
18 | 2 | No | Acknowledged
19 | 3 | No | Acknowledged
20 | 4 | No | Acknowledged
21 | 5 | No | Acknowledged
22 | 6 | No | Acknowledged
23 | 7 | No | Acknowledged
24 | 8 | No | Acknowledged
Additional suggestions or comments can be provided below.
25 | 1 | Excellent report; I noted 2 typos:; Page viii, 4th key finding the date 2008-2025 should be 2008-2015; page 40, line 37, it seems like the sentence ending with using.… is missing words. | Thank you, these typos have been corrected.
26 | 2 | Operational partner should be listed as Office of Women’s Health, not WHRN.; Consider including trauma/experiencing violence as a separate category rather than including under MH. | We have corrected the operational partner identification.; We also organized our categories such that trauma and violence appear as a separate category from mental health as recommended.
27 | 2 | I think it is important to note that there has only been a slight increase in studies of organizational structure/access/utilization and this remains a high priority area as we need continued evidence to support our models of care/or trials of different models of providing care to this complex population | We added access/utilization to areas of minimal growth in the first paragraph of the discussion. We edited language for clarity under the future research section to highlight access/utilization.
28 | 3 | 1. Citation on page 2 leaves off Adelaide who appears to be 1st author on pg 1; same issue on pg 4 under Authors (unless pg 1 is incorrect). Also on pg 1, odd to include MPH for Adelaide and none of other author degrees (e.g., MDs, PhDs). | This is the title page generated by the ESP submission portal and will not be included in the published version of the report.
29 | 3 | 2. Pg 7, as mentioned before, while WHRN did this topic nomination, it was on behalf of the Office of Women’s Health (OWH) and the field, so am wondering whether this section should be amended since I am not an “operational partner” in VA terms. Same true for Dr. Rodriguez who is my deputy – also, please change her title to Deputy Director. On pg 12, under Current Review (lines 13-14), you note the review was requested by OWH, so just needs to be consistent. Can add OWH to front-end operational partners with WHRN tech support, but would then add WHRN under Current Review so consistent with each other. | We have corrected the identification of the operation partner.
30 | 3 | 3. Pg 8, Dr. Hamilton is a Research Career Scientist, not a Career Research Scientist. All HSR&D Centers should now be called HSR Centers (e.g., line 30, line 47). Since some include academic affiliations, would make consistent. Hamilton is a Research Anthropologist, Department of Psychiatry & Biobehavioral Sciences, UCLA Geffen School of Medicine, as one example. Her role as Associate Director for Implementation Science is also a VA HSR Center role, not a VA Greater Los Angeles role. Bevanne left out her VA HSR Center role, so please add Core Investigator, VA HSR Center for the Study of Healthcare Innovation, Implementation & Policy to her affiliations. May want to add that she is a Staff Physician, Comprehensive Women’s Health Center, at GLA rather than just staff physician at GLA. | The suggested changes have been made in the report.
31 | 3 | 4. Pg 11, lines 5-7, may want to help reader by noting the “previous 7-year period” (2016-23 vs. 2008-15, both being 7-year periods so able to compare from that perspective). Lines 16-20, am confused by reference to a “2008-25 map” – suspect that is a typo and should be 2008-15 map. In same bullet, I am somewhat confused by “relatively few prioritized the inclusion of rural-dwelling Veterans…” compared to the increase in transgender/nonbinary Veteran literature. Does this mean there was less of an increase (less than 8-fold)? Or simply few rural WV papers? May want to add “(e.g., LGB+)” to “sexual minoritized Veterans” for clarity or some other way of anchoring term (don’t feel strongly about it – sometimes this kind of clarification helps bring less-experienced readers along). Bottom line, not sure how to interpret this bullet. Pg 11, lines 22-23, was expecting this to sum to 100% (47+44=91), so if not WVs only and not mixed gender, what’s left? | Thank you for these suggestions. They have been incorporated and the identified bullet was rewritten.
32 | 3 | 5. Pg 11, lines 25-26, having one of the largest areas of primary care be ‘other mental health’ makes me confused because I don’t know what “other” means (what is it up against, trauma?). Consider adding an e.g., to clarify what is meant here so readers don’t have read report to understand this key bullet. Line 31, should spell out NSSI here since it has not been described previously. Recommend inclusion of an e.g., after ‘toxic exposures’ as the apostrophes suggest it has a more specific meaning and readers won’t know why without more context (adding “e.g., burn pits” would solve the problem) (this same issue comes up on pg 16, line 23 where there is never an example of what type of toxic exposures are relevant. Line 40, think it more accurate to note “Gaps” because no other section was described as gaps so saying “Additional gaps…” here gives one pause. Or be more explicit about other areas of gap(s) so the Additional makes sense. Lines 42-43, would make the “intersectional effects of chronic disease and conditions…” clearer – addition of the word “other” before “conditions” alone would help. | We changed this category from ‘other mental health’ to ‘general mental health’ and we added some examples for this category and for the toxic exposure category. We spelled out NSSI in the bullets and clarified the Key Findings as suggested.
33 | 3 | 6. Pg 11, lines 51-55 – the lead in phrase is about WVs’ sociodemographics and needs changing but the sentence after the colon is not about their needs changing (e.g., over time) but about their differences from men Veterans. This should be edited accordingly, e.g., describe how changing and/or change lead-in phrase to being about differences from men. Next sentence on lifespan doesn’t relate to sex/gender differences, so there is a logic flow issue here that the authors ought to be able to remedy easily but importantly. [Note: This same logical flow issue comes up on pg 22 under main report Background section not surprisingly, since it was probably written 1st – changes of WV demographics, etc., over time are not actually described other than perhaps that they have aged.] | We edited the wording in the identified section as well as the main report Background for clarity and to address flow issues.
34 | 3 | 7. How do you have 47% of the 933 articles with mixed-sex/gender (page 11, lines 22-23), while requiring that studies have “more than 75% WVs” on page 12, line 25? Were men relatively small samples in those studies? This is clearer in the Methods section (pg 23, lines 29-30) so would make comparably clear up front. | Addressed as noted above. Some studies included women Veterans, Veteran men, and women Civilians and included results disaggregated by WVs. We have rewritten this bullet.
35 | 3 | 8. Pg 12, like comment above about ‘other mental health’ it would be helpful to include an example for line 57 for ‘mental health not otherwise categorized.’ | Note that we have renamed this category to “general mental health”. In addition, an example has been added.
36 | 3 | 9. Pg 14, line 57, think this is missing a word (e.g., “…found only 29 articled targeted prioritized populations…” – is this “on targeted…” or “targeting”?). line 58, “common” repeated in sentence. “common conditions common among WVs…” – there may be a better way to phrase. | We have reworded both sentences for clarity.
37 | 3 | 10. Pg 15, preventive health – have general recollection that in last review, preventive care was a big gap area, which may be worth noting in discussion section. | Added a sentence to the first paragraph of the discussion addressing gaps that persisted between the 2008-2015 map and the current map.
38 | 3 | 11. Pg 16, lines 42-45, think this is a fragment – was looking for verb, not sure it’s there, like “was found” or “focused on” instead of focusing on. | Thank you, this has been updated to ‘focused on’ as suggested.
39 | 3 | 12. Importance of Veteran engagement mentioned a couple of times but never anchored in why important, what it adds, and/or why especially important for WV research. Given that this work will likely to be used to inform future research, I think spending a little bit of time contextualizing why this is mentioned would be helpful to those of us supporting the field. | We have added additional rationale for this recommendation in the executive summary and the discussion of the main report under the “future research” sections.
40 | 3 | 13. Pg 17, under Future Research, mention is made of implementation trials but limited context is provided. Were there any published implementation trials over this time period? Would protocol papers have been excluded? Know there were protocol papers for 2-3 implementation trials during this time, but am assuming those were excluded (?), but sentence on lines 18-20 alludes to efficacy and implementation trials so thinking about whether this means more clinical research (efficacy instead of effectiveness) is needed and then taking of interventions and evidence-based practices to scale through implementation strategies. Might consider making this just a little more clear (e.g., efficacy signals clinical while effectiveness signals HSR). | Thank you for this question. We identified 11 implementation studies as part of this map. The wording in this future research section has been clarified.
41 | 3 | 14. Pg 22, lines 15-16, notes largest proportion of service-connected WVs are 18-44 years of age, but the most recent graphs I have seen suggest they are 45-64 years of age, so would be good to verify with the Women’s Health Evaluation Initiative (Susan Frayne, MD, MPH), as a new WV Sourcebook will soon be out and it would be useful to have this map to the most recent data. Authors are framing a very large group here (18-44) with the comparison group being 45+. Think under Executive Summary, another age group was used, so double checking would be good here. The other distinction here is “service connected” so if another age group was referenced earlier, should be clearer (e.g., vs. eligible for low income?). | Double checked with most recent WV sourcebook vol. V data and edited for clarity.
42 | 3 | 15. Pg 22, line 33 – the PBRN is comprised of 76 VAs and has been for a number of years (rather than 73 noted here – noted citation #4 so maybe authors found link to an older version of WHRN executive summary (?). May want to point to the first VA WH services research agenda published in 2011 (2004 version was enterprise-wide, and map here focuses on HSR, so recommend giving HSR-centric agenda brief attention here as well: Yano EM, Bastian L, Bean-Mayberry B, Eisen S, Frayne SM, Hayes P, Lipson L, Mattocks K, McGlynn G, Sadler AN, Schnurr P, Washington DL. Using research to transform care for women Veterans: Advancing the research agenda and enhancing research-clinical partnerships. Women’s Health Issues. 2011;21(4 Suppl):S73–S83. (PMID:21724148)21724148 Also important since the topics in which this systematic review drew categories fit the 2nd agenda, not the first enterprise-wide one. | Number of WH-PBRNs updated and reference updated.; Added additional information to provide an overview of the 2010 VA women’s health services research agenda.
43 | 3 | 16. Pg 22, lines 36-38: I’m aware of additional systematic reviews than these overviews, including several that relied on the last evidence map to do, for example, a systematic review of the VA reproductive health research literature (Katon JG et al). There was also one on effects of military service on women Veterans: Batuman F, Bean-Mayberry B, Goldzweig C, Huang C, Miake-Lye I, Washington DL, Yano EM, Zephyrin LC, Shekelle PG. Health effects of military service on women Veterans. VA Evidence Synthesis Program (Project # 05-226), Los Angeles, CA: May 2011 . And ESP did several other systematic reviews focused on women Veterans but on specific elements (e.g., telehealth). I get that the systematic reviews and evidence map are the global ones, but readers may not make same distinction. May want to mention other systematic reviews on more specific topics within landscape of WVs research. [NOTE: I see that there is reference to these other reviews on pg 31, lines 12-16. Not sure how to help readers distinguish from ref made to two reviews and one map above except to emphasize that they were literature-wide instead of topically-focused.] | We agree that this is confusing and have reworded this sentence to clarify that we were referring to those articles that sought to summarize this field of literature broadly in similar or parallel way to the current map.
44 | 3 | 17. Figures are fantastic with respect to examining changes over time. Might consider making lines thicker (e.g., Fig 3 and 4). May want to change “preventative health” in Fig 4 to “preventive health” to be consistent with narrative. | We redrafted the figures with thicker lines and renamed the categories for consistency.
45 | 3 | 18. When I look at “assorted mental health” vs. IPV/MST (e.g., Fig 5), I pause because it’s not immediately clear where PTSD lies. Solid proportion of WVs PTSD is MST-related. Think earlier section of report says much of the “other mental health” (which I guess is “assorted” mental health here? should be clarified) is PTSD (figure title says “other mental health” too so may want to make consistent throughout so readers don’t wonder if “other” and “assorted” refer to different classifications. Would recommend making figures self-documenting if possible so that what fits in “assorted” or “other” mental health is clear without having to go elsewhere in report. | Given the multiple compelling reviewer comments on this topic we have made two significant changes. First, we have relabeled “assorted mental health” (sometimes previously labeled as “other mental health”) as general mental health. We realize that this, too, is imperfect but we feel is more clear. Second, we have created a new high-level category for “trauma, violence, and stressful experiences” separate from the larger mental health category. This new category will include interpersonal violence, other violence, and discrimination/harassment. PTSD will remain in the same category now labeled as “general mental health”. We have clarified this organization throughout.
46 | 3 | 19. Pg 31, line 46, think the “a” should be taken out (referring to plural analyses). Also page 31, line 48, refers to an observational study of “N=46,112,675 Veterans” but there are only 16.2 million Veterans in the US as a whole, so this is confusing. Is it a global study? Or is this somehow a weighting issue? Pg 32, line 19, need a space between “1” and “was.” I thought the standard was to spell out single digits like “1” (the authors do spell out “three” in the same sentence. | We have made the suggested changes and clarified that the 46,112,675 is observations and not individual Veterans.
47 | 3 | 20. Pg 33, table, line 14, with SDOH – wasn’t there at least 1 SDOH paper? – if none, would put in zeros or N/A like the toxic exposures row below it. For harassment and discrimination, there is no number for the current map. Under post-deployment health, there is no prior map number for OIF/OEF/OND – none? Or N/A? same for rural-dwelling, lines 34-37. Line 33, Rural Health IS a WHRN strategic priority area (the priority area is called “access/rural health.” So Rural Health should have a superscript “a” next to it as well. Not sure we call out homelessness in the research agenda and do not have a priority area for it currently, so think that superscripted “a” should probably be taken off. Page 33, line 46, would note that the proportion is similar (not the #). Pg 35, line 44, it is National Institutes of Health (rather than “Institute”). Pg 36, lines 6-9, says 4 new mental health related focus areas but five categories are noted. As noted previously, describing category of “other mental health” without ever saying what kinds of studies are there is not as helpful as it could be. Can authors characterize types of “other MH” conditions that reside therein? Pg 39, line 45, need space between “3” and “observational.” Same on pg 41, line 58, space needed between “5” and “studies.” I am sure I didn’t catch all of these, so would be good if someone did another round of review with a “fine-toothed comb.” Pg 43 top (bottom of table 6), again good to be consistent in term use (preventative vs. preventive). | We replaced this table with a figure that represents the changes in literature with more visual interest.
48 | 3 | 21. Pg 49, lines 7-9, says one study included only WVs with a N = 790,726 – as with another study that reports nearly four-fold higher numbers of Veterans than exist in US (not just beyond VA), there are not this many WVs in VA so this number left me wondering whether this was a study of all Veterans (not just VA users) OR if this is a weighted number rather than an actual number. Good to know since it calls into question intent/meaning without that extra piece of info. Same for pg 50, lines 16-17 (N=570,049). Pg 50, lines 7-8, looks like a word is missing in this sentence, e.g., “physical functioning WV compared…” (needs a “with” or something). Pg 51, lines 22-23, think this needs a semi-colon between the two sentences or addition of something like “with” between the two sentences to link them. Broadly, there are times reference numbers are before and sometimes after periods and commas, so consistency would be good (e.g., “…Initiative study225.” vs. “…and Veteran status.228” Pg 64, line 8, is there a number missing for “from both patients and staff…”? Sometimes WV is used as plural and sometimes it’s WVs. Personally, I prefer WVs to represent plural, but either way, would make this consistent throughout. Pg 65, lines 7-8, don’t think a dash should be between “gender” and “using” (don’t know what “gender-using admin data” are). Might consider an e.g., for the “1 described a specific approach to data collection from WVs.” (line 10, same pg). | Both are prevalence studies using VA Corporate Data Warehouse. Caloudas, 2022^12^ pulled data for WVs from October 2019 to September 2020. Ninivaggio, 2018^825^ pulled data for WVs from 1997 to 2015.; The editing suggestions have been addressed.
49 | 3 | 22. Discussion section – given that the volume of transgender/nonbinary research is still so very small, saying “By far, the greatest growth in research…” is about them torques findings in a way that brings far more attention to something where the numbers go from very small numbers to not so small numbers whereas other areas of research that are and continue to be more substantial sounds paltry in comparison. I would encourage authors to not over-emphasize the growth (going from 2-4 is 100% growth but it doesn’t mean it’s vastly more important or represents a dramatic shift in the literature). In this case, number of papers went from 4 to 32 but that’s still a very small literature, especially when one considers the n=933 denominator. If the authors are dead set on making this statement, I urge inclusion of a parenthetical that reminds the reader (who may take this finding out of context) that we are talking about going from 4 to 32 papers. As an epidemiologist, I would even point out that if you consider the change in denominator, the rate of publication for this special population went from 4 out of 440 (or 0.9%) to 32 out of 933 (3.4%) (closer to a 3-fold increase) or something that reminds the reader that somehow transgender/nonbinary work didn’t swamp the entire map. | Reworded section for clarity and to avoid over-emphasizing the amount of literature focused on transgender and/or nonbinary Veterans.
50 | 3 | 23. Discussion – another thing to consider, since WHRN was brought up, is that we have active national collaborative research work groups on repro health (including a repro MH subgroup), suicide prevention, LGBTQ+ Veterans, SUD, and harassment. We also sponsored journal supplements in 2019 (sex/gender differences in clinical trials and HSR studies), 2021 (suicide prevention), and 2023 (general WVs’ research). We only recently launched work groups for menopause, women and aging, and women’s military exposures so wouldn’t expect/hypothesize impacts as yet. We support mental health research broadly and were directly involved in Congressionally mandated IPV work, and there is now an IPV work group overseen by an IPV research center (Portnoy GA, Director), which we indirectly support. I suspect these collaboratives and supplements contributed to growth in some of these areas. So on page 72, lines 23+, it may be worth noting that WHRN has supported collaboration in these priority areas as well. Just a thought. | We agree with the importance of highlighting these successful efforts that have supported the growth outlined in this report. We have added a description of these activities in the discussion.
51 | 3 | 24. Discussion page 72, lines 50-52, the 500 excluded articles that didn’t report stratified outcomes by sex/gender are of interest and make me think about what it might take for us (outside of the context of this report) to do some investigator/author outreach to explore barriers to such reporting. Beyond scope of ESP work, but would it be possible to get access to these excluded papers to pilot test such an approach? | We added this to the future research section of discussion.; ESP will make list of these articles available to OWH.
52 | 3 | 25. Discussion, page 73, lines 8-11 – sentence starting “While such resource-intensive trials…” is a tad hard to get through – had to read it several times and think it would probably be better to divide into a couple of sentences. Next sentence “This is especially true…” is also hard to understand – what are “clinical settings or populations of safety and benefit?” Next sentence a little rough too, e.g., it’s a field of WVs research, rather than a field of literature I think (line 13). Sentence starting new paragraph same page line 19, doesn’t jive. Evidence map is focused on WV then says implications go beyond VA. Do the authors mean evidence map is focused on WVs so the map’s implications go beyond WVs to all women or all Veterans? Or is it that the evidence map chiefly focuses on WVs who use VA? If the latter, then the 2nd phrase works. Given the next sentence starting “First, more WVs receive care outside of the VA” makes it seem like the “who use VA” phrase needs to be added to the 1st sentence of this paragraph to make sense. Line 25 should refer to “clinical” expertise. Lines 30-31, men also experience sexual trauma so may want to make note of that as well (i.e., gender tailoring goes both ways), and in fact we just had a VA HSR CDA funded to study a gender-tailored intervention for men with histories of MST. Line 33, “used by civilian populations” – remember Veterans are also civilians, so we typically have to say “non-Veteran civilian populations” to be more accurate and clear. | We have heavily revised this section of the discussion for clarity and readability and to reflect recommended edits.
53 | 3 | 26. Discussion, page 74, as noted above, please double check whether WVs are “reaching middle age” (line 9) vs. are already there based on the most recent age distribution data. Would consider noting importance of studying mental health/trauma overlay on women in midlife as they age and their chronic care management may be complicated therein. There’s very little literature as I recall on older WVs with PTSD (with the exception of the Longitudinal Vietnam WVs Study, which is no longer funded but from which papers still emerge). Line 23-25, may want to also note WRIISC WOMAN, which has (I think) substantially more funding than COURAGE and is focused on military exposures. It is based at VA Palo Alto and may be worth noting vis a vis the military exposures section, though I don’t think they have published that much as yet. Paragraph starting on line 39, would be good to put the onus of reporting by sex and gender on men Veterans’ research too – it seems that women’s health research bears the burden more in many editorials I’ve reviewed so it would be helpful to the field to add some sort of proviso that this admonition should be applied ORD-wide. New inclusion language is being added to all of the new ORD enterprise-wide RFAs so it’s not just our job to do this right and do it well. Page 75, lines 3-7, do you want to give a nod to the CSP-funded Women’s Enhanced Recruitment Process (WERP) which may contribute to improved inclusion of WVs in VA trials? Seems like a missed opportunity. Recognize this map is coming out of Dr. Goldstein’s group who is a WERP MPI, but I think this is worth noting and do not see that as a conflict of interest. | We altered language in the second paragraph in the future research section to reflect the population of WVs that are currently or will soon be middle age. We added language to highlight the importance of the MH contribution to chronic care management.; We added in further details about other suggested VA programs such as WRIISC WOMAN and WERP where suggested.; Updated the paragraph on line 39 (ie, fourth paragraph of the future research section) to reflect the need for all researchers to consider how they are reporting sex and gender.
54 | 4 | Overall the team has done a tremendous job with this evidence map. For those of us who have been in the field for a while it is truly wonderful to see the immense growth in the literature, not just in terms of the number of articles, but also the variety of topics. I just have a few suggestions:; 1) I thought that many of the figures were great, but the two that showed trends in topics overtime weren’t that useful. The time period is relatively short and w COVID in the middle it is difficult to really draw any conclusions from these. I would be much more interested in an analysis like this that examined characteristics of first and sr authors in various topics overtime. Conversely, I found figures 5 and 6 very interesting. My only suggestion for these is that the topic categories go on the other side of the thick black line (e.g. left side for primary topic) so that they can be read more easily. | We agree that an analysis of first and senior authors would be interesting in this growing field of literature though is outside the scope for this report. We are happy to provide the data collected on first and senior authors.
55 | 4 | 2) For several topics it was mentioned that a large portion of the papers came from one or more specific studies (e.g. WVCS, COMFORT, ECUUN). This is something I am encountering in a systematic review I am doing. In my mind this is both a strength and weakness of the literature (hampers replication of findings, can limit perspectives and innovation in study design, demonstrates really good use of existing data, potentially also demonstrates effective mentorship of early career folks by giving them access to data resources, may reflect a need for more funding for larger survey or cohort studies). Regardless I think it is worth commenting on. | This is a good observation and we have pointed to this in the future research section of the discussion.
56 | 4 | 3) Discussion section, page 55, line 49-50 I found the sentence that began “Yet, the proportion…” confusing. I understand the importance of reporting by sex and gender if you have a mixed sex or gender study and the team explicates that clearly in the remainder of the paragraph. Recommend deleting this sentence as I think the key support for their point is the subsequent sentence noting the 500 articles that were excluded as they did not report outcomes by sex or gender. | We have removed this sentence as suggested.
57 | 4 | 4) Discussion section page 55, lines 42-45. I am not sure that the reference to intersectionality here is appropriate. Most of the literature focuses on describing disparities by race/ethnicity, but the majority is not necessarily informed by the theory of intersectionality as posited by Dr. Crenshaw or by Black Feminism or Critical Race Theory. This concept is complex and involves much more than stratification by race and gender/sex. Therefore, I think invoking intersectionality based on fact that there is growing literature based on comparisons by race and sex/gender does this long lineage of intellectual thought and scholarship a disservice. I would either not use the term at all as I don’t think its use is critical for the primary message of the paragraph. If you do opt to keep it, then add an appropriate set of citations (e.g. Dr. Crenshaw’s article, Combahee River Collective, Patricia Hill Collins). | We appreciate this point and have removed the reference to “interactional identities”.
58 | 4 | 5) I understand why the choice was made to use essentially the same categorizations as the initial evidence map, and this is particularly useful for VA researchers or ORD staff. However, to be more relevant to the conversation regarding women’s health it would be really useful to also map the articles by topic/condition to the framework used by the recent NIH Perspectives on Advancing NIH Research to Inform and Improve the Health of Women report. This report categorizes conditions as: female specific, more common in women or morbidity is greater in women, potentially understudied in women, high morbidity for women. Such an approach would put this literature and the portfolio of women’s health research in VA into perspective with what is going on more broadly in women’s health research. This is particularly important given that VA was included in the recent WH Executive Order on Women’s Health Research and would help to raise the profile of VA as a place where potentially innovative, unique, and high quality women’s health research is happening. I realize that this may be too much additional work for this initial report, but I think it is worth doing either for this report or as a separate product. | This is an excellent idea and agree that this would be a valuable contribution to the literature though is outside of the scope of this specific report. We will explore opportunities to conduct such an analysis in the future.
59 | 5 | - Report needs a table of contents and orientation to the tables at the end | The new standard ESP process is for the table of contents to be generated by the Coordinating Center once the report is finalized.
60 | 5 | - Executive summary page viii - you note that reproductive health is both an area of growth and a gap - might clarify why both (related to peripartum period or not?) | The reproductive mental health section overall increased 3.7-fold compared to prior reports. Additionally, there are few papers in this section unrelated to the peripartum period.
61 | 5 | - Executive summary page viii - isn’t lack of implementation studies also a gap? | Implementation studies was added as a gap.
62 | 5 | - Executive summary page viii could benefit from some references in the background section | According to ESP style standards, references are not included in the executive summary.
63 | 5 | - Executive summary page ix - clarify a bit when you had 1 vs 2 reviewers | This section of the executive summary methods has been clarified.
64 | 5 | - Executive summary page ix and subsequent - I struggled with the category of “other mental health” esp given its prominence in the report. Why not separate out categories - esp given this includes PTSD. Since this is the first main result in the exec summ, at minimum I think you need to explain a bit more what went into this category | Please see above noted changes to the name of this section. In addition, we have expanded on this category in the results as suggested. We have also worked to reframe and define the, now named, general mental health focus area.
65 | 5 | - It would be very helpful for ORD to have some analysis/summary by funding source (exec sum and expand on page 18) | We have added further information about funding sources to the executive summary and the results under the funding sources and engagement section.
66 | 5 | - Might want to note the rationale for grouping violence with mental health | Note that we have regrouped trauma and violence as its own category and is no longer under mental health.
67 | 5 | - Page xi - not clear why under substance use you state that there were few articles on OUD but on page xii you describe 30 studies on chronic pain/opioids. Assume difference in primary code? | The chronic pain/opioids section includes articles addressing pain management including the clinical use of opioids for pain management while the substance use focus area includes articles about opioids used as a part of a substance use disorder. This has been clarified in the report.
68 | 5 | - page 5- please double check the 11% figure as I didn’t think it was quite that high yet - but may have new data available | Double checked figure, changed to 10% with updated reference.
69 | 5 | - page 5 - double check # PBRNs, I thought this was now 76 | This was addressed above.
70 | | - Page 5, there have been more than 7 years since 2015 | Changed to 8 years and added language for clarification.
71 | 5 | - I have a hard time reading the figures - e.g, figure 4, 5 and others. Consider thicker lines or another way to make easier to interpret? These are important figures and recognize the challenge to visualize them - but not sure if there are alternatives | The referenced figures have been adjusted - see response to above comment.
72 | 5 | - p 15, Table 2 - heading doesn’t match with narrative | This table has been removed in the final report.
73 | 5 | - page 33, reference to increase in studies on amputation - I bet the rehab groups would be interested to dig deeper to see if this is about prosthetics given congressional interest - might not be able to do anything here but just noting. | We have added some additional information about the number of amputation studies that also focused on prostheses.
74 | 5 | - It would be Extremely helpful to have these findings in a searchable / tagged database! This would help us better answer Congressional inquires and much much more within ORD | Our team will work with OWH to provide the data for future use.
75 | 5 | - Page 55, postpartum mood and pregnancy care aren’t examples of increase in reproductive age in WV | This was edited for clarity in the final report.
76 | 5 | - p 57, if going to call out the COURAGE, need to explain why this is relevant here etc; p 57, was very surprised that so few studies discussed Veteran engagement but maybe they don’t include this in the articles | Edited to clarify the relevance of COURAGE and other WH focused research groups.; We were also surprised by the lack of discussion of Veteran engagement in the identified articles. We suspect this is underreporting and have noted the importance of this in the future research section.
77 | | This review is excellent. I have only fairly minor comments and suggestions, with the exception of one larger question about the categorization of research topics.; Larger Issues:; - My main set of comments focuses on how research topics were categorized. My comments and reactions are offered as “food for thought,” as I realize that a great deal of consideration went into how this research was categorized and I know that the authors are trying to keep categories as similar to prior categorization strategies (for the last evidence-map) as possible.; ○ A major strength of this review as compared to the prior review (or evidence map) is that there is a more refined examination of the literature on mental health topics.; ○ That said, it strikes this reader as strange to label the category with the most research in it as an “other” category (within the broader mental health category). I would consider relabeling this to be “mental health symptoms/conditions,” as the other subcategories in this category aren’t conditions per se. | See above regarding categorization and labeling of MH topics.
78 | 6 | ○ In addition, some of the research that is categorized within the mental health domain focuses on exposures/stressors/traumas that are often examined as predictors of mental health outcomes (such as MST and IPV), but that can have consequences for many different aspects of Veterans’ lives, including their physical health. Likewise, it seems somewhat inconsistent to have MST in the mental health category and “harassment and discrimination” in another category when both can include persistent harassment experiences. These two issues combined with the placement of toxic exposures (another tricky one to categorize) made this reviewer wonder if there should be a separate (non-mental health specific) category for “stress/trauma/exposure that could include all of these topics. Again, I understand that a great deal of thought went into the current categorization and there are likely good reasons for why it was done the way it was so this is just offered for consideration. | We appreciate this suggestion and have created a new category of trauma, violence, and stressful experiences. We did not include toxic exposures in this new category given the distinct focus on this topic since the 2022 PACT Act.
79 | 6 | - Key Findings – the comparison referenced in the fourth bullet is somewhat awkward and not very intuitive (why compare research on transgender Veterans to the three topics listed here)? | This bullet has been rewritten for clarity. This refers to populations targeted for inclusion which is why they were grouped together.
80 | 6 | - Please rephrase the following sentence in the Methods Section of the Executive Summary as it is awkward -> “Publications with health care team members who provide care to WVs….” | This sentence has been rewritten for clarity.
81 | 6 | - In same section – how are “Investigators” different from “Reviewers”? | Thank you, this has been updated to ‘reviewers’ throughout.
82 | 6 | - The fact that relatively few studies have focused on depression/generalized anxiety is important given how commonly these conditions are experienced by women and the fact that they could potentially be experienced differently for women Veterans compared to non-women Veterans. For example, depression could be more strongly linked to suicide risk among women Veterans due to their greater access to firearms. This might be worth discussing as an area in need of further examination. | Added a sentence to the first paragraph of the discussion addressing gaps that persisted between the 2008-2015 map and the current map – which included depression/anxiety
83 | | - One of the recommendations from the prior review was for more research on women’s experiences of combat and their consequences. I know that this is not a specific category in the current review and that the deployment stress category has been collapsed to be a broader OEF/OIF/OND category, but it does seem like part of the focus of the current review should be on evaluating whether the recommended research has been done. Is there any way to address this? Also, given the large number of studies focused on post-deployment health (now classified into the broader category of OEF/OIF/OND), it is somewhat surprising that there isn’t more discussion of the findings of this research (with regard to post-deployment health issues). Or is this already sufficiently covered in the discussion of general health outcomes? | We appreciate this point and seek to clarify that the OEF/OIF/OND category reflects those articles that specifically sought to include this era of Veterans based on our assessment of eligibility criteria. These 156 articles may or may not include a focus on deployment stress. This is a potential limitation based on the change from the last map and we have added this to the limitations section and mention that there were fewer than 10 articles specifically about combat exposure.
84 | | - The authors introduce the concepts of systematic reviews and evidence maps but do not explain how they are different from one another. | This sentence was rewritten for clarity as noted above.
85 | | - Figure 1 indicates that no additional articles were identified from gray literature searches or expert recommendations which was surprising. Was it that there was no attempt to seek out expert recommendations? This might be fine but if so I would not list this category. | ESP standard reporting is to use the PRISMA literature flow as is without changing the potential article sources.
86 | 6 | - For the excluded category in Figure 1 I would suggest identifying the articles as “other” types rather than as “wrong,” which sounds kind of awkward. | We changed this language to our usual term “ineligible”.
87 | 6 | - For Figures 3 and 4, I wondered if it might be useful to examine change over longer periods of time than a year as there is always some natural (likely not very meaningful) fluctuation year to year. For example, perhaps the years could be grouped into two or three year periods? | This would be an interesting visual representation of the data. However, given the relatively short window between 2016 and 2023, we have elected to show the data yearly rather than in two-year groups.
88 | 6 | - Table 2- shouldn’t there be a number for harassment and discrimination studies? | We are removing Table 2 in the final report.
89 | 6 | - Is toxic exposures really an access and utilization issue? | We are removing Table 2 in the final report.
90 | 6 | - Figure 6 – this figure was somewhat hard to understand and it wasn’t clear that it provided very useful info. | We have added some additional description to orient the reader to the alluvial figure of prioritized populations and corresponding focus areas.
91 | 6 | - Page 20 – second full paragraph – the comparator for the first and last sentence should be specified. | We were unable to identify the relevant location for this comment. However, we have done some additional editing for the final report and may have addressed this comment.
92 | 6 | - Reference to TVMI study on combat – was there really one only article on women’s exposure to combat during this timeframe? | There were 7 other papers reporting on women’s exposure to combat. These papers were categorized across other focus areas including general mental health (k = 3), chronic medical conditions (k = 1), chronic pain (k = 1), interpersonal violence (k = 1), and harassment/discrimination (k = 1).
93 | 6 | - Last sentence of first paragraph on p. 57 – did you mean to say Table 10? | We updated the table numbering for the final report.
94 | 6 | - Other design and reporting considerations in Table 10 – I would use the same sentence structure for each bullet in this section. | Thank you, this has been updated accordingly.
95 | 7 | 1 Page iv line 56-67: Deputy Director | This has been updated accordingly.
96 | 7 | 2 Page ix line 49: consider adding “on average” before “per year” (e.g., 117 on average per year) | Thank you, as recommended ‘per year’ has been added to this sentence for clarity.
97 | 7 | 3 Unsure if “reproductive mental health” (under mental health) is mutually exclusive from “reproductive health” (under medical conditions), or were those parsed out? I imagine there was maternal mental health work, for example. Perhaps warrants including a reminder note to make that clear as a footnote wherever that comes up even though you already do an excellent job of making things clear generally. | Articles were assigned to either reproductive mental health OR reproductive health depending on the stated objectives of the article or the framing. We acknowledge that there is some subjective nature to such decisions. We have clarified this throughout.
98 | 7 | 4 Page xi - 136 or 137 “chronic med conditions” papers? Discrepancy on page xi and page 10. | This discrepancy has been addressed (k = 137).
99 | 7 | 5 Page 5 lines 32-33: “…expansion of the WH-PBRN to 76 VA medical centers…” | Number updated and new reference provided
100 | 7 | 6 Page 57 lines 2-57: consider adding a line about leveraging existing WV engagement resources like WHRN (e.g., WIN from Aim 3) for infusing WV engagement in research. | Examples of VA resources for engagement were added.
101 | 7 | 7 Page 58, lines -7: a possible strategy to improve the inclusion of women Veterans in trials might be to invest in a VA registry of women Veteran studies seeking recruitment. | Examples of strategies to increase inclusion of women Veterans were added.
102 | 7 | 8 Review for typos. Examples; a. Page 169 line 19: “sytematic”; b. “” line 43: “determin” | Thank you, the document has been checked and updated accordingly.
103 | 8 | This is excellent, clearly organized, well-written report describing the scope of women Veterans health research literature. The figures (particularly figures 3-6) and discussion section (for both the executive summary and full report) do an exceptional job of summarizing the key findings and gaps. The organization of results by topic in the main report is clear, thorough, and consistent.; Minor questions/concerns:; Results: (exec summary and full report page 11) - the review repeatedly compares the number of articles identified in the present and previous review to demonstrate growth in the literature. Authors should note the ways in which inclusion/exclusion criteria differed between the two reviews, as a more inclusive approach may also be responsible for the increase in publications identified (for example - the present review included systematic reviews and protocol papers, while the prior review excluded them). | We agree with this reviewer’s comment on the non-parallel comparison between the prior and current map. This is articulated in the limitations section but has also been emphasized in the executive summary as well.
104 | 8 | I would appreciate an explanation for the decision to group PTSD, depression, and anxiety together in “other mental health” - along with very different conditions such as sleep and disordered eating. These seem quite distinct, and in the case of PTSD, particularly significant for women Veterans’ research. | Please see above responses addressing this important issue.
105 | 8 | Limitations: Please acknowledge the lack of dual review for all articles at full text and data abstraction as limitation and describe the potential consequences - though this seems practically necessary given the sheer volume of included articles, single review may result in errors, omissions, or misclassifications. Noting the qualifications of individual reviewers or results of the 20% dual review (ie, proportion with discrepancies or disagreement) may offer some reassurance to the reader. | We have added this to the limitations section.
106 | 8 | Grammatical/copy-edit:; Executive Summary Methods Page ix, line 35-37 mentions data “abstraction” and then “extraction” in the subsequent sentence - are these distinct concepts? How do they differ? | The document has been updated to use ‘extraction’ rather than ‘abstraction’.
107 | 8 | “Men Veterans” is a grammatically uncomfortable phrase, because men is not an adjective (women is also not an adjective, but is much more commonly used this way). Would prefer to see “women Veterans” and “male Veterans.” | The document has been updated to use the term ‘Veteran men’ throughout, for consistency with ‘women Veterans’, rather than conflating terms for sex and gender across the two populations.
108 | 8 | There is an extra space lines 26-27 page 57 of Discussion | Thank you, this extra space has been removed and the rest of the document check for similar instances.