# ACKNOWLEDGMENTS

The authors are grateful to Rebecca Watkin, Liz Wing and Dr. Stacy Lavin for editorial support, Dr. Nicholas J. Parr for data visualization expertise, Kaitlyn Goodwin, Yujung N. Choi, Dr. Jill Sergison for literature screening and abstraction help, and the external peer reviewers. This work was partially supported by the Durham Center of Innovation to Accelerate Discovery and Practice Transformation (ADAPT) (CIN 13-410) at the Durham VA Health Care System.

The authors are also grateful for the contributions of the following individuals:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Sally Haskell, MD, MS
  Acting Chief Officer – Office of Women’s Health
  Veterans Health Administration

- Professor of Medicine
  Yale School of Medicine

## Technical Expert Panel

To ensure robust, scientifically relevant work, the technical expert panel (TEP) guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members included:

- Elizabeth Yano, PhD
  Director
  VA Women’s Health Research Network (Consortium)

- Adriana Rodriguez, PhD
  Deputy Director
  VA Women’s Health Research Network (Consortium)

- Lori Bastian, MD, MPH
  Professor of Medicine (General Medicine)
  Yale School of Medicine

- Section Chief of General Internal Medicine & Director
  Pain Research, Informatics, Multimorbidities, and Education (PRIME) Center

- Associate Chief of Staff for Research
  VA Connecticut Healthcare System

- Amanda Borsky, DrPH, MPP
  Scientific Program Manager – Women’s Health and Healthcare Operations
  Office of Research and Development, Department of Veterans Affairs

- Alison Hamilton, PhD, MPH
  Research Career Scientist
  VA HSR Center for the Study of Healthcare Innovation, Implementation, and Policy

- Associate Director for Implementation Science
  VA HSR Center for the Study of Healthcare Innovation, Implementation, and Policy

- Research Anthropologist
  Department of Psychiatry & Biobehavioral Sciences
  UCLA Geffen School of Medicine

- Jodie Katon, PhD, MS
  Investigator
  VA HSR Center for the Study of Healthcare Innovation, Implementation, and Policy
  VA Greater LA Healthcare System

- Elisheva Danan, MD, MPH
  Staff Physician
  General Internal Medicine
  Minneapolis VA Health Care System

- Core Investigator
  Center for Care Delivery and Outcomes Research

- Assistant Professor of Medicine
  University of Minnesota

- Co-Director
  Advanced Fellowship in Health Services Research

- Bevanne Bean-Mayberry, MD
  Staff Physician
  Comprehensive Women’s Health Center
  VA Greater Los Angeles Healthcare System

- Clinical Professor of Medicine
  UCLA David Geffen School of Medicine

- Core Investigator
  VA HSR Center for the Study of Healthcare Innovation, Implementation, and Policy

- Dawne Vogt, PhD
  Research Scientist
  Women’s Health Sciences Division of the National Center for PTSD

- Professor of Psychiatry
  Boston University Chobanian & Avedisian School of Medicine