# ABBREVIATIONS TABLE

Abbreviation: Definition
ABC-I: Acceptance and commitment therapy for insomnia
ACC: American College of Cardiology
ACEs: Adverse childhood experiences
ADL: Activities of daily life
AHA: American Heart Association
ASCVD: Atherosclerotic cardiovascular disease
AUB: Abnormal uterine bleeding
BMI: Body mass index
BSO: Bilateral salpingo-oophorectomy
CBT-I: Cognitive behavioral therapy for insomnia
CKD: Chronic kidney disease
COMFORT: Center for Maternal and Infant Outcomes and Research in Translation Study
COPD: Chronic obstructive pulmonary disease
DESTRESS: Delivery of Self Training and Education for Stressful Situations
DOD: Department of Defense
ECUUN: Examining Contraceptive Use and Unmet Need
EMPOWER: Enhancing Mental and Physical Health of Women through Engagement and Retention
EPOC: Effective Practice and Organization
ESP: Evidence Synthesis Program
HIV: Human immunodeficiency virus
IPV: Intimate partner violence
MCC: Maternity care coordination
MST: Military sexual trauma
MVP: Million Veteran Program
NESARC-III: National epidemiologic survey on alcohol and related conditions
NIH: National Health Institute
NSSI: Non-suicidal self-harm
OEF/OIF/OND: Operation Enduring Freedom/Operation Iraqi Freedom/Operation New Dawn
PACT: Patient aligned care team
PCP: Primary care provider
PE: Prolonged exposure
PRESS: Peer review of electronic search strategies
QI: Quality improvement
RCT: Randomized controlled trial
SDOH: Social determinants of health
SERV: Survey of experiences of returning veterans
SUD: Substance use disorder
TBI: Traumatic brain injury
TVMI: The Veterans Metris Initiative
VA: Veterans Affairs
VHA: Veterans Health Administration
VALOR: The Veterans After-discharge Longitudinal Registry
WH-PACT: Women’s Health Patient Aligned Care Team
WH-PBRN: Women’s Health Practice-Based Research Network
WHRN: Women’s Health Research Network
WVCS: Women Veterans Cohort Study
WV: Women Veteran