# REFERENCES

1 Centers for Disease Control and Prevention. COVID-19 guidance. Website. Available at: https://www.cdc.gov/coronavirus/2019-ncov/index.html. Accessed January 26, 2022.
2 Baum A, Kaboli PJ, Schwartz MD. Reduced In-Person and Increased Telehealth Outpatient Visits During the COVID-19 Pandemic. Ann Intern Med. 2021;174(1):129–131.32776780
3 Connolly SL, Stolzmann KL, Heyworth L, . Rapid Increase in Telemental Health Within the Department of Veterans Affairs During the COVID-19 Pandemic. Telemed J E Health. 2021;27(4):454–458.32926664
4 Institute of Medicine Committee on Advancing Pain Research C, Education. The National Academies Collection: Reports funded by National Institutes of Health. Relieving Pain in America: A Blueprint for Transforming Prevention, Care, Education, and Research. Washington (DC): National Academies Press (US); 2011.
5 Johannes CB, Le TK, Zhou X, . The prevalence of chronic pain in United States adults: results of an Internet-based survey. J Pain. 2010;11(11):1230–9.20797916
6 Dahlhamer J, Lucas J, Zelaya C, . Prevalence of Chronic Pain and High-Impact Chronic Pain Among Adults - United States, 2016. MMWR Morb Mortal Wkly Rep. 2018;67(36):1001–1006.30212442
7 Chou R, Turner JA, Devine EB, . The effectiveness and risks of long-term opioid therapy for chronic pain: a systematic review for a National Institutes of Health Pathways to Prevention Workshop. Ann Intern Med. 2015;162(4):276–86.25581257
8 Finley EP, Schneegans S, Curtis ME, . Confronting challenges to opioid risk mitigation in the U.S. health system: Recommendations from a panel of national experts. PLoS One. 2020;15(6):e0234425.32542028
9 Qaseem A, Wilt TJ, McLean RM, . Noninvasive Treatments for Acute, Subacute, and Chronic Low Back Pain: A Clinical Practice Guideline From the American College of Physicians. 2017(1539–3704 (Electronic)).
10 Hanlon PA-O, Daines LA-O, Campbell CA-O, . Telehealth Interventions to Support Self-Management of Long-Term Conditions: A Systematic Metareview of Diabetes, Heart Failure, Asthma, Chronic Obstructive Pulmonary Disease, and Cancer. 2017(1438–8871 (Electronic)).
11 Johnston B, Wheeler L, Deuser J, . Outcomes of the Kaiser Permanente Tele-Home Health Research Project. Arch Fam Med. 2000;9(1):40–5.10664641
12 Barlow J, Wright C, Sheasby J, . Self-management approaches for people with chronic conditions: a review. Patient Educ Couns. 2002;48(2):177–87.12401421
13 Cochrane. RoB 2 tool: a revised Cochrane risk of bias tool for randomized trials. Available at: https://sites.google.com/site/riskofbiastool/welcome/rob-2-0-tool?authuser=0. Accessed February 4, 2022.
14 The GRADE handbook. Available at: https://gdt.gradepro.org/app/handbook/handbook.html. Accessed February 4, 2022.
15 Herbert MS, Afari N, Liu L, . Telehealth Versus In-Person Acceptance and Commitment Therapy for Chronic Pain: A Randomized Noninferiority Trial. Journal of Pain. 2017;18(2):200–211.27838498
16 Doiron-Cadrin P, Kairy D, Vendittoli PA, . Feasibility and preliminary effects of a tele-prehabilitation program and an in-person prehablitation program compared to usual care for total hip or knee arthroplasty candidates: a pilot randomized controlled trial. Disability and rehabilitation. 2020;42(7):989–998.30638076
17 Hale L, Devan H, Davies C, . Clinical and cost-effectiveness of an online-delivered group-based pain management programme in improving pain-related disability for people with persistent pain-protocol for a non-inferiority randomised controlled trial (iSelf-help trial). BMJ Open. 2021;11(2):e046376.
18 Mesa-Castrillon CI, Simic M, Ferreira ML, . EHealth to empower patients with musculoskeletal pain in rural Australia (EMPoweR) a randomised clinical trial: study protocol. BMC Musculoskeletal Disorders. 2021;22(1):11.33402161
19 Hinman RS, Kimp AJ, Campbell PK, . Technology versus tradition: a non-inferiority trial comparing video to face-to-face consultations with a physiotherapist for people with knee osteoarthritis. Protocol for the PEAK randomised controlled trial. BMC Musculoskeletal Disorders. 2020;21(1):522.32767989
20 ACTRN12621000267853. Investigating the effect of supported motivational interviewing on physical activity for people with knee osteoarthritis who have already completed a widespread exercise-therapy program (GLA: D(R)). A pilot study. Available at: https://trialsearch.who.int/?TrialID=ACTRN12621000267853. Accessed February 3, 2022. 2021.
21 NCT04613362. TelemEdiciNe-bAsed Cognitive TherapY for Migraines. Available at: https://clinicaltrials.gov/ct2/show/NCT04613362. Accessed February 3, 2022. 2020.
22 ISRCTN15564385. E-rehab for Knee Pain. Available at: https://trialsearch.who.int/?TrialID=ISRCTN15564385. Accessed February 3, 2022. 2020.
23 NCT04441593. Internet-based Video-conferencing to Address Alcohol Use and Pain: a Pilot Trial. Available at: https://clinicaltrials.gov/ct2/show/NCT04441593. Accessed February 3, 2022. 2020.
24 NCT04074109. Feasibility of At-Home Telehealth Yoga for Treating Chronic Pain. Available at: https://clinicaltrials.gov/ct2/show/NCT04074109. Accessed February 3, 2022. 2019.
25 ACTRN12619000235101. Exercise-therapy and education for knee osteoarthritis: comparison of telerehabilitation with face-to-face delivery. Available at: https://trialsearch.who.int/?TrialID=ACTRN12619000235101. Accessed February 3, 2022. 2019.
26 Walumbe J, Belton J, Denneny D. Pain management programmes via video conferencing: a rapid review. Scand J Pain. 2021;21(1):32–40.33027056
27 Adamse C, Dekker-Van Weering MG, van Etten-Jamaludin FS, . The effectiveness of exercise-based telemedicine on pain, physical activity and quality of life in the treatment of chronic pain: A systematic review. J Telemed Telecare. 2018;24(8):511–526.28696152
28 Dario AB, Moreti Cabral A, Almeida L, . Effectiveness of telehealth-based interventions in the management of non-specific low back pain: a systematic review with meta-analysis. Spine J. 2017;17(9):1342–1351.28412562
29 Van Winkle B, Carpenter N, Moscucci M. Why Aren’t Our Digital Solutions Working for Everyone? AMA J Ethics. 2017;19(11):1116–1124. doi: 10.1001/journalofethics.2017.19.11.stas2-1711.29168683
30 Gray DM, II, Joseph JJ, Olayiwola JN. Strategies for Digital Care of Vulnerable Patients in a COVID-19 World—Keeping in Touch. JAMA Health Forum. 2020;1(6):e200734–e200734.36218529
31 Prego-Domínguez J, Khazaeipour Z, Mallah N, . Socioeconomic status and occurrence of chronic pain: a meta-analysis. Rheumatology (Oxford). 2021;60(3):1091–1105.33276382
32 Zelaya CE, Dahlhamer JM, Lucas JW, . Chronic Pain and High-impact Chronic Pain Among U.S. Adults, 2019. NCHS Data Brief. 2020(390):1–8.
33 Adam GP, Springs S, Trikalinos T, . Does information from ClinicalTrials.gov increase transparency and reduce bias? Results from a five-report case series. Syst Rev. 2018;7(1):59.29661214
34 Robinson KA, Saldanha IJ, McKoy NA. Development of a framework to identify research gaps from systematic reviews. J Clin Epidemiol. 2011;64(12):1325–30.21937195
35 Lewinski AA, Rushton S, Van Voorhees E, . Implementing remote triage in large health systems: A qualitative evidence synthesis. Res Nurs Health. 2021;44(1):138–154.33319411
36 Bodenheimer T, Sinsky C. From triple to quadruple aim: care of the patient requires care of the provider. Ann Fam Med. 2014;12(6):573–6.25384822
37 Eaton LH, Gordon DB, Wyant S, . Development and implementation of a telehealth-enhanced intervention for pain and symptom management. Contemp Clin Trials. 2014;38(2):213–20.24846620