# ACKNOWLEDGMENTS

The authors are grateful to Liz Wing, MA, and Stacy Lavin, PhD, for editorial and citation management support, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Lucille Beck, PhD
  Deputy Under Secretary for Health for Policy and Services
  Veterans Health Administration
- Anthony Lisi, DC
  Program Director
  Rehabilitation and Prosthetic Services

## Technical Expert Panel

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Kristin Eneberg-Boldon, PT, DPT
  Rehabilitation Program Manager
  VA Greater Los Angeles Healthcare System
- Julie Fritz, PhD, PT
  Distinguished Professor
  Department of Physical Therapy and Athletic Training, University of Utah
- Friedhelm Sandbrink, MD
  Acting National Program Director Pain Management, Director Pain Management,
  Specialty Care Services, Washington DC VA Medical Center
- Alison M. Whitehead, MPH, RYT, PMP
  Acting Director Integrative Health Coordinating Center (IHCC)
  VHA Office of Patient Centered Care & Cultural Transformation, US Department of Veterans Affairs
- Kate Lorig, DrPH
  Professor Emeritus
  Stanford University School of Medicine
- Francis Keefe, PhD
  Professor in Psychiatry and Behavioral Sciences
  Duke University School of Medicine

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence (see Appendix D for disposition of comments). Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center works to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.