# DISCUSSION

In the United States, approximately 100 million adults live with some form of chronic pain.^4^ Chronic pain disproportionately impacts older adults, those living in rural areas, women, and people living in poverty.^6^ To curb excessive opioid prescribing for pain-related conditions, nonpharmacological approaches such as movement-based therapies (eg, physical therapy) and psychologically informed behavioral approaches (eg, cognitive behavioral therapy) have been adopted.^7,8^ Nonpharmacological approaches to pain management may be well suited for the virtual care environment. Yet it is not widely understood if the effectiveness of this treatment modality translates to the virtual environment when delivered via videoconferencing. Videoconferencing, and telehealth more broadly, present unique limitations associated with these platforms. Barriers such as limited internet connection, lack of access to technology, or lack of education on use of associated technology may impact clinicians’ ability to provide nonpharmacologic treatment as well as patients’ ability to access care remotely. Thus, the purpose of this review was to examine the comparative effectiveness of videoconferencing to in-person care for patients with chronic pain.

## KEY QUESTION 1 SUMMARY

Only 1 study met inclusion criteria for nonpharmacological pain interventions delivered over videoconferencing. Specifically, the study evaluated acceptance and commitment therapy (ACT) in-person compared with video teleconferencing. No difference was detected between arms. The outcomes reported included 5 pain measures, 2 quality-of-life measures, and 1 function measure. Findings from this single study indicate that the impact of virtually delivered pain management is a possible substitute for in-person care. Overall, the evidence was rated as low certainty. These categories were rated down for possible risk of bias and imprecision. Additional research in this area is likely to change the GRADE ratings.

## HORIZON SCAN SUMMARY

We identified 1 pilot study that assessed videoconferencing delivered prehabilitation. While underpowered to detect differences between arms for pain, function, disability, physical performance, or satisfaction outcomes, this study found the in-person and videoconferencing delivery to be equivalent. The 3 protocol papers identified on this topic indicate that future research will focus on real-time physiotherapy, group exercise, guided exercise, reflection, and relaxation techniques. Of the 6 protocols identified via trial registration databases, 2 are psychologically informed intervention studies, and 4 are movement-based intervention studies. These protocols similarly suggest that this is a burgeoning field of research likely to yield results in coming years.

Table 5 Certainty of Evidence

Outcome | Number of Studies (N) | Findings | Certainty of Evidence (Rationale)
Psychologically Informed Interventions
Pain | 1 (128) | BPI interference: 0.70 (95% CI −0.07 to 1.48); BPI severity: −0.06 (95% CI −0.72 to 0.60); PHQ-9: 1.22 (95% CI 0.88 to 3.32); PASS-20: −4.01 (95% CI −11.01 to 3.00); PSQI: −0.14 (95% CI 1.69 to 1.42) | Low certainty; (rated down for serious risk of bias and serious imprecision)
Quality of life | 1 (128) | SF12-MCS: 0.46 (95% CI 3.59 to 4.50); SF12-PCS: −1.56 (95% CI −4.54 to 1.42) | Low certainty; (rated down for serious risk of bias and serious imprecision)
Functionality | 1 (128) | MPI-activity: 0.31 (95% CI 0.02 to 0.60) | Low certainty; (rated down for serious risk of bias and serious imprecision)
Patient engagement | 0 | – | –
Movement-based Interventions
Pain | 0 | – | –
Quality of life | 0 | – | –
Functionality | 0 | – | –
Patient engagement | 0 | – | –

Abbreviations. BPI=Brief Pain Inventory Short Form Interference Scale; MPI=West Haven-Yale Multidimensional Pain Inventory; PASS=Pain Anxiety Symptoms Scale-Short Form; PCS=Physical Component Summary; PHQ=Patient Health Questionnaire; PSQI=Pittsburgh Sleep Quality Index; SF=Medical Outcomes Study 12-Item Short Form Health Survey

## PRIOR SYSTEMATIC REVIEWS

To our knowledge, there is only 1 prior review of the effects of videoconferencing on chronic pain.^26^ This recent review focused on group-based format and identified only 3 studies. All were deemed to be of low methodological quality due to study designs (ie, nonrandomized, pre-post only). Only 1 of the included studies reported outcome data on effectiveness; the other 2 were focused on program descriptions. Thus, this review provides little information on the impacts of nonpharmacological pain management delivered via videoconferencing. When comparing our findings to reviews of non-videoconference telemedicine on chronic pain, our findings are consistent with prior reviews evaluating effectiveness.^27,28^ Adamse and colleagues identified 14 unique trials reporting that telemedicine was noninferior compared with usual care or in addition to usual care for chronic pain.^27^ Eight studies were included in the meta-analysis, which revealed a significant effect (mean difference [MD] −0.57; 95% CI −0.81 to −.034) of telemedicine compared with no intervention on pain. Telemedicine compared with usual care (MD −0.08; 95% CI −0.41 to 0.26) or in addition to usual care (MD −0.25; 95% CI −1.50 to 1.00) showed no significant difference. However, no studies were included that used videoconferencing as the intervention. The included studies that assessed telemedicine interventions were delivered asynchronously through telephone, email, or website. Additionally, Dario and colleagues identified 8 unique trials reporting that telehealth-based interventions were noninferior to minimal intervention (eg, non-health or low back pain information) for non-specific low back pain.^28^ Four studies were included in the meta-analysis that revealed a short-term effect (MD −2.61; 95% CI −5.23 to 0.01) and medium-term effect (MD −0.94; 95% CI −6.71 to 4.84) on pain compared with minimal intervention. However, interventions in the included trials were delivered asynchronously through e-mail, web-based self-management programs, and telephone. There were no included trials that evaluated videoconferencing for non-specific low back pain. Our review identified 1 study assessing videoconferencing for chronic pain reporting noninferior effectiveness compared to in-person therapy.

## CLINICAL AND POLICY IMPLICATIONS

Our review identified limited evidence on the use of videoconferencing to deliver nonpharmacological behavioral and movement-based interventions for chronic pain. The horizon scan identified 6 protocols of relevant studies that will likely contribute evidence on the acceptability, feasibility, and effectiveness of these types of interventions. The 1 included study indicated that delivering a behavioral-based videoconference intervention for Veterans with chronic pain was no less beneficial than the in-person intervention.^15^ While videoconferencing interventions offer the opportunity to improve access to specialty care and are potentially not inferior to in-person care, gaps exist with patient engagement in these interventions. For example, in the included study, 56% of individuals randomized to the videoconference intervention arm did not start the intervention, discontinued it, or were lost to follow-up. Factors contributing to the attrition of participants in this study included lack of interest, time demands, and development of medical illness. Beyond this single study, known factors that contribute to barriers engaging in technology-based interventions include lack of internet or sufficient cellular data, digital device access, and digital health literacy.^29^ Understanding barriers to engage or continue engagement in videoconferencing is especially prudent among at-risk populations with higher prevalence of chronic pain, such as those living in rural settings and low-income populations.^30–32^

## LIMITATIONS

Our review has several strengths, including a protocol-driven design, a comprehensive search, broad inclusion of chronic pain etiology, careful quality assessment via established risk of bias tools, and key input from an expert panel consisting of clinicians and researchers with expertise in virtual care and experts in approaches to nonpharmacological pain management. Yet our findings should be considered within the context of limitations of the included studies and of our methodologic approach. We identified only 1 study that met our eligibility criteria. Given the small number of studies, statistical methods to detect publication bias are not useful. Other strategies, such as searching ClinicalTrials.gov for completed but unpublished studies, are not a particularly effective way to identify publication bias.^33^ Thus, we did not conduct a formal analysis of publication bias. To combat this scant literature, we conducted a prior horizon scan of forthcoming studies on this topic, which yielded 10 potentially relevant studies in the planning phase.

Despite these strengths, limitations exist to our approach. Informed by the information needs of our stakeholder partners from VA operations, we only included randomized studies and those that compared videoconferencing to in-person or telephone nonpharmacological pain-management care. Yet, other comparative study designs may have findings relevant to the provision of nonpharmacological pain management via videoconferencing. We excluded a relatively small number of articles for study design, and a recent rapid review on videoconferencing for group-based chronic pain management with no exclusions for study designs yielded only 3 papers.^26^ Of these papers, only 1 presented outcome data on effects of the intervention. It is possible that there may be a proliferation of additional studies conducted since the onset of the COVID-19 pandemic that may provide useful information. However, our horizon scan identified only 10 potentially eligible studies. Thus, we feel confident we identified the most relevant information to address the key questions of this review.

### Applicability of Findings to the VA Population

The findings of this review are highly relevant to the VA population. The single included study was conducted with Veterans and in the VHA. Of the 10 planned studies identified in the horizon scan, most will be conducted in countries with nationalized health care, which may make findings of these studies more applicable to the VHA health care environment. Additionally, 2 planned studies will be conducted within the VHA.

## FUTURE RESEARCH

We identified several areas in need of further exploration in order to strengthen future research in this area. To systematically identify these gaps in the current literature, we used an existing framework by Robinson and colleagues^34^ that proposes to identify gaps categorically using the PICOTS framework (population, intervention, comparator, outcome, timing, and setting). In addition, they include standardized reasons that the current literature is insufficient to answer the question at hand (insufficient or imprecise information, biased information, inconsistency, and/or not the right information).

Overall, there is scant comparative literature that assesses the impact of nonpharmacological pain-management approaches delivered via videoconferencing. We identified no published studies of movement-based approaches and only 1 published study of an intervention that used psychologically informed behavioral approaches (ie, ACT). In our horizon scan, we identified 6 studies in the planning phase that will focus on movement-based approaches and 2 that will assess videoconferencing interventions using a combination of movement and behavioral approaches. Further studies are needed, and these studies need to have complete descriptions of interventions (eg, content, dose, frequency) and details on implementation considerations, including training of the interventionist and patients on maximizing the virtual care environment. Such details will be needed to implement approaches into practice. Our prior work details several implementation considerations for remotely delivered health care that may serve as a useful blueprint.^35^

While the focus of this review was on comparing the effectiveness of videoconferencing to other synchronous care modalities (eg, in-person care), future studies may want to investigate how best to blend virtual and in-person care to optimize patient, provider, and system outcomes. Contextualizing videoconferencing care as adjunctive or replacement care has different implications for how that care is constructed and by whom it is delivered. Another key consideration of future studies is the need to include system-important and patient-important outcomes in the evaluation of approaches. In collaboration with our operations stakeholder partners, we prioritized pain, function, quality of life, and patient engagement as key patient-level outcomes. At a minimum, future studies should seek to explore these. Yet there are key provider and system outcomes that should also be considered in future studies to optimize. When assessing key outcomes, careful attention should be paid to designing studies that are powered to detect subgroup difference by key populations such as women, underrepresented racial and ethnic groups, those living in rural areas, or by severity and length of chronic pain conditions to assure that the potential benefits of such approaches are shared across populations. Such careful attention to designing future studies could help in developing videoconferencing approaches to chronic pain management that maximize ability to attain the quadruple aim of improving the patient care experience, improving the health of a population, reducing per capita health care costs, and improving the work life of health care providers, including clinicians and staff.^36^ Table 6 describes some of these future research considerations.

Table 6 Evidence Gaps and Areas for Future Research Consideration

Evidence Gap/Area for Future Exploration | Reason | Types of Studies to Consider
Population
- Patients with various levels of comfort with technology or have other telehealth equity issues (eg, bandwidth, hardware); - Patients from rural areas; - Patients from traditionally underrepresented racial and ethnic backgrounds; - Patients who are earlier in their experiences with chronic pain | Insufficient information/not the right information | Well-designed subgroup analyses or individual patient-data meta-analysis from randomized trials; Qualitative and mixed methods studies
Interventions
- Therapeutic exercise and movement interventions (eg., physical therapy) delivered via videoconferencing; - Interventions that combine therapeutic exercise/movement and behavioral health approaches delivered via videoconferencing; - Videoconferencing care to replace some portion of in-person chronic pain management care; - Videoconferencing to replace all of in-person or telephone-delivered chronic pain management care; - Different models of combining video-based and telephone-based care with in-person care for chronic pain management; - Interventions using currently available and widely used virtual care platforms; - Videoconferencing interventions using group classes or peer-led models | Insufficient or imprecise information | Randomized trials; Non-randomized trials; Qualitative and mixed methods studies
Comparators
- Routine in-person care; - Telephone-based care; - Static website or video recorded session; - Group-based sessions | Insufficient information | Randomized trials; Non-randomized trials
Outcomes
- Patient engagement (eg, session attendance, home practice, patient satisfaction, therapeutic alliance); - Patient utilization (eg, downstream in-person care including hospitalization, urgent care visits, opioid use); - Process variables (eg, time providing direct and indirect care, number of missed visits, consultation time); - Costs (including infrastructure and implementation costs, staff training costs); - Clinician satisfaction; - Clinical workflow; - Harms (delayed care, falls/injury, depression); - Fidelity to treatment delivered (eg, topics covered, care delivered) | Insufficient information/imprecise information; inconsistent information | Randomized trials; Non-randomized trials; Qualitative and mixed methods studies
Setting
- Community gym or wellness centers; - Variety of clinical settings (eg, large health care systems, smaller community-based practices) | Insufficient information | Randomized trials; Non-randomized Trials

## CONCLUSIONS

The VHA is the largest integrated health system and largest provider of telehealth in the country. As such, the VHA has a keen interest in optimizing the use of virtual care modalities, such as videoconferencing. The VHA has been a leader in the deployment of virtual care due to the mission to provide quality health care for all who have served in in the military. This review sought to identify and synthesize the evidence on the impact of deploying chronic pain management care via videoconferencing technologies. Yet, we found scant research. Prior systematic reviews showed that telephone-delivered care or other asynchronous modalities are noninferior to usual care approaches for pain management.^27,28^ It is likely that videoconferencing may also be noninferior to usual care approaches.

In non-pandemic times, telehealth technologies were utilized to bridge barriers surrounding physical distance and to increase the quality of care available to patients in rural communities, where specialized health care was often unavailable or difficult to access.^37^ These benefits are likely to extend into the post-COVID era, and can be hypothesized to have more widespread utilization after such extensive efforts have been made to establish these practices. Yet, a central consideration about the accelerated implementation of virtual modalities to deliver care is the possibility that such changes may serve to increase health inequities and disparities, especially among patient groups who have experienced historical and structural bias and racism by the health care system. Populations already on the margins due to existing health care access disparities and technology barriers (eg, lack of broadband, computer cameras, comfort in using technology) will no doubt have greater barriers to meaningfully engaging in videoconferencing as a modality of care delivery.

Further research is needed to investigate the effectiveness of behavioral and movement-based videoconferencing interventions for chronic pain. Likely research is also needed to understand patient preferences as well as the facilitators and barriers for successful implementation and scalability of such interventions within a variety of settings. The VHA is well positioned to conduct needed evaluations of chronic pain management care delivered via videoconferencing given its mission-driven focus, diverse patient populations, robust virtual care infrastructure, and wealth of administrative data. Such evaluations will be needed to guide clinical and operations practice to optimize equitable deployment and access to high-quality health care delivered via videoconferencing.