# RESULTS

## LITERATURE FLOW

The literature flow diagram (Figure 2) summarizes the results of the study selection process. (See Appendix B for a list of excluded studies.)

Figure 2 Literature Flowchart

Abbreviations. CCRCT=Cochrane Central Register of Controlled Trials; CINAHL=Cumulative Index to Nursing and Allied Health Literature; OECD=Organisation for Economic Co-operation and Development

## LITERATURE OVERVIEW

Our search identified 8,252 potentially relevant articles. We conducted our search in MEDLINE (via Ovid), Embase (via Elsevier), CINAHL Complete (via EBSCO), and Cochrane Central Register of Controlled Trials (via Ovid) (Figure 2). After removing duplicates, there was a total of 4,661 articles. After applying inclusion and exclusion criteria to titles and abstracts, 142 articles remained for full-text review. Of these, 1 study was retained for data abstraction. The randomized controlled trial was a VA study conducted in the United States (Table 2). We also identified 6 protocols in trial databases, 1 pilot, and 3 published protocols.

Table 2 Characteristics of the Included Study

Study Design | Sample Size Follow-up | Population | Intervention Characteristics | Comparator | Outcomes Assessed
Psychologically Informed Interventions
Herbert, 2017^15^; Noninferiority RCT | N=129 Veterans; Post-treatment or 6-month follow-up | Male: 82.2%; Mean age: 52 years (SD13.3); White: 47%; Black: 28%; Hispanic: 14%; Asian: 5%; Other: 5% | 8-week individual acceptance and commitment therapy (ACT) intervention (60-min sessions) delivered by Master’s level study therapist (delivered via video vs in person) | In-person ACT | BPI Interference; BPI Severity; PHQ-9; PASS-20; PSQI; SF12-MCS; SF12-PCS; MPI-Activity
Movement-Based Interventions
None | – | – | – | – | –

Abbreviations. ACT=acceptance and commitment therapy; BPI=Brief Pain Inventory Short Form Interference Scale; MCS=Mental Component Summary; MPI=West Haven-Yale Multidimensional Pain Inventory; PASS=Pain Anxiety Symptoms Scale-Short Form; PCS=Physical Component Summary; PSQI=Pittsburgh Sleep Quality Index; RCT=randomized controlled trial; SD=standard deviation; SF=Medical Outcomes Study 12-Item Short Form Health Survey

## KQ1 Among patients with chronic pain, what is the effect of videoconference-delivered psychologically informed interventions for nonpharmacological chronic pain on pain, functionality, quality of life, and patient engagement?

### KEY POINTS

- One randomized noninferiority trial conducted within the VA was included which compared the delivery of acceptance and commitment therapy in-person compared with video teleconferencing.
- Pain interference improved within both treatment arms at 8 weeks and 6 months follow-up.
- No statistically significant difference in outcomes was found between treatment delivery modalities.

### DETAILED FINDINGS

One unique study met eligibility criteria and was retained for data abstraction. This study was a noninferiority randomized trial conducted in the VA San Diego Healthcare System (VASDHS) facilities in the San Diego area.

### CHARACTERISTICS OF INCLUDED STUDY

The included study by Herbert and colleagues compared videoconferencing with in-person delivery of acceptance and commitment therapy (ACT) in the VA San Diego Healthcare System.^15^ The trial consisted of 8 60-minute weekly sessions of manualized ACT treatment delivered by a study therapist (at least master’s level trained in psychology) either in-person or via videoconferencing. The intervention utilizes “experiential exercises to encourage psychological and behavioral flexibility,” and ACT highlights the importance of at-home assignments to reinforce skills developed during treatment sessions.

The study recruited 129 Veterans 25-89 years of age with a diagnosis of chronic pain. Patients with severe psychiatric illness and suicidal ideation were excluded. Six (9%) patients in the in-person group and 18 (28%) in the videoconferencing group discontinued participation. Respectively, 3 and 5 patients were lost to 6-month follow-up. The patient population in this study closely resembled the system-wide VA patient population, with the majority of participants being male (82.2%) at an average age of 52 years old (standard deviation [SD]=13.3). Most patients were married (55%) and the largest proportion of participants (36%) reported an annual income under $20,000. Most patients were from underrepresented racial and ethnic groups with 28% Black, 14% Hispanic/Latino, 5% Asian, 2% Native Hawaiian/Other, 1% American Indian/Alaskan Native, and 3% multiracial. Most patients reported their baseline pain location as being in their low back (78%), with the top 3 specific pain conditions reported as degenerative disc disease (43%), osteoarthritis (20%), and musculoskeletal pain (12%).

#### Summary of Findings

For the purposes of this systematic review, the outcomes of interest were pain (ie, pain interference), physical function (ie, performance-based and self-reported), quality of life, and patient engagement. Herbert et al found that among primary outcomes (ie, pain interference) and secondary outcomes the videoconferencing group was noninferior to the in-person group at both ends of treatment assessments and 6-month follow-up within groups (Table 3). Secondary outcomes included mental and physical quality of life; pain acceptance; and a multidimensional measure of disability, functioning, and pain outcomes. All outcomes, with the exception of sleep quality and activity level, showed significant improvements over time regardless of treatment arm allocation, but there were no statistically significant between-group differences. While no significant differences in patient satisfaction were found, a statistically significant number of patients withdrew from the videoconferencing group compared to the in-person group from baseline to posttreatment at 8 weeks (46% vs 23%; p = 0.01).

Table 3 KQ1 Results Table

Study | Intervention | Outcomes
Psychologically Informed Interventions
Herbert, 2017^15^ | 8-week individual acceptance and commitment therapy (ACT) intervention (60-min sessions) delivered by Master’s level study therapist (delivered via video vs in person). | Pain 6-month follow-up; BPI interference: 0.70 (−0.07 to 1.48); BPI severity: −0.06 (−0.72 to 0.60); PHQ-9: 1.22 (0.88 to 3.32); PASS-20: −4.01 (−11.01 to 3.00); PSQI: −0.14 (1.69 to 1.42)
Herbert, 2017^15^ | 8-week individual acceptance and commitment therapy (ACT) intervention (60-min sessions) delivered by Master’s level study therapist (delivered via video vs in person). | Quality of life 6-month follow-up; SF12-MCS: .46 (3.59 to 4.50); SF12-PCS: −1.56 (−4.54 to 1.42)
Herbert, 2017^15^ | 8-week individual acceptance and commitment therapy (ACT) intervention (60-min sessions) delivered by Master’s level study therapist (delivered via video vs in person). | Functionality 6-month follow-up; MPI-Activity: 0.31 (0.02 to 0.60)
Herbert, 2017^15^ | 8-week individual acceptance and commitment therapy (ACT) intervention (60-min sessions) delivered by Master’s level study therapist (delivered via video vs in person). | Patient engagement 6-month follow-up; NR

Abbreviations. BPI=Brief Pain Inventory Short Form Interference Scale; MCS=Mental Component Summary; MPI=West Haven-Yale Multidimensional Pain Inventory; PASS=Pain Anxiety Symptoms Scale-Short Form; PCS=Physical Component Summary; PHQ=Patient Health Questionnaire; PSQI=Pittsburgh Sleep Quality Index; SF=Medical Outcomes Study 12-Item Short Form Health Survey

### QUALITY OF EVIDENCE FOR KEY QUESTION 1

The overall risk of bias (ROB) assessment as well as the rating by domain are outlined below (Figure 3). Our included study was rated as “some concerns” for the overall ROB. The sources of bias in this study were centered around concerns over participant retention. The study reported a substantial number of participants who discontinued participation in the study or were lost to follow-up (28% videoconferencing group vs 9% in person). The research staff did reach out to participants to gather reasons for participant drop-out, including time demands of the study, time and transportation, and lost interest and illness. There was also concern over the administration of outcomes, as patient-reported outcomes were likely administered differently in the in-person arm compared to the video teleconferencing arm. The study did not outline how the patient-reported outcomes were administered for the video teleconferencing arm or the timeline with which these outcomes were returned to the study staff.

Figure 3 Risk of Bias Summary

## KQ2 Among patients with chronic pain, what is the effect of videoconference-delivered therapeutic exercise and movement interventions for nonpharmacological chronic pain on pain, functionality, quality of life, and patient engagement?

No studies were identified that met eligibility criteria for KQ2.

### HORIZON SCAN OF EMERGING STUDIES

### KEY POINTS

- We identified 1 pilot study, 3 published protocols, and 6 protocols registered in trial databases of studies that could be potentially relevant to this topic.
- Most of the identified studies in the horizon scan planned to use movement-based approaches for nonpharmacological pain management. Only 1 identified protocol described an intervention that used a combination of behavioral and movement therapies.
- Most planned studies will be conducted outside the United States, but 2 identified registered protocols are for forthcoming studies within the VA.

### DETAILED FINDINGS

Given that only 1 study was identified that met eligibility criteria, we evaluated pilot studies, protocol papers, and protocol registrations to provide some forecast for emerging research in this field. We identified 1 pilot study, 3 published protocols, and 6 protocols registered in trial databases. Of the 10 forthcoming studies, most (n=7) are focused on assessing movement-based approaches to nonpharmacological pain management delivered via videoconferencing. Of the 3 that have some behavioral components, all use approaches informed by CBT. All but 4 of these planned studies will be conducted outside the United States, and 2 of the US-based studies will be conducted within the VA.

Next we detail key aspects of the 3 approaches of the planned studies (ie, published pilot studies, published protocol papers, registered protocols). See Table 4 for the characteristics of these studies.

#### Pilot Studies

We identified 1 pilot study, which was a Canadian-based randomized trial comparing the feasibility and efficacy of a 12-week tele-prehabilitation and in-person program as compared to treatment as usual on pain and disability for 34 individuals waiting for a total knee or hip arthroplasty.^16^ Prehabilitation is a phase of rehabilitation that takes place prior to a surgery. The goal of prehabilitation is to improve a patient’s functional capacity so they are able to withstand inactivity following surgery and avoid associated functional decline. In both the in-person and tele-prehabilitation groups, participants met with a physiotherapist twice per week and followed an established and tailored protocol of exercises, including hip, knee, and proprioceptive muscle range of motion and strengthening exercises, with a cardiovascular warm-up, as well as education about medication use and ice application. Participants were asked to repeat the exercises daily outside of sessions. Participants in the treatment as usual group met with a community-based physiotherapist for one home visit and received a booklet with information about the surgery, medication, and post-surgery rehabilitation.

This study was underpowered to detect differences between groups. Yet, 100% of participants in the tele-prehabilitation group reported that they felt their treatment goals were met, and 91% reported that they perceived their care to be just as good as in-person care. Compliance with the rehabilitation programs was high, ranging from 73% to 77% (unsupervised and supervised sessions, respectively) in the tele-prehabilitation group and 80 to 86% in the in-person group. Authors reported issues with the primary technology platform used for the study (Reacts Lite app), so alternative software (eg, Facetime, Skype) was used for 28 of the 191 tele-prehabilitation sessions, and 9 sessions were conducted by telephone. Authors also noted that four participants in the tele-prehabilitation group requested to be seen in person due to exacerbated pain, so guidance was given to these participants so that they could complete the exercise protocol through tele-prehabilitation as intended.

#### Published Protocol Papers

We identified 3 relevant published protocol papers describing studies that met our eligibility criteria.^17–19^ Two of these were movement-focused only,^18,19^ and 1 included both behavioral and movement components.^17^ One study will recruit participants with persistent pain in any location,^17^ while the other studies specified osteoarthritis pain of the knee^19^ or knee and/or lower back.^18^ All planned studies will be conducted outside the United States, with two set in New Zealand^17,19^ and one in rural Australia.^18^ Two studies were designed as noninferiority trials.^17,19^

In the only protocol to combine both movement and behavioral approaches, adults with persistent chronic pain (n=180) will be randomized to receive either an in-person or a virtual group-based pain management program.^17^ The virtual program, called iSelf-help, will be conducted via videoconferencing platform (ie, Zoom) and will consist of 2 60-minute sessions weekly for 12 weeks. The first weekly session will be conducted by 2 pain management clinicians and will focus on CBT-informed educational content and guidance on exercises. The second weekly session is to be held by a peer-support facilitator and focus on self-reflection, goal setting, and fostering social support.

The other 2 published protocol papers described interventions focused on movement-based approaches to nonpharmacological pain management. In the first protocol, 394 participants with pain from knee osteoarthritis will be randomized to received 5 individual consultations with a physical therapist over 3 months delivered in-person or via videoconferencing.^19^ The other movement-based protocol will randomize 156 rural Australians with chronic lower back or knee pain to a maximum of 8 videoconference consultations over 3 months with a physical therapist compared with usual care, which could vary based on what was available in the local community and was not restricted by the protocol.^18^

#### Registered Study Protocols

We identified 6 registered protocols in trial databases that met our search criteria.^20–25^ Of the included registered protocols, 2 are psychologically informed intervention studies (KQ1)^21,23^ and 3 are movement-based intervention studies (KQ2),^20,22,24,25^ with 1 study combining psychologically informed physical therapy through the use of motivational interviewing.^20^ The studies identified as registered protocols investigate multiple chronic pain diagnoses including knee pain/knee osteoarthritis,^20,22,25^ chronic musculoskeletal pain,^21,24^ and chronic pain associated with HIV.^23^

These studies are set in the United Kingdom,^22^ Australia,^20,25^ and the United States.^21,23,24^ Of particular note, 2 protocols from the United States are studies taking place in the VA Health Care System—1 study utilizing cognitive behavioral therapy (KQ1)^21^ and 1 utilizing telehealth for at-home yoga (KQ2).^24^ Most of the studies are currently actively recruiting at their sites.^21,23,24^ One study is listed as ongoing^22^ and the remaining study is not yet recruiting.^20^

It important to note that, although no studies were identified at the full-text level for KQ2, our search through registered protocols in trial databases identified 4 studies that potentially meet our inclusion criteria for exercise and movement-based interventions. The registered protocols for movement-based interventions vary widely in their treatment approach from targeted physical therapy exercises to group exercise and activity tracking. The included studies with interventions related to KQ1 use cognitive behavioral management techniques.

Table 4 Horizon Scan Study Characteristics^a^

Study; Design; Country; Registration # | Target Sample Size; Recruitment Target; Population; Planned Duration | Intervention | Comparator | Primary Outcome; Other Outcomes
Pilot Study
Doiron-Cadrin, 2018^16^; Pilot RCT; Canada; NCT02636751 | N=34; Patients on a wait list for a hip or knee joint arthroplasty; 2 sessions per week for 12 weeks | Group exercise delivered by a physical therapist.; Participants were asked to repeat the same exercise program between visits at home and to write down the exercises in a logbook. | In-person prehab | Primary outcome: Lower Extremity Functional Scale (LEFS); Other outcomes: Patient-reported functional; physical performance
Protocol Papers
Hinman, 2020^19^; Noninferiority RCT; Australia; ACTRN12619001240134 | N=394; Knee OA; 5 sessions for 3 months | Physiotherapists will prescribe an individualized exercise program consisting of 5–6 strengthening exercises to be performed at home 3 times/week. Strengthening: quads, hip abductor/gluteal, hamstring/gluteal, calf, and balancing (if appropriate).; Physiotherapists will also work with participants to come up with individual physical activity to increase/maintain physical activity at recommended articles.; Patients are provided an “Exercise Booklet” in both arms as well as the “Knee Plan and Logbook.” Patients receive education at all visits. The video consultations will take place using Zoom. | Face-to-face, clinic-based delivery of the same intervention | Primary outcome: Knee pain on walking; physical function; Other outcomes: Pain; self-reported physical function; patient engagement; quality of life
Hale, 2021^17^; Noninferiority RCT; New Zealand; ACTRN12619000771156 | N=180; Persistent non-cancer pain; 2 group sessions weekly for 12 weeks | Each video session is composed of education, advice on guided exercises, and reflection and relaxation techniques.; Education sessions will focus on knowledge and CBT-based self-management skills (eg, pain education, activity pacing, relaxation, and distraction techniques). Later in the same week, a 60-minute video session held by a peer-support facilitator will focus on self-reflection, goal setting, and the sharing of experiences with peers about what went well and what did not over the week and developing a peer support network. It will also provide an opportunity for practicing guided relaxation techniques and exercises. | In-person, group-based pain management program | Primary outcome: Roland Morris Disability Questionnaire; Other outcomes: Pain; patient engagement; quality of life
Mesa-Castrillon, 2021^18^; RCT; Australia; ACTRN12618001494224 | N=156; Non-specific LBP; knee OA; 8 sessions for 3 months | eHealth-delivered physical activity plan and a progressive resistance exercise program designed during remote video consultations with a physiotherapist. | Usual care (unrestricted by study protocol or rules) | Primary outcome: Patient-Specific Functional Scale (PSFS); Other outcomes: Pain; self-reported physical function; patient engagement
Registered Protocols in Trial Databases
Barton, 2019^25^; Noninferiority RCT; Australia; Recruiting; ACTRN12619000235101 | Adults 45+ with knee OA; 60 minutes twice a week; 8 weeks | The telerehabilitation intervention will be delivered via a validated system that allows clinicians to provide services to their patients via real-time videoconferencing into the home.; Intervention details will include an 8-week exercise therapy and education program for people with OA (GLA:DTM), supported by evidence and clinical guidelines. | Active control (face-to-face) | Primary outcome: Knee-related burden (KOOS4)
Bayley, 2019^24^; RCT; US; Active, not recruiting; NCT04074109 | Veterans 18+ years with chronic musculoskeletal pain; 12 weeks | At home tele-yoga for musculoskeletal pain using tablet. | In-person yoga | Primary outcome: Treatment satisfaction; attrition
Groves-Williams, 2020^22^; RCT; UK; Ongoing; ISRCTN15564385 | Age 45+, knee pain, and ability to connect to Skype/Zoom video calls.; 7 sessions over 12 weeks; 45-60 minutes each | Group E-Rehab is an internet-delivered group exercise program. A physiotherapist will conduct sessions over Skype/Zoom. Attendees will be given lower limb strengthening exercises to complete 3 times a week at home. The intervention also includes self-paced interactive educational sessions via internet (4 modules). | Usual Care: one or two sessions with physiotherapist (may not be conducted face-to-face given COVID-19 restrictions) | Primary outcome: Feasibility
Palfai, 2020^23^; RCT; US; Recruiting; NCT04441593 | Adults aged 18+ years engaged in HIV care, who exhibit heavy drinking and have chronic pain; 3- and 6-month assessments | Integrated behavioral telehealth intervention for heavy drinking & chronic pain delivered via videoconferencing. Intervention includes motivational and cognitive-behavioral management of pain and alcohol. | Usual care with psychoeducation and information about treatment resources | Primary outcome: Pain severity; pain interference; heavy drinking episodes; average drinks per week
Damush, 2020^21^; RCT; US; Recruiting; NCT04613362 | Veterans with chronic migraine; 3 months | Intervention includes 6 sessions of telehealth-delivered cognitive behavioral therapy for migraines in addition to standard educational and self-management materials. | Usual Care Outpatient Cognitive Behavioral Therapy for Migraines Face to Face | Primary outcome: # of days of pain; implementation
Bell, 2021^20^; RCT; Australia; Not yet recruiting; ACTRN12621000267853 | Diagnosis of knee osteoarthritis for participation in GLA:D is performed by a trained physiotherapist and guided by the NICE guidelines, that is:; i) Aged >45 years; ii) Activity-related knee pain; iii) Morning stiffness of the knee which lasts less than 30 minutes or no knee stiffness; Have completed GLA:D in the past 12 months at time of recruitment; Sessions occur in weeks 1,2,4,7,10 | Motivational interviewing sessions led by physiotherapist.; Sessions are individualized and may include components of engagement, focusing, evoking, and planning. Discussions may include personal barriers and enablers to physical activity and strategies to navigate these, reflections about personal change, and managing pain. Patients will receive Zoom or phone call depending on preference. | Controls do not have access to feedback website | Primary outcome: Feasibility

a While we identified protocol NCT03385083 registered by Zwibel in 2017, this protocol was listed as terminated in clintrials.gov (http://clinicaltrials.gov) and not included in the horizon scan table.