# METHODS

## TOPIC DEVELOPMENT

This topic was developed at the request of the Office of Rehabilitation and Prosthetic Services, the Office of Patient Centered Care and Cultural Transformation, and the Office for Pain Management and Opioid Safety. Key questions as outlined below were driven in particular by shifts in virtual care during the COVID-19 pandemic. Findings from this review will be used to optimize the delivery of virtual care among Veterans with chronic pain.

## KEY QUESTIONS

The following key questions (KQs) were the focus of this review:

KQ1 Among patients with chronic pain, what is the effect of videoconference-delivered psychologically informed interventions for nonpharmacological chronic pain on pain, functionality, quality of life, and patient engagement?
KQ2 Among patients with chronic pain, what is the effect of videoconference-delivered therapeutic exercise and movement interventions for nonpharmacological chronic pain on pain, functionality, quality of life, and patient engagement?

## ANALYTIC FRAMEWORK

The analytic framework shown in Figure 1 provides a conceptual overview of this review. The population of interest was adults with chronic pain. The interventions evaluated included nonpharmacological modalities for pain management that may be effective in the virtual care environment, including psychologically informed behavioral approaches like cognitive behavioral therapy (KQ1) and movement-based therapies like physical therapy (KQ2). The outcomes of interest were pain (eg, interference), physical function (eg, performance-based physical function and self-report), quality of life, and patient engagement (eg, home practice, session completion rates, self-reported engagement or satisfaction).

Figure 1 Analytic Framework

Abbreviations: ACT=Acceptance and Commitment Therapy; BA=Behavioral Activation; CBT=Cognitive Behavioral Therapy; PCST=Pain Coping Skills Training; PIP=Psychologically Informed Physical Therapy

## PROTOCOL

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (http://www.crd.york.ac.uk/PROSPERO/; registration number CRD42021279069).

## DATA SOURCES AND SEARCHES

We conducted a primary literature search from inception to June 10, 2021, of MEDLINE (via Ovid), Embase (via Elsevier), CINAHL Complete (via EBSCO), and Cochrane Central Register of Controlled Trials (via Ovid) using a combination of database-specific controlled vocabulary and selected terms (eg, chronic pain, videoconferencing) to search titles and abstracts (see Appendix A for complete search strategies). To ensure completeness, search strategies were developed and executed by an expert medical librarian, with input from the other authors. We hand-searched previous systematic reviews conducted on this topic for potential inclusion.

## STUDY SELECTION

### Eligibility Criteria

Studies identified through our primary search were classified independently by 2 investigators for relevance to the KQs based on title and abstract from our a priori established eligibility criteria. All citations classified for inclusion by at least 1 investigator were reviewed at the full-text review level. The citations designated for exclusion by 1 investigator at the title and abstract level underwent screening by a second investigator. If both investigators agreed on exclusion, the study was excluded. All articles meeting eligibility criteria were included for data abstraction. All results were tracked in an electronic database (for referencing, EndNote, Clarivate Analytics, Philadelphia, PA; for data abstraction, DistillerSR; Evidence Partners Inc., Manotick, ON, Canada).

Table 1 describes the study eligibility criteria organized by PICOTS elements (population, intervention, comparator, outcome, timing, setting) and other criteria such as study design, language, and publication type. Specifically, for the intervention we sought to identify studies that evaluated the effect of synchronously delivered videoconferencing interventions explicitly focused on nonpharmacological pain management. We focused our review on psychologically informed and movement-based nonpharmacological approaches. Psychologically informed interventions encompassing psychological and behavioral therapies (eg, cognitive behavioral therapy [CBT]/acceptance and commitment therapy [ACT], meditation, mindfulness) and/or self-management education and support approaches^12^ (eg, back school, pain education) are defined as tasks undertaken by patients to manage the symptoms, treatments, lifestyle changes, and physical and psychosocial consequences associated with chronic pain. Movement-based interventions included supervised exercise and movement therapies (ie, active, structured physical activity or activities designed to reduce impairments and improve movement-related function). We excluded studies that evaluated videoconferencing pain management compared with other video-based controls (ie, not in person), as the operations partners who commissioned this report were keenly interested in the comparison of videoconferencing care with in-person care.

Table 1 Study Eligibility Criteria

Study Characteristic | Inclusion Criteria | Exclusion Criteria
Population | Community-dwelling adults (≥18 years of age) with chronic (3+ months) non-cancer pain | - Inpatient populations (eg, tele-ICU, inpatient rehab); - Patients receiving care in an emergency room or tele-urgent care setting; - Populations with less than 75% patients with chronic (3+ months) non-cancer pain; - Postoperative patients
Intervention | All KQs: Synchronous videoconference care delivered over at least 2 encounters in which:; 1. All (or the majority; ie, greater than 50%) of in-person nonpharmacological pain care is supplanted by virtual care.; 2. Care is delivered remotely by a provider of a patient who is not physically present in the same location.; 3. Care is administered within the context of longitudinal care provision (even if individual visits are for acute concerns).; 4. Care is focused on pain management.; * Interventions are not required to be exclusively virtual care by a provider as described above; rather, they may include the above with other asynchronous telehealth tools (eg, remote monitoring systems).; KQ1: Behavioral interventions encompassing psychological and behavioral therapies and/or self-management education and support approaches; KQ2: Therapeutic exercise and movement interventions: Supervised exercise and movement therapies | - Remote monitoring, wearables if not associated with virtual synchronous care; - Telehealth interventions that do not involve synchronous care delivered by provider to a patient (eg, one-way automated texts, reminder systems, self-management apps, or internet-based interventions that patients access outside their health care system); - Interventions delivered only by telephone; - Majority not delivered by videoconferencing; KQ1: Non-specific counseling even if focused on pain (ie, not manualized); KQ2: Non-evidence-based approaches as defined by current clinical guidance (eg, Up-to-Date)
Comparators | - In-person care without any videoconference delivery; - Telephone delivered; - Combination of in-person and telephone delivered | No comparator
Outcome | - Pain (eg, interference); - Physical function performance-based physical function and self-report; - Quality of life; - Patient engagement (eg, home practice, session completion rates, patient-reported engagement, satisfaction) | Any outcomes not listed
Timing | No limit | NA
Setting | Any outpatient setting (ie, general medical or specialty care clinic) | - Intervention delivered primarily in hospital inpatient setting (including emergency room); - Subacute rehabilitation
Study design | Randomized trials | - Not a clinical study (eg, editorial, letter to an editor); - Uncontrolled clinical study; - Qualitative studies; - Prospective or retrospective observational studies; - Clinical guidelines; - Measurement or validation studies; - Studies self-identified as pilot or feasibility studies or studies of N <20
Countries | OECD^a^ | Non-OECD
Publication types | Full publication in a peer-reviewed journal | Letters, editorials, reviews, dissertations, meeting abstracts, protocols without results

a OECD (2021) = Organization for Economic Co-operation and Development includes Australia, Austria, Belgium, Canada, Chile, Colombia, Costa Rica, Czech Republic, Denmark, Estonia, Finland, France, Germany, Greece, Hungary, Iceland, Ireland, Israel, Italy, Japan, Korea, Latvia, Lithuania, Luxembourg, Mexico, Netherlands, New Zealand, Norway, Poland, Portugal, Slovak Republic, Slovenia, Spain, Sweden, Switzerland, Turkey, United Kingdom, United States

## DATA ABSTRACTION AND ASSESSMENT

Data from published reports were abstracted into a customized DistillerSR database by 1 reviewer and over-read by a second reviewer. Disagreements were resolved by consensus or by obtaining a third reviewer’s opinion when consensus was not reached between the first and second reviewers. Data elements include descriptors to assess applicability, quality elements, intervention details, and outcomes.

Key characteristics abstracted were participant descriptors (eg, age, sex, race), intervention characteristics (eg, provider type, movement-based or behavioral-based approach), comparator, and outcomes (See Appendix C for full list of outcomes reported in the identified literature). Multiple reports from a single study were treated as a single data point, prioritizing results based on the most complete and appropriately analyzed data. Key features relevant to applicability include the match between the sample and target populations (eg, age, Veteran status).

We used the Cochrane EPOC risk of bias 2 (ROB 2) tool, which is applicable to randomized studies.^13^ These criteria are adequacy of randomization, deviation from indented interventions, missing outcome data, measurement of outcome, and selective outcomes reporting. We assigned a summary ROB score (low, some concerns, or high) to individual studies.

The strength of evidence was assessed using the approach described by Grading of Recommendations Assessment, Development and Evaluation (GRADE).^14^ We limited GRADE ratings to those outcomes identified by the stakeholders and technical expert panel as critical to decision-making. In brief, this approach requires assessment of four domains: risk of bias, consistency, directness, and precision. Additional domains to be used when appropriate are coherence, dose-response association, impact of plausible residual confounders, strength of association (magnitude of effect), and publication bias. These domains were considered qualitatively, and a summary rating was assigned after discussion by 2 investigators as high, moderate, low, or very low strength of evidence. In some cases, high, moderate, low, or very low ratings are impossible or imprudent to make. In these situations, a grade of insufficient is assigned.

## SYNTHESIS

We summarized the literature using relevant data abstracted from the eligible studies. Summary tables describe the key study characteristics of the primary studies: study design, patient demographics, and details of the intervention and comparator. We were unable to conduct quantitative synthesis (ie, meta-analysis) to estimate summary effects, given the paucity of literature that met edibility criteria.

We analyzed the data narratively, as quantitative synthesis was not feasible. The narrative synthesis focused on documenting the intervention components and outcome categories.

## HORIZON SCAN

Given that little information meeting eligibility criteria was available in the published literature , we conducted a horizon scan to forecast when studies on this topic may become available in the published literature and the types of interventions likely to be forthcoming. We conducted a systematic search for potently relevant published pilot studies and protocol papers. We also conducted a search of protocol registrations in Cochrane Central Register of Controlled Trials for potential studies that may address the key questions of this review.