# INTRODUCTION

## PURPOSE

The Evidence Synthesis Program (ESP) responded to a request from the Office of Rehabilitation and Prosthetic Services, the Office of Patient Centered Care and Cultural Transformation, and the Office for Pain Management and Opioid Safety for a review of effectiveness of videoconferencing to delivered nonpharmacological treatments for chronic pain. Findings from this review will be used to optimize the delivery of virtual care among Veterans with chronic pain.

## BACKGROUND

With the onset of the COVID-19 pandemic, many health care professions needed to change their practice for the safety of the public at large in an attempt to decrease community exposures to the SARS-CoV-2 virus. Elective procedures were put on hold early in the pandemic due to overcrowding of hospitals; meanwhile, conservative care treatments were encouraged to adopt remote practice to maintain social distancing in adherence with local and national guidelines.^1^ As a result, telehealth technology grew in prominence and has played a central role in maintaining the availability and continuity of care during pandemic times for providers across the health care continuum—from physicians to nurses to therapists—in settings ranging from primary care to specialty care. The Veterans Health Administration (VHA) was uniquely adept at applying this change in delivery, as it has long utilized telehealth services to deliver care to Veterans across the country.

Telehealth services are available on a variety of platforms, providing patients and practitioners with a range of resources to be connected to one another. Currently, the VHA offers telehealth services and communication with providers via instant messaging on MyHealtheVet, telephone calls, and videoconferencing on VA Video Connect (VVC). During the first 10 weeks of the pandemic, in-person ambulatory visits within the VHA decreased by nearly 56%.^2^ Meanwhile, telephone visits increased by approximately 139% and VVC visits rose by about 72%.^2^ Early in the pandemic, telephone appointments made up a significantly greater share of virtual care due to the lower complexity and ease of implementation of this virtual modality.^3^ For VVC, implementation barriers include the need for hardware such as camera-enabled devices for both providers and patients, access to adequate connectivity for streaming video, and skills and confidence navigating a telehealth platform.^3^

Both within the VA Health Care System and in the civilian population, chronic pain is highly prevalent in the United States. Approximately 100 million adults in the United States live with some form of chronic pain, with the expectation that this number will continue to grow over the next decade.^4^ Estimates of the prevalence of chronic pain in adults in the United States range from 15% to 64%,^5^ with a higher prevalence of both chronic pain and high-impact chronic pain reported among women, older adults, those living in poverty or with public health insurance, and people residing in rural areas.^6^ While pharmacological approaches to pain management can be effective, interest in nonpharmacological approaches is growing as an effective strategy to cope with chronic pain and to combat excessive opioid prescribing for pain-related conditions.^7,8^ In the case of chronic low back pain, the Clinical Practice Guideline on noninvasive treatments for low back pain recommends that clinicians and patients should initially select nonpharmacologic treatment with exercise, multidisciplinary rehabilitation, and other moderate-quality evidence treatment forms. Providers are only recommended to consider opioids when patients have failed nonpharmacologic treatment and nonsteroidal anti-inflammatory drugs.^9^ Thus, early in the pandemic, treatment for chronic pain was a specific practice that was quickly pushed to adopt remote practice. Although face-to-face visits were discouraged, public health recommendations continue to encourage nonpharmacological pain management approaches such as behavioral therapy, exercise-based therapies, and self-management approaches to stem the use of prescription opioids. Yet this meant that the supply of nonpharmacological pain services needed to quickly pivot to meet the sustained high demand for this type of care. Telehealth has been used as a safe option for self-management of diabetes, heart failure, asthma, cancer, and other chronic disease management. The proposed benefits of telehealth include addressing concerns in the environment where they occur by treating patients in their homes or usual environment, improving adherence, and increasing cost effectiveness.^10^ While the impact of using telehealth delivery has been examined for other chronic conditions, the benefits of virtual care for the nonpharmacological treatment of chronic pain remain less certain.^11^

Nonpharmacological approaches to pain management may be well suited for the virtual care environment. As a part of the Whole Health approach, the VHA is a leader in this area with the implementation of telehealth in complementary and integrative health services (Tele-CIH) to foster nonpharmacologic approaches to care. The application of videoconferencing for the delivery of nonpharmacological pain care is a promising area. Yet it is not widely understood if the effectiveness of this treatment modality translates to the virtual environment when delivered via videoconferencing. Thus, the purpose of this review is to examine the effectiveness of videoconferencing compared with in-person care for patients with chronic pain.