# APPENDIX D PEER REVIEW DISPOSITION

Question Text | Reviewer Number | Comment | Response
Are the objectives, scope, and methods for this review clearly described? | 1 | Yes | Thank you.
Are the objectives, scope, and methods for this review clearly described? | 3 | Yes | Thank you
Are the objectives, scope, and methods for this review clearly described? | 4 | Yes | Thank you
Are the objectives, scope, and methods for this review clearly described? | 5 | Yes | Thank you
Are the objectives, scope, and methods for this review clearly described? | 6 | Yes | Thank you
Are the objectives, scope, and methods for this review clearly described? | 7 | Yes | Thank you
Are the objectives, scope, and methods for this review clearly described? | 8 | Yes | Thank you
Is there any indication of bias in our synthesis of the evidence? | 1 | No | Thank you
Is there any indication of bias in our synthesis of the evidence? | 3 | No | Thank you
Is there any indication of bias in our synthesis of the evidence? | 4 | No | Thank you
Is there any indication of bias in our synthesis of the evidence? | 5 | No | Thank you
Is there any indication of bias in our synthesis of the evidence? | 6 | No | Thank you
Is there any indication of bias in our synthesis of the evidence? | 7 | No | Thank you
Is there any indication of bias in our synthesis of the evidence? | 8 | No | Thank you
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 1 | No | Thank you
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 3 | No | Thank you
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 4 | No | Thank you
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 5 | No | Thank you
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 6 | No | Thank you
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 7 | Yes - o Schulz-Heik R.J., Meyer H., Mahoney L., .: Results from a clinical yoga program for veterans: yoga via telehealth provides comparable satisfaction and health improvements to in-person yoga. BMC Complement Altern Med 2017; 17: pp. 198 28376861 o Results from a clinical yoga program for veterans: yoga via telehealth provides comparable satisfaction and health improvements to in-person yoga - PubMed (nih.gov) | Thank you. In collaboration with the VA operations leaders who nominated this topic, and the Technical Expert Panel who advised us on this review, we focused this review on effectiveness of videoconference-delivered non-pharmacological chronic pain intervention. These groups guided us on our eligibility for this review. The study on yoga would not meet eligibility for several reasons (eg, population exposed to intervention of unknow chronic pain status, inclusion of hospitalized patients, not a randomized trial, not required to be more than one session).
Are you aware of any [underlined: published] or [underlined: unpublished] studies that we may have overlooked? | 8 | Yes - A potential suggestion to improve the Evidence Synthesis Report is to broaden the inclusion criteria of the studies. Currently, the inclusion criteria leads to only 1 completed study included in the manuscript and thus the utility of this paper becomes limited for the intended audience. By broadening the inclusion criteria to include all studies that include videoconferencing of nonpharmacological interventions for chronic pain. Examples of additional articles that can be included are:; Palyo, S. A., Schopmeyer, K. A., & McQuaid, J. R. (2012). Tele-pain management: Use of videoconferencing technology in the delivery of an integrated cognitive–behavioral and physical therapy group intervention. Psychological Services, 9(2), 200–202. 10.1037/a0025987 22662734; Glynn, L. H., Chen, J. A., Dawson, T. C., Gelman, H., & Zeliadt, S. B. (2021). Bringing chronic-pain care to rural veterans: A telehealth pilot program description. Psychological Services, 18(3), 310–318. 10.1037/ser0000408 31944817; Evaluating distance education of a mindfulness-based meditation programme for chronic pain management by Jacqueline Gardner-Nix ., 2008 (10.1258/jtt.2007.070811) | Thank you for these suggested studies. We included studies that were of greatest value to answer the key areas of uncertainty of our nominating VA operations partners. Their main focus was on effectiveness of videoconferencing compared to in-person non-pharmacological pain management. That is, the focus was on “Does this work?’ and not “How this works?”. As such, we limited to comparative study designs best suited to address individual-level outcomes. We did not include descriptive studies (eg., no data on relevant outcomes) and quasi-experimental designs. We added a horizon scan to this review as our TEP advised us that this literature on effectiveness was likely nascent at this time.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 1 | Page v, line 54, please list Dr Beck’s title as: Deputy Under Secretary for Health for Policy and Services | Thank you, this change has been made.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 3 | This is an excellent report. I’m wondering if the authors might want the report to cite on p. 6 the most recent CPGs for non-pharmacological options for pain management, the evidence that was used to shape the CPGs, and the National Pain Strategy:; Skelly AC, Chou R, Dettori JR, . Noninvasive Nonpharmacological Treatment for Chronic Pain: A Systematic Review Update. Agency for Healthcare Research and Quality (US); 2020. http://www.ncbi.nlm.nih.gov/books/NBK556229/; Qaseem A, Wilt TJ, McLean RM, Forciea MA, . Clinical Guidelines Committee of the American College of Physicians. Noninvasive Treatments for Acute, Subacute, and Chronic Low Back Pain: A Clinical Practice Guideline from the American College of Physicians. Ann Intern Med. 2017;166(7):514–530. doi:10.7326/M16-2367 28192789; Department of Health and Human Services, Interagency Pain Research Coordinating Committee. National Pain Strategy – A Comprehensive Population Health-Level Strategy for Pain. NIH Interagency Pain Research Coordinating Committee. HHS National Pain Strategy 508C. | We have added these references. Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | This review is on a timely and important topic to the VHA and general population. The report is thorough and well written. Unfortunately, very little literature meeting the review criteria was found. The authors made the most of what was found and provided a fair and informative overview. I have a few minor issues for editorial consideration. | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | - KQ1 focuses on “psychologically informed behavioral interventions.” This term is shortened to “behavioral interventions” throughout the report. The term “behavioral” has a specific meaning, especially within the psychotherapy literature. The term would not bring to mind acceptance and commitment therapy, as the focus of ACT is largely on changing thinking (i.e., cognitive). Perhaps a different term would be more clear? | We have made this suggested wording change.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | - Page 15, lines 5-9. The first two lines of the Conclusions section identify the need for research on effectiveness of videoconference interventions for chronic pain, patient preferences, and facilitators and barriers for implementation. I would note that this review did not explore those exact questions, but rather the comparative effectiveness of videoconference interventions and in-person services. Because the authors did not explicitly seek out and systematically review the literature on the overall effectiveness, patient preferences regarding, and implementation of videoconference pain interventions, they may wish to deemphasize or otherwise soften these sentences. | We have revised this wording per the reviewer’s suggestions.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | - Page 30, line 58. “prehabilitation” is a novel term and should be defined. | We have defined this term in the report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 4 | - There are a few minor typos. Page 12, line 50 should read “study risk of bias.” Page 31, line 53 should read “in-person or via videoconferencing.” | Thank you, these changes have been made.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | vi-13 Please correct spelling and credentials to Kristin Eneberg-Boldon, PT, DPT | These changes have been made
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 5 | p28-line 34 ‘with via’; line 35 ‘form’ should be ‘from’ | Thank you, these typos have been corrected.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | The authors have summitted a well written and concise manuscript. They adequately defined two questions, provided a thorough search strategy. The results were unexpected. Based on the importance of the question, the inadequate answer that the results provide is still worthy of publication. And an update and new information is expected in several years. The authors should be commended for their quality work. | Thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | I do, however, have a few recommends:; 1) the title of the manuscript be more precise. Videoconferencing of Nonpharmacological Interventions for Chronic Pain, implies it is covering nonpharmacological interventions. The interventions of interest are nonpharmacological interventions, however it is not inclusive of all nonpharmacological interventions. And there are some studies in which a self-administered non-pharmacological intervention, such as an electrotherapy, was excluded.; The VHA convened a state-of-the-art (SOTA) conference on non-pharmacological management of chronic musculoskeletal pain defined four areas of focus: psychological/behavioral therapies; exercise/movement therapies; manual therapies; and multimodal delivery of care. This paper clearly looks at psychological/behavioral therapies; exercise/movement therapies, but may exclude other non-pharmacological treatments. Just a recommendation. | Thank you, we changed the title to Videoconferencing of Movement-based and Psychologically Informed Interventions for Chronic Pain: A Systematic Review and Horizon Scan.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | 2) Table 1. Lack of comparator had 12 studies excluded. I agree with the exclusion of those studies as I do not believe those studies had an adequate comparator. However, Treatment as usual may include some form of in person care or telephone follow-up. Perhaps expanding the definition to be a “similar” or “like” intervention / “a like or similar” psychological/behavioral therapy; exercise/movement therapy delivered in person without any videoconference delivery, telephone or combination of in-person and telephone. | Thank you for these thoughtful comments. We have tried to clarify the comparator eligibility criteria in table 1. To isolate the impact of videoconferencing, the ideal study for inclusion would compare the same treatment delivered by videoconferencing compared to in-person (or telephone or the combination of in-person and telephone). Yet, we did not want to further limit studies that did not have perfect parity in the non-videoconferencing conditions.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 6 | One requested clarification, multiple sclerosis was excluded because it is not a chronic pain condition? | We excluded studies that only recruited based on a diagnosis of multiple sclerosis. Many patients who have multiple sclerosis do have associated pain, but pain is not a marker or defining characteristic in diagnosing multiple sclerosis. This phenomena was similarly discussed for studies recruiting participants based on a diagnosis of osteoarthritis. However, the diagnosis of osteoarthritis is defined by the presence of pain or stiffness, so therefore patients with OA will have pain or stiffness. Many studies investigating multiple sclerosis were looking at fatigue, function, etc. If a study was recruiting for patients with multiple sclerosis and chronic pain, we would have included the study because the study would have been looking for only patients with multiple sclerosis and chronic pain.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 7 | I was surprised by the lack of research/studies in this area. Hopefully this can help support the need for me in VA. | Agreed, thank you.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 7 | In KQ1 - I don’t recall the term “psychologically informed behavioral interventions” as a category | We have clarified this language throughout the report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 7 | Were clinical hypnosis, biofeedback, or guided imagery included as non-pharm approaches for pain? I didn’t see them referenced. Would recommend using “movement-based” over “exercise-based” throughout. | We took a broad approach to the included modalities of treatments for non-pharmacological pain management. This would include any evidence-based approaches for non-pharmacological pain.; We have changed the wording throughout the report to “movement-based” to improve clarity per your suggestion.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 7 | I know this is focused on live video visits compared to in person care, but wonder if there would be room to discuss recorded content, use of mobile apps, or use of virtual reality in delivering some of these approaches compared to in-person care? I know that these are growing modalities for delivering care (see examples below); - Blödt S., Pach D., von Eisenhart-Rothe S., .: Effectiveness of app-based self-acupressure for women with menstrual pain compared to usual care: a randomized pragmatic trial. Am J Obstet Gynecol 2018; 218: pp. 227.e1–e9.; - Rousseaux F., Bicego A., Ledoux D., .: Hypnosis associated with 3D immersive virtual reality technology in the management of pain: a review of the literature. J Pain Res 2020; 13: pp. 1129–1138.32547176; - Askay S.W., Patterson D.R., Sharar S.R.: Virtual reality hypnosis. Contemp Hypn 2009; 26: pp. 40–47.20737029 | Thank you but these modalities are beyond the scope of the review and the focus of the VA operations partners who commissioned this systematic review.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 7 | I know this is an ESP report, but I know that VA is doing a lot in the area of Tele-health including Tele-CIH and other non-pharm approaches to care. Would it be appropriate to add any of that into the report as background? | This is an excellent point and we have added this information to the report.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 8 | Major overall comments:; The ESP report is very well done, but the utility of this work needs to be better communicated. As part of an evidence synthesis program, the overall purpose of this paper should be to inform current healthcare providers with actionable suggestions based on the current literature. This particular report included only 1 completed study with fairly inconclusive findings and had some concerns about its risk of bias, leaving the reader wondering about the utility of this study. Using the horizontal scan to mention how there are upcoming studies is greatly appreciated, however, there needs to be more included studies in this report to support conclusions that will be meaningful to healthcare workers in the VA and generally today (see methods section for suggestions). | Thank you for this comment. We too are frustrated by the low yield of relevant studies to address the areas of uncertainty of the VA operations partners. Including other studies that do not address effectiveness likely would provide limited guidance on the impact of this innovation on outcomes that are meaningful to clinicians and patients.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 8 | Introduction; - The introduction section is well organized and follows a great flow to give background information about the importance of chronic pain management through nonpharmacological treatments and why videoconferencing may be feasible. | Thank you
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 8 | - In paragraph 3 (page 7, line 11), it is mentioned that telehealth delivery has been examined for other chronic conditions. Elaborate upon this comment so that the author gets an idea of the different types of benefits videoconferencing provides for other chronic conditions and how this may relate to videoconferencing becoming an appropriate modality for chronic pain. | Thank you and we have added this information.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 8 | - Page 7 line 12 has a typo: currently the sentence reads “the benefits of virtual care the for nonpharmacological…” and could be changed to “the benefits of virtual care for the nonpharmacological…” | Thank you, this typo has been corrected.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 8 | Methods; - The methods overall are well-written and clearly describe the steps taken to gather the data. I especially appreciated the PICOTS table included as well as the analytic framework depiction.; - A potential suggestion to improve the Evidence Synthesis Report is to broaden the inclusion criteria of the studies. Currently, the inclusion criteria leads to only 1 completed study included in the manuscript and thus the utility of this paper becomes limited for the intended audience. By broadening the inclusion criteria to include all studies that include videoconferencing of nonpharmacological interventions for chronic pain. Examples of additional articles that can be included are:; Palyo, S. A., Schopmeyer, K. A., & McQuaid, J. R. (2012). Tele-pain management: Use of videoconferencing technology in the delivery of an integrated cognitive–behavioral and physical therapy group intervention. Psychological Services, 9(2), 200–202. 10.1037/a0025987 22662734; Glynn, L. H., Chen, J. A., Dawson, T. C., Gelman, H., & Zeliadt, S. B. (2021). Bringing chronic-pain care to rural veterans: A telehealth pilot program description. Psychological Services, 18(3), 310–318. 10.1037/ser0000408 31944817; Evaluating distance education of a mindfulness-based meditation programme for chronic pain management by Jacqueline Gardner-Nix ., 2008 (10.1258/jtt.2007.070811); - If the authors choose not to take the approach to broaden their inclusion criteria, then further justification is required. | Thank you. Please see comments above about scoping of this report to meet the needs of the VA operations partners who commissioned this review. The scope of this review is focused on effectiveness of the interventions. Broadening the scope to include all studies that include videoconferencing of nonpharmacological interventions for chronic pain would not be feasible on our programmatic timelines and budgets. Further, such a review scope would not meet the key information needs of the VA nominating operations partners.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 8 | To make it easier for the reader to follow along, include the initials of the researchers who were involved in the tasks described in the methods section. | Thank you. This is not part of our ESP style guide for reporting. We take a team science approach; nearly every investigator is involved in all steps of the review process.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 8 | Results; I appreciate the use of the included Tables and the Appendix, which are clearly written and provide digestible and relevant information. | Thank you
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 8 | Include a table in the Appendix with the different outcomes assessed and include a brief description of what those outcomes are and what they mean in a clinical setting. | Thank you, we have added all of the outcomes from the identified literature into Appendix C.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 8 | The inclusion of the horizontal scan to shed light on the different research projects that are currently being conducted is very beneficial to this study and strengthens the overall paper. | Thank you
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 8 | Discussion; Mention limitations to videoconferencing as a platform for chronic pain treatment. Issues such as limited internet connection, lack of access to technology, or lack of education on how to use technology may negatively impact a patient’s experience using videoconferencing. | Thank you and we have added this information.
Additional suggestions or comments can be provided below. If applicable, please indicate the page and line numbers from the draft report. | 8 | I appreciate the mention of future research that can be explored based on the results from the study including specifics regarding system-level studies, patient-important outcomes, and looking at the differences in outcomes across patient-level subgroups. | Thank you