# APPENDIX C OUTCOMES REPORTED IN IDENTIFIED LITERATURE

Study | Type of outcome | Outcomes
Psychologically Informed Intervention
Herbert, 2017^15^ | Pain outcomes | - Brief Pain Inventory Short Form Interference Scale (BPI) - interference; - Brief Pain Inventory Short Form Interference Scale (BPI) -severity; - Patient Health Questionnaire (PHQ) - 9; - Chronic Pain Acceptance Questionnaire-revised (CPAQ); - Pain Anxiety Symptoms Scale-Short Form (PASS-20)
Herbert, 2017^15^ | Patient-reported functional measures | - West Haven-Yale Multidimensional Pain Inventory (MPI) - Activity
Herbert, 2017^15^ | Quality-of-life outcomes | - Medical Outcomes Study 12-Item Short Form Health Survey (SF12) - Mental Component Summary; - Medical Outcomes Study 12-Item Short Form Health Survey (SF12) - Physical Component Summary
Herbert, 2017^15^ | Other patientreported outcomes | - Depressive symptoms (PHQ-9); - Pittsburgh Sleep Quality Index (PSQI); - Credibility and Expectancy Questionnaire-Participant expectancies for improvement; - Client Satisfaction Questionnaire (CSQ)
Pilot Study
Doiron-Cadrin, 2020^16^ | Patient-reported functional measures | - Total Lower Extremity Functional Scale (LEFS); - Total Western Ontario and McMaster universities osteoarthritis index (WOMAC) - pain (0–20); - Total Western Ontario and McMaster universities osteoarthritis index (WOMAC)- function (0–68); - Total Medical Outcomes Study 12-Item Short Form Health Survey (SF36) - physical component summary; - Total Medical Outcomes Study 12-Item Short Form Health Survey (SF-36) - mental component summary
Doiron-Cadrin, 2020^16^ | Physical performance measures | - Total timed up and go; - Total stair test; - Total self-paced walk
Doiron-Cadrin, 2020^16^ | Other objective outcomes | - Adverse events; - Recruitment rate
Doiron-Cadrin, 2020^16^ | Other patient-reported outcomes | - Technical issues using the software; - Patient satisfaction; - Number of telerehabilitation sessions; - Compliance with the prehabilitation programs; - The Global Rating of Change scale (GRC) -- patients perceived improvement/deterioration
Protocol Studies
Hinman, 2020^19^ | Pain outcomes | - Numerical rating scale
Hinman, 2020^19^ | Self-reported physical function outcomes | - Western Ontario and McMaster universities osteoarthritis index (WOMAC)
Hinman, 2020^19^ | Patient engagement outcomes | - Session completion rates; - Adherence with strengthening program: 11-point numeric rating scale; - Adherence with physical activity plan - 11-point numeric rating scale
Hinman, 2020^19^ | Quality-of-life outcomes | - Assessment of Quality of Life (AQoL)-6D
Hinman, 2020^19^ | Other patient-reported outcomes | - Physical Activity Scale for the Elderly (PASE); - Arthritis Self Efficacy Scale (8-item); - Participant-perceived global change (7-point Likert Scale); - Satisfaction with the physiotherapy consultations (7-point Likert scale); - Working Alliance Inventory Short Form; - Convenience 11-point numeric rating scale; - Co-interventions (self-report medications or any other treatments for knee pain); - Adverse events; - Health service usage (self-report); - Participant time (self-report); - Physiotherapist time (self-report); - Participant travel (self-report); - Descriptive measures (self-report) (demographics, geographic residential location, employment, confidence with technology, etc.)
Hale, 2021^17^ | Pain outcomes | - Brief Pain Inventory; - Roland Morris Disability Questionnaire; - Pain self-efficacy questionnaire; - Pain catastrophizing scale
Hale, 2021^17^ | Patient engagement outcomes | - Patient-reported engagement
Hale, 2021^17^ | Quality-of-life outcomes | - Descriptive system for health-related quality of life (EQ-5D-5L)
Hale, 2021^17^ | Other patient-reported outcomes | - Depression, Anxiety, Stress Scale (DASS-21); - Chronic pain acceptance questionnaire; - Tampa scale for kinesiophobia; - Current medications; - Health care use; - Acceptability and satisfaction; - Adverse events
Mesa-Castrillon, 2021^18^ | Pilot outcomes | - Acceptability (Self-reported satisfaction on overall experience with the study, accessibility of reaching mental health professional, time to get an appointment, cost of intervention, distance traveled, app and exercise equipment received)
Mesa-Castrillon, 2021^18^ | Pain outcomes | - Numerical rating scale; - Pain self-efficacy questionnaire
Mesa-Castrillon, 2021^18^ | Self-reported physical function outcomes | - Patient-Specific Functional Scale; - Western Ontario and McMaster universities osteoarthritis index (WOMAC); - IPAQ-short form
Mesa-Castrillon, 2021^18^ | Patient engagement outcomes | - Home practice; - Session completion rates; - Quality of life
Mesa-Castrillon, 2021^18^ | Other objective outcomes | - Recruitment rate; - Follow-up rate
Mesa-Castrillon, 2021^18^ | Other patient-reported outcomes | - Roland-Morris Disability Questionnaire (RDQ); - International Physical Activity Questionnaire-Short Form (IPAQ-SF); - Adverse events; - Medication and health care use; - Distance travelled to utilize health care
Registered Protocols in Trial Databases
Barton, 2019^25^ | Primary outcome | - Knee-related burden (KOOS4)
Bayley, 2019^24^ | Primary outcome | - Treatment satisfaction; - Attrition
Groves-Williams, 2020^22^ | Primary outcome | - Feasibility
Palfai, 2020^23^ | Primary outcome | - Pain severity; - Pain interference; - Heavy drinking episodes; - Average drinks per week
Damush, 2020^21^ | Primary outcome | - Number of days of pain; - Implementation
Bell, 2021^20^ | Primary outcome | - Feasibility