# APPENDIX B EXCLUDED STUDIES

Exclude reasons: 1= Ineligible publication type, 2=Non-OECD, 3=Ineligible population, 4=Ineligible intervention, 5=Ineligible comparator, 6=Ineligible study design. (Reference list follows the table.)

Citation | Exclusion Reason
Ahn, 2020^1^ | 5
Amorim, 2016^2^ | 4
Azma, 2018^3^ | 2
Bekkelund, 2019^4^ | 4
Bennell, 2020^5^ | 5
Bennell, 2017^6^ | 5
Berglind, 2018^7^ | 3
Boersma, 2019^8^ | 4
Buhrman, 2004^9^ | 4
Buhrman, 2013^10^ | 4
Burke, 2019^11^ | 4
Carlos-Vivas, 2020^12^ | 5
Castro-Sanchez, 2020^13^ | 4
Cavalera, 2019^14^ | 3
Cooper, 2017^15^ | 4
Cottrell, 2019^16^ | 6
Dadarkhah, 2020^17^ | 2
Dagenais, 2021^18^ | 4
Davins Riu, 2018^19^ | 4
Day, 2020^20^ | 5
De Bruijn, 2007^21^ | 3
De Oliveira Silva, 2020^22^ | 4
de Thurah, 2018^23^ | 4
Dear, 2018^24^ | 4
Dear, 2015^25^ | 4
Dear, 2021^26^ | 4
Dear, 2016^27^ | 4
Dear, 2013^28^ | 4
Devineni, 2005^29^ | 4
Dobson, 2014^30^ | 5
Doiron-Cadrin, 2016^31^ | 6
Doiron-Cadrin, 2020^32^ | 6
Domenech, 2013^33^ | 4
Domenech, 2018^34^ | 4
Fanning, 2020^35^ | 4
Fatoye, 2020^36^ | 2
Faux, 2018^37^ | 4
Finkelstein, 2020^38^ | 3
Fioratti, 2020^39^ | 2
Fjeldstad, 2016^40^ | 3
Flynn, 2017^41^ | 4
Fowler, 2019^42^ | 4
Friedman, 2019^43^ | 4
Friesen, 2017^44^ | 4
Galea Holmes, 2019^45^ | 4
Gannon, 2019^46^ | 5
Geraghty, 2020^47^ | 4
Gialanella, 2017^48^ | 4
Gohir, 2021^49^ | 4
Hale, 2021^50^ | 6
Hayes, 2014^51^ | 4
Heapy, 2020^52^ | 4
Heapy, 2017^53^ | 4
Hearn, 2018^54^ | 4
Hemphill, 2021^55^ | 4
Hernando-Garijo, 2021^56^ | 4
Hinman, 2020^57^ | 6
Isrctn, 2020^58^ | 1
Jacobs, 2021^59^ | 6
Jay, 2014^60^ | 3
Jongen, 2020^61^ | 3
Khan, 2020^62^ | 4
Klaren, 2014^63^ | 3
Kline, 2019^64^ | 4
Konstantinou, 2020^65^ | 4
Kosterink, 2010^66^ | 4
Kowatsch, 2021^67^ | 5
Kristjansdottir, 2013^68^ | 4
Kristjansdottir, ^69^ | 4
Kroenke, 2019^70^ | 4
Lamargue, 2020^71^ | 3
Landtblom, 2019^72^ | 3
Lee, 2016^73^ | 1
Lee, 2018^74^ | 2
Licciardone, 2020^75^ | 4
Lowe, 2021^76^ | 1
Mace, 2021^77^ | 5
Malliaras, 2020^78^ | 6
Mariano, 2021^79^ | 6
Martin, 2019^80^ | 4
Mayer, 2020^81^ | 4
Mbada, 2019^82^ | 4
McDonald, 2013^83^ | 5
McDonald, 2012^84^ | 4
Mecklenburg, 2018^85^ | 4
Mesa-Castrillon, 2021^86^ | 6
Moessner, 2012^87^ | 4
Moessner, 2014^88^ | 4
Monreal-Bartolome, 2019^89^ | 5
Moss-Morris, 2015^90^ | 3
Motl, 2018^91^ | 3
Motl, 2019^92^ | 3
Moumane, 2015^93^ | 1
Muller, 2016^94^ | 4
Müller, 2017^95^ | 4
Nct, 2021^96^ | 1
Nct, 2020^97^ | 4
Nct, 2020^98^ | 6
Nelligan, 2019^99^ | 4
Palacin-Marin, 2013^100^ | 4
Palyo, 2012^101^ | 6
Pardo, 2016^102^ | 3
Paul, 2019^103^ | 4
Peolsson, 2017^104^ | 4
Peolsson, 2019^105^ | 4
Peters, 2017^106^ | 4
Petrozzi, 2019^107^ | 4
Pilutti, 2014^108^ | 3
Prvu Bettger, 2020^109^ | 3
Raiszadeh, 2021^110^ | 4
Rickardsson, 2021^111^ | 4
Rickardsson, 2020^112^ | 4
Robb, 2019^113^ | 3
Robb, 2016^114^ | 3
Robson, 2019^115^ | 4
Rutledge, 2018^116^ | 5
Sandsjo, 2010^117^ | 4
Sarig Bahat, 2018^118^ | 4
Shaw, 2017^119^ | 1
Shebib, 2019^120^ | 4
Shigaki, 2013^121^ | 4
Slattery, 2019^122^ | 4
Smith, 2019^123^ | 4
Steiner, 2020^124^ | 3
Tam, 2019^125^ | 3
Tan, 2015^126^ | 4
Tarakci, 2021^127^ | 3
Taylor-Gjevre, 2018^128^ | 4
Thurah, 2017^129^ | 1
Toelle, 2019^130^ | 4
Trompetter, 2015^131^ | 4
Trompetter, 2015^132^ | 4
Vallejo, 2015^133^ | 4
van Beek, 2020^134^ | 3
van den Berg, 2007^135^ | 3
van Tilburg, 2021^136^ | 4
Vranceanu, 2021^137^ | 3
Williamson, 2017^138^ | 1
Yeo, 2021^139^ | 4
Yilmaz Yelvar, 2017^140^ | 4
Ziegenfuss, 2018^141^ | 1

## EXCLUDED STUDIES REFERENCE LIST

1 Ahn H, Galle K, Mathis KB, . Feasibility and efficacy of remotely supervised cranial electrical stimulation for pain in older adults with knee osteoarthritis: A randomized controlled pilot study. Journal of Clinical Neuroscience. 2020;77:128–133.32402609
2 Amorim AB, Pappas E, Simic M, . Integrating Mobile health and Physical Activity to reduce the burden of Chronic low back pain Trial (IMPACT): a pilot trial protocol. BMC Musculoskeletal Disorders. 2016;17:36.26787469
3 Azma K, RezaSoltani Z, Rezaeimoghaddam F, Dadarkhah A, Mohsenolhosseini S. Efficacy of tele-rehabilitation compared with office-based physical therapy in patients with knee osteoarthritis: A randomized clinical trial. Journal of Telemedicine & Telecare. 2018;24(8):560–565.28771070
4 Bekkelund SI, Müller KI. Video consultations in medication overuse headache. A randomized controlled trial. Brain and Behavior. 2019;9(7).
5 Bennell KL, Keating C, Lawford BJ, . Better Knee, Better Me TM: effectiveness of two scalable health care interventions supporting self-management for knee osteoarthritis - protocol for a randomized controlled trial. BMC Musculoskeletal Disorders. 2020;21(1):160.32164604
6 Bennell KL, Nelligan R, Dobson F, . Effectiveness of an Internet-Delivered Exercise and Pain-Coping Skills Training Intervention for Persons With Chronic Knee Pain: A Randomized Trial. Annals of Internal Medicine. 2017;166(7):453–462.28241215
7 Berglind D, Nyberg G, Willmer M, Persson M, Wells M, Forsell Y. An eHealth program versus a standard care supervised health program and associated health outcomes in individuals with mobility disability: study protocol for a randomized controlled trial. Trials [Electronic Resource]. 2018;19(1):258.29703242
8 Boersma K, Sodermark M, Hesser H, Flink IK, Gerdle B, Linton SJ. Efficacy of a transdiagnostic emotion-focused exposure treatment for chronic pain patients with comorbid anxiety and depression: a randomized controlled trial. Pain. 2019;160(8):1708–1718.31335641
9 Buhrman M, Faltenhag S, Strom L, Andersson G. Controlled trial of Internet-based treatment with telephone support for chronic back pain. Pain. 2004;111(3):368–377.15363881
10 Buhrman M, Skoglund A, Husell J, . Guided internet-delivered acceptance and commitment therapy for chronic pain patients: a randomized controlled trial. Behaviour Research & Therapy. 2013;51(6):307–315.23548250
11 Burke D, Lennon O, Blake C, . An internet-delivered cognitive behavioural therapy pain management programme for spinal cord injury pain: A randomized controlled trial. European Journal of Pain. 2019;23(7):1264–1282.31002442
12 Carlos-Vivas J, Perez-Gomez J, Delgado-Gil S, . Cost-Effectiveness of “Tele-Square Step Exercise” for Falls Prevention in Fibromyalgia Patients: A Study Protocol. International Journal of Environmental Research & Public Health [Electronic Resource]. 2020;17(3):21.
13 Castro-Sanchez AM, Mataran-Penarrocha GA, Gomez-Garcia S, . Study protocol randomised controlled trial comparison of cost-utility and cost-effectiveness of a face-to-face rehabilitation programme versus a telemedicine programme in the treatment of patients with chronic low back pain. BMJ Open. 2020;10(12):e040633.
14 Cavalera C, Rovaris M, Mendozzi L, . Online meditation training for people with multiple sclerosis: A randomized controlled trial. Multiple Sclerosis. 2019;25(4):610–617.29485319
15 Cooper K, Klein S, Smith BH, Schofield P. Peer support for community dwelling older adults with chronic low back pain: a mixed-methods feasibility study. Physiotherapy. 2017;103:e117–e118.
16 Cottrell MA, O’Leary SP, Raymer M, Hill AJ, Comans T, Russell TG. Does telerehabilitation result in inferior clinical outcomes compared with in-person care for the management of chronic musculoskeletal spinal conditions in the tertiary hospital setting? A non-randomised pilot clinical trial. Journal of telemedicine and telecare. 2019:1357633X19887265.
17 Dadarkhah A, Rezaimoghadam F, Najafi S, Mohebi B, Azarakhsh A, Rezasoltani Z. Remote Versus in-Person Exercise Instruction for Chronic Nonspecific Low Back Pain Lasting 12 Weeks or Longer: A Randomized Clinical Trial. Journal of the National Medical Association. 2020;18:18.
18 Dagenais S, Hayflinger DC, Mayer JM. Economic Evaluation of an Extended Telehealth Worksite Exercise Intervention to Reduce Lost Work Time from Low Back Pain in Career Firefighters. Journal of Occupational Rehabilitation. 2021;31(2):431–443.33394268
19 Davins Riu M, Borràs Pérez X, Artigas Raventós V, Palomera Fanegas E, Serra Prat M, Alós Villacrosa J. Use of Telehealth as a New Model for Following Intermittent Claudication and Promoting Patient Expertise. Telemedicine journal and e-health : the official journal of the American Telemedicine Association. 2018;24(10):773–781.29323628
20 Day MA, Ehde DM, Burns J, . A randomized trial to examine the mechanisms of cognitive, behavioral and mindfulness-based psychosocial treatments for chronic pain: Study protocol. Contemporary Clinical Trials. 2020;93:106000.32302791
21 De Bruijn C, de Bie R, Geraets J, . General practitioners apply the usual care for shoulder complaints better than expected-analysis of videotaped consultations. BMC Family Practice. 2007;8:13.17394636
22 De Oliveira Silva D, Pazzinatto MF, Crossley KM, Azevedo FM, Barton CJ. Novel Stepped Care Approach to Provide Education and Exercise Therapy for Patellofemoral Pain: Feasibility Study. Journal of Medical Internet Research. 2020;22(7):e18584.32706674
23 de Thurah A, Stengaard-Pedersen K, Axelsen M, . Tele-Health Followup Strategy for Tight Control of Disease Activity in Rheumatoid Arthritis: Results of a Randomized Controlled Trial. Arthritis care & research. 2018;70(3):353–360.28511288
24 Dear BF, Gandy M, Karin E, . The Pain Course: 12- and 24-Month Outcomes From a Randomized Controlled Trial of an Internet-Delivered Pain Management Program Provided With Different Levels of Clinician Support. Journal of Pain. 2018;19(12):1491–1503.30099209
25 Dear BF, Gandy M, Karin E, . The Pain Course: a randomised controlled trial examining an internet-delivered pain management program when provided with different levels of clinician support. Pain. 2015;156(10):1920–1935.26039902
26 Dear BF, Karin E, Fogliati R, . A Cost-effectiveness Analysis of an Internet-delivered Pain Management Program Delivered With Different Levels of Clinician Support: Results From a Randomised Controlled Trial. Journal of Pain. 2021;22(3):344–358.33227510
27 Dear BF, Gandy M, Karin E, . The Pain Course: exploring predictors of clinical response to an Internet-delivered pain management program. Pain. 2016;157(10):2257–2268.27257857
28 Dear BF, Titov N, Perry KN, . The Pain Course: a randomised controlled trial of a clinician-guided Internet-delivered cognitive behaviour therapy program for managing chronic pain and emotional well-being. Pain. 2013;154(6):942–950.23688830
29 Devineni T, Blanchard EB. A randomized controlled trial of an internet-based treatment for chronic headache. Behaviour Research & Therapy. 2005;43(3):277–292.15680926
30 Dobson F, Hinman RS, French S, . Internet-mediated physiotherapy and pain coping skills training for people with persistent knee pain (IMPACT - knee pain): a randomised controlled trial protocol. BMC Musculoskeletal Disorders. 2014;15:279.25125068
31 Doiron-Cadrin P, Kairy D, Vendittoli PA, Lowry V, Poitras S, Desmeules F. Effects of a tele-prehabilitation program or an in-person prehabilitation program in surgical candidates awaiting total hip or knee arthroplasty: Protocol of a pilot single blind randomized controlled trial. Contemporary Clinical Trials Communications. 2016;4:192–198.29736482
32 Doiron-Cadrin P, Kairy D, Vendittoli PA, Lowry V, Poitras S, Desmeules F. Feasibility and preliminary effects of a tele-prehabilitation program and an in-person prehablitation program compared to usual care for total hip or knee arthroplasty candidates: a pilot randomized controlled trial. Disability and rehabilitation. 2020;42(7):989–998.30638076
33 Domenech J, Banos R, Penalver L, . Design considerations of a randomized clinical trial on a cognitive behavioural intervention using communication and information technologies for managing chronic low back pain. BMC Musculoskeletal Disorders. 2013;14:142.23607895
34 Domenech J, Penalver L, Rio ED, . Cognitive behavioural therapy supported with information and communication technologies in the treatment of chronic low back pain: a randomized clinical trial. European spine journal. 2018;27.
35 Fanning J, Brooks AK, Ip E, . A Mobile Health Behavior Intervention to Reduce Pain and Improve Health in Older Adults With Obesity and Chronic Pain: The MORPH Pilot Trial. Frontiers in Digital Health. 2020;2.
36 Fatoye F, Gebrye T, Fatoye C, . The Clinical and Cost-Effectiveness of Telerehabilitation for People With Nonspecific Chronic Low Back Pain: Randomized Controlled Trial. JMIR MHealth and UHealth. 2020;8(6):e15375.32357128
37 Faux SG, Gardner T, Schultz R, . ‘Reboot Online’: a randomised controlled trial demonstrating that an internet-delivered multidsipclinary pain management program is effective in chronic pain. Neurorehabilitation and neural repair. 2018;32(4–5):354–355.
38 Finkelstein J, Jeong I, Karpatkin H. Physical telerehabilitation ameliorates impact of multiple sclerosis in a randomized control trial. Multiple sclerosis journal. 2020;26(1 SUPPL):159-.31478790
39 Fioratti I, Saragiotto BT, Reis FJJ, . Evaluation of the efficacy of an internet-based pain education and exercise program for chronic musculoskeletal pain in comparison with online self-management booklet: a protocol of a randomised controlled trial with assessor-blinded, 12-month follow-up, and economic evaluation. BMC Musculoskeletal Disorders. 2020;21(1):404.32590959
40 Fjeldstad C, Thiessen A, Pardo G. Telerehabilitation in multiple sclerosis: results of a randomized, 3-arm, rater blinded, feasibility and efficacy pilot study; patient-reported outcomes report. Multiple sclerosis. 2016;22(390).
41 Flynn DM, Eaton LH, McQuinn H, . TelePain: Primary Care Chronic Pain Management through Weekly Didactic and Case-based Telementoring. Contemporary Clinical Trials Communications. 2017;8:162–166.29497708
42 Fowler CA, Ballistrea LM, Mazzone KE, . A virtual reality intervention for fear of movement for Veterans with chronic pain: protocol for a feasibility study. Pilot & Feasibility Studies. 2019;5:146.31890259
43 Friedman DI, Rajan B, Seidmann A. A randomized trial of telemedicine for migraine management. Cephalalgia. 2019;39(12):1577–1585.31450969
44 Friesen LN, Hadjistavropoulos HD, Schneider LH, Alberts NM, Titov N, Dear BF. Examination of an Internet-Delivered Cognitive Behavioural Pain Management Course for Adults with Fibromyalgia: A Randomized Controlled Trial. Pain. 2017;158(4):593–604.27984490
45 Galea Holmes MN, Weinman JA, Bearne LM. A randomized controlled feasibility trial of a home-based walking behavior-change intervention for people with intermittent claudication. Journal of vascular nursing : official publication of the Society for Peripheral Vascular Nursing. 2019;37(2):135–143.31155161
46 Gannon J, Atkinson JH, Chircop-Rollick T, . Telehealth Therapy Effects of Nurses and Mental Health Professionals From 2 Randomized Controlled Trials for Chronic Back Pain. Clinical Journal of Pain. 2019;35(4):295–303.30664550
47 Geraghty AWA, Roberts L, Hill J, . Supporting self-management of low back pain with an internet intervention in primary care: a protocol for a randomised controlled trial of clinical and cost-effectiveness (SupportBack 2). BMJ Open. 2020;10(8):e040543.
48 Gialanella B, Ettori T, Faustini S, . Home-Based Telemedicine in Patients with Chronic Neck Pain. American Journal of Physical Medicine & Rehabilitation. 2017;96(5):327–332.27584139
49 Gohir SA, Eek F, Kelly A, Abhishek A, Valdes AM. Effectiveness of Internet-Based Exercises Aimed at Treating Knee Osteoarthritis: The iBEAT-OA Randomized Clinical Trial. JAMA Network Open. 2021;4(2):e210012.33620447
50 Hale L, Devan H, Davies C, . Clinical and cost-effectiveness of an online-delivered group-based pain management programme in improving pain-related disability for people with persistent pain-protocol for a non-inferiority randomised controlled trial (iSelf-help trial). BMJ Open. 2021;11(2):e046376.
51 Hayes S, Hogan M, Dowd H, . Comparing the clinical-effectiveness and cost-effectiveness of an internet-delivered Acceptance and Commitment Therapy (ACT) intervention with a waiting list control among adults with chronic pain: study protocol for a randomised controlled trial. BMJ Open. 2014;4(7):e005092.
52 Heapy AA, Driscoll MA, Buta E, . Co-Operative Pain Education and Self-management (COPES) Expanding Treatment for Real-World Access (ExTRA): Pragmatic Trial Protocol. Pain Medicine. 2020;21(12 Suppl 2):S21–S28.33313733
53 Heapy AA, Higgins DM, Goulet JL, . Interactive Voice Response-Based Self-management for Chronic Back Pain: The COPES Noninferiority Randomized Trial. JAMA Internal Medicine. 2017;177(6):765–773.28384682
54 Hearn JH, Finlay KA. Internet-delivered mindfulness for people with depression and chronic pain following spinal cord injury: a randomized, controlled feasibility trial. Spinal Cord. 2018;56(8):750–761.29581519
55 Hemphill S, Rodriguez S, Wang E, . Virtual Reality Augments Movement during Physical Therapy: A Pragmatic Randomized Trial. American Journal of Physical Medicine & Rehabilitation. 2021;30:30.
56 Hernando-Garijo I, Ceballos-Laita L, Mingo-Gomez MT, . Immediate Effects of a Telerehabilitation Program Based on Aerobic Exercise in Women with Fibromyalgia. International Journal of Environmental Research & Public Health [Electronic Resource]. 2021;18(4):20.
57 Hinman RS, Kimp AJ, Campbell PK, . Technology versus tradition: a non-inferiority trial comparing video to face-to-face consultations with a physiotherapist for people with knee osteoarthritis. Protocol for the PEAK randomised controlled trial. BMC Musculoskeletal Disorders. 2020;21(1):522.32767989
58 Isrctn. E-rehab for Knee Pain. http://www.who.int/trialsearch/Trial2.aspx?TrialID=ISRCTN15564385. 2020.
59 Jacobs CA, Mace RA, Greenberg J, . Development of a mind body program for obese knee osteoarthritis patients with comorbid depression. Contemporary Clinical Trials Communications. 2021;21:100720.33553798
60 Jay K, Schraefel MC, Brandt M, Andersen LL. Effect of video-based versus personalized instruction on errors during elastic tubing exercises for musculoskeletal pain: a randomized controlled trial. BioMed Research International. 2014;2014:790937.24734244
61 Jongen PJ, Ter Veen G, Lemmens W, Donders R, van Noort E, Zeinstra E. The Interactive Web-Based Program MSmonitor for Self-Management and Multidisciplinary Care in Persons With Multiple Sclerosis: Quasi-Experimental Study of Short-Term Effects on Patient Empowerment. Journal of Medical Internet Research. 2020;22(3):e14297.32149713
62 Khan F, Granville N, Malkani R, Chathampally Y. Health-Related Quality of Life Improvements in Systemic Lupus Erythematosus Derived from a Digital Therapeutic Plus Tele-Health Coaching Intervention: Randomized Controlled Pilot Trial. Journal of Medical Internet Research. 2020;22(10):e23868.33079070
63 Klaren RE, Hubbard EA, Motl RW. Efficacy of a behavioral intervention for reducing sedentary behavior in persons with multiple sclerosis: a pilot examination. American Journal of Preventive Medicine. 2014;47(5):613–616.25070271
64 Kline PW, Melanson EL, Sullivan WJ, . Improving Physical Activity Through Adjunct Telerehabilitation Following Total Knee Arthroplasty: Randomized Controlled Trial Protocol. Physical Therapy. 2019;99(1):37–45.30329126
65 Konstantinou K, Lewis M, Dunn KM, . Stratified care versus usual care for management of patients presenting with sciatica in primary care (SCOPiC): a randomised controlled trial. The Lancet Rheumatology. 2020;2(7):e401–e411.32617529
66 Kosterink SM, Huis in ‘t Veld RM, Cagnie B, Hasenbring M, Vollenbroek-Hutten MM. The clinical effectiveness of a myofeedback-based teletreatment service in patients with non-specific neck and shoulder pain: a randomized controlled trial. Journal of Telemedicine & Telecare. 2010;16(6):316–321.20798425
67 Kowatsch T, Lohse KM, Erb V, . Hybrid Ubiquitous Coaching With a Novel Combination of Mobile and Holographic Conversational Agents Targeting Adherence to Home Exercises: Four Design and Evaluation Studies. Journal of Medical Internet Research. 2021;23(2):e23612.33461957
68 Kristjansdottir OB, Fors EA, Eide E, . A smartphone-based intervention with diaries and therapist-feedback to reduce catastrophizing and increase functioning in women with chronic widespread pain: randomized controlled trial. Journal of Medical Internet Research. 2013;15(1):e5.23291270
69 Kristjansdottir OB, Fors EA, Eide E, . The effect of web-based diaries and situational feedback on catastrophizing in women with chronic widespread pain - A randomized trial. European Journal of Pain Supplements.5(1):259–260.
70 Kroenke K, Baye F, Lourens SG, . Automated Self-management (ASM) vs. ASM-Enhanced Collaborative Care for Chronic Pain and Mood Symptoms: the CAMMPS Randomized Clinical Trial. Journal of General Internal Medicine. 2019;34(9):1806–1814.31228055
71 Lamargue D, Koubiyr I, Deloire M, . Effect of cognitive rehabilitation on neuropsychological and semiecological testing and on daily cognitive functioning in multiple sclerosis: The REACTIV randomized controlled study. Journal of the Neurological Sciences. 2020;415:116929.32460145
72 Landtblom AM, Guala D, Martin C, . RebiQoL: A randomized trial of telemedicine patient support program for health-related quality of life and adherence in people with MS treated with Rebif. PLoS ONE [Electronic Resource]. 2019;14(7):e0218453.31276502
73 Lee MH, Wu HC, Chen WC, Chen YF. Multidisciplinary self-management telecare system may improve quality of life in patients with interstitial cystitis / bladder pain syndrome (IC/BPS)-a randomized controlled trial. Neurourology and urodynamics. 2016;35:S94–S95.
74 Lee MH, Wu HC, Tseng CM, Ko TL, Weng TJ, Chen YF. Health Education and Symptom Flare Management Using a Video-based m-Health System for Caring Women With IC/BPS. Urology. 2018;119:62–69.29894774
75 Licciardone JC, Pandya V. Feasibility Trial of an eHealth Intervention for Health-Related Quality of Life: Implications for Managing Patients with Chronic Pain during the COVID-19 Pandemic. Healthcare. 2020;8(4):01.
76 Lowe R, Barlow C, Lloyd B, . Lifestyle, Exercise and Activity Package for People living with Progressive Multiple Sclerosis (LEAP-MS): adaptions during the COVID-19 pandemic and remote delivery for improved efficiency. Trials. 2021;22(1):286.33863342
77 Mace RA, Doorley JD, Popok PJ, Vranceanu AM. Live Video Adaptations to a Mind-Body Activity Program for Chronic Pain and Cognitive Decline: Protocol for the Virtual Active Brains Study. JMIR Research Protocols. 2021;10(1):e25351.33208301
78 Malliaras P, Cridland K, Hopmans R, . Internet and Telerehabilitation-Delivered Management of Rotator Cuff-Related Shoulder Pain (INTEL Trial): Randomized Controlled Pilot and Feasibility Trial. JMIR MHealth and UHealth. 2020;8(11):e24311.33206059
79 Mariano TY, Wan L, Edwards RR, Lazaridou A, Ross EL, Jamison RN. Online group pain management for chronic pain: Preliminary results of a novel treatment approach to teletherapy. Journal of Telemedicine & Telecare. 2021;27(4):209–216.31431133
80 Martin KR, Bachmair EM, Aucott L, . Protocol for a multicentre randomised controlled parallel-group trial to compare the effectiveness of remotely delivered cognitive-behavioural and graded exercise interventions with usual care alone to lessen the impact of fatigue in inflammatory rheumatic diseases (LIFT). BMJ Open. 2019;9(1).
81 Mayer JM, Lane CL, Brady O, . Comparison of Supervised and Telehealth Delivery of Worksite Exercise for Prevention of Low Back Pain in Firefighters: A Cluster Randomized Trial. Journal of Occupational & Environmental Medicine. 2020;62(10):e586–e592.32796259
82 Mbada CE, Olaoye MI, Dada OO, . Comparative Efficacy of Clinic-Based and Telerehabilitation Application of Mckenzie Therapy in Chronic Low-Back Pain. International Journal of Telerehabilitation. 2019;11(1):41–58.31341546
83 McDonald DD, Walsh S, Vergara C, Gifford T. Effect of a virtual pain coach on pain management discussions: a pilot study. Pain Management Nursing. 2013;14(4):200–209.24315243
84 McDonald DD, Walsh S, Vergara C, Gifford T, Weiner DK. The effect of a Spanish virtual pain coach for older adults: a pilot study. Pain Medicine. 2012;13(11):1397–1406.22994410
85 Mecklenburg G, Smittenaar P, Erhart-Hledik JC, Perez DA, Hunter S. Effects of a 12-Week Digital Care Program for Chronic Knee Pain on Pain, Mobility, and Surgery Risk: Randomized Controlled Trial. Journal of Medical Internet Research. 2018;20(4):e156.29695370
86 Mesa-Castrillon CI, Simic M, Ferreira ML, . EHealth to empower patients with musculoskeletal pain in rural Australia (EMPoweR) a randomised clinical trial: study protocol. BMC Musculoskeletal Disorders. 2021;22(1):11.33402161
87 Moessner M, Schiltenwolf M, Neubauer E. Internet-based aftercare for patients with back pain-a pilot study. Telemedicine Journal & E-Health. 2012;18(6):413–419.22676398
88 Moessner M, Aufdermauer N, Baier C, . [Efficacy of an internet-delivered aftercare program for patients with chronic back pain]. Psychotherapie, Psychosomatik, Medizinische Psychologie. 2014;64(2):47–53.24101036
89 Monreal-Bartolome A, Barcelo-Soler A, Castro A, . Efficacy of a blended low-intensity internet-delivered psychological programme in patients with multimorbidity in primary care: study protocol for a randomized controlled trial. BMC Psychiatry. 2019;19(1):66.30744610
90 Moss-Morris R, Bogosian A, Chadwick P, McCrone P, Norton S. A pilot randomized controlled trial of the clinical and cost effectiveness of a skype delivered group mindfulness intervention for distressed people with progressive multiple sclerosis. Psychosomatic medicine. 2015;77(3):A20–A21.
91 Motl RW, Sandroff BM, Wingo BC, . Phase-III, randomized controlled trial of the behavioral intervention for increasing physical activity in multiple sclerosis: Project BIPAMS. Contemporary Clinical Trials. 2018;71:154–161.29959105
92 Motl RW, Backus D, Neal WN, . Rationale and design of the STEP for MS Trial: Comparative effectiveness of Supervised versus Telerehabilitation Exercise Programs for Multiple Sclerosis. Contemporary Clinical Trials. 2019;81:110–122.31022481
93 Moumane N, Lozeron P, Viala K, . A medico-economic study with the stepped wedge cluster randomized controlled trial design to assess efficiency (cost-effectiveness) of a telemedicine system for the management of home-based ivig treated patients with chronic inflammatory neuropathies. Journal of the peripheral nervous system : JPNS. 2015;20(2):195–196.
94 Muller KI, Alstadhaug KB, Bekkelund SI. Acceptability, Feasibility, and Cost of Telemedicine for Nonacute Headaches: A Randomized Study Comparing Video and Traditional Consultations. Journal of Medical Internet Research. 2016;18(5):e140.27241876
95 Müller KI, Alstadhaug KB, Bekkelund SI. Telemedicine in the management of non-acute headaches: A prospective, open-labelled non-inferiority, randomised clinical trial. Cephalalgia. 2017;37(9):855–863.27301460
96 Nct. Feasibility and Impact of a Tele-rehabilitation Program in Patients With Chronic and Non-specific Neck Pain. https://clinicaltrials.gov/show/NCT04841642. 2021.
97 Nct. TelemEdiciNe-bAsed Cognitive TherapY for Migraines. https://clinicaltrials.gov/show/NCT04613362. 2020.
98 Nct. EMG Biofeedback Treatment for Chronic Low Back Pain. https://clinicaltrials.gov/show/NCT04607460. 2020.
99 Nelligan RK, Hinman RS, Kasza J, Bennell KL. Effectiveness of internet-delivered education and home exercise supported by behaviour change SMS on pain and function for people with knee osteoarthritis: a randomised controlled trial protocol. BMC Musculoskeletal Disorders. 2019;20(1):342.31351449
100 Palacin-Marin F, Esteban-Moreno B, Olea N, Herrera-Viedma E, Arroyo-Morales M. Agreement between telerehabilitation and face-to-face clinical outcome assessments for low back pain in primary care. Spine. 2013;38(11):947–952.23238489
101 Palyo SA, Schopmeyer KA, McQuaid JR. Tele-pain management: Use of videoconferencing technology in the delivery of an integrated cognitive-behavioral and physical therapy group intervention. Psychological Services. 2012;9(2):200–202.22662734
102 Pardo G, Thiessen A, Fjeldstad C. Telerehabilitation in multiple sclerosis: results of a randomized, 3-arm, rater blinded, feasibility and efficacy pilot study; gait and balance report. Multiple sclerosis. 2016;22(30).
103 Paul L, Renfrew L, Freeman J, . Web-based physiotherapy for people affected by multiple sclerosis: a single blind, randomized controlled feasibility study. Clinical Rehabilitation. 2019;33(3):473–484.30514108
104 Peolsson A, Landen Ludvigsson M, Peterson G. Neck-specific exercises with internet-based support compared to neck-specific exercises at a physiotherapy clinic for chronic whiplash-associated disorders: study protocol of a randomized controlled multicentre trial. BMC Musculoskeletal Disorders. 2017;18(1):524.29233141
105 Peolsson A, Peterson G, Hermansen A, Ludvigsson ML, Dedering A, Lofgren H. Physiotherapy after anterior cervical spine surgery for cervical disc disease: study protocol of a prospective randomised study to compare internet-based neck-specific exercise with prescribed physical activity. BMJ Open. 2019;9(2):e027387.
106 Peters ML, Smeets E, Feijge M, . Happy Despite Pain: A Randomized Controlled Trial of an 8-Week Internet-delivered Positive Psychology Intervention for Enhancing Well-being in Patients With Chronic Pain. Clinical Journal of Pain. 2017;33(11):962–975.28379873
107 Petrozzi MJ, Leaver A, Ferreira PH, Rubinstein SM, Jones MK, Mackey MG. Addition of MoodGYM to physical treatments for chronic low back pain: A randomized controlled trial. Chiropractic & manual therapies. 2019;27:54.31673330
108 Pilutti LA, Dlugonski D, Sandroff BM, Klaren R, Motl RW. Randomized controlled trial of a behavioral intervention targeting symptoms and physical activity in multiple sclerosis. Multiple Sclerosis. 2014;20(5):594–601.24009162
109 Prvu Bettger J, Green CL, Holmes DN, . Effects of Virtual Exercise Rehabilitation In-Home Therapy Compared with Traditional Care After Total Knee Arthroplasty: VERITAS, a Randomized Controlled Trial. Journal of Bone & Joint Surgery - American Volume. 2020;102(2):101–109.31743238
110 Raiszadeh K, Tapicer J, Taitano L, Wu J, Shahidi B. In-Clinic Versus Web-Based Multidisciplinary Exercise-Based Rehabilitation for Treatment of Low Back Pain: Prospective Clinical Trial in an Integrated Practice Unit Model. Journal of Medical Internet Research. 2021;23(3):e22548.33734088
111 Rickardsson J, Gentili C, Holmstrom L, . Internet-delivered acceptance and commitment therapy as microlearning for chronic pain: A randomized controlled trial with 1-year follow-up. European Journal of Pain. 2021;25(5):1012–1030.33460240
112 Rickardsson J, Zetterqvist V, Gentili C, . Internet-delivered acceptance and commitment therapy (iACT) for chronic pain-feasibility and preliminary effects in clinical and self-referred patients. Began with 2015. 2020;6:27.
113 Robb JF, Hyland MH, Goodman AD. Comparison of telemedicine versus in-person visits for persons with multiple sclerosis: A randomized crossover study of feasibility, cost, and satisfaction. Multiple Sclerosis and Related Disorders. 2019;36:101258.31472419
114 Robb JF, Hyland MH, Goodman AD. Comparison of cost, feasibility and satisfaction of telemedicine versus in-person visits for multiple sclerosis patients: a randomised cross-over study. Multiple sclerosis. 2016;22(147).
115 Robson EK, Kamper SJ, Davidson S, . Healthy Lifestyle Program (HeLP) for low back pain: protocol for a randomised controlled trial. BMJ Open. 2019;9(9):e029290.
116 Rutledge T, Atkinson JH, Holloway R, . Randomized Controlled Trial of Nurse-Delivered Cognitive-Behavioral Therapy Versus Supportive Psychotherapy Telehealth Interventions for Chronic Back Pain. Journal of Pain. 2018;19(9):1033–1039.29673974
117 Sandsjo L, Larsman P, Huis in ‘t Veld RM, Vollenbroek-Hutten MM. Clinical evaluation of a myofeedback-based teletreatment service applied in the workplace: a randomized controlled trial. Journal of Telemedicine & Telecare. 2010;16(6):329–335.20798427
118 Sarig Bahat H, Croft K, Carter C, Hoddinott A, Sprecher E, Treleaven J. Remote kinematic training for patients with chronic neck pain: a randomised controlled trial. European Spine Journal. 2018;27(6):1309–1323.29018956
119 Shaw M, Dobbs B, Pawlak N, Pau W, Charvet L. At-home transcranial direct current stimulation (tDCS) improves mood in multiple sclerosis: results from a randomized, sham-controlled trial. Multiple sclerosis journal. 2017;23(3):962-.
120 Shebib R, Bailey JF, Smittenaar P, Perez DA, Mecklenburg G, Hunter S. Randomized controlled trial of a 12-week digital care program in improving low back pain. npj Digital Medicine. 2019;2(1).
121 Shigaki CL, Smarr KL, Siva C, Ge B, Musser D, Johnson R. RAHelp: an online intervention for individuals with rheumatoid arthritis. Arthritis care & research. 2013;65(10):1573–1581.23666599
122 Slattery BW, O’Connor LL, Haugh S, . Investigating the effectiveness of an online acceptance and commitment therapy (ACT) intervention versus a waiting list control condition on pain interference and quality of life in adults with chronic pain and multimorbidity: protocol for a randomised controlled trial. BMJ Open. 2019;9(5):e012671.
123 Smith J, Faux SG, Gardner T, . Reboot Online: A Randomized Controlled Trial Comparing an Online Multidisciplinary Pain Management Program with Usual Care for Chronic Pain. Pain Medicine. 2019;20(12):2385–2396.31498393
124 Steiner B, Elgert L, Saalfeld B, . Health-Enabling Technologies for Telerehabilitation of the Shoulder: A Feasibility and User Acceptance Study. Methods of Information in Medicine. 2020;59(S 02):e90–e99.32777826
125 Tam J, Lacaille D, Liu-Ambrose T, . Effectiveness of an online self-management tool, OPERAS (an On-demand Program to EmpoweR Active Self-management), for people with rheumatoid arthritis: a research protocol. Trials [Electronic Resource]. 2019;20(1):712.31829286
126 Tan G, Rintala DH, Jensen MP, Fukui T, Smith D, Williams W. A randomized controlled trial of hypnosis compared with biofeedback for adults with chronic low back pain. European Journal of Pain. 2015;19(2):271–280.24934738
127 Tarakci E, Tarakci D, Hajebrahimi F, Budak M. Supervised exercises versus telerehabilitation. Benefits for persons with multiple sclerosis. Acta Neurologica Scandinavica. 2021;07:07.
128 Taylor-Gjevre R, Nair B, Bath B, . Addressing rural and remote access disparities for patients with inflammatory arthritis through video-conferencing and innovative inter-professional care models. Musculoskeletal Care. 2018;16(1):90–95.28967235
129 Thurah A, Steengaard-Pedersen K, Axelsen M, . A TELE-health follow-up strategy for tight control of disease activity in rheumatoid arthritis: results of the non-inferiority randomised controlled trail (the Tera study). Annals of the rheumatic diseases. 2017;76:454–455.
130 Toelle TR, Utpadel-Fischler DA, Haas KK, Priebe JA. App-based multidisciplinary back pain treatment versus combined physiotherapy plus online education: a randomized controlled trial. Npj Digital Medicine. 2019;2:34.31304380
131 Trompetter HR, Bohlmeijer ET, Fox JP, Schreurs KM. Psychological flexibility and catastrophizing as associated change mechanisms during online Acceptance & Commitment Therapy for chronic pain. Behaviour Research & Therapy. 2015;74:50–59.26409158
132 Trompetter HR, Bohlmeijer ET, Veehof MM, Schreurs KM. Internet-based guided self-help intervention for chronic pain based on Acceptance and Commitment Therapy: a randomized controlled trial. Journal of Behavioral Medicine. 2015;38(1):66–80.24923259
133 Vallejo MA, Ortega J, Rivera J, Comeche MI, Vallejo-Slocker L. Internet versus face-to-face group cognitive-behavioral therapy for fibromyalgia: A randomized control trial. Journal of Psychiatric Research. 2015;68:106–113.26228408
134 van Beek JJW, van Wegen EEH, Rietberg MB, . Feasibility of a Home-Based Tablet App for Dexterity Training in Multiple Sclerosis: Usability Study. JMIR MHealth and UHealth. 2020;8(6):e18204.32515747
135 van den Berg MH, Ronday HK, Peeters AJ, . Engagement and satisfaction with an Internet-based physical activity intervention in patients with rheumatoid arthritis. Rheumatology. 2007;46(3):545–552.17043050
136 van Tilburg ML, Kloek CJJ, Pisters MF, . Stratified care integrated with eHealth versus usual primary care physiotherapy in patients with neck and/or shoulder complaints: protocol for a cluster randomized controlled trial. BMC Musculoskeletal Disorders. 2021;22(1):143.33546656
137 Vranceanu AM, Bakhshaie J, Reichman M, . A Live Video Program to Prevent Chronic Pain and Disability in At-Risk Adults With Acute Orthopedic Injuries (Toolkit for Optimal Recovery): Protocol for a Multisite Feasibility Study. JMIR Research Protocols. 2021;10(4):e28155.33908886
138 Williamson OD. 2017 - An online exercise program plus automated coping skills raining improved pain and function in chronic knee pain. ACP Journal Club. 2017;166(12):6–6.
139 Yeo SM, Lim JY, Do JG, Lim JY, In Lee J, Hwang JH. Effectiveness of interactive augmented reality-based telerehabilitation in patients with adhesive capsulitis: protocol for a multi-center randomized controlled trial. BMC Musculoskeletal Disorders. 2021;22(1):386.33902546
140 Yilmaz Yelvar GD, Cirak Y, Dalkilinc M, Parlak Demir Y, Guner Z, Boydak A. Is physiotherapy integrated virtual walking effective on pain, function, and kinesiophobia in patients with non-specific low-back pain? Randomised controlled trial. European Spine Journal. 2017;26(2):538–545.27981455
141 Ziegenfuss J, Benitez GV, Lawson K, Whitebird R, Grossman E, Fricton JR. PACT-a transformative selfmanagement program for chronic pain utilizing online education and telehealth coaching. Global advances in health and medicine. 2018;7:223–224.