# APPENDIX A SEARCH STRATEGIES

Database: Medline (via Ovid, ALL 1946 to June 9, 2021)

Search date: 6/10/2021

Search set | Search strategy | Results
#1; Chronic pain terms and conditions | exp chronic pain/ or exp neuralgia/ or exp fibromyalgia/ or exp arthritis, rheumatoid/ or exp arthritis, psoriatic/ or exp gout/ or exp lupus erythematosus, systemic/ or exp complex regional pain syndromes/ or exp migraine disorders/ or exp cluster headache/ or exp tension-type headache/ or exp cystitis, interstitial/ or exp multiple sclerosis/ or exp ehlers-danlos syndrome/ or exp musculoskeletal pain/ or exp neck pain/ or exp back pain/ or exp low back pain/ or exp pelvic girdle pain/ or exp flank pain/ or exp pelvic pain/ or exp shoulder pain/ or exp patellofemoral pain syndrome/ or exp arthralgia/ or exp abdominal pain/ or exp myofascial pain syndromes/ or exp facial pain/ or exp chest pain/ or exp facial neuralgia/ or exp phantom limb/ or exp myalgia/ or exp metatarsalgia/ or exp osteoarthritis/ or ((chronic* or persisten* or long?lasting or long?term or intermittent* or continuous) adj3 (pain* or ache* or myalg* or arthralg* or allodynia or arthrit* or spondyl* or neuropath* or radiculopath*)).ti,ab. or “consistent pain”.ti,ab. or “perpetual pain”.ti,ab. or neuralgia.ti,ab. or fibromyalgia.ti,ab. or “rheumatoid arthritis”.ti,ab. or “psoriatic arthritis”.ti,ab. or gout.ti,ab. or “systemic lupus erythematosus”.ti,ab. or “complex regional pain”.ti,ab. or ((cluster or tension) adj3 headache*).ti,ab. or migrane*.ti,ab. or “interstitial cystitis”.ti,ab. or “bladder pain syndrome”.ti,ab. or “multiple sclerosis”.ti,ab. or “Ehlers-Danlos syndrome”.ti,ab. or ((MSK or musculo* or muscular or joint or joints or radicular or shoulder* or “rotator cuff” or elbow* or hip or hips or pelvic or pelvis or flank or buttock or knee* or patell* or myofascial or “phantom limb”) adj3 (pain* or ache* or myalg* or arthralg*)).ti,ab. or osteoarthritis.ti,ab. or (degenerative adj joint adj disease).ti,ab. or (frozen adj shoulder*).ti,ab. or metatarsalgia.ti,ab. or “pelvic floor disorder”.ti,ab. or “pelvic floor disorders”.ti,ab. or ((back or low?back or spine or spinal or thoracic or vertebr* or intervertebr* or sciatic or lumbar or lumbro* or lumbo*) adj3 (pain* or ache* or radiculopath*)).ti,ab. or lumbago.ti,ab. or sciatica.ti,ab. or ((neck or cervical or cervicodynia) adj3 (pain* or ache* or radiculopath*)).ti,ab. or cervicalgia*.ti,ab. | 795957
#2; Tele / Video terms | exp Telemedicine/ or exp Remote Consultation/ or Videoconferencing/ or Telephone/ or exp Cell Phone/ or exp Computers, Handheld/ or (videoconferenc* or video-conferenc* or webconferenc* or web-conferenc* or webex or zoom or skype or ooVoo or FaceTime or Tango or GoToMeeting or web-delivered or internet-delivered or computer-delivered).ti,ab. or ((remote* or video* or internet or internet-based or web or web-based or online or online-based or computer or computer-based) adj2 (meet* or call* or chat* or conferenc* or consult* or counsel* or visit*)).ti,ab. or ((video* or remote* or web-based or internet-based) adj2 care).ti,ab. or (virtual or virtually or telepain or tele-pain or telehealth or tele-health or telemedicine or tele-medicine or telemedical or tele-medical or telecare or tele-care or teleconsult* or tele-consult* or telecommunicat* or tele-communicat* or telemanag* or tele-manag* or telehome or tele-home or telepharmac* or tele-pharmac* or telecardiol* or tele-cardiol* or tele-cardiac or tele-rehabilitat* or telerehabilitat* or teleintervention* or tele-intervention* or teleconferenc* or tele-conferenc* or telephon* or tele-phon* or cellphon* or cell-phon* or smartphon* or “mobile phone” or “mobile phones” or e-visit* or evisit* or e-care or ecare or e-consult* or econsult* or e-diagnos* or ediagnos* or e-medicine or emedicine or e-physician* or ephysician* or eclinician* or e-clinician* or e-pharm* or epharm* or “communication technology” or “communication technologies” or eHealth or e- health or “e health” or mHealth or m-health or “m health” or wireless).ti,ab. or ((mobile or digital) adj health*).ti,ab. or (tele adj (care or diagnos* or health* or intervention* or manag* or therap* or treat* or medicine or medical or prescrib* or prescript* or pain)).ti,ab. | 306186
#3; combining | 1 and 2 | 7539
#4; RCT filter | randomized controlled trial.pt. OR controlled clinical trial.pt. OR randomized.ti,ab. OR randomised.ti,ab. OR randomization.ti,ab. OR randomisation.ti,ab. OR placebo.ti,ab. OR randomly.ti,ab. OR trial.ti,ab. OR groups.ti,ab. | 3280926
#5 | 3 and 4 | 2388
#6; Animal-only exclusion | 5 not (exp animals/ not exp humans/) | 2365
#7; Pediatric-only exclusion | 6 not ((exp adolescent/ or exp child/ or exp infant/) not exp adult/) | 2296
#8; Study design exclusion | 7 not (Editorial or Letter or Case Reports or Comment).pt. | 2267

Database: Embase (via Elsevier)

Search date: 6/10/2021

Note: Search from the Results page

Search set | Search strategy | Results
#1; Chronic pain terms and conditions | ‘chronic pain’/exp OR ‘neuralgia’/exp OR ‘fibromyalgia’/exp OR ‘rheumatoid arthritis’/exp OR ‘psoriatic arthritis’/exp OR ‘gout’/exp OR ‘systemic lupus erythematosus’/exp OR ‘complex regional pain syndrome’/exp OR ‘migraine’/exp OR ‘cluster headache’/exp OR ‘tension headache’/exp OR ‘interstitial cystitis’/exp OR ‘multiple sclerosis’/exp OR ‘ehlers danlos syndrome’/exp OR ‘musculoskeletal pain’/exp OR ‘neck pain’/exp OR ‘backache’/exp OR ‘low back pain’/exp OR ‘pelvic girdle pain’/exp OR ‘flank pain’/exp OR ‘pelvic pain’/exp OR ‘shoulder pain’/exp OR ‘patellofemoral pain syndrome’/exp OR ‘arthralgia’/exp OR ‘abdominal pain’/exp OR ‘myofascial pain’/exp OR ‘face pain’/exp OR ‘musculoskeletal chest pain’/exp OR ‘facial neuralgia’/exp OR ‘phantom pain’/exp OR ‘myalgia’/exp OR ‘metatarsalgia’/exp OR ‘osteoarthritis’/exp OR ((chronic* OR persisten* OR long?lasting OR long?term OR intermittent* OR continuous) NEAR/3 (pain* OR ache* OR myalg* OR arthralg* OR allodynia OR arthrit* OR spondyl* OR neuropath* OR radiculopath*)):ti,ab OR ‘consistent pain’:ti,ab OR ‘perpetual pain’:ti,ab OR neuralgia:ti,ab OR fibromyalgia:ti,ab OR ‘rheumatoid arthritis’:ti,ab OR ‘psoriatic arthritis’:ti,ab OR gout:ti,ab OR ‘systemic lupus erythematosus’:ti,ab OR ‘complex regional pain’:ti,ab OR ((cluster OR tension) NEAR/3 headache*):ti,ab OR migrane*:ti,ab OR ‘interstitial cystitis’:ti,ab OR ‘bladder pain syndrome’:ti,ab OR ‘multiple sclerosis’:ti,ab OR ‘Ehlers Danlos syndrome’:ti,ab OR ((MSK OR musculo* OR muscular OR joint OR joints OR radicular OR shoulder* OR ‘rotator cuff’ OR elbow* OR hip OR hips OR pelvic OR pelvis OR flank OR buttock OR knee* OR patell* OR myofascial OR ‘phantom limb’) NEAR/3 (pain* OR ache* OR myalg* OR arthralg*)):ti,ab OR osteoarthritis:ti,ab OR (degenerative NEXT/1 joint NEXT/1 disease):ti,ab OR (frozen NEXT/1 shoulder*):ti,ab OR metatarsalgia:ti,ab OR ‘pelvic floor disorder’:ti,ab OR ‘pelvic floor disorders’:ti,ab OR ((back OR low?back OR spine OR spinal OR thoracic OR vertebr* OR intervertebr* OR sciatic OR lumbar OR lumbro* OR lumbo*) NEAR/3 (pain* OR ache* OR radiculopath*)):ti,ab OR lumbago:ti,ab OR sciatica:ti,ab OR ((neck OR cervical OR cervicodynia) NEAR/3 (pain* OR ache* OR radiculopath*)):ti,ab OR cervicalgia*:ti,ab | 1458785
#2; Tele / Video terms | ‘Telemedicine’/exp OR ‘Teleconsultation’/exp OR ‘Videoconferencing’/de OR ‘Telephone’/de OR ‘Mobile Phone’/exp OR (videoconferenc* OR video?conferenc* OR webconferenc* OR web?conferenc* OR webex OR zoom OR skype OR ooVoo OR FaceTime OR Tango OR GoToMeeting OR web?delivered OR internet?delivered OR computer?delivered):ti,ab OR ((remote* OR video* OR internet OR internet-based OR web OR web-based OR online OR online?based OR computer OR computer?based) NEAR/2 (meet* OR call* OR chat* OR conferenc* OR consult* OR counsel* OR visit*)):ti,ab OR ((video* OR remote* OR web?based OR internet?based) NEAR/2 care):ti,ab OR (virtual OR virtually OR telepain OR tele?pain OR telehealth OR tele?health OR telemedicine OR tele?medicine OR telemedical OR tele?medical OR telecare OR tele?care OR teleconsult* OR tele?consult* OR telecommunicat* OR tele?communicat* OR telemanag* OR tele?manag* OR telehome OR tele?home OR telepharmac* OR tele?pharmac* OR telecardiol* OR tele?cardiol* OR tele?cardiac OR tele?rehabilitat* OR telerehabilitat* OR teleintervention* OR tele?intervention* OR teleconferenc* OR tele?conferenc* OR telephon* OR tele?phon* OR cellphon* OR cell?phon* OR smartphon* OR ‘mobile phone’ OR ‘mobile phones’ OR e?visit* OR evisit* OR e?care OR ecare OR e?consult* OR econsult* OR ediagnos* OR e?medicine OR emedicine OR e?physician* OR ephysician* OR eclinician* OR e?clinician* OR e?pharm* OR epharm* OR ‘communication technology’ OR ‘communication technologies’ OR eHealth OR “e health” OR ‘e health’ OR mHealth OR m?health OR ‘m health’ OR wireless):ti,ab OR ((mobile OR digital) NEXT/1 health*):ti,ab OR (tele NEXT/1 (care OR diagnos* OR health* OR intervention* OR manag* OR therap* OR treat* OR medicine OR medical OR prescrib* OR prescript* OR pain)):ti,ab | 401829
#3; combining | #1 AND #2 | 14,828
#4; RCT filter | ‘randomized controlled trial’/exp OR ‘controlled clinical trial’/exp OR ‘single blind procedure’/exp OR ‘double blind procedure’/exp OR ‘crossover procedure’/exp OR randomized:ti,ab OR randomised:ti,ab OR randomization:ti,ab OR randomisation:ti,ab OR placebo:ti,ab OR randomly:ti,ab OR trial:ti,ab OR groups:ti,ab OR cross?over:ti,ab OR ((single OR double) NEAR/1 blind*):ti,ab | 4715525
#5 | #3 AND #4 | 4350
#6; Animal-only exclusion | #5 AND [humans]/lim | 4119
#7; Study design exclusion | #6 NOT (‘case report’/exp OR ‘case study’/exp OR ‘editorial’/exp OR [editorial]/lim OR ‘letter’/exp OR [letter]/lim OR ‘note’/exp OR [note]/lim OR [conference abstract]/lim OR ‘conference abstract’/exp OR ‘conference abstract’/it) | 2,631

Database: Cochrane Central Register of Controlled Trials (via Ovid, May 2021)

Search date: 6/10/2021

Search set | Search strategy | Results
#1; Chronic pain terms and conditions | exp chronic pain/ or exp neuralgia/ or exp fibromyalgia/ or exp arthritis, rheumatoid/ or exp arthritis, psoriatic/ or exp gout/ or exp lupus erythematosus, systemic/ or exp complex regional pain syndromes/ or exp migraine disorders/ or exp cluster headache/ or exp tension-type headache/ or exp cystitis, interstitial/ or exp multiple sclerosis/ or exp ehlers-danlos syndrome/ or exp musculoskeletal pain/ or exp neck pain/ or exp back pain/ or exp low back pain/ or exp pelvic girdle pain/ or exp flank pain/ or exp pelvic pain/ or exp shoulder pain/ or exp patellofemoral pain syndrome/ or exp arthralgia/ or exp abdominal pain/ or exp myofascial pain syndromes/ or exp facial pain/ or exp chest pain/ or exp facial neuralgia/ or exp phantom limb/ or exp myalgia/ or exp metatarsalgia/ or exp osteoarthritis/ or ((chronic* or persisten* or long?lasting or long?term or intermittent* or continuous) adj3 (pain* or ache* or myalg* or arthralg* or allodynia or arthrit* or spondyl* or neuropath* or radiculopath*)).ti,ab. or “consistent pain”.ti,ab. or “perpetual pain”.ti,ab. or neuralgia.ti,ab. or fibromyalgia.ti,ab. or “rheumatoid arthritis”.ti,ab. or “psoriatic arthritis”.ti,ab. or gout.ti,ab. or “systemic lupus erythematosus”.ti,ab. or “complex regional pain”.ti,ab. or ((cluster or tension) adj3 headache*).ti,ab. or migrane*.ti,ab. or “interstitial cystitis”.ti,ab. or “bladder pain syndrome”.ti,ab. or “multiple sclerosis”.ti,ab. or “Ehlers-Danlos syndrome”.ti,ab. or ((MSK or musculo* or muscular or joint or joints or radicular or shoulder* or “rotator cuff” or elbow* or hip or hips or pelvic or pelvis or flank or buttock or knee* or patell* or myofascial or “phantom limb”) adj3 (pain* or ache* or myalg* or arthralg*)).ti,ab. or osteoarthritis.ti,ab. or (degenerative adj joint adj disease).ti,ab. or (frozen adj shoulder*).ti,ab. or metatarsalgia.ti,ab. or “pelvic floor disorder”.ti,ab. or “pelvic floor disorders”.ti,ab. or ((back or low?back or spine or spinal or thoracic or vertebr* or intervertebr* or sciatic or lumbar or lumbro* or lumbo*) adj3 (pain* or ache* or radiculopath*)).ti,ab. or lumbago.ti,ab. or sciatica.ti,ab. or ((neck or cervical or cervicodynia) adj3 (pain* or ache* or radiculopath*)).ti,ab. or cervicalgia*.ti,ab. | 115124
#2; Tele / Video terms | exp Telemedicine/ or exp Remote Consultation/ or Videoconferencing/ or Telephone/ or exp Cell Phone/ or exp Computers, Handheld/ or (videoconferenc* or video-conferenc* or webconferenc* or web-conferenc* or webex or zoom or skype or ooVoo or FaceTime or Tango or GoToMeeting or web-delivered or internet-delivered or computer-delivered).ti,ab. or ((remote* or video* or internet or internet-based or web or web-based or online or online-based or computer or computer-based) adj2 (meet* or call* or chat* or conferenc* or consult* or counsel* or visit*)).ti,ab. or ((video* or remote* or web-based or internet-based) adj2 care).ti,ab. or (virtual or virtually or telepain or tele-pain or telehealth or tele-health or telemedicine or tele-medicine or telemedical or tele-medical or telecare or tele-care or teleconsult* or tele-consult* or telecommunicat* or tele-communicat* or telemanag* or tele-manag* or telehome or tele-home or telepharmac* or tele-pharmac* or telecardiol* or tele-cardiol* or tele-cardiac or tele-rehabilitat* or telerehabilitat* or teleintervention* or tele-intervention* or teleconferenc* or tele-conferenc* or telephon* or tele-phon* or cellphon* or cell-phon* or smartphon* or “mobile phone” or “mobile phones” or e-visit* or evisit* or e-care or ecare or e-consult* or econsult* or e-diagnos* or ediagnos* or e-medicine or emedicine or e-physician* or ephysician* or eclinician* or e-clinician* or e-pharm* or epharm* or “communication technology” or “communication technologies” or eHealth or e- health or “e health” or mHealth or m-health or “m health” or wireless).ti,ab. or ((mobile or digital) adj health*).ti,ab. or (tele adj (care or diagnos* or health* or intervention* or manag* or therap* or treat* or medicine or medical or prescrib* or prescript* or pain)).ti,ab. | 49113
#3; combining | 1 and 2 | 3332
#4; RCT filter | 3 and (randomized.ti,ab. OR randomised.ti,ab. OR randomization.ti,ab. OR randomisation.ti,ab. OR placebo.ti,ab. OR randomly.ti,ab. OR trial.ti,ab. OR groups.ti,ab.OR RCT.ti,ab.) | 2863
#5; Pediatric-only exclusion | 4 not ((exp adolescent/ or exp child/ or exp infant/) not exp adult/) | 2816

Database: CINAHL Complete (via EBSCO)

Search date: 6/10/2021

Search set | Search strategy | Results
#1; Chronic pain terms and conditions | (MH “chronic pain”) OR (MH “neuralgia+”) OR (MH “fibromyalgia”) OR (MH “arthritis, rheumatoid+”) OR (MH “arthritis, psoriatic”) OR (MH “gout”) OR (MH “lupus erythematosus, systemic+”) OR (MH “complex regional pain syndromes+”) OR (MH “migraine”) OR (MH “cluster headache”) OR (MH “tension headache”) OR (MH “interstitial cystitis”) OR (MH “multiple sclerosis+”) OR (MH “ehlers-danlos syndrome”) OR (MH “neck pain”) OR (MH “back pain+”) OR (MH “low back pain”) OR (MH “knee pain+”) OR (MH “pelvic pain+”) OR (MH “shoulder pain+”) OR (MH “patellofemoral pain syndrome+”) OR (MH “arthralgia+”) OR (MH “abdominal pain+”) OR (MH “myofascial pain syndromes+”) OR (MH “facial pain+”) OR (MH “chest pain+”) OR (MH “facial neuralgia”) OR (MH “phantom pain”) OR (MH “muscle pain”) OR (MH “metatarsalgia”) OR (MH “osteoarthritis+”) OR (((TI chronic* OR AB chronic*) OR (TI persisten* OR AB persisten*) OR (TI long-lasting OR AB long-lasting) OR (TI long-term OR AB long-term) OR (TI intermittent* OR AB intermittent*) OR (TI continuous OR AB continuous)) N3 ((TI pain* OR AB pain*) OR (TI ache* OR AB ache*) OR (TI myalg* OR AB myalg*) OR (TI arthralg* OR AB arthralg*) OR (TI allodynia OR AB allodynia) OR (TI arthrit* OR AB arthrit*) OR (TI spondyl* OR AB spondyl*) OR (TI neuropath* OR AB neuropath*) OR (TI radiculopath* OR AB radiculopath*))) OR (TI “consistent pain” OR AB “consistent pain”) OR (TI “perpetual pain” OR AB “perpetual pain”) OR (TI neuralgia OR AB neuralgia) OR (TI fibromyalgia OR AB fibromyalgia) OR (TI “rheumatoid arthritis” OR AB “rheumatoid arthritis”) OR (TI “psoriatic arthritis” OR AB “psoriatic arthritis”) OR (TI gout OR AB gout) OR (TI “systemic lupus erythematosus” OR AB “systemic lupus erythematosus”) OR (TI “complex regional pain” OR AB “complex regional pain”) OR (((TI cluster OR AB cluster) OR (TI tension OR AB tension)) N3 (TI headache* OR AB headache*)) OR (TI migrane* OR AB migrane*) OR (TI “interstitial cystitis” OR AB “interstitial cystitis”) OR (TI “bladder pain syndrome” OR AB “bladder pain syndrome”) OR (TI “multiple sclerosis” OR AB “multiple sclerosis”) OR (TI “Ehlers-Danlos syndrome” OR AB “Ehlers-Danlos syndrome”) OR (((TI MSK OR AB MSK) OR (TI musculo* OR AB musculo*) OR (TI muscular OR AB muscular) OR (TI joint OR AB joint) OR (TI joints OR AB joints) OR (TI radicular OR AB radicular) OR (TI shoulder* OR AB shoulder*) OR (TI “rotator cuff” OR AB “rotator cuff”) OR (TI elbow* OR AB elbow*) OR (TI hip OR AB hip) OR (TI hips OR AB hips) OR (TI pelvic OR AB pelvic) OR (TI pelvis OR AB pelvis) OR (TI flank OR AB flank) OR (TI buttock OR AB buttock) OR (TI knee* OR AB knee*) OR (TI patell* OR AB patell*) OR (TI myofascial OR AB myofascial) OR (TI “phantom limb” OR AB “phantom limb”)) N3 ((TI pain* OR AB pain*) OR (TI ache* OR AB ache*) OR (TI myalg* OR AB myalg*) OR (TI arthralg* OR AB arthralg*))) OR (TI osteoarthritis OR AB osteoarthritis) OR ((TI degenerative OR AB degenerative) N1 (TI joint OR AB joint) N1 (TI disease OR AB disease)) OR ((TI frozen OR AB frozen) N1 (TI shoulder* OR AB shoulder*)) OR (TI metatarsalgia OR AB metatarsalgia) OR (TI “pelvic floor disorder” OR AB “pelvic floor disorder”) OR (TI “pelvic floor disorders” OR AB “pelvic floor disorders”) OR (((TI back OR AB back) OR (TI low-back OR AB low-back) OR (TI spine OR AB spine) OR (TI spinal OR AB spinal) OR (TI thoracic OR AB thoracic) OR (TI vertebr* OR AB vertebr*) OR (TI intervertebr* OR AB intervertebr*) OR (TI sciatic OR AB sciatic) OR (TI lumbar OR AB lumbar) OR (TI lumbro* OR AB lumbro*) OR (TI lumbo* OR AB lumbo*)) N3 ((TI pain* OR AB pain*) OR (TI ache* OR AB ache*) OR (TI radiculopath* OR AB radiculopath*))) OR (TI lumbago OR AB lumbago) OR (TI sciatica OR AB sciatica) OR (((TI neck OR AB neck) OR (TI cervical OR AB cervical) OR (TI cervicodynia OR AB cervicodynia)) N3 ((TI pain* OR AB pain*) OR (TI ache* OR AB ache*) OR (TI radiculopath* OR AB radiculopath*))) OR (TI cervicalgia* OR AB cervicalgia*) | 288921
#2; Tele / Video terms | (MH “Telemedicine+”) OR (MH “Telerehabilitation”) OR (MH “Telepyschiatry”) OR (MH “Telehealth+”) OR (MH “Remote Consultation”) OR (MH “Videoconferencing+”) OR (MH “Telenursing”) OR (MH “Telephone”) OR (MH “Cell Phone+”) OR (MH “Computers, Hand-held+”) OR ((TI videoconferenc* OR AB videoconferenc*) OR (TI video-conferenc* OR AB video-conferenc*) OR (TI webconferenc* OR AB webconferenc*) OR (TI web-conferenc* OR AB web-conferenc*) OR (TI webex OR AB webex) OR (TI zoom OR AB zoom) OR (TI skype OR AB skype) OR (TI ooVoo OR AB ooVoo) OR (TI FaceTime OR AB FaceTime) OR (TI Tango OR AB Tango) OR (TI GoToMeeting OR AB GoToMeeting) OR (TI web-delivered OR AB web-delivered) OR (TI internet-delivered OR AB internet-delivered) OR (TI computer-delivered OR AB computer-delivered)) OR (((TI remote* OR AB remote*) OR (TI video* OR AB video*) OR (TI internet OR AB internet) OR (TI internet-based OR AB internet-based) OR (TI web OR AB web) OR (TI web-based OR AB web-based) OR (TI online OR AB online) OR (TI online-based OR AB online-based) OR (TI computer OR AB computer) OR (TI computer-based OR AB computer-based)) N2 ((TI meet* OR AB meet*) OR (TI call* OR AB call*) OR (TI chat* OR AB chat*) OR (TI conferenc* OR AB conferenc*) OR (TI consult* OR AB consult*) OR (TI counsel* OR AB counsel*) OR (TI visit* OR AB visit*))) OR (((TI video* OR AB video*) OR (TI remote* OR AB remote*) OR (TI web-based OR AB web-based) OR (TI internet-based OR AB internet-based)) N2 (TI care OR AB care)) OR ((TI virtual OR AB virtual) OR (TI virtually OR AB virtually) OR (TI telepain OR AB telepain) OR (TI tele-pain OR AB tele-pain) OR (TI telehealth OR AB telehealth) OR (TI tele-health OR AB tele-health) OR (TI telemedicine OR AB telemedicine) OR (TI tele-medicine OR AB tele-medicine) OR (TI telemedical OR AB telemedical) OR (TI tele-medical OR AB tele-medical) OR (TI telecare OR AB telecare) OR (TI tele-care OR AB tele-care) OR (TI teleconsult* OR AB teleconsult*) OR (TI tele-consult* OR AB tele-consult*) OR (TI telecommunicat* OR AB tele-communicat*) OR (TI telecommunicat* OR AB tele-communicat*) OR (TI telemanag* OR AB telemanag*) OR (TI tele-manag* OR AB tele-manag*) OR (TI telehome OR AB telehome) OR (TI tele-home OR AB tele-home) OR (TI telepharmac* OR AB telepharmac*) OR (TI tele-pharmac* OR AB tele-pharmac*) OR (TI telecardiol* OR AB telecardiol*) OR (TI tele-cardiol* OR AB tele-cardiol*) OR (TI tele-cardiac OR AB tele-cardiac) OR (TI tele-rehabilitat* OR AB tele-rehabilitat*) OR (TI telerehabilitat* OR AB telerehabilitat*) OR (TI teleintervention* OR AB teleintervention*) OR (TI tele-intervention* OR AB tele-intervention*) OR (TI teleconferenc* OR AB teleconferenc*) OR (TI tele-conferenc* OR AB tele-conferenc*) OR (TI telephon* OR AB telephon*) OR (TI tele-phon* OR AB tele-phon*) OR (TI cellphon* OR AB cellphon*) OR (TI cell-phon* OR AB cell-phon*) OR (TI smartphon* OR AB smartphon*) OR (TI “mobile phone” OR AB “mobile phone”) OR (TI “mobile phones” OR AB “mobile phones”) OR (TI e-visit* OR AB e-visit*) OR (TI evisit* OR AB evisit*) OR (TI e-care OR AB e-care) OR (TI ecare OR AB ecare) OR (TI e-consult* OR AB e-consult*) OR (TI econsult* OR AB econsult*) OR (TI e-diagnos* OR AB e-diagnos*) OR (TI ediagnos* OR AB ediagnos*) OR (TI e-medicine OR AB e-medicine) OR (TI emedicine OR AB emedicine) OR (TI e-physician* OR AB e-physician*) OR (TI ephysician* OR AB ephysician*) OR (TI eclinician* OR AB eclinician*) OR (TI e-clinician* OR AB e-clinician*) OR (TI e-pharm* OR AB e-pharm*) OR (TI epharm* OR AB epharm*) OR (TI “communication technology” OR AB “communication technology”) OR (TI “communication technologies” OR AB “communication technologies”) OR (TI eHealth OR AB eHealth) OR (TI “e- health” OR AB “e- health”) OR (TI “e health” OR AB “e health”) OR (TI mHealth OR AB mHealth) OR (TI m-health OR AB m-health) OR (TI “m health” OR AB “m health”) OR (TI wireless OR AB wireless)) OR (((TI mobile OR AB mobile) OR (TI digital OR AB digital)) W1 (TI health* OR AB health*)) OR ((TI tele OR AB tele) W1 ((TI care OR AB care) OR (TI diagnos* OR AB diagnos*) OR (TI health* OR AB health*) OR (TI intervention* OR AB intervention*) OR (TI manag* OR AB manag*) OR (TI therap* OR AB therap*) OR (TI treat* OR AB treat*) OR (TI medicine OR AB medicine) OR (TI medical OR AB medical) OR (TI prescrib* OR AB prescrib*) OR (TI prescript* OR AB prescript*) OR (TI pain OR AB pain))) | 131328
#3; combining | S1 AND S2 | 4,153
#4; RCT filter | (ZT “randomized controlled trial”) OR (MH “Randomized Controlled Trials”) OR TI (“randomized controlled trial” OR “controlled clinical trial” OR randomized OR randomised OR randomization OR randomisation OR placebo OR randomly OR trial OR trials OR groups OR “single blind” OR “single blinded” OR “double blind” OR “double-blinded) OR AB (“randomized controlled trial” OR “controlled clinical trial” OR randomized OR randomised OR randomization OR randomisation OR placebo OR randomly OR trial OR trials OR groups OR “single blind” OR “single blinded” OR “double blind” OR “double-blinded) | 295687
#5 | S3 AND S4 | 607
#6; Animal-only exclusion | S5 NOT (((MH “Animals+”) OR (MH “Animal Studies”) OR (TI “animal model*”)) NOT (MH “human”)) | 607
#7; Pediatric-only exclusion | S6 NOT ((MH “Adolescence+” OR MH “Infant+” OR MH “Child+”) NOT (MH “Adult+”)) | 585
#8; Study design exclusion | S7 NOT PT ( Abstract OR Book OR Book Chapter OR Book Review OR Case Study OR Commentary OR Editorial OR Letter OR Masters Thesis OR Pamphlet OR Pamphlet Chapter OR Poetry ) | 538