# REFERENCES

1 Elliott V. Department of Veterans Affairs (VA): A Primer on Telehealth. Congressional Research Service R45834. July 26, 2019.
2 Department of Veterans Affairs. VA reports significant increase in Veteran use of telehealth services. Office of Public Affairs Media Relations News Release. November 22, 2019. Available at: https://www.va.gov/opa/pressrel/includes/viewPDF.cfm?id=5365. Accessed July 12, 2021.
3 Department of Veterans Affairs. VA expands Veteran access to telehealth with iPad services. VA Office of Public and Intergovernmental Affairs. September 15, 2020. https://www.va.gov/opa/pressrel/pressrelease.cfm?id=55215. Accessed July 12, 2021.
4 Department of Veterans Affairs. Telehealth Services Fact Sheet. Office of Public Affairs and Media Relations. https://www.va.gov/communitycare/docs/news/VA_telehealth_services.pdf. Accessed July 12, 2021.
5 Agha Z, Lofgren RP, VanRuiswyk JV, . Are patients at Veterans Affairs medical centers sicker? A comparative analysis of health status and medical resource use. Arch Intern Med. 2000;160(21):3252–7.11088086
6 Selim AJ, Berlowitz DR, Fincke G, . The health status of elderly veteran enrollees in the Veterans Health Administration. J Am Geriatr Soc. 2004;52(8):1271–6.15271113
7 Totten AM, Womack DM, Eden KB, . AHRQ Comparative Effectiveness Technical Briefs. Telehealth: Mapping the Evidence for Patient Outcomes From Systematic Reviews. Rockville (MD): Agency for Healthcare Research and Quality (US); 2016.
8 Mehrotra A, Chernew M, Linetsky D, . The Impact of the COVID-19 Pandemic on Outpatient Visits: Practices Are Adapting to the New Normal. Commonwealth Fund. June 2020. Available at: https://www.commonwealthfund.org/publications/2020/jun/impact-covid-19-pandemic-outpatient-visits-practices-adapting-new-normal. Accessed July 12, 2021.
9 Wosik J, Fudim M, Cameron B, . Telehealth transformation: COVID-19 and the rise of virtual care. J Am Med Inform Assoc. 2020;27(6):957–962.32311034
10 Heyworth L, Kirsh S, Zulman D, . Expanding Access through Virtual Care: The VA’s Early Experience with COVID-19. NEJM Catalyst. July 1, 2020. Available at: https://catalyst.nejm.org/doi/full/10.1056/cat.20.0327. Accessed July 12, 2021.
11 Artandi M, Thomas S, Shah NR, . Rapid system transformation to more than 75% primary care video visits within three weeks at Stanford: response to public safety crisis during a pandemic. NEJM Catalyst. April 21, 2020. Available at: https://catalyst.nejm.org/doi/full/10.1056/CAT.20.0100. Accessed July 12, 2021
12 Baum A, Kaboli PJ, Schwartz MD. Reduced In-Person and Increased Telehealth Outpatient Visits During the COVID-19 Pandemic. Annals of internal medicine. 2021;174(1):129–131.32776780
13 Mehrotra A, Ray K, Brockmeyer DM, . Rapidly Converting to “Virtual Practices”: Outpatient Care in the Era of Covid-19. NEJM Catalyst. April 1, 2020. Available at: https://catalyst.nejm.org/doi/full/10.1056/CAT.20.0091. Accessed July 13, 2021.
14 Centers for Medicare and Medicaid Services. Trump Administration Makes Sweeping Regulatory Changes to Help U.S. Healthcare System Address COVID-19 Patient Surge. Centers for Medicare and Medicaid Services. Press Release. March 30, 2020. Available at: https://www.cms.gov/newsroom/press-releases/trump-administration-makes-sweeping-regulatory-changes-help-us-healthcare-system-address-covid-19. Accessed July 12, 2021.
15 Patel SY, Mehrotra A, Huskamp HA, . Trends in Outpatient Care Delivery and Telemedicine During the COVID-19 Pandemic in the US. JAMA Internal Medicine. 2021;181(3):388–391.
16 Faruque LI, Wiebe N, Ehteshami-Afshar A, . Effect of telemedicine on glycated hemoglobin in diabetes: a systematic review and meta-analysis of randomized trials. Cmaj. 2017;189(9):E341–e364.27799615
17 Lin MH, Yuan WL, Huang TC, . Clinical effectiveness of telemedicine for chronic heart failure: a systematic review and meta-analysis. J Investig Med. 2017;65(5):899–911.
18 Frayne SM, Phibbs CS, Saechao F, . Sourcebook: Women Veterans in the Veterans Health Administration. Volume 4: Longitudinal Trends in Sociodemographics, Utilization, Health Profile, and Geographic Distribution. Women’s Health Evaluation Initiative, Women’s Health Services, Veterans Health Administration, Department of Veterans Affairs, Washington DC. February 2018.
19 Yu W, Ravelo A, Wagner TH, . Prevalence and costs of chronic conditions in the VA health care system. Med Care Res Rev. 2003;60(3 Suppl):146s–167s.15095551
20 Lewinski AA, Sullivan C, Allen KD, . Accelerating Implementation of Virtual Care in an Integrated Health Care System: Future Research and Operations Priorities. J Gen Intern Med. 2021.
21 Page MJ, McKenzie JE, Bossuyt PM, . Updating guidance for reporting systematic reviews: development of the PRISMA 2020 statement. J Clin Epidemiol. 2021;134:103–112.33577987
22 McGowan J, Sampson M, Salzwedel DM, . PRESS Peer Review of Electronic Search Strategies: 2015 Guideline Statement. J Clin Epidemiol. 2016;75:40–6.27005575
23 Cochrane Effective Practice and Organisation of Care. EPOC resources for review authors. Vol. 2020.
24 Klingeman H, Funnell M, Jhand A, . Type 2 diabetes specialty clinic model for the accountable care organization era. Journal of Diabetes & its Complications. 2017;31(10):1521–1526.28793967
25 Wan X, Wang W, Liu J, . Estimating the sample mean and standard deviation from the sample size, median, range and/or interquartile range. BMC Med Res Methodol. 2014;14:135.25524443
26 Hultcrantz M, Rind D, Akl EA, . The GRADE Working Group clarifies the construct of certainty of evidence. J Clin Epidemiol. 2017;87:4–13.28529184
27 Jeong JY, Jeon JH, Bae KH, . Smart Care Based on Telemonitoring and Telemedicine for Type 2 Diabetes Care: Multi-Center Randomized Controlled Trial. Telemedicine Journal & E-Health. 2018;24(8):604–613.29341843
28 Hansen C, Loges C, Seidl K, . INvestigation on Routine Follow-up in CONgestive HearT FAilure Patients with Remotely Monitored Implanted Cardioverter Defibrillators SysTems (InContact). BMC Cardiovascular Disorders. 2018;18(1):131.29954340
29 Rasmussen OW, Lauszus FF, Loekke M. Telemedicine compared with standard care in type 2 diabetes mellitus: A randomized trial in an outpatient clinic. Journal of Telemedicine & Telecare. 2016;22(6):363–8.26468213
30 Whitlock WL, Brown A, Moore K, . Telemedicine improved diabetic management. Military Medicine. 2000;165(8):579–84.10957848
31 Totten AM, Womack DM, Eden KB, .
32 Lee SWH, Chan CKY, Chua SS, . Comparative effectiveness of telemedicine strategies on type 2 diabetes management: A systematic review and network meta-analysis. Scientific Reports. 2017;7(1):12680.28978949
33 Hu Y, Wen X, Wang F, . Effect of telemedicine intervention on hypoglycaemia in diabetes patients: A systematic review and meta-analysis of randomised controlled trials. J Telemed Telecare. 2019;25(7):402–413.29909748
34 Chakranon P, Lai YK, Tang YW, . Distal technology interventions in people with diabetes: an umbrella review of multiple health outcomes. Diabetic Medicine. 2020;37(12):1966–1976.31631398
35 Polisena J, Tran K, Cimon K, . Home telehealth for diabetes management: a systematic review and meta-analysis. Diabetes Obes Metab. 2009;11(10):913–30.19531058
36 Yun JE, Park JE, Park HY, . Comparative Effectiveness of Telemonitoring Versus Usual Care for Heart Failure: A Systematic Review and Meta-analysis. Journal of Cardiac Failure. 2018;24(1):19–28.28939459
37 Bashi N, Karunanithi M, Fatehi F, . Remote Monitoring of Patients With Heart Failure: An Overview of Systematic Reviews. J Med Internet Res. 2017;19(1):e18.28108430
38 Cajita MI, Gleason KT, Han HR. A Systematic Review of mHealth-Based Heart Failure Interventions. Journal of Cardiovascular Nursing. 2016;31(3):E10–22.
39 Rovner B. Reducing Emergency Diabetes Care for Older African Americans. https://clinicaltrials.gov/show/NCT03466866. 2018.
40 Rodrigues DLG. Teleconsultation study in diabetic patients. http://www.who.int/trialsearch/Trial2.aspx?TrialID=RBR (http://www.who.int/trialsearch/Trial2.aspx?TrialID=RBR8) 8gpgyd. 2019.
41 Denis Komkov DS, Myasnikov RP, Fedotova NP, . Effect of education and telephone monitoring on exercise tolerance and healthrelated quality of life in patients with chronic heart failure: A prospective randomized controlled parallel-group study. European Journal of Preventive Cardiology;22(1 SUPPL. 1):S194.
42 Ferguson JM, Jacobs J, Yefimova M, . Virtual care expansion in the Veterans Health Administration during the COVID-19 pandemic: clinical services and patient characteristics associated with utilization. J Am Med Inform Assoc. 2021;28(3):453–462.33125032
43 Herzer KR, Pronovost PJ. Ensuring Quality in the Era of Virtual Care. JAMA. 2021;325(5):429–430.33528544
44 Robinson KA, Saldanha Ij Fau - McKoy NA, McKoy NA. Development of a framework to identify research gaps from systematic reviews. (1878–5921 (Electronic)).
45 Eysenbach G. CONSORT-EHEALTH: improving and standardizing evaluation reports of Web-based and mobile health interventions. J Med Internet Res. 2011;13(4):e126.22209829
46 Cavalheiro AA-OX, Silva Cardoso J, Rocha AA-O, . Effectiveness of Tele-rehabilitation Programs in Heart Failure: A Systematic Review and Meta-analysis. (1178–6329 (Print)).