# ACKNOWLEDGMENTS

This topic was developed in response to a nomination by Carolyn Turvey, Office of Rural Health, for the purpose of informing future research and to support adoption of effective virtual care service models. The scope was further developed with input from the topic nominators (ie, Operational Partners), the ESP Coordinating Center, the review team, and the Technical Expert Panel (TEP).

In designing the study questions and methodology at the outset of this report, the ESP consulted several technical and content experts. Broad expertise and perspectives were sought. Divergent and conflicting opinions are common and perceived as healthy scientific discourse that results in a thoughtful, relevant systematic review. Therefore, in the end, study questions, design, methodologic approaches, and/or conclusions do not necessarily represent the views of individual technical and content experts.

## Operational Partners

Operational partners are system-level stakeholders who have requested the report to inform decision-making. They recommend TEP participants; assure VA relevance; help develop and approve final project scope and timeframe for completion; provide feedback on draft report; and provide consultation on strategies for dissemination of the report to field and relevant groups.

- Carolyn Turvey, PhD
  Office of Rural Health
  Rural Health Resource Center, Iowa City

## Technical Expert Panel (TEP)

To ensure robust, scientifically relevant work, the TEP guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members are listed below:

- Bryan Batch, MD
  Durham VA Medical Center
  Durham, NC
- Hayden Bosworth, PhD
  Durham VA Medical Center
  Durham, NC
- Marla Clayman, PhD, MPH, BA
  Edith Nourse Rogers Memorial Veterans Hospital
  Bedford, MA
- Christopher Mosher, MD
  Duke University Medical Center
  Durham, NC
- Scott Sherman, MD, MPH
  VA New York Harbor Healthcare System
  New York, NY

## Peer Reviewers

The Coordinating Center sought input from external peer reviewers to review the draft report and provide feedback on the objectives, scope, methods used, perception of bias, and omitted evidence. Peer reviewers must disclose any relevant financial or non-financial conflicts of interest. Because of their unique clinical or content expertise, individuals with potential conflicts may be retained. The Coordinating Center and the ESP Center work to balance, manage, or mitigate any potential nonfinancial conflicts of interest identified.