# SUMMARY AND DISCUSSION

## SUMMARY OF EVIDENCE BY KEY QUESTION

KQ 1a: The 1 study that met inclusion criteria enrolled patients with CHF who had a recent implantation of either an ICD or a CRT-D and randomized them to receive quarterly automated web-based review and follow-up of telemetry data versus synchronous personal follow-up (in-person vs phone-based) for 1 year and found no significant differences in clinical outcomes between the 3 groups. The certainty of evidence was downgraded to very low certainty because of serious ROB, indirectness, and imprecision (Table 3).

KQ 1b: The included study did not report outcomes by race/ethnicity, gender, age, and rural status.

KQ 2a, KQ 2b: We found no studies on the effect of synchronous virtual compared to in-person care for chronic management of COPD.

KQ 3a: We identified 4 studies (n = 466 participants)^24,27,29,30^ that evaluated the provision of synchronous virtual care compared to in-person care for chronic management of T2DM. The 1 adequately powered, low ROB study found no statistically significant reduction in A1c between synchronous virtual care compared to usual care and asynchronous virtual care. Overall, findings from this review indicate that the impact of virtual care as a substitute for in-person care on A1c remains unclear. Hospitalizations, ER visits, number of contacts, and utilization were not uniformly reported across studies. Number of contacts and utilization varied by study and were not consistently reported. The certainty of evidence was downgraded to very low certainty because of serious ROB, indirectness, and imprecision.

KQ 3b: The 1 adequately powered, low ROB study was the only to report subgroup analyses by patient characteristics of interest, specifically age and gender. They found no statistically significant difference in reduction of A1c by age (< 55 years of age, ≥ 55 years) or gender.

KQ 4: Two of the studies on diabetes reported adverse events. There were small event rates and no evidence of differences by study arms.

Table 3 Certainty of Evidence for KQ 1 and 3

Outcome | Number of Studies (N patients) | Range of Effects | Certainty of Evidence (Rationale)
Type 2 Diabetes Mellitus
A1c | 4 randomized trials (339 patients) | Range from −0.15 to −1.30 difference in mean difference between intervention and comparator A1c | Very low certainty that virtual care has an effect on A1c; (rated down for serious risk of bias, indirectness, and imprecision)
Hospital admission | 2 randomized trials (285 patients) | Range from 0 to 3 admissions in the intervention arm and 0 to 7 admissions in comparator arm | Very low certainty that virtual care has an effect on hospital admissions; (rated down for serious risk of bias, indirectness, and imprecision)
Emergency department visits | 2 randomized trials (285 patients) | 0 emergency department visits in the intervention arms and range from 0 to 1 visit in comparator arm | Very low certainty that virtual care has an effect on emergency department attendance; (rated down for serious risk of bias, indirectness, and imprecision)
Congestive Heart Failure
NYHA class/symptoms | 1 randomized trial (219 patients) | Between-group difference p = 0.967 | Very low certainty that virtual care has an effect on NYHA class/symptoms; (rated down for serious risk of bias, inconsistency, indirectness, and imprecision)
Hospital admission | 1 randomized trial 219 patients) | RM (9.8%) vs RM + phone (11.3%) vs in-person visit (12.7%), p = 0.851 | Very low certainty that virtual care has an effect on hospital admission; (rated down for serious risk of bias, inconsistency, indirectness, and imprecision)

Abbreviations. A1c = Hemoglobin A1c; NYHA = New York Heart Association; RM = Remote Monitoring

## PRIOR SYSTEMATIC REVIEWS

A 2016 AHRQ evidence map found 58 existing systematic reviews supporting the use of telehealth interventions for communication/counseling or remote monitoring for chronic conditions.^31^ Previous systematic reviews have examined various ways of utilizing virtual care modalities in the context of these conditions of interest, but none focused on replacing in-person care with virtual visits. Our review sought to extend the existing literature by addressing telehealth as a replacement for in-person care in chronic disease management. We found scant evidence examining chronic disease management delivered by synchronous virtual care compared to in-person delivery for T2DM, COPD, and CHF.

Based on prior reviews, there is evidence that virtual care as an adjunctive strategy to typical in-person care can be associated with a decrease in A1c in patients with both type 1 and type 2 diabetes. For example, 1 systematic review by Hu et al included studies using various strategies such as remote monitoring, smart device, software, or web-based applications for patients with type I and II diabetes which led to decreased hemoglobin A1c compared to control. Additionally, Lee et al found a 0.43% reduction in A1c in patients with T2DM at 6 months across 107 randomized control trials with implementation of telemedicine strategies such as tele-monitoring, tele-education, or tele-consultation delivered by a variety of disciplines in comparison to usual care.^32,33^ This is also supported by an umbrella review of 95 systematic reviews for patients with type 1 and type 2 diabetes noting a reduction in A1c by 0.2-0.4% when using mHealth (messaging or mobile applications) and virtual care (synchronous electronic communication) specifically.^34^ Polisena et al^35^ completed a systematic review on home remote monitoring and telephone support for patients with diabetes. The home remote monitoring led to a decrease in A1c and a decrease in overall hospital utilization and mixed emergency department use. The telephone support group had mixed results related to A1c with a non-significant effect on hospital and emergency department utilization (based on a single study for each). Utilization was not specifically related to T2DM complications. Patient satisfaction was equal to or improved in both groups compared to usual care.

While we only found 1 study on virtual care for chronic management of heart failure as a substitution for in-person care, prior systematic reviews report on the impact of other types of virtual care on heart failure outcomes. A systematic review by Yun et al^36^ included 37 studies evaluating telemonitoring which found reductions in all-cause and heart failure-related mortality compared to usual care. The same study also observed a non-statistically significant trend towards decreased heart failure-related hospitalizations, but no differences in all-cause hospitalizations. The Yun et al review showed improvement in the quality of life, but not patient satisfaction for the intervention compared to usual care. Similarly, an umbrella review on telemonitoring for heart failure by Bashi et al^37^ found reductions in hospitalizations and mortality with increased quality of life. However, a systematic review of mHealth interventions (mobile devices for monitoring or messaging) with heart failure patients found mixed results for all-cause and cardiovascular mortality, heart failure-related hospitalizations and NYHA classification score.^38^

Overall, there is a strong body of evidence that virtual care modalities can improve health outcomes through the supplementation of in-person management of certain chronic diseases, particularly with approaches such as remote monitoring and patient education. Our review sought to build on this existing body of literature by evaluating the effectiveness of virtual care-delivered visits as a substitute for in-person visits for chronic disease management. However, we found that the research in this field remains insufficient and methodologically inconsistent.

## HORIZON SCAN

Given the limited amount of existing literature we identified that addressed our key question, we sought to assess the pool of ongoing studies in the pipeline that would add relevant findings in the near future. To conduct such a scan of the literature on the horizon, we applied our previously developed search terms to the Cochrane Central Register of Controlled Trials. This search identified 1,787 unique records (see Table 4). At least 1 reviewer screened these at title and abstract. Included records were verified by a second reviewer.

We found only 3 records^39–41^ that referenced studies without published results in our horizon scan (see Table 4). Studies that may potentially meet the inclusion criteria of our systemic review. All 3 of these studies are randomized controlled trials that were designed before the COVID-19 pandemic. Two of the 3 studies focus on T2DM^39,40^ while the other is on CHF.^41^ One of the T2DM studies is a non-inferiority study^40^; however, it is being conducted in Brazil (a non-OECD country) and therefore the findings may not be applicable to the Veteran population. The other T2DM study^39^ is specifically focused on reducing emergency diabetes care for older (> 50 years) African Americans. The CHF study by Komkov et al has very limited detail. Thus, it appears that there is little trial-based research currently in the pipeline to inform our key questions in this review.

Table 4 Ongoing Studies on Virtual Care for Chronic Conditions

First author, year | Recruitment target; Study design | Disease state | Intervention/Comparator | Planned duration | Clinical trials #
Rovner, 2018^39^ | African Americans, > 50 years, T1DM or T2DM, after DM-related emergency department visit; Single blind, Randomized controlled trial | T2DM | Multi-component intervention including behavioral activation and the facilitation of telehealth visits with primary care and a DM nurse educator vs multi-component intervention without telehealth facilitation or behavioral activation | 12 months | NCT03466866 (https://clinicaltrials.gov/show/NCT03466866)
Rodrigues, 2019^40^ | Patients with T2DM, > 18 years, referred from primary care; Pragmatic, open-label, phase 2, non-inferiority, randomized controlled trial | T2DM | Teleconsultation with endocrinologist by video vs face-to-face | unclear | WHO Clinical Trials Registry ID: RBR-8gpgyd
Komkov, date unknown^41^ | Patients with CHF discharged from the hospital; Randomized controlled trial | CHF | Short-term education + active telephone calls by physician vs usual care | 12 months | unknown

Abbreviations. CHF = congestive heart failure; DM = diabetes mellitus; T1DM = type 1 diabetes mellitus; T2DM = type 2 diabetes mellitus; WHO = World Health Organization.

## CLINICAL AND POLICY IMPLICATIONS

We found limited literature evaluating the effect of synchronous virtual care compared to in-person care for chronic disease management of common conditions, namely T2DM, COPD, and CHF. Among the included studies, there was significant heterogeneity around the structure, purpose, and delivery of virtual care visits. While not statistically significant and with very low certainty of evidence, our analysis suggested a trend toward greater A1c reduction among virtual care interventions versus comparators. The clinical significance of this finding is unknown. In addition, the generalizability of these findings is limited as all included studies took place in specialty care clinics whereas much of the long-term management for chronic conditions such as T2DM, CHF, and COPD occurs within the context of primary care. Primary care teams provide care for multiple conditions simultaneously which may not support the single disease-focused care described in the included studies.

The COVID-19 pandemic led to an increase in the use of virtual care as a way of making health care more accessible to patients while reducing potential infection risk associated with in-person care.^42^ Specifically, the pandemic necessitated replacement of in-person care with virtual care, rather than simply supplementing existing visits. The significant shift in patient care delivery from in-person to virtual care has impacted clinical workflows, workforce needs, and patient experience. However, there is currently a paucity of trial data to describe the outcomes associated with replacing in-person care with virtual care for chronic disease management or to recommend substituting video visits as the standard of care for managing CHF, COPD, or T2DM moving forward. In addition, none of the included studies evaluated patient satisfaction with this change in patient care delivery. Ultimately, it will be critical to clarify if the scientific question of interest is whether virtual care delivery for chronic conditions is more effective than in-person or if it is as effective as in-person care. The difference between these objectives will need to drive study design. A recent commentary by Hertzer and Pronovost^43^ pointed out that a better understanding of virtual care with respect to patient safety, effectiveness, efficiency, and equity will be necessary in order for optimal incorporation into clinical practice.

## LIMITATIONS

Our findings should be considered within the context of limitations of the included studies and of our methodologic approach.

### Limitations of Identified Literature

#### Publication Bias

Given the small number of studies we identified, statistical methods to detect publication bias were not conducted. While it is possible that individual health systems or clinics have conducted quality improvement studies evaluating differences in experiences between synchronous and in-person care – especially during the COVID-19 pandemic – we suspect it is unlikely that studies meeting EPOC criteria on this intervention have not been published given the recent emphasis on the role of virtual care.

#### Study Quality

We identified few studies overall and most had fewer than 100 patients and were assessed as unclear or high ROB. Intervention core components, intervention fidelity, or the impact of intervention on clinical workflow were not reported by any study. In addition, the interactions between clinicians and patients during virtual care episodes were not adequately or explicitly described. These omissions limit the interpretation and replication of evaluated interventions. While all studies for T2DM reported change in A1c, this is likely inappropriate for shorter durations of follow-up. Taking the standard duration for measuring changes from diabetes chronic management into account, studies should be at least 6 months in length, while durations of 12 months would be preferable. The majority of our outcomes of interest were not consistently reported across the studies. For example, while several studies provided some information on utilization and adverse events, this information on outcomes was not consistently or thoroughly reported. Only 1 study by Jeong et al^27^ had an optimal study design for our question regarding the effectiveness of synchronous virtual care compared to in-person care; the other included studies featured this comparison as a secondary focus or delivered the virtual care intervention with co-interventions such as remote monitoring and other clinical activities.

#### Heterogeneity

Heterogeneity was noted across the identified literature. First, included virtual care interventions used different virtual care modalities (eg, email, phone, video), with different hardware, delivered via different numbers of clinical interactions between patients and clinicians, and over a wide range of intervention durations. Second, studies occurred in different health care systems and countries, which likely have varied broadband access, existing virtual care infrastructure, clinical resources, and workflow processes. Finally, the identified interventions demonstrated marked variation around the clinical focus (eg, short-term stabilization of recently hospitalized poorly controlled diabetes, longer-term management of patients with diabetes not on insulin) and team structure of virtual care delivery (eg, clinicians alone vs nurses with clinician consultation).

### Limitations of Our Methodologic Approach

Our review benefited from being protocol driven, leveraging input from an expert panel consisting of clinicians and virtual care researchers, identifying disease-specific clinical outcomes, using a conceptual model to guide understanding of virtual care modalities, and using a detailed approach to categorizing and defining virtual care components in chronic disease self-management. Despite these strengths, limitations exist to our approach. We only included studies that met EPOC criteria in this review; however, observational studies may have findings relevant to the provision of synchronous virtual care for chronic illness management. Only 6 studies were excluded due to study design. It is possible that additional observational studies conducted since the onset of the COVID-19 pandemic may provide useful information (eg, NCT02788903). In addition, we focused this review on 3 of the most prevalent chronic diseases, but there may be appropriately designed studies that targeted other conditions that we did not include. Finally, we only included studies conducted in OECD countries, and as a result we may have missed relevant studies not conducted in these countries.

### Applicability of Findings to the VA Population

None of the included studies were conducted in VHA or reported specifically targeting Veterans. However, 1 study among patients with T2DM occurred in a military setting with an average age of 63 years. Two studies were conducted in countries with nationalized health care (ie, South Korea, Denmark), which may increase relevancy to VHA. Identified studies included primarily older participants, which is similar to the population of Veterans who have chronic disease.

## RESEARCH GAPS

We identified several areas that are worthy of further exploration in order to strengthen future research in this area. To systematically identify these gaps in the current literature, we used an existing framework (Table 5) by Robinson and colleagues^44^ which proposes to identify gaps categorically using the PICOTS framework (population, intervention, comparator, outcome, timing, and setting). In addition, they include standardized reasons that the current literature is insufficient to answer the question at hand (insufficient or imprecise information, biased information, inconsistency, and/or not the right information).

Overall, there are 5 key areas in which future research on this topic could fill existing gaps and/or could improve the approach. First, and perhaps most importantly, virtual care interventions should be thoroughly described in order to be replicated (eg, number of patient contacts, the type of training for clinician using virtual care) and to determine if findings are generalizable to specific clinical setting. Guidance exists on mobile and web-based interventions which may provide indirect suggestions about key characteristics for virtual care intervention description.^45^ Further efforts to outline key characteristics of virtual care interventions could be valuable. Second, there is a need to evaluate how best to integrate virtual care as a substitute for in-person care (eg, replace all vs a portion), when to include other adjunctive virtual care technologies (eg, remote monitoring), and in which clinical settings (eg, primary care vs specialty care settings) as the challenges and effectiveness can be expected to vary across settings with different workflow patterns, clinical resources, and competing clinical demands. Third, outcomes varied across included studies and omitted some key outcomes relevant to interpreting the benefits and risks of this type of intervention including impact on clinical workflow, patient satisfaction with virtual care experience, and subsequent utilization. Fourth, investigators should consider utilization of non-inferiority analytic approaches when, in fact, the question at hand is whether or not virtually delivered care is as good as in-person delivered care. Finally, investigators should be encouraged to consider a priori identified subgroup evaluations or make individual patient-level data available for future combined analyses that could identify which patient-level characteristics are associated with better outcomes with virtual care as a substitute for in-person care. The VA is well-positioned to conduct needed evaluations of synchronous virtual care given its well-established virtual care infrastructure, uptake of virtual visits, regular assessment of patient satisfaction, and available administrative data. Such information could guide clinics and health care systems to offer optimal patient-centered virtual care delivery.

A critical concern about the proliferation and acceleration of virtual modalities to deliver health care is the potential to introduce or increase existing health care access disparities. Individuals without camera-ready devices, adequate broad-band internet connections, or comfort with technology will have greater challenges in fully engaging in virtual health care offerings. This disparity may be more common amongst some patient populations (eg, rural dwelling, older age, racial/ethnic underrepresented groups) and may exacerbate historically inequitable treatment and institutional racism by the medical establishment. To adequately study such disparities in future systematic reviews, specific methodological approaches are needed. As noted above, primary research studies must include adequately powered a priori subgroup analysis of patient populations of interest and include enhanced recruitment and retention strategies to achieve enrollment targets. In addition, reporting outcomes by subpopulation could support hypothesis generation for future study even when not adequately powered for definitive analysis. Reporting findings by subpopulation and making patient-level data available for individual patient data meta-analysis could support the ability to generate meaningful evidence synthesis about effect variation by patient-level characteristics. New platforms and open access websites have developed to enable the sharing of deidentified datasets for such purposes. Such steps would allow future research to address concerns about equitable benefit and access to virtual care.

Table 5 Evidence Gaps and Areas for Future Research Consideration

Evidence Gap/Area for Future Exploration | Reason | Types of Studies to Consider
Population
- Patients with poorly controlled chronic conditions; - Patients with well-controlled chronic conditions; - Patients with various social/digital determinants of health; - Patients who are earlier in their course of chronic illness or at various stages of disease | Insufficient information/Not the right information | Well-designed subgroup analyses or individual patient-data meta-analysis from randomized trials; Qualitative and mixed methods studies
Interventions
- Video-based and/or phone-based care to replace some portion of in-person all chronic disease management by specialists and/or primary care; - Video-based and/or phone-based care to replace all chronic disease management by specialists and/or primary care; - Different models of combining video-based and/or phone-based care with in-person care for chronic disease management; - Interventions using currently available and widely used virtual care platforms (eg, Zoom, Apple Health etc) | Insufficient or imprecise information | Randomized trials; Non-randomized trials; Qualitative and mixed methods studies
Comparators
- Routine in-person care; - Telephone vs video-based care | Insufficient information | Randomized trials; Non-randomized trials
Outcomes
- Patient utilization (eg, downstream in-person care including hospitalization and urgent care visits); - Process variables (eg, time providing direct and indirect care, number of missed visits, consultation time); - Costs; - Patient satisfaction; - Clinician satisfaction; - Impact on clinical workflow; - Harms (delayed care, missed diagnoses, etc); - Fidelity to virtual care and in-person care (eg, topics covered, care delivered) | Insufficient information/imprecise information; inconsistent information | Randomized trials; Non-randomized trials; Qualitative and mixed methods studies
Setting
- Primary care; - Variety of clinical settings (eg, large health care systems, smaller community-based practices) | Insufficient information | Randomized Trials; Non-randomized Trials

## CONCLUSIONS

Virtual modalities such as video or telephone have increasingly been used to replace in-person clinic visits with prescribing clinicians for the management of chronic conditions, particularly during the COVID-19 pandemic. However, currently there is scant evidence of the effect of virtual care as a replacement for in-person visits in the context of common chronic conditions such as T2DM or CHF, and no evidence for COPD. Health care systems need evidence-based guidance about the effect of well-described virtual care interventions in order to deliver high-quality care using the right modality for the right patients with the right clinical condition at the right time.