# RESULTS

## LITERATURE FLOW

We identified 11,245 studies through searches of MEDLINE® (via Ovid®) and EMBASE (Figure 2). After removing duplicates, there were 8,662 articles. After applying inclusion and exclusion criteria to titles and abstracts, 129 articles remained for full-text review. Of these, 5 unique studies were retained for data abstraction. Of the studies retained, 4 were related to diabetes and 1 was related to CHF. Table 2 summarizes the details of the included studies. Common reasons for excluding studies by intervention included virtual care that supplemented rather than replaced in-person care, virtual care interventions delivered by non-prescribing clinicians, and virtual care delivered asynchronously only.

Figure 2 Literature Flow Chart

* Search results from Medline (4,713) and Embase (3,949) were combined.

Table 2 Evidence Profile of Included Studies (n = 5)

Number of studies: 5 randomized studies
Number of participants: 676 participants^a^
Regions: USA (n = 2); Europe (n = 2); Asia (n = 1)
Disease focus: T2DM (n = 4); CHF (n = 1); COPD (n = 0)
Patient demographics: Median age = 58 years old; 25% Women; Race: 92% White (3 studies NR); 10% Black (4 studies NR); 2% Hispanic (4 studies NR); 2% Other (4 studies NR)
Intervention mode:^b^ RM + video (n = 1); video (n = 2); RM + telephone (n = 1); telephone (n = 1);
Comparisons:^b^ RM + in-person care (n = 2); Usual in-person care(n=3)
Outcomes reported: A1c (n = 4); NYHA class/symptoms (n = 1); hospitalization (n = 3); ED visit (n = 2)
Risk of bias:
Objective: High Risk (n = 2), Unclear Risk (n = 1), Low Risk (n = 2)
Patient reported: High Risk (n = 2), Unclear Risk (n = 1), Low Risk (n = 1), Not Applicable (n = 1).

Abbreviations. A1c= hemoglobin A1c; CHF = congestive heart failure; COPD = chronic obstructive pulmonary disease; NR = not reported; NYHA= New York Heart Association; RM= remote monitoring; T2DM = type 2 diabetes mellitus.

a One study^27^ reported half of the participants (n = 338)

b More than 1 category possible per study

## KEY QUESTION 1

1A Among adults, what is the effect of synchronous virtual care (ie, phone and/or video) compared to in-person care (or compared to phone if synchronous video care) for chronic management of congestive heart failure (CHF) on key disease-specific clinical outcomes and health care utilization (ie, hospital admission, hospital re-admission, ER visits)?
1B Does this effect differ by race/ethnicity, gender, age, and rural status?

### [image]Key Points

- Only 1 study met the inclusion criteria for synchronous virtual care for chronic management of CHF.
- The 1 included study enrolled 210 patients with CHF and a recent implantation of either an implanted cardio-defibrillator (ICD) or cardiac resynchronization therapy-defibrillator (CRT-D) and randomized them to receive quarterly automated asynchronous web-based review and follow-up of telemetry data versus synchronous personal follow-up (in-person vs phone-based) for 1 year. The comparison of the 2 types of synchronous follow-up met our inclusion criteria. A 3-way comparison across study arms found no significant differences in reported composite Packer scores or other clinical outcomes such as mortality, CHF-related admissions, NYHA class, and change in reported quality of life.
- Outcomes based on race/ethnicity, gender, age, and rural status were not reported.

### [image]Detailed Findings: KQ 1a

We identified only 1 study that met the inclusion criteria for synchronous virtual care for chronic CHF management^28^ and found it to have a high ROB. Based in Germany, this study enrolled 210 patients with CHF with recent placement of an ICD or CRT-D who were then randomized to receive completely asynchronous web-based automated review and follow-up of telemetry data every 3 months (n = 102) or personal physician contact every 3 months in addition to remote monitoring. The personal contact group was further randomized to personal contact via telephone calls (n = 53) or personal contact via in-person visits (n = 55). The primary outcome was the proportion of patients with worse Packer Heart Failure Clinical Composite Response scores at 13 months compared to 1 month after device placement. The Packer composite response score gives a stepwise assessment and incorporates CHF death/hospitalization, change in NYHA class, and self-assessed health status. Secondary outcomes assessed were all-cause mortality, CHF-related hospitalizations, arrhythmias, and change in reported quality of life. There were no significant differences in Packer scores in a 3-way comparison between the telemetry arm compared to the personal contact subgroups (remote + phone vs remote + in-person visit) (p = 0.967). Similarly, there were no significant differences in secondary outcomes in mortality between subgroups (4.9% vs 7.5% vs 3.6%, p = 0.645), CHF-related hospitalization between subgroups (9.8% vs 11.3% vs 12.7%, p = 0.851), the detection of supraventricular tachycardia between subgroups (17.6% vs 7.5% vs 12.7%, p = 0.216), detection of ventricular tachycardia (19.6% vs 15.1% vs 16.4%, p = 0.752), or reported change in quality of life (p = 0.724). Overall, the authors found that there were no significant differences between the subgroups in any outcome measured.

### Quality of Evidence for KQ 1a

The single study that met our inclusion criteria^28^ was found to have a high ROB due to low numbers of patients enrolled, an unclear method for patient randomization, and poor description of both patient dropout and how primary outcomes were assessed.

### [image]Detailed Findings: KQ 1b

The single study that met inclusion criteria^28^ described the age (overall mean 63.8 years) and gender of their patient population (84.3% male); however, details regarding race/ethnicity and rural status were not reported. Furthermore, the authors did not perform any subgroup analyses examining the effect of age or gender on outcomes.

## KEY QUESTION 2

2A Among adults, what is the effect of synchronous virtual care (ie, phone and/or video) compared to in-person care (or compared to phone if synchronous video care) for chronic management of chronic obstructive pulmonary disease (COPD) on key disease-specific clinical outcomes and health care utilization (ie, hospital admission, hospital re-admission, ER visits)?
2B Does this effect differ by race/ethnicity, gender, age, and rural status?

No studies were identified that addressed KQ 2.

## KEY QUESTION 3

3A Among adults, what is the effect of synchronous virtual care (ie, phone and/or video) compared to in-person care (or compared to phone if synchronous video care) for chronic management of Type 2 diabetes mellitus (T2DM) on key disease-specific clinical outcomes and health care utilization (ie, hospital admission, hospital re-admission, ER visits)?
3B Does this effect differ by race/ethnicity, gender, age, and rural status?

### [image]Key Points

- Four studies (n = 466) evaluated synchronous chronic care for patients with diabetes in comparison to in-person care. All were conducted in specialty endocrine clinics.
- No studies were conducted in VHA or reported enrolling Veterans.
- Interventions may decrease A1c, but the certainty of evidence is very low. In the 1 adequately powered study, there was no significant effect.
- Minimal data was provided on hospitalizations, ER visits, and utilization.
- Intervention approaches to the use of virtual care varied greatly, from remote monitoring of blood glucose combined with video versus in-person visits, a specialized endocrinology clinic that individually tailored the frequency of virtual visits, to a brief, 3-week intervention to stabilize uncontrolled diabetes remotely.

### Characteristics of Included Studies

For KQ 3a, we present the detailed results ordered by outcome: (1) A1c, (2) hospitalizations, (3) ER visits, and (4) number of contacts and utilization.

We identified 4 studies – all of which were randomized trials^24,27,29,30^ – that evaluated the provision of synchronous virtual care compared to in-person care for chronic management of T2DM. Two studies were conducted in the United States,^24,30^ 1 in South Korea,^27^ and 1 in Denmark.^29^ One study was conducted with military patients.^30^ Intervention duration varied across studies from fewer than 8 weeks to 52 weeks. Intervention approach varied across the 4 studies in duration and mode of incorporating virtual care into chronic diabetes management. Three studies included 60 or fewer patients^24,29,30^ and 1 study included 338.^27^ Three studies used technology that facilitated synchronous bidirectional communication between the patient and clinician^27,29,30^ and 1 study relied on telephone and email.^24^ Two studies included remote monitoring.^27,30^ Additional details on study characteristics are in Appendix B, and intervention characteristics are in Appendix C.

### [image]Detailed Findings: KQ 3a

#### A1c

All 4 studies compared change in A1c reduction from baseline to end of study between synchronous virtual care and in-person study arms (Figure 3).^24,27,29,30^

The first study^27^ by Jeong et al was a 24-week 3-arm trial that compared usual care, telemonitoring (remote monitoring with automated clinical decision support with in-person endocrine follow-up appointments), and telemedicine (remote monitoring with automated clinical decision support with video-based endocrine follow-up appointments). They enrolled 338 patients with a baseline mean age of 53. No statistically significant difference was seen at baseline for A1c across groups: usual care (8.39% SD 1.10), telemonitoring (8.21, SD 0.93%), and telemedicine (8.39, SD 1.10). A statistically significant difference was seen for within-group decrease in A1c from baseline to 24 weeks for all groups ranging from −0.66 to −0.81 (p < 0.001). No statistically significant difference was noted for size of A1c reduction across groups: usual care versus telemonitoring groups (p = 0.6127), usual care versus telemedicine (p = 0.162), and telemonitoring versus telemedicine groups (p = 0.343).

The second study^24^ led by Klingeman et al was a 52-week, 2-arm trial consisting of usual endocrine care versus an experimental group that enrolled 60 patients with T2DM. The setting for the study was an endocrinology clinic at an academic medical center where patient care was provided by endocrinologists. Patients not in the experimental arm received usual care provided by usual clinic endocrinologists. The specialty clinic model in the experimental group included an endocrinologist and nurse educator who focused on patients with advanced diabetes; contact with the patients in this arm was designed to be variable and patient-specific. Pre-planned contacts (via email, phone) were determined at baseline and amended over time, and ad hoc in person visits occurred if clinically required. Contact was individually tailored upon each patient’s outcomes, adverse reactions, and changes in disease state. The control arm received usual endocrine care which included the ability for the patients to contact (via email and phone) clinicians as needed. Hemoglobin A1c levels were noted between groups at baseline usual care (8.9% SD 0.8%) versus specialty clinic model (9.5%, SD 0.9%). Additionally, a greater proportion of White patients were enrolled in the intervention arm (96.6%) compared to the usual care (76.8%) group. Analysis of data at 52 weeks found a greater decrease in A1c with the specialty clinic model of −1.7% (from 9.6 to 7.9%) as compared to the usual endocrine care at 0.3% (from 8.9 to 8.6%) with p = 0.004. Of note, a sensitivity analysis was conducted that dropped data from 1 outlier patient in the usual care group with worsened A1c values (8.3% to 13.5%), but this did not change the results.

The third study^29^ by Rasmussen et al was a 2-arm trial comparing 3 weeks of brief standard in-person endocrine care versus telemedicine (video-based endocrine care) to stabilize patients with poorly controlled T2DM. They enrolled 40 patients with baseline A1c in standard care group of 8.1% (range 6.1 to 10.7) and 9.0% (7.6 to 12) in the telemedicine group. At 6 months the A1c ranged from 8.1% to 7.2% for the standard care group and 9.1% to 7.7% for the telemedicine group. The percent change in A1c was statistically significant with a decrease of 14.6% in telemedicine and 10.6% in standard care (p = 0.016) across groups. Of note, although this study framed its hypothesis as that “the treatment by telemedicine at home was similar to standard care”, the analysis methods employed did not employ non-inferiority analytic approaches.

The fourth study by Whitlock et al, which tested usual care and telemonitoring visits with a case manager and physician,^30^ enrolled 28 patients in a 36-week 2-arm trial consisting of a standard of care control versus experimental telemonitoring group. In this study, both groups were referred for multidisciplinary diabetic education classes, and the experimental group then received weekly telemonitoring with video by a case manager and then monthly telemonitoring by video with study physicians. Standard of care patients received routine in-person care with their primary care clinician. A statistically significant within-group difference (p < 0.05) was noted for the experimental telemonitoring arm from baseline A1c of 9.5 (8.1 to 12.6) to an end A1c of 8.2 (5.7 to 10.2). For the comparator, the mean baseline A1c was 9.5 (8.1 to 11.9) and end A1c was 8.6 (7.1 to 11.9).

Figure 3 Change in A1c Between Intervention and Comparator Arms Across KQ 3a Studies

#### Hospitalizations

Two studies examined hospitalizations.^24,27^ In the study^27^ by Jeong et al, only 1 patient in the telemonitoring arm experienced a diabetes complication-related hospitalization, and no patients in the control or telemedicine arms experienced diabetes-related hospitalizations. In the second study^24^ by Klingeman et al, 3 patients out of 30 in the experimental arm and 7 patients out of 30 in the control arm experienced a diabetes-related hospital admission.

#### ER Visits

Two studies examined emergency room (ER) visits.^24,27^ In the first study^27^ by Jeong et al, across the 3 study arms, no patients experienced diabetes-related visits to the ER out of the 338 patients enrolled in the study. In the second study^24^ by Klingeman et al, no patients in the experimental arm and 1 patient in the control arm experienced a T2DM-related ER visit.

#### Number of Contacts and Utilization

Three studies reported collecting data on number of contacts and utilization^24,29,30^ among patients receiving in-person or virtual care.

The study^24^ by Klingeman et al reported on (1) study completion, (2) diabetes education referrals, (3) diabetes-related visits, (4) utilization of modality, and (5) number of interactions and A1c. The study by Klingeman et al designed the experimental arm for variable frequency of contact using a specialty clinic model. Pre-planned contacts (via email, phone call, or visit) were determined at baseline and amended over time; contact was tailored upon each patient’s outcomes, adverse reactions, and changes in disease state; the control arm received usual endocrine care. Klingeman et al reported that when diabetes education visits were combined with clinician diabetes-related visits in the endocrinology clinic, the experimental group had fewer overall visits than the control group. Specifically, the experimental group had 1.5 (SD 0.7) visits versus 3.6 (SD 4.0) visits over 12 months (p = 0.0001). However, the experimental group had significantly more email contacts than in the control arm, with 11.1 (SD 6.4) email interactions in the experimental group and 1.8 (SD 3.5) email interactions in the control group (p < 0.0001). (Note: email communication was a focus in the experimental arm.)

The study by Rasmussen et al, which tested standard care and video consultation for home treatment of T2DM,^29^ reported on (1) study completion, (2) number of visits and missed visits, and (3) consultation time. Study completion did not differ significantly between telemedicine (n = 20) and standard care (n = 20) groups. The telemedicine group had 4.1 visits on average with no missed visits; however, the usual care group had on average 3.8 visits with 13% missed visits. In regards to consultation time, the telemedicine group averaged 18 minutes and the usual care group averaged 23 minutes.

The study by Whitlock et al,^30^ reported no results on number of contacts and utilization despite describing collecting the number of clinic visits before and during the study in the methods.

### Quality of Evidence for KQ 3a

For the 4 randomized studies, the ROB (Figure 4) for patient-reported outcomes was judged low for 1 study, unclear for 1 study, and high for 1 study; 1 study did not report this type of outcome.^24,27,29,30^ For objective outcomes, ROB was judged low for 2 studies^27,29^ and high for 2 studies.^24,30^ Patterns that led to judgements of low ROB (Figure 5) included (1) noting randomization of study participants; (2) collecting objective outcome data; and (3) general limited expected impact of bias from patient knowledge of treatment arm. Patterns that led to high ROB included (1) missing or unclear data on randomization methods, data collection, and analysis; (2) unblinded treatment arm; (3) no predetermined intervention assessment patterns in the protocol; (4) unclear primary outcomes; and (5) unclear or missing reporting of patient-reported outcomes.

Figure 4 Risk of Bias Assessment for Included Studies in KQ 3a

Abbreviations. ROB = risk of bias.

Figure 5 Risk of Bias Assessment Across Included Studies (n = 4) in KQ 3a

Abbreviations. ROB = risk of bias.

### [image]Detailed Findings: KQ 3b

Only 1 of the included studies reported on subgroup analysis^27^ by patient characteristics. Jeong et al analyzed 2 subgroups of a priori interest: gender and age. No statistically significant difference in reduction of A1c was found for men (−0.76 ± 1.11 telemonitoring vs −0.89 ± 1.12 telemedicine; p = 0.88) or women (−0.46 ± 1.05 vs −0.63 ± 0.87; p = 0.16). Nor was a statistically significant difference in reduction of A1c seen by age < 55 years of age (−0.63 ± 1.26 telemonitoring vs −0.87 ± 1.15 telemedicine; p = 0.21) nor with age ≥ 55 years (−0.68 ± 0.88 telemonitoring vs −0.73 ± 0.93 telemedicine; p = 0.83). In addition, Jeong et al reported on additional subgroups of potential interest. High compliance users (defined as users with > 90% of number of records or data transmitted compared to recommended number of records) had no difference in reduction of A1c versus those with lower compliance levels across the study arms of interest (−0.93 ± 0.99 telemonitoring vs −1.08 ± 0.96; p = 0.47). Similarly, there was no significant difference in reduction of A1c between patients who had a high school education or less in the telemonitoring (−0.65 ± 0.93) and telemedicine (−0.94%, ±1.1) arms (p = 0.26).

## KEY QUESTION 4

What are the adverse effects of synchronous virtual care for chronic management of CHF, COPD, and T2DM as compared to in-person care (or compared to phone if synchronous video care) on patients (ie, hypoglycemic events), clinical team members (ie, burnout), and clinics (ie, increase in resource costs)?

### [image]Detailed Findings: KQ 4

Two studies on T2DM reported adverse events.^24,27^ The study^27^ by Jeong et al described 4 groups of adverse events: (1) general events, (2) diabetes-related events, (3) serious events, and (4) biochemical events. Adverse events were noted in the control (n = 33 or 29.20%, in-person appointments at 8, 16, 24 weeks), telemonitoring (n = 30 or 26.55%, in-person appointments at 8, 16, 24 weeks with remote monitoring of blood glucose data), and telemedicine (n = 23 or 20.54%, video visits at 8 and 16 weeks, in-person visit at 24 weeks) arms. Diabetes-related events were noted in the control (n = 7 or 6.19%), telemonitoring (n = 7 or 6.19%), and telemedicine (n = 3 or 2.68%) arms. Serious reported adverse events were noted in the control (n = 2 or 1.7%), telemonitoring (n = 2 or 1.70%), and telemedicine (n = 1 or 0.90%) arms, and included angina pectoris, rotator cuff syndrome, malignant hepatic neoplasm, skin ulcer, and hematuria^27^. Biochemical parameters for serum alanine aminotransferase (ALT), aspartate aminotransferase (AST), and creatinine levels were measured and samples obtained at baseline and 24 weeks^27^; each value was classified as normal or abnormal. ALT was the only parameter that showed a significant worsening from a normal baseline across groups; specifically, 0 telemonitoring arm participants (0%) versus 7 telemedicine participants (6.7%) (p = 0.014) experienced a worsening of ALT values. Authors also noted that 5 patients (4.8%) in the control arm experienced a decline in ALT from a baseline normal value. The study by Klingeman et al described 2 types of adverse events: (1) severe hypoglycemia and (2) foot ulcers.^24^ Severe hypoglycemia was noted in the experimental (n = 1 or 3.3%) arm but not in the control (n = 0 or 0%) arm. Foot ulcer was noted in the experimental (n = 1 or 3.3%) and control (n = 3 or 10%) arms.