# METHODS

We followed a standard protocol for this review developed in collaboration with operational partners and a technical expert panel. The PROSPERO registration number is CRD42021239756. The protocol was developed prior to conducting the review, and there were no significant deviations after registration. Each step was pilot tested to train and calibrate study investigators. We adhered to the Preferred Reporting Items for Systematic Reviews and Meta Analyses (PRISMA) guidelines.^21^

## TOPIC DEVELOPMENT

This topic was proposed by the leadership of the Office of Rural Health (ORH). Key questions as outlined below were driven in particular by the ORH’s desire to better understand virtual care access and use by marginalized patient populations given inequities exposed by shifts in care during the COVID-19 pandemic and concerns about the potential worsening of existing or creation of new sources of health disparities. Findings will be used to inform the development of Request for Applications (RFAs) on virtual care implementation research and to support the adoption of effective virtual care service models.

### Key Questions

The Key Questions (KQs) for this report were:

KQ 1a Among adults, what is the effect of synchronous virtual care (ie, phone and/or video) compared to in-person care (or compared to phone if synchronous video care) for chronic management of congestive heart failure (CHF) on key disease-specific clinical outcomes and health care utilization (ie, hospital admission, hospital re-admission, ER visits)?
KQ 1b Does this effect differ by race/ethnicity, gender, age, and rural status?
KQ 2a Among adults, what is the effect of synchronous virtual care (ie, phone and/or video) compared to in-person care (or compared to phone if synchronous video care) for chronic management of chronic obstructive pulmonary disease (COPD) on key disease-specific clinical outcomes and health care utilization (ie, hospital admission, hospital re-admission, ER visits)?
KQ 2b Does this effect differ by race/ethnicity, gender, age, and rural status?
KQ 3a Among adults, what is the effect of synchronous virtual care (ie, phone and/or video) compared to in-person care (or compared to phone if synchronous video care) for chronic management of type 2 diabetes mellitus (T2DM) on key disease-specific clinical outcomes and health care utilization (ie, hospital admission, hospital re-admission, ER visits)?
KQ 3b Does this effect differ by race/ethnicity, gender, age, and rural status?
KQ 4 What are the adverse effects of synchronous virtual care for chronic management of CHF, COPD, and T2DM as compared to in-person care (or compared to phone if synchronous video care) on patients (ie, hypoglycemic events), clinical team members (ie, burnout), and clinics (ie, increase in resource costs)?

### Conceptual Model

Figure 1 depicts our conceptual model. Our analysis of virtual care begins with the patient who has a chronic disease (eg, CHF, COPD, or T2DM), and the clinical visit (eg, purposeful interaction between the prescribing clinician and patient), which encompasses all activities between the prescribing clinician and patient. Following review of the literature and team discussions, we are considering the virtual care modality (eg, telephone, video, in-person) to mediate the relationship between the clinical visit and prespecified clinical- and system-level outcomes. Of note, we acknowledge that individual patient characteristics (eg, race/ethnicity, gender, age, rural status) may moderate the relationship between the modality in which the clinical visit occurs and any clinical- and system-level outcomes. Given the focus of our key questions, we also specified that the care delivered virtually should be for clinical activities provided by a prescribing clinician such as evaluation, diagnosis, or medication prescription and not for the provision of self-management education and/or other support provided adjunctively by a clinical team member other than the prescribing clinician (eg, nurse care manager) as such interventions have been previously evaluated.^7^ The conceptual model outlines the population, outcomes, mediation effect of the modality, moderation effect of patient characteristics, and any adverse effects. The virtual care interventions map to our operationalized definition of virtual care and also include important contextual elements such as delivery mode (eg, telephone, video, in-person), dose (eg, duration and frequency of contact), and clinical context of care provision.

Figure 1 Virtual Care Conceptual Model

## SEARCH STRATEGY

In collaboration with an expert medical librarian, we conducted a primary literature search from inception to February 7, 2021, of MEDLINE^®^ (via Ovid^®^), Embase (via Elsevier). We used database-specific subject headings and keywords searched in the titles and abstracts (Appendix A). The search strategies were peer reviewed by another expert medical librarian prior to execution using the Peer Review of Electronic Search Strategies (PRESS) Checklist.^22^ We hand-searched previous systematic reviews conducted on this or a related topic for potential inclusion.

## STUDY SELECTION

Studies identified through our primary search were classified independently by 2 investigators for relevance to the KQs based on title and abstract from our a priori established eligibility criteria. All citations classified for inclusion by at least 1 investigator were reviewed at the full-text review level. The citations designated for exclusion by 1 investigator at the title and abstract level underwent screening by a second investigator. If both investigators agreed on exclusion, the study was excluded. All articles meeting eligibility criteria were included for data abstraction. All results were tracked in an electronic database (for referencing, EndNote®, Clarivate Analytics, Philadelphia, PA; for data abstraction, DistillerSR; Evidence Partners Inc., Manotick, ON, Canada).

Table 1 describes the study eligibility criteria organized by PICOTS elements (population, intervention, comparator, outcome, timing, setting) and other criteria such as study design, language, and publication type. Specifically, for the virtual care intervention we sought to identify studies that evaluated the effect of synchronously delivered care for relevant chronic conditions that occurred over ≥ 2 encounters and in which some or all in-person care is supplanted by virtual care (ie, phone or video). The virtual care must be delivered remotely by a clinician with a scope of practice that includes independent prescribing, diagnosis, and/or chronic management (ie, physician, nurse practitioner, physician assistant, clinical pharmacist) for a patient who is not physically present in the same clinic (ie, teleconsultation, video conferencing) and that is administered within the context of longitudinal care provision (even if individual visits are for acute concerns). Interventions are not required to be exclusively virtual care provided by a clinician as described above; rather, they may include the above with other asynchronous virtual care tools (eg, remote monitoring systems), virtual care manager support, or in-person visits with a prescribing clinician as well. Remote monitoring that triggers synchronous care would be eligible if remote monitoring occurs in both treatment and comparison arm and visits are with a prescribing clinician. We did not include studies that tested virtual care interventions in which the virtual care component was care provided in addition to regular in-person care rather than as a substitute.

Table 1 Study Eligibility

Study Characteristic | Inclusion Criteria | Exclusion Criteria
Population | - Adults ( ≥ 18 years of age) with the following chronic conditions:; ○ CHF; ○ COPD; ○ T2DM; at least 75% if a mix of type 1 and type 2; - Clinicians/clinics conducting virtual care for chronic conditions if relevant to harms | - Inpatient populations (eg, tele-ICU); - Patients receiving care in an ER or tele-urgent care setting; - Intervention limited only to the management of complications of these chronic conditions such as stroke, retinopathy, neuropathy, and foot ulcers
Intervention | - Synchronous care delivered over ≥ 2 encounters for the long-term management of relevant chronic conditions in which some or all in-person care is supplanted by virtual care (ie, phone or video) and which is delivered remotely by an independently licensed clinician; - May include asynchronous virtual care tools (eg, remote monitoring systems), if in both arms. | - Supplemental nurse care management; - Virtual care interventions that don’t involve synchronous care delivered by a clinician to a patient (eg, one-way automated texts, reminder systems,); - Tele-cardiac or tele-pulmonary rehabilitation
Comparator | In-person care without any virtual care delivery, or care delivered by telephone if compared to video | No comparator
Outcome | - Key clinical outcomes (eg, medication adherence, quality of life, depression) and by condition:; ○ CHF (eg, NYHA class/symptoms); ○ COPD (eg, exercise tolerance, dyspnea); ○ T2DM (eg, A1c); - Clinical utilization (ie, hospitalization, hospital re-admissions, emergency room visits/urgent care); - Adverse effects (eg, hypoglycemic episodes, inappropriate treatment, clinician burnout) | Any outcomes not listed
Timing | No limit | Not applicable
Setting | Any outpatient setting (ie, general medical or specialty care clinic) | Intervention delivered primarily in hospital inpatient setting (including emergency room)
Study design | - EPOC criteria studies that have prospective data collection:; ○ Randomized trials; ○ Non-randomized trials; - Controlled before-after studies; - Interrupted time-series studies or repeated measures studies | - Not a clinical study (eg, editorial, letter to an editor); - Uncontrolled clinical study; - Qualitative studies; - Prospective or retrospective observational studies; - Clinical guidelines; - Measurement or validation studies; - Studies that look at mixed chronic conditions if results for specified conditions are not reported separately
Countries | OECD^a^ | Non-OECD
Publication types | Full publication in a peer-reviewed journal | Letters, editorials, reviews, dissertations, meeting abstracts, protocols without results

Abbreviations. A1c = hemoglobin A1c; CHF = congestive heart failure; COPD = chronic obstructive pulmonary disease; EPOC = effective practice and organization of care; ER = emergency room; ICU = intensive care unit; NYHA = New York Heart Association; T2DM = type 2 diabetes mellitus.

a OECD = Organization for Economic Co-operation and Development includes Australia, Austria, Belgium, Canada, Chile, Czech Republic, Denmark, Estonia, Finland, France, Germany, Greece, Hungary, Iceland, Ireland, Israel, Italy, Japan, Korea, Latvia, Luxembourg, Mexico, Netherlands, New Zealand, Norway, Poland, Portugal, Slovak Republic, Slovenia, Spain, Sweden, Switzerland, Turkey, United Kingdom, and United States.

## DATA ABSTRACTION

Data from published reports were abstracted into a customized DistillerSR database by 1 reviewer and over-read by a second reviewer. Disagreements were resolved by consensus or by obtaining a third reviewer’s opinion. Data elements included descriptors to assess applicability, quality elements, intervention details, and outcomes including adverse events.

Key characteristics abstracted included participant descriptors (eg, race/ethnicity, gender, age, rural status), intervention characteristics (eg, clinician type, virtual care modality), comparator, and outcomes. We abstracted all outcomes used to evaluate virtual care but prioritized outcomes identified a priori in collaboration with our stakeholders for analysis. Multiple reports from a single study were treated as a single data point, prioritizing results based on the most complete and appropriately analyzed data. When critical data were missing or unclear in published reports, we requested supplemental data from the study authors. Key features relevant to applicability included the match between the sample and target populations (eg, age, Veteran status).

For details of study characteristics, see Appendix B. Appendix C presents details of the intervention characteristics. Appendix D lists all outcomes reported in the included studies, and Appendix E lists excluded studies and the reason for exclusion.

## RISK OF BIAS (QUALITY) ASSESSMENT

Quality assessment was done by the investigator abstracting or evaluating the included article and was over-read by a second, highly experienced investigator. Disagreements were resolved by consensus between the 2 investigators or, when needed, by arbitration by a third investigator.

For randomized, non-randomized, and controlled before-after studies, we used criteria from the Cochrane EPOC ROB tool.^23^ These criteria are adequacy of randomization and allocation concealment; comparability of groups at baseline; blinding; completeness of follow-up and differential loss to follow-up; whether incomplete data were addressed appropriately; validity of outcome measures; protection against contamination; selective outcomes reporting; and conflict of interest. We assigned a summary ROB score (low, unclear, high) to individual studies, defined as follows:

- Low ROB: Bias, if present, is unlikely to alter the results seriously.
- Unclear ROB: Information required to determine ROB was not clearly specified in the peer-reviewed paper or unable to be obtained to make a judgment.
- High ROB: Bias may alter the results seriously.

## DATA SYNTHESIS

We summarized the primary literature using relevant data abstracted from the eligible studies. Summary tables describe the key study characteristics of the primary studies: study design, patient demographics, and details of the intervention and comparator. Because of the conceptual heterogeneity of the identified study interventions, we did not complete a quantitative synthesis (ie, meta-analysis) to estimate summary effects. Rather we describe the findings from included studies narratively focusing on documenting and identifying patterns in efficacy and safety of the interventions across conditions and outcome categories.

Continuous outcomes were summarized using the mean difference (follow-up minus baseline) when all studies reported the outcome using the same scale. For studies not directly reporting mean and standard deviation of patient differences, we used difference in means between follow-up and baseline. For 1 study,^24^ we computed standard deviation of difference based on reported p-value for difference between the 2 arms, assuming the same correlation between follow-up and baseline in each arm. When studies reported only medians and ranges, we translated them to means and standard deviations^25^ and if a study reported only baseline standard deviation, assumed the same standard deviation at follow-up. Finally, in absence of other information, we assumed 0.5 correlation between follow-up and baseline.

### Analysis of Subgroups or Subsets

We sought to consider variations of effect by subgroup of interest, specifically age, rurality, gender, and race/ethnicity. Prespecified potential effect modifiers of interest included study design characteristics (eg, allocation concealment), disease context (ie, CHF, COPD, T2DM), and potentially intervention type (eg, virtual care modality). Regarding patient-level characteristics of interest (ie, race/ethnicity, gender, age, rural status), we looked for analyses conducted within the primary literature that sought to identify effect modification (eg, subgroup analyses, regression model explanatory variables). We narratively considered the representation of subgroups within identified studies in comparison to the VA population.

## GRADING THE CERTAINTY OF EVIDENCE

The certainty of evidence for each key question was assessed using the approach described by Grading of Recommendations Assessment, Development and Evaluation (GRADE).^26^ We limited GRADE ratings to those key questions which had at least 2 includes. In brief, this approach requires assessment of 4 domains: ROB, consistency, directness, and precision. Additional domains to be used when appropriate are coherence, dose-response association, impact of plausible residual confounders, strength of association (magnitude of effect), and publication bias. We considered these domains qualitatively and assigned a summary rating after discussion by a sub-team of 5 investigators (KG, CW, AL, AG, and BE) as high, moderate, or low strength of evidence. In some cases, high, moderate, or low ratings were impossible or imprudent to make. In these situations, a grade of insufficient was assigned.

## PEER REVIEW

A draft version of this report was reviewed by technical experts and clinical leadership. A transcript of their comments and our responses is in Appendix F.