# INTRODUCTION

As both the largest integrated health system and largest provider of telehealth in the country, the Veterans Health Administration (VHA) has a particular interest in understanding how best to implement and utilize virtual care. VHA has long embraced virtual care as part of its mission to “serve all who have served” regardless of their socioeconomic and geographic circumstances. Having begun conducting “virtual care” in the 1960s when doctors first communicated with patient’s via TV screens,^1^ VHA has since provided over 2.6 million episodes of care to more than 900,000 Veterans in 2019^2^ and has distributed over 50,000 data- and video-enabled iPads for Veterans throughout the country.^3^ Virtual care within VHA includes services such as MyHealtheVet secure messaging, the Home Telehealth program that combines case management principles with remote monitoring to improve access and coordinate care, and the VA Video Connect (VVC) video platform for synchronous visits within both specialty and primary care.^4^ Increasing Veteran access to care via virtual care has been an integral part of VHA’s strategy for improving chronic disease management for a population that is on average older and sicker than their civilian counterparts.^5,6^ Given the importance that virtual care has for Veteran care even beyond the COVID-19 pandemic, understanding the strengths and limitations associated with synchronous virtual care will be critical in shaping how VHA utilizes virtual care going forward.

Virtual care can be defined as the use of technology to facilitate an interaction between a patient and their health care team across distance or time.^7^ This broad definition includes a wide variety of technologies and interventions, such as text messages and email communications, asynchronous remote monitoring, and synchronous (ie, real-time) phone/video visits.^7^ Given the large heterogeneity of care delivery that falls under the umbrella of virtual care, its impact is dependent upon the specific modality and application as well as the patient populations involved. For example, a systemic review and evidence map of virtual care literature in 2016 published by the Agency for Healthcare Research and Quality (AHRQ) which focused largely on virtual care when used in addition to in-person care found consistent evidence of benefit for virtual care with counseling and remote monitoring of chronic conditions but found unclear evidence supporting virtual care for clinical consultation or maternal and child health among other clinical circumstances.^7^ Importantly, specific virtual care modalities can have different impacts depending on the clinical situation and patient population. For example, chronic conditions which depend on physical assessment to determine clinical status (eg, congestive heart failure [CHF] or chronic obstructive pulmonary disease [COPD]) or the presence of complications (eg, diabetes mellitus) may have different challenges compared to other conditions which can largely be managed without physical exam (eg, mental health). Understanding when virtual care is most effective will be particularly important as we try to right size the implementation of virtual modalities after the initial dramatic increase due the COVID-19 pandemic.

COVID-19 has had a profound impact on ambulatory care delivery. The onset of the COVID-19 pandemic in early 2020 led to an unprecedented growth in synchronous virtual care delivery via phone and video encounters as a means of mitigating the risk of viral transmission for both patients and clinicians. The impact of COVID-19 on ambulatory care was so profound that it is estimated that outpatient visits across the entire country decreased by nearly 60% by the end of March.^8^ In response, many health systems rapidly converted 70% or more of their outpatient visits to virtual care delivery via phone or video.^9–13^ To support the US health care system during the crisis, the Centers for Medicare and Medicaid Services issued an emergency ruling aimed at decreasing regulatory requirements for virtual care and created payment parity between in-person care and virtual care delivered via phone or video.^14^ Although in-person care visits have since increased, as more has become known about COVID-19 transmission and prevention practices, virtual care continues to have a much larger role in outpatient care than prior to the pandemic.^8,15^ Even after the pandemic recedes, it is likely that synchronous virtual care will remain a large part of ambulatory care. Therefore, a close examination of this specific model of virtual care and its strengths and limitations is warranted.

Prior to the pandemic, virtual care was used to shift workload from clinicians to other clinical team members and to supplement rather than replace in-person care. For example, remote monitoring has been combined with phone calls from virtual care nurses or case managers to supplement care for patients with CHF and type 2 diabetes mellitus (T2DM).^16,17^ In essence, many prior virtual care studies focused on augmentation of usual care, whereas now it is important to understand which patients and conditions can be managed by clinicians with only limited in-person evaluation. In this context, there are many unanswered questions. First, does synchronous virtual care result in similar clinical outcomes compared with in-person care? Second, in what context is virtual care appropriate as a substitute for in-person care? Furthermore, what are the risks for harm such as missed or delayed diagnoses, increased health care disparities, and worse clinical outcomes? Understanding the evidence for benefit and harm with this specific application of virtual care will help shape current practice and inform future research and investments in virtual care.

Particularly important within VHA is the chronic management of CHF, COPD, and T2DM, as these are among the most common and costly conditions affecting nearly 5%, 10%, and 25% of all Veterans, respectively.^18,19^ In addition, these conditions typically require physical assessment to establish disease status and the presence and extent of exacerbations. Despite the reliance on physical assessment, during the COVID pandemic we experienced a near complete shift to managing care of such conditions virtually. Moving forward, we will need to match the best care modality by condition for specific patient populations. This is a priority within VHA.^20^ Thus, our systematic review examined the use of virtual care as a substitute for in-person care in the context of chronic management for CHF, COPD, and T2DM.