# APPENDIX E EXCLUDED STUDIES

| Exclusion Reason
Study | Not OECD | Not Population | Not Intervention | Not Outcomes | Not Comparator | Not Design
Antonicelli, 2010^1^ | | | X
Basudev, 2016^2^ | | | X
Bekelman, 2015^3^ | | | X
Benatar, 2003^4^ | | | X
Bentley, 2014^5^ | | | X
Berkhof, 2015^6^ | | | X
Biermann, 2000^7^ | | X
Blumenthal, 2014^8^ | | | X
Bowles, 2009^9^ | | | X
Brandon, 2009^10^ | | | X
Carral, 2015^11^ | | X
Cartwright, 2013^12^ | | | X
Chen, 2019^13^ | X
Chen, 2011^14^ | X
Choe, 2005^15^ | | | X
Chwalow, 1989^16^ | | | X
Clifford, 2005^17^ | | | X
Cohen, 2020^18^ | | | | | X
Comin-Colet, 2016^19^ | | | X
Creason, 2001^20^ | | | X
Cui, 2013^21^ | | | X
Dadosky, 2018^22^ | | | X
Dale, 2007^23^ | | | | | | X
Dansky, 2008^24^ | | | X
Dansky, 2009^25^ | | | X
de la Porte, 2007^26^ | | | X
De Simone, 2015^27^ | | | X
de Vries, 2011^28^ | | | X
Dienstl, 2011^29^ | | | | | | X
Dixon, 2020^30^ | | | | | X
Doyle, 2017^31^ | | | X
Durso, 2003^32^ | | | X
Egede, 2018^33^ | | | X
Egede, 2017^34^ | | | X
Ell, 2012^35^ | | X
Farrero, 2001^36^ | | | X
Farsaei, 2011^37^ | X
Gamez-Lopez, 2012^38^ | | | X
Gellis, 2012^39^ | | | X
González-Guerrero, 2018^40^ | | | X
Gorodeski, 2020^41^ | | | X
Hallberg, 2018^42^ | | | X
Hansen, 2017^43^ | | | X
Haynes, 2020^44^ | | | X
Herold, 2018^45^ | | | X
Holmen, 2016^46^ | | | X
Hsu, 2016^47^ | | | X
Huizinga, 2010^48^ | | | X
Inoriza, 2017^49^ | | | X
Jakobsen, 2015^50^ | | X
Jakobsson, 2015^51^ | | X
Jerant, 2003^52^ | | | X
Jimenez-Marrero, 2020^53^ | | | X
Kashem, 2008^54^ | | | X
Kashem, 2006^55^ | | | X
Kaur, 2015^56^ | X
Kessler, 2018^57^ | | | X
King, 2009^58^ | | | X
Kobb, 2003^59^ | | X
Koehler, 2018^60^ | | | X
Koehler, 2011^61^ | | | X
Koehler, 2012^62^ | | | X
Krein, 2004^63^ | | | X
LaFramboise, 2003^64^ | | | X
Lam, 2011^65^ | | | | | X
Lauffenburger, 2019^66^ | | | | | X
Lauffenburger, 2019^67^ | | | | | X
Layman, 2020^68^ | | | X
Lehmann, 2006^69^ | | | X
Leichter, 2013^70^ | | X
Lilholt, 2017^71^ | | | X
Liou, 2014^72^ | X
Litke, 2018^73^ | | | | | X
Lopez Cabezas, 2006^74^ | | | X
Lyons, 2016^75^ | | X
Majithia, 2020^76^ | | | | | X
Martinez, 2013^77^ | | | | X
Mayes, 2010^78^ | | | X
McElroy, 2016^79^ | | X
Moayeri, 2019^80^ | | | X
Moore, 2017^81^ | | X
Morguet, 2008^82^ | | X
Mortara, 2009^83^ | | | X
Moyer-Knox, 2004^84^ | | | | | | X
Myers, 2020^85^ | | | | | X
Nakayama, 2020^86^ | | | X
Nguyen, 2008^87^ | | | X
Nield, 2012^88^ | | | X
Nouryan, 2019^89^ | | | X
Odegard, 2005^90^ | | | X
Odeh, 2015^91^ | | | X
Oh, 2003^92^ | | | X
Pare, 2006^93^ | | | X
Pedone, 2015^94^ | | | X
Perez-Rodriguez, 2015^95^ | | | X
Polonsky, 2020^96^ | | | | | X
Quinn, 2016^97^ | | | X
Ringbaek, 2015^98^ | | | X
Rodriguez-Idigoras, 2009^99^ | | | X
Rüter, 2014^100^ | | | X
Salvo, 2012^101^ | | | | | | X
Sarayani, 2018^102^ | X
Scalvini, 2005^103^ | | | | | | X
Scalvini, 2006^104^ | | | | | | X
Schmidt, 2019^105^ | | | | | X
Smith, 2008^106^ | | | | X
Sorocco, 2013^107^ | | X
Steventon, 2014^108^ | | | X
Stewart, 2015^109^ | | | X
Stone, 2010^110^ | | | | | X
Tabak, 2014^111^ | | | X
Taylor, 2009^112^ | | | X
Veenstra, 2015^113^ | | | | | X
Vidula, 2020^114^ | | | X
Vitacca, 2009^115^ | | X
Wakefield, 2012^116^ | | | X
Wakefield, 2008^117^ | | | X
Whitten, 2007^118^ | | | X
Wild, 2016^119^ | | | X
Woodend, 2008^120^ | | | X
Wright, 2019^121^ | | | X
Wu, 2005^122^ | | | X
Yan, 2018^123^ | X
Yoo, 2009^124^ | | | X

## REFERENCES TO APPENDIX E

1 Antonicelli R, Mazzanti I, Abbatecola AM, Parati G. Impact of home patient telemonitoring on use of beta-blockers in congestive heart failure. Drugs Aging. 2010;27(10):801–805.20883060
2 Basudev N, Crosby-Nwaobi R, Thomas S, Chamley M, Murrells T, Forbes A. A prospective randomized controlled study of a virtual clinic integrating primary and specialist care for patients with Type 2 diabetes mellitus. Diabet Med. 2016;33(6):768–776.27194175
3 Bekelman DB, Plomondon ME, Carey EP, . Primary Results of the Patient-Centered Disease Management (PCDM) for Heart Failure Study: A Randomized Clinical Trial. JAMA Internal Medicine. 2015;175(5):725–732.25822284
4 Benatar D, Bondmass M, Ghitelman J, Avitall B. Outcomes of chronic heart failure. Arch Intern Med. 2003;163(3):347–352.12578516
5 Bentley CL, Mountain GA, Thompson J, . A pilot randomised controlled trial of a Telehealth intervention in patients with chronic obstructive pulmonary disease: challenges of clinician-led data collection. Trials [Electronic Resource]. 2014;15:313.
6 Berkhof FF, van den Berg JW, Uil SM, Kerstjens HA. Telemedicine, the effect of nurse-initiated telephone follow up, on health status and health-care utilization in COPD patients: a randomized trial. Respirology. 2015;20(2):279–285.25400242
7 Biermann E, Dietrich W, Standl E. Telecare of diabetic patients with intensified insulin therapy. A randomized clinical trial. Stud Health Technol Inform. 2000;77:327–332.11187566
8 Blumenthal JA, Emery CF, Smith PJ, . The effects of a telehealth coping skills intervention on outcomes in chronic obstructive pulmonary disease: primary results from the INSPIRE-II study. Psychosom Med. 2014;76(8):581–592.25251888
9 Bowles KH, Holland DE, Horowitz DA. A comparison of in-person home care, home care with telephone contact and home care with telemonitoring for disease management. J Telemed Telecare. 2009;15(7):344–350.19815903
10 Brandon AF, Schuessler JB, Ellison KJ, Lazenby RB. The effects of an advanced practice nurse led telephone intervention on outcomes of patients with heart failure. Appl Nurs Res. 2009;22(4):e1–7.19875032
11 Carral F, Ayala Mdel C, Fernandez JJ, . Web-based telemedicine system is useful for monitoring glucose control in pregnant women with diabetes. Diabetes Technol Ther. 2015;17(5):349–354.25629547
12 Cartwright M, Hirani SP, Rixon L, . Effect of telehealth on quality of life and psychological outcomes over 12 months (Whole Systems Demonstrator telehealth questionnaire study): nested study of patient reported outcomes in a pragmatic, cluster randomised controlled trial. BMJ. 2013;346:f653.23444424
13 Chen C, Li X, Sun L, . Post-discharge short message service improves short-term clinical outcome and self-care behaviour in chronic heart failure. ESC heart failure. 2019;6(1):164–173.30478888
14 Chen SY, Chang YH, Hsu HC, Lee YJ, Hung YJ, Hsieh CH. One-year efficacy and safety of the telehealth system in poorly controlled type 2 diabetic patients receiving insulin therapy. Telemed J E Health. 2011;17(9):683–687.21882998
15 Choe HM, Mitrovich S, Dubay D, Hayward RA, Krein SL, Vijan S. Proactive case management of high-risk patients with type 2 diabetes mellitus by a clinical pharmacist: a randomized controlled trial. Am J Manag Care. 2005;11(4):253–260.15839185
16 Chwalow AJ, Costagliola D, Stern J, Mesbah M, Eschwege E. Telephone versus face to face interviewing as a means of collecting data relevant to the management of diabetes among general practitioners in France: a randomized design. Diabete et Metabolisme. 1989;15(4):157–160.2806701
17 Clifford RM, Davis WA, Batty KT, Davis TM, Fremantle Diabetes S. Effect of a pharmaceutical care program on vascular risk factors in type 2 diabetes: the Fremantle Diabetes Study. Diabetes Care. 2005;28(4):771–776.15793171
18 Cohen LB, Taveira TH, Wu WC, Pirraglia PA. Pharmacist-led telehealth disease management program for patients with diabetes and depression. J Telemed Telecare. 2020;26(5):294–302.30691328
19 Comin-Colet J, Enjuanes C, Verdu-Rotellar JM, . Impact on clinical events and healthcare costs of adding telemedicine to multidisciplinary disease management programmes for heart failure: Results of a randomized controlled trial. J Telemed Telecare. 2016;22(5):282–295.26350543
20 Creason H. Congestive heart failure telemanagement clinic. Lippincott’s Case Management. 2001;6(4):146–156.16398064
21 Cui Y, Doupe M, Katz A, Nyhof P, Forget EL. Economic evaluation of Manitoba Health Lines in the management of congestive heart failure. Healthcare Policy = Politiques de sante. 2013;9(2):36–50.24359716
22 Dadosky A, Overbeck H, Barbetta L, . Telemanagement of Heart Failure Patients Across the Post-Acute Care Continuum. Telemed J E Health. 2018;24(5):360–366.28910238
23 Dale J, Caramlau I, Docherty A, Sturt J, Hearnshaw H. Telecare motivational interviewing for diabetes patient education and support: a randomised controlled trial based in primary care comparing nurse and peer supporter delivery. Trials [Electronic Resource]. 2007;8:18.
24 Dansky KH, Vasey J, Bowles K. Impact of telehealth on clinical outcomes in patients with heart failure. Clin Nurs Res. 2008;17(3):182–199.18617707
25 Dansky K, Vasey J. Managing heart failure patients after formal homecare. Telemed J E Health. 2009;15(10):983–991.19929234
26 de la Porte PW, Lok DJ, van Veldhuisen DJ, . Added value of a physician-and-nurse-directed heart failure clinic: results from the Deventer-Alkmaar heart failure study. Heart. 2007;93(7):819–825.17065182
27 De Simone A, Leoni L, Luzi M, . Remote monitoring improves outcome after ICD implantation: the clinical efficacy in the management of heart failure (EFFECT) study. Europace. 2015;17(8):1267–1275.25842271
28 de Vries AE, de Jong RM, van der Wal MH, Jaarsma T, van Dijk RB, Hillege HL. The value of INnovative ICT guided disease management combined with Telemonitoring in OUtpatient clinics for Chronic Heart failure patients. Design and methodology of the IN TOUCH study: a multicenter randomised trial. BMC Health Serv Res. 2011;11:167.21752280
29 Dienstl M, Kempf K, Schulz C, Kruse J, Martin S. Effect of telemedicine on glucometabolic control and quality of life in patients with type 2 diabetes mellitus. Diabetologie und Stoffwechsel. 2011;6(3):164–169.
30 Dixon RF, Zisser H, Layne JE, . A Virtual Type 2 Diabetes Clinic Using Continuous Glucose Monitoring and Endocrinology Visits. J Diabetes Sci Technol. 2020;14(5):908–911.31762302
31 Doyle C, Bhar S, Fearn M, . The impact of telephone-delivered cognitive behaviour therapy and befriending on mood disorders in people with chronic obstructive pulmonary disease: A randomized controlled trial. Br J Health Psychol. 2017;22(3):542–556.28544504
32 Durso SC, Wendel I, Letzt AM, Lefkowitz J, Kaseman DF, Seifert RF. Older adults using cellular telephones for diabetes management: a pilot study. Medsurg Nurs. 2003;12(5):313–317.14608688
33 Egede LE, Walker RJ, Payne EH, Knapp RG, Acierno R, Frueh BC. Effect of psychotherapy for depression via home telehealth on glycemic control in adults with type 2 diabetes: Subgroup analysis of a randomized clinical trial. J Telemed Telecare. 2018;24(9):596–602.28945160
34 Egede LE, Williams JS, Voronca DC, Gebregziabher M, Lynch CP. Telephone-Delivered Behavioral Skills Intervention for African American Adults with Type 2 Diabetes: A Randomized Controlled Trial. J Gen Intern Med. 2017;32(7):775–782.28337686
35 Ell K, Katon W, Lee PJ, . Depressive symptom deterioration among predominantly Hispanic diabetes patients in safety net care. Psychosomatics. 2012;53(4):347–355.22458987
36 Farrero E, Escarrabill J, Prats E, Maderal M, Manresa F. Impact of a hospital-based home-care program on the management of COPD patients receiving long-term oxygen therapy. Chest. 2001;119(2):364–369.11171710
37 Farsaei S, Sabzghabaee AM, Zargarzadeh AH, Amini M. Effect of pharmacist-led patient education on glycemic control of type 2 diabetics: a randomized controlled trial. J Res Med Sci. 2011;16(1):43–49.21448382
38 Gamez-Lopez AL, Bonilla-Palomas JL, Anguita-Sanchez M, Castillo-Dominguez JC, Arizon del Prado JM, Suarez de Lezo J. [Effects of three different disease management programs on outcomes in patients hospitalized with heart failure: a randomized trial]. Med Clin (Barc). 2012;138(5):192–198.21605879
39 Gellis ZD, Kenaley B, McGinty J, Bardelli E, Davitt J, Ten Have T. Outcomes of a telehealth intervention for homebound older adults with heart or chronic respiratory failure: a randomized controlled trial. Gerontologist. 2012;52(4):541–552.22241810
40 González-Guerrero JL, Hernández-Mocholi MA, Ribera-Casado JM, García-Mayolín N, Alonso-Fernández T, Gusi N. Cost-effectiveness of a follow-up program for older patients with heart failure: a randomized controlled trial. Eur Geriatr Med. 2018;9(4):523–532.34674493
41 Gorodeski EZ, Moennich LA, Riaz H, Jehi L, Young JB, Tang WHW. Virtual Versus In-Person Visits and Appointment No-Show Rates in Heart Failure Care Transitions. Circ Heart Fail. 2020:298–300.
42 Hallberg SJ, McKenzie AL, Williams PT, . Effectiveness and Safety of a Novel Care Model for the Management of Type 2 Diabetes at 1 Year: An Open-Label, Non-Randomized, Controlled Study. Diabetes Therapy Research, Treatment and Education of Diabetes and Related Disorders. 2018;9(2):583–612.29417495
43 Hansen CR, Perrild H, Koefoed BG, Zander M. Video consultations as add-on to standard care among patients with type 2 diabetes not responding to standard regimens: a randomized controlled trial. European Journal of Endocrinology. 2017;176(6):727–736.28325823
44 Haynes SC, Tancredi DJ, Tong K, . Association of Adherence to Weight Telemonitoring With Health Care Use and Death: A Secondary Analysis of a Randomized Clinical Trial. JAMA Network Open. 2020;3(7):e2010174.32648924
45 Herold R, van den Berg N, Dörr M, Hoffmann W. Telemedical Care and Monitoring for Patients with Chronic Heart Failure Has a Positive Effect on Survival. Health Serv Res. 2018;53(1):532–555.28138988
46 Holmen H, Wahl A, Torbjornsen A, Jenum AK, Smastuen MC, Ribu L. Stages of change for physical activity and dietary habits in persons with type 2 diabetes included in a mobile health intervention: the Norwegian study in RENEWING HEALTH. BMJ Open Diabetes Research & Care. 2016;4(1):e000193.
47 Hsu WC, Lau KH, Huang R, . Utilization of a Cloud-Based Diabetes Management Program for Insulin Initiation and Titration Enables Collaborative Decision Making Between Healthcare Providers and Patients. Diabetes Technol Ther. 2016;18(2):59–67.26645932
48 Huizinga MM, Gebretsadik T, Garcia Ulen C, . Preventing glycaemic relapse in recently controlled type 2 diabetes patients: a randomised controlled trial. Diabetologia. 2010;53(5):832–839.20084363
49 Inoriza JM, Ibanez A, Perez-Berruezo X, Inoriza-Nadal C, Coderch J, en representacion de Grupo G. [Effectiveness and economic impact of a program of integrated care with telemedicine support on insulin-treated type 2 diabetic patients (Study GITDIABE)]. Aten Primaria. 2017;49(3):131–139.27423246
50 Jakobsen AS, Laursen LC, Rydahl-Hansen S, . Home-based telehealth hospitalization for exacerbation of chronic obstructive pulmonary disease: findings from “the virtual hospital” trial. Telemed J E Health. 2015;21(5):364–373.25654366
51 Jakobsson S, Irewall AL, Bjorklund F, Mooe T. Cardiovascular secondary prevention in high-risk patients: a randomized controlled trial sub-study. BMC Cardiovasc Disord. 2015;15:125.26466804
52 Jerant AF, Azari R, Martinez C, Nesbitt TS. A randomized trial of telenursing to reduce hospitalization for heart failure: patient-centered outcomes and nursing indicators. Home Health Care Serv Q. 2003;22(1):1–20.
53 Jimenez-Marrero S, Yun S, Cainzos-Achirica M, . Impact of telemedicine on the clinical outcomes and healthcare costs of patients with chronic heart failure and mid-range or preserved ejection fraction managed in a multidisciplinary chronic heart failure programme: A sub-analysis of the iCOR randomized trial. J Telemed Telecare. 2020;26(1–2):64–72.30193564
54 Kashem A, Droogan MT, Santamore WP, Wald JW, Bove AA. Managing heart failure care using an internet-based telemedicine system. J Card Fail. 2008;14(2):121–126.18325458
55 Kashem A, Droogan MT, Santamore WP, . Web-based Internet telemedicine management of patients with heart failure. Telemed J E Health. 2006;12(4):439–447.16942416
56 Kaur R, Kajal KS, Kaur A, Singh P. Telephonic Consultation and follow-up in Diabetics: Impact on Metabolic Profile, Quality of Life, and Patient Compliance. N Am J Med Sci. 2015;7(5):199–207.26110131
57 Kessler R, Casan-Clara P, Koehler D, . CoMET: A multicomponent home-based disease-management programme versus routine care in severe COPD. Eur Respir J. 2018;51(1).
58 King AB, Wolfe GS. Evaluation of a diabetes specialist-guided primary care diabetes treatment program. J Am Acad Nurse Pract. 2009;21(1):24–30.19125892
59 Kobb R, Hoffman N, Lodge R, Kline S. Enhancing elder chronic care through technology and care coordination: report from a pilot. Telemed J E Health. 2003;9(2):189–195.12855041
60 Koehler F, Koehler K, Deckwart O, . Efficacy of telemedical interventional management in patients with heart failure (TIM-HF2): a randomised, controlled, parallel-group, unmasked trial. Lancet. 2018;392(10152):1047–1057.30153985
61 Koehler F, Winkler S, Schieber M, . Impact of remote telemedical management on mortality and hospitalizations in ambulatory patients with chronic heart failure: the telemedical interventional monitoring in heart failure study. Circulation. 2011;123(17):1873–1880.21444883
62 Koehler F, Winkler S, Schieber M, . Telemedicine in heart failure: pre-specified and exploratory subgroup analyses from the TIM-HF trial. Int J Cardiol. 2012;161(3):143–150.21982700
63 Krein SL, Klamerus ML, Vijan S, . Case management for patients with poorly controlled diabetes: a randomized trial. Am J Med. 2004;116(11):732–739.15144909
64 LaFramboise LM, Todero CM, Zimmerman L, Agrawal S. Comparison of Health Buddy with traditional approaches to heart failure management. Fam Community Health. 2003;26(4):275–288.14528134
65 Lam A. Practice innovations: delivering medication therapy management services via Videoconference interviews. Consult Pharm. 2011;26(10):764–774.22005142
66 Lauffenburger JC, Ghazinouri R, Jan S, . Impact of a novel pharmacist-delivered behavioral intervention for patients with poorly-controlled diabetes: The ENhancing outcomes through Goal Assessment and Generating Engagement in Diabetes Mellitus (ENGAGE-DM) pragmatic randomized trial. PLoS ONE [Electronic Resource]. 2019;14(4):e0214754.
67 Lauffenburger JC, Lewey J, Jan S, . Effectiveness of Targeted Insulin-Adherence Interventions for Glycemic Control Using Predictive Analytics Among Patients With Type 2 Diabetes: A Randomized Clinical Trial. JAMA Network Open. 2019;2(3):e190657.30874782
68 Layman SN, Elliott WV, Regen SM, Keough LA. Implementation of a pharmacist-led transitional care clinic. Am J Health Syst Pharm. 2020;77(12):966–971.32374382
69 Lehmann CA, Mintz N, Giacini JM. Impact of telehealth on healthcare utilization by congestive heart failure patients. Disease Management and Health Outcomes. 2006;14(3):163–169.
70 Leichter SB, Bowman K, Adkins RA, Jelsovsky Z. Impact of remote management of diabetes via computer: the 360 study--a proof-of-concept randomized trial. Diabetes Technol Ther. 2013;15(5):434–438.23537419
71 Lilholt PH, Witt Udsen F, Ehlers L, Hejlesen OK. Telehealthcare for patients suffering from chronic obstructive pulmonary disease: effects on health-related quality of life: results from the Danish ‘TeleCare North’ cluster-randomised trial. BMJ Open. 2017;7(5):e014587.
72 Liou JK, Soon MS, Chen CH, . Shared care combined with telecare improves glycemic control of diabetic patients in a rural underserved community. Telemed J E Health. 2014;20(2):175–178.24320193
73 Litke J, Spoutz L, Ahlstrom D, Perdew C, Llamas W, Erickson K. Impact of the clinical pharmacy specialist in telehealth primary care. Am J Health Syst Pharm. 2018;75(13):982–986.29941537
74 Lopez Cabezas C, Falces Salvador C, Cubi Quadrada D, . Randomized clinical trial of a postdischarge pharmaceutical care program vs regular follow-up in patients with heart failure. Farmacia Hospitalaria. 2006;30(6):328–342.17298190
75 Lyons I, Barber N, Raynor DK, Wei L. The Medicines Advice Service Evaluation (MASE): a randomised controlled trial of a pharmacist-led telephone based intervention designed to improve medication adherence. BMJ Quality & Safety. 2016;25(10):759–769.
76 Majithia AR, Kusiak CM, Armento Lee A, . Glycemic Outcomes in Adults With Type 2 Diabetes Participating in a Continuous Glucose Monitor-Driven Virtual Diabetes Clinic: Prospective Trial. J Med Internet Res. 2020;22(8):e21778.32856597
77 Martinez AS, Saef J, Paszczuk A, Bhatt-Chugani H. Implementation of a pharmacist-managed heart failure medication titration clinic. Am J Health Syst Pharm. 2013;70(12):1070–1076.23719886
78 Mayes PA, Silvers A, Prendergast JJ. New direction for enhancing quality in diabetes care: utilizing telecommunications and paraprofessional outreach workers backed by an expert medical team. Telemed J E Health. 2010;16(3):358–363.20406123
79 McElroy I, Sareh S, Zhu A, . Use of digital health kits to reduce readmission after cardiac surgery. J Surg Res. 2016;204(1):1–7.27451860
80 Moayeri F, Dunt D, Hsueh YA, Doyle C. Cost-utility analysis of telephone-based cognitive behavior therapy in chronic obstructive pulmonary disease (COPD) patients with anxiety and depression comorbidities: an application for willingness to accept concept. Expert Rev Pharmacoecon Outcomes Res. 2019;19(3):331–340.30324818
81 Moore AB, Krupp JE, Dufour AB, . Improving Transitions to Postacute Care for Elderly Patients Using a Novel Video-Conferencing Program: ECHO-Care Transitions. Am J Med. 2017;130(10):1199–1204.28551043
82 Morguet AJ, Kuhnelt P, Kallel A, Jaster M, Schultheiss HP. Impact of telemedical care and monitoring on morbidity in mild to moderate chronic heart failure. Cardiology. 2008;111(2):134–139.18376125
83 Mortara A, Pinna GD, Johnson P, . Home telemonitoring in heart failure patients: the HHH study (Home or Hospital in Heart Failure). Eur J Heart Fail. 2009;11(3):312–318.19228800
84 Moyer-Knox D, Mueller TM, Vuckovic K, Mischke L, Williams RE. Remote titration of carvedilol for heart failure patients by advanced practice nurses. J Card Fail. 2004;10(3):219–224.15190531
85 Myers A, Presswala L, Bissoonauth A, . Telemedicine for Disparity Patients With Diabetes: The Feasibility of Utilizing Telehealth in the Management of Uncontrolled Type 2 Diabetes in Black and Hispanic Disparity Patients: A Pilot Study. J Diabetes Sci Technol. 2020:1932296820951784.
86 Nakayama A, Takayama N, Kobayashi M, . Remote cardiac rehabilitation is a good alternative of outpatient cardiac rehabilitation in the COVID-19 era. Environ Health Prev Med. 2020;25(1):48.32891113
87 Nguyen HQ, Donesky-Cuenco D, Wolpin S, . Randomized controlled trial of an internet-based versus face-to-face dyspnea self-management program for patients with chronic obstructive pulmonary disease: pilot study. J Med Internet Res. 2008;10(2):e9.18417444
88 Nield M, Hoo GW. Real-time telehealth for COPD self-management using Skype TM. Copd: Journal of Chronic Obstructive Pulmonary Disease. 2012;9(6):611–619.22946768
89 Nouryan CN, Morahan S, Pecinka K, . Home Telemonitoring of Community-Dwelling Heart Failure Patients After Home Care Discharge. Telemed J E Health. 2019;25(6):447–454.30036166
90 Odegard PS, Goo A, Hummel J, Williams KL, Gray SL. Caring for poorly controlled diabetes mellitus: a randomized pharmacist intervention. Ann Pharmacother. 2005;39(3):433–440.15701763
91 Odeh B, Kayyali R, Nabhani-Gebara S, Philip N, Robinson P, Wallace CR. Evaluation of a Telehealth Service for COPD and HF patients: Clinical outcome and patients’ perceptions. J Telemed Telecare. 2015;21(5):292–297.25766852
92 Oh JA, Kim HS, Yoon KH, Choi ES. A telephone-delivered intervention to improve glycemic control in type 2 diabetic patients. Yonsei Med J. 2003;44(1):1–8.12619168
93 Pare G, Sicotte C, St-Jules D, Gauthier R. Cost-minimization analysis of a telehomecare program for patients with chronic obstructive pulmonary disease. Telemed J E Health. 2006;12(2):114–121.16620165
94 Pedone C, Rossi FF, Cecere A, Costanzo L, Antonelli Incalzi R. Efficacy of a Physician-Led Multiparametric Telemonitoring System in Very Old Adults with Heart Failure. J Am Geriatr Soc. 2015;63(6):1175–1180.26031737
95 Perez-Rodriguez G, Brito-Zurita OR, Sistos-Navarro E, Benitez-Arechiga ZM, Sarmiento-Salazar GL, Vargas-Lizarraga JF. [Telemetric monitoring reduces visits to the emergency room and cost of care in patients with chronic heart failure]. Cir Cir. 2015;83(4):279–285.26116037
96 Polonsky WH, Layne JE, Parkin CG, . Impact of Participation in a Virtual Diabetes Clinic on Diabetes-Related Distress in Individuals With Type 2 Diabetes. Cd (Clinical Diabetes). 2020;38(4):357–362.
97 Quinn CC, Shardell MD, Terrin ML, . Mobile Diabetes Intervention for Glycemic Control in 45- to 64-Year-Old Persons With Type 2 Diabetes. J Appl Gerontol. 2016;35(2):227–243.25098253
98 Ringbaek T, Green A, Laursen LC, Frausing E, Brondum E, Ulrik CS. Effect of tele health care on exacerbations and hospital admissions in patients with chronic obstructive pulmonary disease: a randomized clinical trial. International Journal of Copd. 2015;10:1801–1808.26366072
99 Rodriguez-Idigoras MI, Sepulveda-Munoz J, Sanchez-Garrido-Escudero R, . Telemedicine influence on the follow-up of type 2 diabetes patients. Diabetes Technol Ther. 2009;11(7):431–437.19580356
100 Rüter G, Mons U, Brenner H. New approaches to optimize general practitioner care in type 2 diabetes. Results of the DIANA study. Diabetologe. 2014;10(3):207–216.
101 Salvo MC, Brooks AM. Glycemic control and preventive care measures of indigent diabetes patients within a pharmacist-managed insulin titration program vs standard care. Ann Pharmacother. 2012;46(1):29–34.22202497
102 Sarayani A, Mashayekhi M, Nosrati M, . Efficacy of a telephone-based intervention among patients with type-2 diabetes; a randomized controlled trial in pharmacy practice. Int J Clin Pharm. 2018;40(2):345–353.29435911
103 Scalvini S, Capomolla S, Zanelli E, . Effect of home-based telecardiology on chronic heart failure: costs and outcomes. J Telemed Telecare. 2005;11 Suppl 1:16–18.16035980
104 Scalvini S, Zanelli E, Paletta L, . Chronic heart failure home-based management with a telecardiology system: a comparison between patients followed by general practitioners and by a cardiology department. J Telemed Telecare. 2006;12 Suppl 1:46–48.16884578
105 Schmidt K, Caudill JA, Hamilton T. Impact of clinical pharmacy specialists on glycemic control in veterans with type 2 diabetes. Am J Health Syst Pharm. 2019;76(Supplement_1):S9–S14.30753315
106 Smith B, Hughes-Cromwick PF, Forkner E, Galbreath AD. Cost-effectiveness of telephonic disease management in heart failure. Am J Manag Care. 2008;14(2):106–115.18269306
107 Sorocco KH, Bratkovich KL, Wingo R, Qureshi SM, Mason PJ. Integrating care coordination home telehealth and home based primary care in rural Oklahoma: a pilot study. Psychol Serv. 2013;10(3):350–352.23937085
108 Steventon A, Bardsley M, Doll H, Tuckey E, Newman SP. Effect of telehealth on glycaemic control: analysis of patients with type 2 diabetes in the Whole Systems Demonstrator cluster randomised trial. BMC Health Serv Res. 2014;14:334.25100190
109 Stewart SA, Worth L, Burton C. Evaluating a Telehealth Follow-up Program for Cardiology Patients Using Administrative Data. Stud Health Technol Inform. 2015;209:156–161.25980719
110 Stone RA, Rao RH, Sevick MA, . Active care management supported by home telemonitoring in veterans with type 2 diabetes: the DiaTel randomized controlled trial. Diabetes Care. 2010;33(3):478–484.20009091
111 Tabak M, Brusse-Keizer M, van der Valk P, Hermens H, Vollenbroek-Hutten M. A telehealth program for self-management of COPD exacerbations and promotion of an active lifestyle: a pilot randomized controlled trial. International Journal of Copd. 2014;9:935–944.25246781
112 Taylor S, Hourihan F, Krass I, Armour C. Measuring consumer preference for models of diabetes care delivered by pharmacists. Pharm Pract (Granada). 2009;7(4):195–204.25136394
113 Veenstra W, Op den Buijs J, Pauws S, Westerterp M, Nagelsmit M. Clinical effects of an optimised care program with telehealth in heart failure patients in a community hospital in the Netherlands. Neth Heart J. 2015;23(6):334–340.25947078
114 Vidula H, Cheyne C, Dick S, . Feasibility and Patient Perceptions of Tele-Videoconferencing Visits for LVAD Patients (TeleLVAD Study). The Journal of heart and lung transplantation : the official publication of the International Society for Heart Transplantation. 2020;39(4):S133.
115 Vitacca M, Bianchi L, Guerra A, . Tele-assistance in chronic respiratory failure patients: a randomised clinical trial. Eur Respir J. 2009;33(2):411–418.18799512
116 Wakefield BJ, Holman JE, Ray A, . Outcomes of a home telehealth intervention for patients with diabetes and hypertension. Telemed J E Health. 2012;18(8):575–579.22873700
117 Wakefield BJ, Ward MM, Holman JE, . Evaluation of home telehealth following hospitalization for heart failure: a randomized trial. Telemed J E Health. 2008;14(8):753–761.18954244
118 Whitten P, Mickus M. Home telecare for COPD/CHF patients: outcomes and perceptions. J Telemed Telecare. 2007;13(2):69–73.17359569
119 Wild SH, Hanley J, Lewis SC, . Supported Telemonitoring and Glycemic Control in People with Type 2 Diabetes: The Telescot Diabetes Pragmatic Multicenter Randomized Controlled Trial. PLoS Medicine / Public Library of Science. 2016;13(7):e1002098.
120 Woodend AK, Sherrard H, Fraser M, Stuewe L, Cheung T, Struthers C. Telehome monitoring in patients with cardiac disease who are at high risk of readmission. Heart Lung. 2008;37(1):36–45.18206525
121 Wright EA, Graham JH, Maeng D, . Reductions in 30-day readmission, mortality, and costs with inpatient-to-community pharmacist follow-up. Journal of the American Pharmacists Association: JAPhA. 2019;59(2):178–186.30655090
122 Wu RC, Delgado D, Costigan J, Maciver J, Ross H. Pilot study of an Internet patient-physician communication tool for heart failure disease management. J Med Internet Res. 2005;7(1):e8.15829480
123 Yan Y, Liu L, Zeng J, Zhang L. Evaluation and Exploration on the Effect of the Management of Chronic Obstructive Pulmonary Disease in Rural Areas through an Internet-Based Network Consulting Room. Med Princ Pract. 2018;27(3):222–226.29558756
124 Yoo HJ, Park MS, Kim TN, . A Ubiquitous Chronic Disease Care system using cellular phones and the internet. Diabet Med. 2009;26(6):628–635.19538239