# APPENDIX D REPORTED OUTCOMES TABLE

Study | Outcomes reported
Type 2 diabetes mellitus
Jeong, 2018^27^ | - Change in A1c
Klingeman, 2017^24^ | - Change in A1c
Rasmussen, 2016^29^ | - Change in A1c
Whitlock, 2000^30^ | - Change in A1c
Klingeman, 2017^24^ | - Hospitalization
Klingeman, 2017^24^ | - Hospitalization
Jeong, 2018^27^ | - ED attendance
Klingeman, 2017^24^ | - ED attendance
Congestive heart failure
Hansen, 2018^28^ | - NYHA class/symptoms
Hansen, 2018^28^ | - Hospitalization
Harms
Jeong, 2018^27^ | - Adverse events; - Death
Klingeman, 2017^24^ | - Hypoglycemia
Other utilization outcomes
Hansen, 2018^28^ | - Unscheduled follow-ups; - Proportion of all follow-ups that had disease-relevant findings
Klingeman, 2017^24^ | - Additional diabetes education; - Face-to-face visits; - Phone calls; - Emails
Rasmussen, 2016^29^ | - Consultations
Other clinical outcomes
Hansen, 2018^28^ | - Arrhythmias; - Number of delivered/appropriate ICD Therapies; - Changes in QoL; - All-cause mortality
Jeong, 2018^27^ | - Frequency of hypoglycemia; - Changes in fasting blood glucose; - Lipid profiles; - Body weight; - BMI; - Percent achieving goal A1c; - Compliance with medications; - Compliance with self-monitoring of blood glucose; - Labs: AST, ALT, creatinine
Klingeman, 2017^24^ | - Statin use; - Insulin use; - Foot ulcers; - Blood pressure; - BMI
Rasmussen, 2016^29^ | - Mean glucose; - Systolic blood pressure; - Diastolic blood pressure; - Cholesterol; - LDL; - Weight
Whitlock, 2000^30^ | - Total body weight; - Microalbumin; - Creatinine; - Triglycerides; - LDL
Other outcomes
Whitlock, 2000^30^ | - DQOL survey and SF36; - Clinician survey (limited results reported in this paper)

Abbreviations. A1c = hemoglobin A1c; ALT = alanine aminotransferase; AST = aspartate aminotransferase; BMI = body mass index; DQOL = Diabetes Quality of Life; ED = emergency department; ICD = implanted cardio-defibrillator; LDL = low density lipoprotein cholesterol; NYHA = New York Heart Association; QoL = quality of life; SF36 = Medical Outcome Study Health Survey