# REFERENCES

1 Elliott MN, Beckett MK, C WC, . Inpatient Care Experiences Differ for VA and Non-VA Hospitals, With Different Patterns by Health, Race, and Ethnicity. Med Care Res Rev. Apr 2025;82(2):195–200. doi:10.1177/10775587241300645 39636048
2 Chan DC, Card D, Taylor L. Is There a VA Advantage? Evidence from Dually Eligible Veterans. Am Econ Rev. Nov 2023;113(11):3003–3043. doi:10.1257/aer.20211638 39816722
3 Matula SR, Trivedi AN, Miake-Lye I, Glassman PA, Shekelle P, Asch S. Comparisons of quality of surgical care between the US Department of Veterans Affairs and the private sector. J Am Coll Surg. Dec 2010;211(6):823–32. doi:10.1016/j.jamcollsurg.2010.09.001 21109159
4 O’Hanlon C, Huang C, Sloss E, . Comparing VA and Non-VA Quality of Care: A Systematic Review. J Gen Intern Med. Jan 2017;32(1):105–121. doi:10.1007/s11606-016-3775-2 27422615
5 Institute of Medicine. Crossing the Quality Chasm: A New Health System for the 21st Century. Institute of Medicine; 2001.
6 Veterans Access, Choice, and Accountability Act of 2014, (2014).
7 VA MISSON Act of 2018 (2018).
8 U.S. Department of Veterans Affairs. VA makes it easier for Veterans to use community care. https://news.va.gov/press-room/va-makes-it-easier-for-veterans-to-use-community-care/
9 U.S. Department of Veterans Affairs. VA offers yearlong community care authorizations for 30 services. https://news.va.gov/press-room/va-offers-yearlong-community-care-authorizations-for-30-services/
10 Trivedi AN, Matula S, Miake-Lye I, Glassman PA, Shekelle P, Asch S. Systematic review: comparison of the quality of medical care in Veterans Affairs and non-Veterans Affairs settings. Med Care. Jan 2011;49(1):76–88. doi:10.1097/MLR.0b013e3181f53575 20966778
11 Apaydin EA, Paige NM, Begashaw MM, Larkin J, Miake-Lye IM, Shekelle PG. Veterans Health Administration (VA) vs. Non-VA Healthcare Quality: A Systematic Review. J Gen Intern Med. Jul 2023;38(9):2179–2188. doi:10.1007/s11606-023-08207-2 37076605
12 Blegen M, Ko J, Salzman G, . Comparing Quality of Surgical Care Between the US Department of Veterans Affairs and Non-Veterans Affairs Settings: A Systematic Review. J Am Coll Surg. Aug 1 2023;237(2):352–361. doi:10.1097/xcs.0000000000000720 37154441
13 Jones LG, Sin MK, Hage FG, . Characteristics and outcomes of patients with advanced chronic systolic heart failure receiving care at the Veterans Affairs versus other hospitals: insights from the Beta-blocker Evaluation of Survival Trial (BEST). Circ Heart Fail. Jan 2015;8(1):17–24. doi:10.1161/circheartfailure.114.001300 25480782
14 Florez HJ, Ghosh A, Pop-Busui R, . Differences in complications, cardiovascular risk factor, and diabetes management among participants enrolled at veterans affairs (VA) and non-VA medical centers in the glycemia reduction approaches in diabetes: A comparative effectiveness study (GRADE). Diabetes Res Clin Pract. Dec 28 2021;184:109188. doi:10.1016/j.diabres.2021.109188 34971663
15 Augustine JJ, Arrigain S, Balabhadrapatruni K, Desai N, Schold JD. Significantly Lower Rates of Kidney Transplantation among Candidates Listed with the Veterans Administration: A National and Local Comparison. J Am Soc Nephrol. Oct 2018;29(10):2574–2582. doi:10.1681/asn.2017111204 30006419
16 Burke JF, Kerr EA, McCammon RJ, Holleman R, Langa KM, Callaghan BC. Neuroimaging overuse is more common in Medicare compared with the VA. Neurology. Aug 23 2016;87(8):792–8. doi:10.1212/wnl.0000000000002963 27402889
17 Lee D, Begley CE. Delays in Seeking Health Care: Comparison of Veterans and the General Population. J Public Health Manag Pract. Mar/Apr 2017;23(2):160–168. doi:10.1097/phh.0000000000000420 27115981
18 Fortney JC, Carey EP, Rajan S, Rise PJ, Gunzburger EC, Felker BL. A comparison of patient-reported mental health outcomes for the Department of Veterans Affairs’ regional telehealth and Community Care Programs. Health Serv Res. Aug 2022;57(4):755–763. doi:10.1111/1475-6773.13993 35467011
19 Petros V, Tsambikos E, Madhoun M, Tierney WM. Impact of Community Referral on Colonoscopy Quality Metrics in a Veterans Affairs Medical Center. Clin Transl Gastroenterol. Jan 1 2022;13(3):e00460. doi:10.14309/ctg.0000000000000460 35081542
20 O’Hanlon CE, Zeliadt SB, DeFaccio R, Gaj L, Bokhour BG, Taylor SL. Patient-reported pain and physical health for acupuncture and chiropractic care delivered by Veterans Affairs versus community providers. PLoS One. 2024;19(5):e0303651. doi:10.1371/journal.pone.0303651 38748671
21 Heidenreich PA, Zapata A, Shieh L, Oliva N, Sahay A. Patient ratings of Veterans Affairs and affiliated hospitals. Am J Manag Care. Jun 2017;23(6):382–384.28817300
22 Mody L, Greene MT, Saint S, . Comparing Catheter-Associated Urinary Tract Infection Prevention Programs Between Veterans Affairs Nursing Homes and Non-Veterans Affairs Nursing Homes. Infect Control Hosp Epidemiol. Mar 2017;38(3):287–293. doi:10.1017/ice.2016.279 27917728
23 Axon RN, Gebregziabher M, Everett CJ, Heidenreich P, Hunt KJ. Dual health care system use is associated with higher rates of hospitalization and hospital readmission among veterans with heart failure. Am Heart J. Apr 2016;174:157–63. doi:10.1016/j.ahj.2015.09.023 26995383
24 Shields MC, Rosenthal MB. Quality of Inpatient Psychiatric Care at VA, Other Government, Nonprofit, and For-Profit Hospitals: A Comparison. Psychiatr Serv. Mar 1 2017;68(3):225–230. doi:10.1176/appi.ps.201600074 27745537
25 Presley CJ, Kaur K, Han L, . Aggressive End-of-Life Care in the Veterans Health Administration versus Fee-for-Service Medicare among Patients with Advanced Lung Cancer. J Palliat Med. Jun 2022;25(6):932–939. doi:10.1089/jpm.2021.0436 35363053
26 Barnett PG, Hong JS, Carey E, Grunwald GK, Joynt Maddox K, Maddox TM. Comparison of Accessibility, Cost, and Quality of Elective Coronary Revascularization Between Veterans Affairs and Community Care Hospitals. JAMA Cardiol. Feb 1 2018;3(2):133–141. doi:10.1001/jamacardio.2017.4843 29299607
27 Nuti SV, Qin L, Rumsfeld JS, . Association of Admission to Veterans Affairs Hospitals vs Non-Veterans Affairs Hospitals With Mortality and Readmission Rates Among Older Men Hospitalized With Acute Myocardial Infarction, Heart Failure, or Pneumonia. JAMA. Feb 9 2016;315(6):582–92. doi:10.1001/jama.2016.0278 26864412
28 Thorpe CT, Gellad WF, Mor MK, . Effect of Dual Use of Veterans Affairs and Medicare Part D Drug Benefits on Antihypertensive Medication Supply in a National Cohort of Veterans with Dementia. Health Serv Res. Dec 2018;53 Suppl 3(Suppl Suppl 3):5375–5401. doi:10.1111/1475-6773.13055 30328097
29 Yoon J, Phibbs CS, Ong MK, . Outcomes of Veterans Treated in Veterans Affairs Hospitals vs Non-Veterans Affairs Hospitals. JAMA Netw Open. Dec 1 2023;6(12):e2345898. doi:10.1001/jamanetworkopen.2023.45898 38039003
30 Weeda ER, Ward R, Gebregziabher M, Axon RN, Taber DJ. Medication Safety Events After Acute Myocardial Infarction Among Veterans Treated at VA Versus Non-VA Hospitals. Med Care. Oct 4 2023;doi:10.1097/mlr.0000000000001935
31 Intrator O, O’Hanlon CE, Makineni R, Scott WJ, Saliba D. Comparing Post-Acute Populations and Care in Veterans Affairs and Community Nursing Homes. J Am Med Dir Assoc. Dec 2021;22(12):2425–2431.e7. doi:10.1016/j.jamda.2021.10.007 34740562
32 Jia H, Pei Q, Sullivan CT, . Poststroke Rehabilitation and Restorative Care Utilization: A Comparison Between VA Community Living Centers and VA-contracted Community Nursing Homes. Med Care. Mar 2016;54(3):235–42. doi:10.1097/mlr.0000000000000494 26807537
33 Wang V, Coffman CJ, Stechuchak KM, . Survival among Veterans Obtaining Dialysis in VA and Non-VA Settings. J Am Soc Nephrol. Jan 2019;30(1):159–168. doi:10.1681/asn.2018050521 30530657
34 Wang V, Coffman CJ, Stechuchak KM, . Comparative Assessment of Utilization and Hospital Outcomes of Veterans Receiving VA and Non-VA Outpatient Dialysis. Health Serv Res. Dec 2018;53 Suppl 3(Suppl Suppl 3):5309–5330. doi:10.1111/1475-6773.13022 30094837
35 Kurella Tamura M, Thomas IC, Montez-Rath ME, . Dialysis Initiation and Mortality Among Older Veterans With Kidney Failure Treated in Medicare vs the Department of Veterans Affairs. JAMA Intern Med. May 1 2018;178(5):657–664. doi:10.1001/jamainternmed.2018.0411 29630695
36 Cashion W, Gellad WF, Sileanu FE, . Source of Post-Transplant Care and Mortality among Kidney Transplant Recipients Dually Enrolled in VA and Medicare. Clin J Am Soc Nephrol. Mar 8 2021;16(3):437–445. doi:10.2215/CJN.10020620 33602753
37 Blay E, Jr., DeLancey JO, Hewitt DB, Chung JW, Bilimoria KY. Initial Public Reporting of Quality at Veterans Affairs vs Non-Veterans Affairs Hospitals. JAMA Intern Med. Jun 1 2017;177(6):882–885. doi:10.1001/jamainternmed.2017.0605 28418527
38 Anhang Price R, Sloss EM, Cefalu M, Farmer CM, Hussey PS. Comparing Quality of Care in Veterans Affairs and Non-Veterans Affairs Settings. J Gen Intern Med. Oct 2018;33(10):1631–1638. doi:10.1007/s11606-018-4433-7 29696561
39 Eid MA, Lands H, Soybel D, Wong SL. Factors Contributing to Patient Satisfaction Among VA Medical Center and Non-VA Medical Center Hospitals. J Surg Res. Aug 2024;300:199–204. doi:10.1016/j.jss.2024.03.014 38823270
40 Bagshaw K, Gettel CJ, Qin L, . Inclusion of Veterans Health Administration hospitals in Centers for Medicare & Medicaid Services Overall Hospital Quality Star Ratings. J Hosp Med. Oct 21 2024;doi:10.1002/jhm.13523
41 LaBedz SL, Krishnan JA, Chung YC, . Chronic Obstructive Pulmonary Disease Outcomes at Veterans Affairs Versus Non-Veterans Affairs Hospitals. Chronic Obstr Pulm Dis. Jul 28 2021;8(3):306–313. doi:10.15326/jcopdf.2021.0201 33975417
42 Vercammen-Grandjean C, Schopfer DW, Zhang N, Whooley MA. Participation in Pulmonary Rehabilitation by Veterans Health Administration and Medicare Beneficiaries After Hospitalization for Chronic Obstructive Pulmonary Disease. J Cardiopulm Rehabil Prev. Nov 2018;38(6):406–410. doi:10.1097/hcr.0000000000000357 30252780
43 Watkins KE, Smith B, Akincigil A, . The Quality of Medication Treatment for Mental Disorders in the Department of Veterans Affairs and in Private-Sector Plans. Psychiatr Serv. Apr 1 2016;67(4):391–6. doi:10.1176/appi.ps.201400537 26567931
44 Ohl ME, Richardson Miell K, Beck BF, . Mortality Among US Veterans Admitted to Community vs Veterans Health Administration Hospitals for COVID-19. JAMA Netw Open. May 1 2023;6(5):e2315902. doi:10.1001/jamanetworkopen.2023.15902 37252740
45 Chan DC, Danesh K, Costantini S, Card D, Taylor L, Studdert DM. Mortality among US veterans after emergency visits to Veterans Affairs and other hospitals: retrospective cohort study. BMJ. Feb 16 2022;376:e068099. doi:10.1136/bmj-2021-068099 35173019
46 Gidwani-Marszowski R, Faricy-Anderson K, Asch SM, Illarmo S, Ananth L, Patel MI. Potentially avoidable hospitalizations after chemotherapy: Differences across medicare and the Veterans Health Administration. Cancer. Jul 15 2020;126(14):3297–3302. doi:10.1002/cncr.32896 32401340
47 Scheuner MT, Huynh AK, Chanfreau-Coffinier C, . Demographic Differences Among US Department of Veterans Affairs Patients Referred for Genetic Consultation to a Centralized VA Telehealth Program, VA Medical Centers, or the Community. JAMA Netw Open. Apr 1 2022;5(4):e226687. doi:10.1001/jamanetworkopen.2022.6687 35404460
48 Yoon J, Chow A, Jiang H, Wong E, Chang ET. Comparing Quality, Costs, and Outcomes of VA and Community Primary Care for Patients with Diabetes. J Gen Intern Med. Aug 5 2024;doi:10.1007/s11606-024-08968-4
49 Ramanathan S, Evans CT, Hershow RC, . Comparison of guideline concordant antibiotic prophylaxis in Veterans Affairs and non-Veterans Affairs dental settings among those with cardiac conditions or prosthetic joints. BMC Infect Dis. Jun 23 2023;23(1):427. doi:10.1186/s12879-023-08400-y 37353757
50 Axon RN, Ward R, Mohamed A, . Trends in Veteran hospitalizations and associated readmissions and emergency department visits during the MISSION Act era. Health Serv Res. Oct 2024;59(5):e14332. doi:10.1111/1475-6773.14332 38825849
51 Penn M, Bhatnagar S, Kuy S, . Comparison of Wait Times for New Patients Between the Private Sector and United States Department of Veterans Affairs Medical Centers. JAMA Netw Open. Jan 4 2019;2(1):e187096. doi:10.1001/jamanetworkopen.2018.7096 30657532
52 Gurewich D, Shwartz M, Beilstein-Wedel E, Davila H, Rosen AK. Did Access to Care Improve Since Passage of the Veterans Choice Act?: Differences Between Rural and Urban Veterans. Med Care. Jun 1 2021;59(Suppl 3):S270–S278. doi:10.1097/MLR.0000000000001490 33976076
53 Griffith KN, Ndugga NJ, Pizer SD. Appointment Wait Times for Specialty Care in Veterans Health Administration Facilities vs Community Medical Centers. JAMA Netw Open. Aug 3 2020;3(8):e2014313. doi:10.1001/jamanetworkopen.2020.14313 32845325
54 Feyman Y, Asfaw DA, Griffith KN. Geographic Variation in Appointment Wait Times for US Military Veterans. JAMA Netw Open. Aug 1 2022;5(8):e2228783. doi:10.1001/jamanetworkopen.2022.28783 36006640
55 Vanneman ME, Wagner TH, Shwartz M, . Veterans’ Experiences With Outpatient Care: Comparing The Veterans Affairs System With Community-Based Care. Health Aff (Millwood). Aug 2020;39(8):1368–1376. doi:10.1377/hlthaff.2019.01375 32744943
56 Davila H, Rosen AK, Beilstein-Wedel E, Shwartz M, Chatelain L, Jr., Gurewich D. Rural Veterans’ Experiences With Outpatient Care in the Veterans Health Administration Versus Community Care. Med Care. Jun 1 2021;59(Suppl 3):S286–S291. doi:10.1097/MLR.0000000000001552 33976078
57 Wachterman MW, Smith D, Carpenter JG, . A comparison of end-of-life care quality for Veterans receiving hospice in VA nursing homes and community nursing homes. J Am Geriatr Soc. Jan 2024;72(1):59–68. doi:10.1111/jgs.18606 37947240
58 Makarov DV, Ciprut S, Walter D, . Association Between Guideline-Discordant Prostate Cancer Imaging Rates and Health Care Service Among Veterans and Medicare Recipients. JAMA Netw Open. Aug 3 2018;1(4):e181172. doi:10.1001/jamanetworkopen.2018.1172 30646111
59 Gidwani R, Asch SM, Needleman J, . End-of-Life Cost Trajectories in Cancer Patients Treated by Medicare versus the Veterans Health Administration. J Am Geriatr Soc. Apr 2021;69(4):916–923. doi:10.1111/jgs.16941 33368171
60 Pickering AN, Zhao X, Sileanu FE, . Assessment of Care Cascades Following Low-Value Prostate-Specific Antigen Testing Among Veterans Dually Enrolled in the US Veterans Health Administration and Medicare Systems. JAMA Netw Open. Dec 1 2022;5(12):e2247180. doi:10.1001/jamanetworkopen.2022.47180 36520431
61 Gaffney A, Himmelstein DU, Dickman S, McCormick D, Woolhandler S. Uptake and Equity in Influenza Vaccination Among Veterans with VA Coverage, Veterans Without VA Coverage, and Non-Veterans in the USA, 2019-2020. J Gen Intern Med. Sep 26 2022:1–8. doi:10.1007/s11606-022-07797-7
62 Wadhwa A, Roscoe C, Duran EA, . Neighborhood Deprivation, Race and Ethnicity, and Prostate Cancer Outcomes Across California Health Care Systems. JAMA Netw Open. Mar 4 2024;7(3):e242852. doi:10.1001/jamanetworkopen.2024.2852 38502125
63 Harris AHS, Beilstein-Wedel EE, Rosen AK, . Comparing Complication Rates After Elective Total Knee Arthroplasty Delivered Or Purchased By The VA. Health Aff (Millwood). Aug 2021;40(8):1312–1320. doi:10.1377/hlthaff.2020.01679 34339235
64 Rosen A, Beilstein-Wedel EE, Harris AH, . Comparing Postoperative Readmission Rates between Veterans Receiving Total Knee Arthroplasty in the Veterans Health Administration (VA) versus Community Care. Medical Care. 2021.
65 Frisch NB, Courtney PM, Darrith B, Copeland LA, Gerlinger TL. Veterans Undergoing Total Hip and Knee Arthroplasty: 30-day Outcomes as Compared to the General Population. J Am Acad Orthop Surg. Nov 15 2020;28(22):923–929. doi:10.5435/jaaos-d-19-00775 32004175
66 Regenbogen SE ON, Dimick JB. Hospital Characteristics and Participation in the National Surgical Quality Improvement Program. Journal of Surgical Research. 2012;172(2)
67 Hutt E, Radcliff TA, Henderson W, Maciejewski M, Cowper-Ripley D, Whitfield E. Comparing Survival Following Hip Fracture Repair in VHA and Non-VHA Facilities. Geriatr Orthop Surg Rehabil. Mar 2015;6(1):22–7. doi:10.1177/2151458514561787 26246949
68 Buys MJ, Anderson Z, Bayless K, . Postsurgical opioid prescribing among veterans using community care for orthopedic surgery at non-VA hospitals compared to a VA hospital with a transitional pain service: a retrospective cohort study. Reg Anesth Pain Med. Apr 27 2024;doi:10.1136/rapm-2023-105162
69 Williams CD, Alpert N, Redding TSt, . Racial Differences in Treatment and Survival among Veterans and Non-Veterans with Stage I NSCLC: An Evaluation of Veterans Affairs and SEER-Medicare Populations. Cancer Epidemiol Biomarkers Prev. Jan 2020;29(1):112–118. doi:10.1158/1055-9965.Epi-19-0245 31624076
70 Kesseli SJ, Samoylova ML, Moris D, . Outcomes in Kidney Transplantation Between Veterans Affairs and Civilian Hospitals: Considerations in the Context of the MISSION Act. Ann Surg. Sep 1 2020;272(3):506–510. doi:10.1097/sla.0000000000004119 32773623
71 Mull HJ, Kabdiyeva A, Ndugga N, Gordon SH, Garrido MM, Pizer SD. What is the role of selection bias in quality comparisons between the Veterans Health Administration and community care? Example of elective hernia surgery. Health Serv Res. Dec 7 2022;doi:10.1111/1475-6773.14113
72 Simmonds A, Keller-Biehl L, Khader A, Timmerman W, Amendola M. Comparing Outcomes in Patients Undergoing Colectomy at Veteran Affairs Hospitals and Non-Veteran Affairs Hospitals: A Multiinstitutional Study. J Surg Res. Mar 2024;295:449–456. doi:10.1016/j.jss.2023.11.034 38070259
73 George EL, Massarweh NN, Youk A, . Comparing Veterans Affairs and Private Sector Perioperative Outcomes After Noncardiac Surgery. JAMA Surg. Dec 29 2021;doi:10.1001/jamasurg.2021.6488
74 George EL, Jacobs MA, Reitz KM, . Outcomes of Women Undergoing Noncardiac Surgery in Veterans Affairs Compared With Non-Veterans Affairs Care Settings. JAMA Surg. May 1 2024;159(5):501–509. doi:10.1001/jamasurg.2023.8081 38416481
75 Rosen AK, Vanneman ME, O’Brien WJ, . Comparing cataract surgery complication rates in veterans receiving VA and community care. Health Serv Res. Oct 2020;55(5):690–700. doi:10.1111/1475-6773.13320 32715468
76 Tripathi SH, Adams SM, Wong EM, . Comparison of Outcomes After Cochlear Implantation in a Veteran Versus Nonveteran Population. Otol Neurotol Open. Sep 2024;4(3):e058. doi:10.1097/ono.0000000000000058 39328868
77 Wu AM, Wu CM, Tseng VL, . Characteristics Associated With Receiving Cataract Surgery in the US Medicare and Veterans Health Administration Populations. JAMA Ophthalmol. Jul 1 2018;136(7):738–745. doi:10.1001/jamaophthalmol.2018.1361 29800973
78 Billig JI, Evans RR, Kerr EA, Hayward RA, Sears ED. The Impact of Community Care Referral on Time to Surgery for Veterans With Carpal Tunnel Syndrome. Med Care. Jun 1 2021;59(Suppl 3):S279–S285. doi:10.1097/MLR.0000000000001469 33976077
79 Pettey WBP, Wagner TH, Rosen AK, Beilstein-Wedel E, Shwartz M, Vanneman ME. Comparing Driving Miles for Department of Veterans Affairs-delivered Versus Department of Veterans Affairs-purchased Cataract Surgery. Med Care. Jun 1 2021;59(Suppl 3):S307–S313. doi:10.1097/MLR.0000000000001491 33976081
80 Eid MA, Barnes JA, Trooboff SW, Goodney PP, Wong SL. A Comparison of Surgical Quality and Patient Satisfaction Indicators Between VA Hospitals and Hospitals Near VA Hospitals. J Surg Res. Nov 2020;255:339–345. doi:10.1016/j.jss.2020.05.071 32599453
81 Wagner TH, Lo J, Beilstein-Wedel E, Vanneman ME, Shwartz M, Rosen AK. Estimating the Cost of Surgical Care Purchased in the Community by the Veterans Health Administration. MDM Policy Pract. Jul–Dec 2021;6(2):23814683211057902. doi:10.1177/23814683211057902 34820527
82 Heiden BT, Eaton DB, Jr., Chang SH, . Comparison between Veteran and Non-Veteran Populations with Clinical Stage I Non-Small Cell Lung Cancer Undergoing Surgery. Ann Surg. May 11 2021;doi:10.1097/sla.0000000000004928
83 Reddy A, Nelson KM, Wong ES. Primary Care Spending in the Veterans Health Administration in 2014 and 2018. JAMA Netw Open. Jul 1 2021;4(7):e2117533. doi:10.1001/jamanetworkopen.2021.17533 34279651
84 Straus E, Norman SB, Tripp JC, . Behavioral Epidemic of Loneliness in Older U.S. Military Veterans: Results From the 2019-2020 National Health and Resilience in Veterans Study. Am J Geriatr Psychiatry. Mar 2022;30(3):297–310. doi:10.1016/j.jagp.2021.07.006 34417085
85 Tsai J, Mitchell L, Nakashima J, Blue-Howells J. Unmet needs of homeless U.S. veterans by gender and race/ethnicity: Data from five annual surveys. Psychol Serv. Feb 2023;20(1):149–156. doi:10.1037/ser0000557 34780210