# ACKNOWLEDGMENTS

The authors are grateful to the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Tamara L. Box, PhD, FAMIA
  Executive Director, Office of Analytics and Performance Integration
  VHA

- Sachin Yende, MD, MS
  Chief Medical Officer, Office of Integrated Veterans Care (IVC)
  VHA

- Traci L. Solt, DNP, FACHE, NEA-BC, AMC-BC
  Acting Chief Nursing Officer/Senior Nursing Advisor IVC
  VHA

- Amy M. Kilbourne, PhD, MPH
  Acting Director, Investigators, Scientific Review and Management (ISRM)
  VHA

- Charles Wray, DO, MS
  Staff Physician, San Francisco VA Medical Center
  Core Investigator, Center for Data to Discovery and Delivery Innovation (3DI)

- Robert E. Burke, MD, MS, SFHM
  Staff Physician, Corporal Michael J. Crescenz VA Medical Center
  Core Investigator, Center for Health Evaluation, Research, and Promotion