# Executive Summary

KEY FINDINGS

► This biannual report updates an earlier review of evidence on the quality of VA care compared with non-VA care available through April 2025. One additional study published through April 2025 was included in this update, bringing the total number of relevant studies published since 2015 to 70 (24 of surgical care, 52 of non-surgical care, and 5 of both).
► In this update we also assess comparisons of the quality of hospital-based care for acute medical conditions (N = 13)
► Most available studies have found that the quality and safety of VA care is as good as, or better than, care in the community.
► Fewer studies have examined access to care, patient experience, and efficiency/cost of care. Findings from available studies are mixed but tend to favor VA care.
► These findings are consistent when looking at the subset of studies assessing hospital care for acute medical conditions.

The Department of Veterans Affairs (VA) Veterans Health Administration (VHA) is the nation’s largest integrated health care system. Comparing the quality of VA-delivered health care to care delivered in non-VA settings is one way of ensuring VA maintains its commitment to providing high-quality care to Veterans. To support this aim, the VA’s Evidence Synthesis Program (ESP) maintains a living systematic review of studies comparing the quality of VA and non-VA health care, which is frequently updated with the most recently available evidence.

## CURRENT REVIEW

To identify relevant studies, a research librarian conducted broad searches using terms relating to Veterans health and community health services or private sector in PubMed, APA PsycINFO, and Web of Science databases (1/1/2015–4/20/2025). Studies were included at either the abstract or the full-text level if they were original research studies of any design and made comparisons about the quality of care provided in VA Medical Centers and outpatient clinics compared with care provided in other health systems, ie, the general population. We included outcomes in any Institute of Medicine health care domain (clinical quality, safety, efficiency/cost, access, patient experience, or equity). Data were collected by 2 reviewers working independently, with any disagreements resolved by consensus.

From 3,053 titles, we identified 52 studies of non-surgical care meeting inclusion criteria. From 3,126 titles, we identified 24 studies of surgical care meeting inclusion criteria. Five studies contributed data to both. We identified 13 studies specifically regarding the care of acute medical conditions in the hospital setting (ie, about hospital medicine). Characteristics and findings of included studies are summarized in the figures below. In each plot, the domains of care are listed on the horizontal axis (quality/safety, access, patient experience, cost/efficiency, equity), the results of the study are listed on the vertical axis (VA care is better than community care, VA care and community care are about equal, or results are mixed, and community care is better than VA care), and then each study is entered as a shape, with larger shapes being studies of better quality and representativeness than studies depicted by smaller shapes. The color of the shape indicates the type of comparison: blue for studies comparing Veterans getting care from VA to Veterans getting VA-paid care in the community; orange for studies comparing Veterans getting care from VA and non-Veterans, or a general population, getting care in the community; and yellow for studies comparing Veterans getting care from VA to Veterans getting community care not paid by VA. Next to each shape is a brief thumbnail of what the study was about, and inside the shape is the year of publication (’18 = 2018, ’19 = 2019, etc).

ES Figure 1 Evidence Map of Studies on the Quality of Non-Surgical Care

This is a bubble plot of non-surgical care where each bubble represents an outcome reported in a study and they are classified into three categories: VA care is better than non-VA care for all or most outcomes; VA care and non-VA care are equal or there were mixed results; and non-VA care is better than VA care for all or most outcomes. The bubbles on this plot are all within the domain of quality and safety. There are 24 bubbles in the “VA care is better” category, 11 bubbles in the “equal or mixed results” category, and 5 bubbles in the “non-VA care is better” category.

This is a bubble plot of non-surgical care where each bubble represents an outcome reported in a study and they are classified into three categories: VA care is better than non-VA care for all or most outcomes; VA care and non-VA care are equal or there were mixed results; and non-VA care is better than VA care for all or most outcomes. The bubbles are further categorized using shapes into the outcome domains of access, patient experience, cost/efficiency, and equity. In the domain of access, there is 1 bubble in the “VA care is better” category, 3 bubbles in the “about equal or mixed results” category, and 4 bubbles in the “non-VA care is better” category. In the domain of patient experience, there are 5 bubbles in the “VA is better” category, 4 bubbles in the “about equal or mixed results” category, and no bubbles in the “non-VA care is better” category. In the domain of cost/efficiency, there are 4 bubbles in the “VA is better” category, 4 bubbles in the “about equal or mixed results” category, and 1 bubble in the “non-VA care is better” category. In the domain of equity, there are only two bubbles, 3 bubbles, all in the “VA care is better” category.

ES Figure 2 Evidence Map of Studies on the Quality of Surgical Care

This is a bubble plot of surgical care where each bubble represents an outcome reported in a study and they are classified into three categories: VA care is better than non-VA care for all or most outcomes; VA care and non-VA care are equal or there were mixed results; and non-VA care is better than VA care for all or most outcomes. The bubbles on this plot are about outcomes in all domains. There are 8 bubbles in the “VA care is better” category, 6 of which are in quality/safety and 2 of which are in access. There are 14 bubbles in the “equal or mixed results” category, 11 of which are in quality/safety, 2 of which are in access, and 1 of which is in patient experience. There are 9 bubbles in the “non-VA care is better” category, 2 of which are in quality/safety, 2 are in access, and 5 are in cost/efficiency.

ES Figure 3 Evidence Map of Hospital-Based Care for Acute Medical Conditions (Composite Outcomes Plotted as One Bubble or Not Plotted)

This is a bubble plot of hospital care for acute medical conditions where each bubble represents an outcome reported in a study and they are classified into three categories: VA care is better than non-VA care for all or most outcomes; VA care and non-VA care are equal or there were mixed results; and non-VA care is better than VA care for all or most outcomes. The bubbles on this plot are about outcomes in all domains. There are 18 bubbles in the “VA care is better” category, 17 of which are in quality/safety and 1 in patient experience. There are 5 bubbles in the in the “equal or mixed results” category, 3 of which are in quality/safety, and 1 each in patient experience and cost/efficiency. There are 5 bubbles in the “non-VA care is better” category, 3 of which are in quality/safety, and 1 each in access and cost/efficiency.

ES Figure 4 Evidence Map of Hospital-Based Care for Acute Medical Conditions (Composite Outcomes Disaggregated)

This is a bubble plot of hospital care for acute medical conditions where each bubble represents an outcome reported in a study and they are classified into three categories: VA care is better than non-VA care for all or most outcomes; VA care and non-VA care are equal or there were mixed results; and non-VA care is better than VA care for all or most outcomes. The bubbles on this plot are about outcomes in all domains. There are 18 bubbles in the “VA care is better” category, 17 of which are in quality/safety and 1 in patient experience. There are 13 bubbles in the in the “equal or mixed results” category, 9 of which are in quality/safety, 3 in patient experience and 1 in cost/efficiency. There are 7 bubbles in the “non-VA care is better” category, and 1 in cost/efficiency.

This is a bubble plot of hospital care for acute medical conditions where each bubble represents an outcome reported in a study and they are classified into three categories: VA care is better than non-VA care for all or most outcomes; VA care and non-VA care are equal or there were mixed results; and non-VA care is better than VA care for all or most outcomes. The bubbles on this plot are about outcomes in all domains. There are 18 bubbles in the “VA care is better” category, 17 of which are in quality/safety and 1 in patient experience. There are 13 bubbles in the in the “equal or mixed results” category, 9 of which are in quality/safety, 3 in patient experience and 1 in cost/efficiency. There are 7 bubbles in the “non-VA care is better” category, and 1 in cost/efficiency.

The majority of studies assessed quality and safety, followed by comparisons of access to care. Few studies assessed patient experience or cost/efficiency. We found 2 studies comparing VA to non-VA care on equity. Most studies found that the quality and safety of VA care is as good as, or better than, care in the community. This was the case for surgical care and non-surgical care, hospital care for acute medical conditions, and for community care of Veterans and community care of non-Veterans. For the domains of access and of cost/efficiency, findings were more mixed and about the same number of studies found that VA care is better, VA and community care are about the same, or that community care is better. The few studies of patient experience found that VA care and community care were about the same, or VA care was better. We did not identify any study the found that patient experience was better in community care. With only 1 exception in both the surgical and the non-surgical studies, VA-delivered care was as good as or better than Veterans received from VA-paid community care. We did not identify any studies comparing care for some conditions for which the MISSION act has resulted in increased community care, such as physical medicine and rehabilitation.

## NEW EVIDENCE SINCE OCTOBER 2024

This report updates an earlier review, which included evidence available through October 2024. Two additional studies published through April 2025 were included in this update.

Elliott and colleagues used data from national surveys of patient experience using HCAHPS, the Hospital Consumer Assessment of Health Care Providers and Systems.^1^ Data are presented over the time period 2017-2021, and focus on results for certain patient groups. In this review, the focus is primarily on data from 2021 and the overall population. Whereas in 2017 VA HCAHPS summary scores (from 127 VA hospitals) were significantly worse than the scores for non-VA hospitals (N = 4500 hospitals), in 2021 the VA HCAHPS summary score was significantly better for VA (N = 122 hospitals) than non-VA (N = 4,429 hospitals). This result was consistently seen regardless of patient subgroups by baseline health status and race. These findings are consistent with the overall conclusions from prior versions of this report. The addition of this new study resulted in the adding of a symbol to the evidence map indicating that VA care was better than the general population getting non-VA care for all or most outcomes in the domain of patient experience.

Chan and colleagues took advantage of differences in where different ambulance companies deliver patients to act as an instrumental variable and compare mortality outcomes among dually eligible Veterans (VA and Medicare) with similar key characteristics who are transported to either a VA or a non-VA hospital.^2^ The time period of the study was 2001-2014 and data come from more than 400,000 ambulance rides. Patient characteristics, information on medical conditions, and prior utilization came from VA records and Medicare claims data. Results show a substantial difference in mortality depending on site of care, with Veterans treated at VA hospitals having an absolute reduction of 4.5% (and a relative reduction of 46%) in 28-day mortality. This mortality benefit persists out to 180 days. Several possible mechanisms for this survival advantage are explored, with indirect evidence suggesting that health IT plays a role. Spending was also less at VA hospitals relative to non-VA hospitals. The addition of this new study resulted in the adding of symbols to the evidence map for quality/safety and for cost/efficiency indicating that VA care was better than Veterans getting community care not paid by VA.

These findings are consistent with the overall conclusions from prior versions of this report.

This update also includes a new section with additional analyses, focusing specifically on the care of acute medical conditions in the hospital (ie, hospital medicine, or patients usually cared for by hospitalists). This section begins on page 31.

## CONCLUSIONS

In general, most published studies of comparisons of quality of care show that Veterans getting care from VA get the same or better quality care than Veterans getting community care or the general public getting non-VA care. The most recently available evidence, published between November 2024 and April 2025, continues to support this conclusion. This conclusion is also supported by the evidence regarding care of acute medical conditions in the hospital.