# RESULTS

## LITERATURE FLOW DIAGRAM

The literature flow diagram summarizes the results of the study selection process. A full list of excluded studies is provided in the Supplementary Materials. As the surgical literature was considered separate from the non-surgical literature, we present 2 flow diagrams.

Figure 1A Literature Flow Diagram: Non-Surgical Care

Literature flow diagram summarizing results of study selection process.

Figure 1B Literature Flow Diagram: Surgical Care

Literature flow diagram summarizing results of study selection process.

## OVERVIEW OF INCLUDED STUDIES

The non-surgical literature search identified 3,133 potentially relevant citations after deduplication, 241 of which were included at the abstract screening level. From these, a total of 129 abstracts were excluded for the following reasons: ineligible comparison (N = 77), ineligible outcome (N = 33), ineligible setting (surgery) (N = 13), ineligible design (N = 3), and ineligible publication type (N = 3). With an additional 34 recommended by operational partners, this left 146 publications for full-text review, of which 94 publications were excluded for the following reasons: ineligible comparison (N = 62), ineligible outcome (N = 4), ineligible design (non-research or qualitative study) (N = 9), ineligible setting (surgery) (N = 8), ineligible publication type (N = 6), and unrepresentative sample or comparison (N = 5). A total of 52 publications were identified at full-text review as meeting initial inclusion criteria. Of these, 13 were identified as being about care in the hospital for acute medical conditions.

The surgical literature search identified 3,146 potentially relevant citations after deduplication, 178 of which were included at the abstract screening level. From these, a total of 126 abstracts were excluded for the following reasons: ineligible comparison (N = 34), ineligible setting (non-surgery) (N = 90), and ineligible publication type (N = 2). With an additional 38 recommended by operational partners, this left 90 publications for full-text review, of which 66 publications were excluded for the following reasons: ineligible comparison (N = 21), ineligible setting (non-surgery) (N = 25), ineligible publication type (N = 11), ineligible design (non-research) (N = 7), and unrepresentative sample or comparison (N = 2). A total of 24 publications were identified at full-text review as meeting initial inclusion criteria.

Characteristics of included studies are summarized in the Supplementary Materials.

## QUALITY OF NON-SURGICAL CARE

After dual review of identified publications, 52 publications met inclusion criteria (see Figure 1A). Key findings from each study were organized into 5 quality domains and are presented in the following order: (1) quality and safety, (2) access, (3) patient experience, (4) cost and efficiency, and (5) equity. Most studies reported outcomes in only 1 quality domain; studies that reported findings in multiple domains will appear in multiple sections below. Within domain, studies are organized by their clinical condition.

### Risk of Bias/Quality

Thirty-three of the included studies met all our risk of bias criteria and were considered to be “good” quality. These studies were given more weight in our narrative synthesis than studies that did not meet 1 or more criteria. Of the studies not meeting all our criteria, 2 of these studies analyzed pre-existing samples from clinical trials.^13,14^ Three studies had very unbalanced samples; either VA or non-VA groups were much smaller than the others.^15–17^ Three studies had balanced but small samples, and 1 of these only analyzed data from 1 site and did not adjust for patient characteristics in their models, while another study relied on patient self-report via survey for clinical outcomes.^18–20^ Heidenreich and colleagues only analyzed the Yelp ratings of 39 VA hospitals (out of a possible 131) and their university affiliates due to the lack of reviews of the remaining facilities.^21^ Mody et al only had data on VA and non-VA nursing homes from approximately half of all states.^22^ Another study only analyzed VA and non-VA facilities in the state of South Carolina.^23^ Shields and colleagues were not able to adjust for patient characteristics in their analysis of quality of inpatient psychiatric care, so different patient populations between VA and non-VA facilities may have biased their results.^24^ Presley and colleagues also did not adjust for patient characteristics in their analysis of aggressive end-of-life care for non-small cell lung cancer, and the composition of their multi-component outcome was unclear.^25^ We included all of these studies but gave them less weight when reaching our conclusions. Complete risk of bias ratings are provided in the Supplementary Materials.

Our overall results for nonsurgical care are presented in the bubble plot/evidence map in Figure 2. Studies are listed by domains of care of the outcomes they report by shape: circles for clinical quality/safety, diamonds for access, squares for patient experience, triangles for cost/efficiency, and octagons for equity. Studies are also listed on the vertical axis by their qualitative results (VA care is better than community care, VA care and community care are about equal or results are mixed, and community care is better than VA care), and then each study is entered as a shape, with larger shapes being studies of better quality and representativeness than studies depicted by smaller shapes. The color of the shape indicates the type of comparison: blue for studies comparing Veterans getting care from VA to Veterans getting VA-paid care in the community; orange for studies comparing Veterans getting care from VA and non-Veterans, or a general population, getting care in the community; and yellow for studies comparing Veterans getting care from VA to Veterans getting community care not paid by VA. Next to each shape is a brief thumbnail of what the study was about, and inside the shape is the year of publication (’18 = 2018, ’19 = 2019, etc).

Figure 2 Evidence Map of Studies on the Quality of Non-Surgical Care

This is a bubble plot of non-surgical care where each bubble represents an outcome reported in a study and they are classified into three categories: VA care is better than non-VA care for all or most outcomes; VA care and non-VA care are equal or there were mixed results; and non-VA care is better than VA care for all or most outcomes. The bubbles on this plot are all within the domain of quality and safety. There are 24 bubbles in the “VA care is better” category, 11 bubbles in the “equal or mixed results” category, and 5 bubbles in the “non-VA care is better” category.

This is a bubble plot of non-surgical care where each bubble represents an outcome reported in a study and they are classified into three categories: VA care is better than non-VA care for all or most outcomes; VA care and non-VA care are equal or there were mixed results; and non-VA care is better than VA care for all or most outcomes. The bubbles are further categorized using shapes into the outcome domains of access, patient experience, cost/efficiency, and equity. In the domain of access, there is 1 bubble in the “VA care is better” category, 3 bubbles in the “about equal or mixed results” category, and 4 bubbles in the “non-VA care is better” category. In the domain of patient experience, there are 5 bubbles in the “VA is better” category, 4 bubbles in the “about equal or mixed results” category, and no bubbles in the “non-VA care is better” category. In the domain of cost/efficiency, there are 4 bubbles in the “VA is better” category, 4 bubbles in the “about equal or mixed results” category, and 1 bubble in the “non-VA care is better” category. In the domain of equity, there are only two bubbles, 3 bubbles, all in the “VA care is better” category.

### Quality and Safety

#### Cardiovascular Disease Outcomes

We identified 7 studies that compared cardiovascular outcomes. The first study^26^ compared the quality of cardiovascular revascularization procedures between VA and VA-paid community care (CC) hospitals between 2008–2011. Adjusted 30-day mortality after percutaneous coronary intervention (PCI) was lower in VA (0.65%) compared to community care (1.54%, p < 0.001). There was no difference in 30-day adjusted readmission rates.

In the second study,^27^ the authors compared patient outcomes between 2010–2013 for admissions to VA hospitals versus non-VA hospitals for acute myocardial infarction (AMI), heart failure (HF), and pneumonia. In a national sample, 30-day risk-adjusted mortality was lower in VA for Veterans with AMI (13.5%) compared to patients in the community (13.7%, p < 0.02). This was also true for HF outcomes (11.4% vs 11.9%, p = 0.008). Mortality rates were higher in the VA for pneumonia (12.6% vs 12.2%, p = 0.045). VA had slightly higher readmission rates for all 3 conditions. When VA hospitals were compared to community hospitals in their same metropolitan statistical area, VA hospitals had again lower 30-day mortality rates for AMI and HF; mortality rates for pneumonia were not significantly different. Overall, the differences between the VA hospitals and non-VA hospitals were small.

In the third study,^28^ the authors examined a national cohort of Veterans with dementia to determine the effect of dual use of VA and Medicare on their supply of antihypertensive medication. When compared to dual users, VA-only users had lower adjusted odds ratios for undersupply, oversupply, and oversupply and undersupply for at least 1 class. When compared to VA-only patients, Medicare-only patients had a higher adjusted odds ratio for undersupply (1.13, 95% CI [1.03, 1.25]), but lower adjusted odds ratio for oversupply (0.39, 95% CI [0.32, 0.47]) or oversupply and undersupply of 1 class (0.48, 95% CI [0.40, 0.57]).

In the fourth study,^13^ the authors from the Insights from the Beta-blocker Evaluation of Survival Trial (BEST) evaluated outcomes of patients with heart failure and reduced ejection fraction receiving care at VA versus non-VA hospitals. The BEST trial took place from 1995–1999. The authors concluded that patients with heart failure and reduced ejection fraction receiving care in the VA were older and sicker, yet their risk of mortality and hospitalization was similar to the younger and healthier patients receiving care at non-VA hospitals.

In the fifth study,^23^ the authors examined the use of dual systems of care from 2007–2011 on rates of hospitalization and readmission in Veterans with HF. They found that dual use was associated with higher rates of emergency department (ED) visits, hospitalizations, and 30-day readmissions for patients with HF diagnosis at admission when compared to VA-only users and non-VA-only users. This persisted for patients with HF admitted for any diagnosis. When compared to VA-only users, non-VA-only patients had lower rates of ED visits (0.62, 95% CI [0.60, 0.64]), hospitalizations (0.98, 95% CI [0.95, 1.02]), and 30-day hospital readmissions (0.87, 95% CI [0.83, 0.90]). While this study was able to adjust for the presence or absence of more than a dozen comorbidities and service-connected status, it was not able to adjust for severity of heart failure.

In the sixth study, the authors used data from VA and from 11 states with all-payer discharge data about non-VA care to compare mortality following Veterans being hospitalized for acute myocardial infarction, CABG (discussed in Quality of Surgical Care, below), gastrointestinal hemorrhage, heart failure, pneumonia, and stroke at VA or non-VA hospitals.^29^ In models adjusted for numerous clinical factors, Veteran patients treated in VA hospitals had lower 30-day mortality for stroke and for heart failure, although the latter was only seen in patients 65 years of age and over. There were no statistically significant differences in mortality outcomes for patients discharged for the other conditions.

The last study compared “medication safety events” after acute myocardial infarction among Veterans treated at VA or non-VA hospitals.^30^ Medication safety events were defined as “omissions in outpatient medications with compelling indications for secondary prevention after myocardial infarction” and included drugs like statins and beta-blockers. Using merged VA and Medicare data, the authors identified 118,456 Veterans hospitalized for acute myocardial infarction between 2013–2018 who survived to discharge. About 14% of patients received care from VA hospitals. The adjusted odds of omissions in any drug class were 3 times higher among patients treated at non-VA hospitals as compared with patients treated at VA hospitals (example: beta-blocker omission in 47.4% of non-VHA hospital admissions, vs 23.7% of VHA hospital admissions).

#### Nursing Home Care Outcomes

We identified 3 studies that compared a national sample of quality and safety outcomes in VA Community Living Centers (CLC) versus nursing homes (NH) in the private sector from 2015–2016. In the first study,^31^ the authors compared risk-adjusted claims-based measures including unplanned rehospitalization and emergency department visits within 30 days of admission and successful discharge within 100 days of nursing home admission. Risk-adjusted emergency department visits and successful discharges were statistically significantly better in VA than the private sector (8.27 vs 11.85, p < 0.001, and 67.74 vs 57.04, p < 0.001). Adjusted rehospitalizations were slightly worse in the VA versus the private sector (22.5% vs 21.1%, p < 0.001). When aggregated, the authors noted that combined rehospitalization rates and emergency room visits were lower in the VA CLC group (30.8%) compared to the community (33.0%).

In the second study,^32^ the authors compared post-stroke rehabilitation therapy and restorative nursing among Veterans residing in VA CLCs versus those Veterans in VA-paid community NH from 2006–2009. In a national sample, Veterans at CLCs were significantly more likely to receive rehabilitation therapy and restorative nursing care. This study adjusted for sociodemographic characteristics, baseline depression, activities of daily living, cognition, and comorbidities. In the third study,^22^ the authors compared programs to prevent catheter-associated urinary tract infection (CAUTI) in VA versus non-VA NH. In a national representative sample of NH participating in an AHRQ-funded safety program, the VA reported more hours/week devoted to infection prevention-related activities (31 vs 12 hours, p < 0.001), and a higher percentage of tracking CAUTI rates (94% vs 66%, p = 0.014). In contrast, fewer VA NH reported having polices for appropriate catheter use (64% vs 81%, p = 0.04) and catheter insertion (83% vs 94%, p = 0.004).

#### Dialysis and End-Stage Renal Disease Outcomes

We identified 5 studies that compared mortality outcomes for Veterans receiving care for end-stage renal disease (ESRD) or for dialysis through the VA versus outside the VA. In the first study,^33^ the authors examined 2-year mortality among 27,241 Veterans who initiated chronic dialysis in 2008–2011 at the VA, at a dialysis center being paid by the VA, at a private sector clinic under Medicare, or in dual settings. Adjusted 2-year mortality was lowest (28.9%) in dual care and in the VA (32.4%) versus Medicare (36.7%) or VA-purchased care (36.0%). This study adjusted for sociodemographic characteristics, as well as pre-dialysis clinical status and care, type of vascular access, cause of ESRD, comorbidities, and prior utilization.

A similar cohort of 27,301 Veterans in the second study^34^ compared rates of utilization of dialysis in VA settings and VA-paid purchased care settings. The authors noted that sites of utilization were similar to the above study. Furthermore, they noted in their main outcome that risk of hospitalization was similar across all settings (p < 0.0001, but authors noted that the differences found were so small as to not be clinically meaningful).

The third study^35^ evaluated pre-ESRD care from 2008–2011 in Veterans receiving care in the VA or through Medicare. Two-year mortality was lower for Veterans who received pre-ESRD care in the VA (44%) than in those who received their care using Medicare (53%). Likewise, patients who received pre-ESRD nephrology care with the VA (53%) were less likely to transition to dialysis than if they had their care under Medicare (82%).

Furthermore, we found 1 study^15^ that studied rates of kidney transplantation among Veterans with VA as the primary insurance versus patients with Medicare or other private insurance. Although the VA was the payor in only 1.2% of the 302,457 patients analyzed who underwent kidney transplant, the authors noted that the VA had a lower hazard ratio for transplant (lower rate of transplant) when compared to privately insured (0.72, 95% CI [0.68, 0.76]) or Medicare-insured patients (0.85, 95% CI [0.81, 0.90]). There was no difference found between VA and Medicaid patients.

In a related study,^36^ authors examined mortality among Veterans who received VA-paid and Medicare-paid post-kidney transplant care. After 5 years, mortality was 11% among the 792 Veterans who received post-transplant care in VA, but 20% among the 2,092 Veterans who received care paid by Medicare. After adjusting for covariates, the hazard ratio of 5-year mortality was over twice as high among Veterans receiving post-transplant care paid by Medicare compared to those receiving care in VA (2.2, 95% CI [1.5, 3.1]).

#### Hospital Patient Safety Indicators and Outpatient Quality of Care

We identified 4 studies that compared a number of quality indicators between Veterans getting VA care and non-Veterans getting non-VA care.^37–40^ All 4 studies assessed national samples for both VA and non-VA care, including more than 100 VA facilities and hundreds or thousands of non-VA facilities. Three of the studies compared hospital patient safety indicators, such as 30-day risk-standardized mortality rate for 2 conditions, iatrogenic pneumothorax and post-operative wound dehiscence. One study also assessed outpatient quality using measures from the Healthcare Effectiveness Data and Information Set, such as process and intermediate outcome measures for patients with diabetes, screening and prevention, and control of blood pressure and lipids.^38^ One study compared Centers for Medicare & Medicaid Star Ratings for VA and non-VA hospitals.^40^ All 4 studies were in general agreement: quality of care in VA was better than non-VA care for most measures. In 1 study, however, VA had higher 30-day risk-standardized readmission rates than non-VA care,^38^ and in another study patients treated in VA hospitals were more likely to have readmissions than patients treated in non-VA hospitals.^40^

#### Chronic Obstructive Pulmonary Disease (COPD) Outcomes

We identified 2 studies that compared outcomes for patients with COPD using a national sample of VA hospitals versus non-VA hospitals. In 1 study^41^ that evaluated readmission rates and mortality post hospitalization after a COPD exacerbation from 2015 to 2018, 30-day readmissions rates were significantly lower in VA (15.3 days) versus non-VA hospitals (19.5 days, p < 0.001). Thirty-day mortality rates were also significantly lower in VA (6%) versus non-VA hospitals (8.5%, p < 0.02). These differences persisted no matter the type of non-VA hospital, including teaching hospitals, non-teaching hospitals, and safety net hospitals. The study itself was not limited to Veteran patients, as it compared Veteran patients in VA to CMS-derived risk adjustment models in non-VA hospitals.

In the second study,^42^ the authors compared the rates of participation in pulmonary rehabilitation by Veterans and Medicare beneficiaries after they were hospitalized for COPD. Pulmonary rehabilitation can improve symptom burden and morbidity associated with COPD. In the study, utilization by Medicare beneficiaries was low, approximately 2% of discharges. In the VA it was slightly lower, at 1.5% of hospital discharges.

#### Mental Health Conditions

We identified 3 studies that assessed quality and safety outcomes for persons with mental health conditions^24,43^. Both studies compared Veterans getting care within VA to non-Veterans getting care in non-VA settings. Both were national studies. One study^43^ assessed the quality of medication treatment, which was probably mostly outpatient care, using 7 measures such as “proportion of schizophrenia patients who filled prescriptions for a 12-week supply of an antipsychotic medication in the 12 weeks following the start of a new treatment episode.” This study stratified patients by their mental health condition, namely bipolar disorder, major depressive disorder, posttraumatic stress disorder, schizophrenia, and substance use disorder. This study found much better quality in VA-treated patients than in non-VA-treated patients. The second study assessed only inpatient psychiatric care, using 7 of the Joint Commission’s Hospital-based Inpatient Psychiatric Services measures, which are used both for accreditation and in a pay-for-reporting initiative.^24^ Included measures were “admission screening for violence risk, substance use, psychological trauma and patient strengths completed” and “hours of physical restraint used,” etc. This study found worse quality in VA hospitals as compared to non-VA hospitals. This study was not able to stratify or adjust for potential differences in case mix between different hospitals; for example, the potential use of physical restraints might differ between patients admitted for major depressive disorder as compared to patients admitted for schizophrenia. The last study found lower depression symptoms and equivalent posttraumatic stress disorder symptoms among Veterans receiving in-person, VA-paid community care compared to those who received VA tele-mental health care.^18^

#### Cancer Outcomes

Two studies^19,25^ of cancer care also met our inclusion criteria. In the first study^19^ of colorectal cancer care, the adenoma detection rate (OR = 0.39, 95% CI [0.25, 0.63]) and compliance with surveillance guidelines (OR = 0.21, 95% CI [0.09, 0.45]) was worse in non-VA compared to VA. In the second study^25^ of non-small cell lung cancer, aggressive care at end of life in some measures declined more significantly in VA (p < 0.001) compared to non-VA from 2006 to 2012. For other measures, there was no difference between systems.

#### COVID-19 Outcomes

One study assessed mortality among Veterans admitted to community hospitals and Veterans admitted to VA hospitals during the COVID-19 pandemic.^44^ VHA and Medicare data were merged for the period 3/2020–12/31/2021, and included 64,856 Veterans (nearly entirely men) who had 127,156 hospitalizations. VHA enrollees admitted to community hospitals were more likely to be older, White, and less likely to live in urban areas than VHA enrollees admitted to VA hospitals, and to have somewhat more comorbidities such as heart failure, stroke, and kidney disease. In both unadjusted and adjusted analyses, Veterans admitted to community hospitals had higher mortality: 27.1% versus 17.7% in the unadjusted analysis, and risk-adjusted odds ratio of 1.37 (95% CI [1.21, 1.55]). Readmission within 30 days was lower in community hospitals (12.6% vs 14.0%).

#### Miscellaneous Conditions

We identified 10 studies that reported quality and safety outcomes in miscellaneous conditions. Six studies compared care of Veterans getting VA care with Veterans getting non-VA community care not paid for by VA,^2,20,45–48^ and 3 studies compared Veterans getting VA care with non-Veterans getting non-VA care.^14,16,49^ One study compared Veterans getting VA care both to non-Veterans getting non-VA care and to Veterans getting VA-paid care in the community.^50^ Six of the studies were national in scope, whereas 3 studies were narrower, in 1 case comparing Veterans and non-Veterans with diabetes who enrolled in a large comparative effectiveness trial, providing answers to a survey about clinical outcome after receiving acupuncture or chiropractic care, and in the other comparing a large number of VA cases with a very much smaller number of Medicare cases.

In the first study, more than 500,000 Veterans making more than 1 million ED visits between 2001 and 2018 and being transported by ambulance were classified as to whether they got ED care at a VA facility (N = 231,611) or a non-VA facility (N = 1,238,546).^45^ After adjusting for a number of patient, clinical, and ED transport characteristics, the 30-day mortality rate was less for patients seen in VA hospitals than for patients seen at non-VA hospitals (9.15 vs 11.67 deaths per 100 patients). For patients who had received prior care at the index hospital, the mortality advantage for ED care at a VA hospital was even greater.

In the second study,^2^ done by the same first author as the study just above (David Chan), the authors again took advantage of differences in where different ambulance companies deliver patients to act as an instrumental variable and compare mortality outcomes among dually eligible Veterans (VA and Medicare) with similar key characteristics who were transported to either a VA or a non-VA hospital. The time period of the study was 2001–2014 and data come from more than 400,000 ambulance rides. Patient characteristics, information on medical conditions, and prior utilization came from VA records and Medicare claims data. Results show a substantial difference in mortality depending on site of care, with Veterans treated at VA hospitals having an absolute reduction of 4.5% (and a relative reduction of 46%) in 28-day mortality. This mortality benefit persists out to 180 days. Several possible mechanisms for this survival advantage are explored, with indirect evidence suggesting that health information technology plays a role. Spending was also less at VA hospitals relative to non-VA hospitals.

In the third study, investigators used Centers for Medicare & Medicaid Services measures for avoidable hospitalizations following chemotherapy to assess the care of 27,443 Veterans dually enrolled in Medicare and VA, of whom 9,522 received their chemotherapy in VA.^46^ Veterans receiving care through Medicare were more likely than Veterans receiving chemotherapy through VA to have an avoidable hospitalization, with an odds ratio of 1.58 (95% CI [1.41, 1.78]). The most common reasons for hospitalization were pneumonia, sepsis, and anemia.

In the fourth study, Veterans completed genetic consultations they were referred for less often in VA-paid community care (OR = 0.43, 95% CI [0.28, 0.65]), compared to VA care ).^47^ Patients who had VA-paid community care genetic consultations were also less likely to receive follow-up cancer surveillance and risk-reducing procedures (OR = 0.64, 95% CI [0.52, 0.78]) than patients in VA care.

The fifth study compared the use of guideline-concordant antibiotic prophylaxis prior to dental procedures in patients with prosthetic joints or cardiac conditions being treated at VA or non-VA dental settings.^49^ VA administrative data were used for the VA sample (N = 18,292) and Marketscan data were used for the non-VA sample (N = 42,832). Guideline-concordant antibiotic prophylaxis was low across all groups, being 32.7% of visits, with slightly higher use of guideline-concordant care in VA-treated patients as compared to non-VA treated patients (adjusted prevalence ratio of 1.21, 95% CI [1.16, 1.25]). The results varied by the reason for antibiotic prophylaxis, with lower rates in VA care for patients without a prosthetic joint and higher rates in VA care for patients with a prosthetic joint, compared to non-VHA care.

The sixth study used data from the Corporate Data Warehouse (CDW) and from CMS to identify more than 1.7 million Veterans with at least 1 hospitalization and at least 2 VA primary care visits between 2016–2021.^50^ After controlling for numerous covariates, regression models showed that during this time period, which includes when the MISSION Act went into effect, VA-paid community care hospitalizations increased while hospitalizations at VA facilities and non-VA facilities decreased. Hospitalization at a community care facility was associated with a 47% greater risk of 7-day readmission and a 20% increased risk of 30-day readmission compared to hospitalization at a VA facility, while by the end of the time period 30-day ED visits were less in community care (5.5% lower).

The seventh study compared quality, costs, and outcomes of Veterans with diabetes receiving care at VA or at VA-paid community care clinics.^48^ Data came from the CDW and patients were required to have had at least 2 primary care visits in a 12-month period during fiscal years 2021–2022. The investigators identified 652,648 patients in VA care and 3,650 patients in community care. Patients receiving VA care were more likely to have received diabetes-related tests such as hemoglobin A1c, a urine microalbumin test, and an eye exam than were patients receiving community care. There were no differences between patients in ambulatory care sensitive hospital admissions, but there was a slight statistically significant increase in the odds of any acute care hospitalization for Veterans receiving community care.

The last 3 studies looked at, respectively, measures of control of diabetes among enrollees in a large national comparative effectiveness study,^14^ the self-report of clinical outcomes by several hundred patients who received VA-delivered or community care-delivered acupuncture or chiropractic care,^20^ and linked data from VA, the Health and Retirement Survey, and Medicare to assess possibly inappropriate neuroimaging studies in patients presenting with headache or neuropathy.^16^ The first and last studies reported better care quality in VA care than in non-VA care. The middle study reported no differences in outcomes.

### Access

Eleven studies reported outcomes related to access. Five of these studies described wait times, 4 listed different patient-reported access outcomes, 1 reported median distance to a transplant center, and 1 noted self-reported delays in care. Seven of these studies were of good quality that met all 4 risk of bias criteria, while 3 were of fair quality and did not meet 1 or more criteria to a minor degree.

#### Wait Times

Five studies evaluated wait times in various primary and specialty care settings. Wait times were shorter in VA care in the 4 good quality studies and longer in VA care in the sole fair quality study.^19^

The first study evaluated differences in wait times to the next appointment for outpatient primary care, dermatology, cardiology, and orthopedics visits at VA medical centers and in the private sector in 15 major metropolitan areas from 2014–2017.^51^ VA data were pulled from VA medical center scheduling systems, and private sector data were obtained via the secret shopper method. Consultant Merritt Hawkins had their research associates call 10–20 randomly selected physician offices in each metropolitan area in each of the above specialties and schedule new appointments. VA wait times decreased from a mean of 22.5 days (SD 7.3 days) in 2014 to 17.6 days (SD 4.9 days; p = 0.046) in 2017. Private sector wait times did not significantly change over the same time period. By specialty, wait times did not change in VA or the private sector for primary care, dermatology, or cardiology. In orthopedics, VA wait times declined from 23.9 to 18.5 days (p = 0.05). Private sector orthopedic wait times did not change.

In the second study, the authors and colleagues examined differences in wait times in rural and urban Veterans for outpatient physical therapy, cardiology, optometry, orthopedics, and dental care between VA and VA-paid CC between fiscal year (FY) 2015 and 2018.^52^ Using data from the VA Corporate Data Warehouse, these authors found that both rural and urban Veterans saw declines in wait times for VA and VA-paid CC care across all 5 services during this time period, with some small exceptions. Wait times did not change for urban Veterans seeking VA-paid CC physical therapy, rural and urban Veterans seeking VA-paid CC cardiology care, and rural and urban Veterans seeking VA-paid CC dental care. VA wait times declined more significantly for all services (p < 0.001) other than cardiology. In FY18, VA-paid CC wait times were 2–3 days longer than VA wait times, for all services except for orthopedics, where they were 4–5 days longer.

In the third study, authors used VA administrative data to examine differences in VA and Veterans Choice Program (VCP; a version of VA-paid community care) wait times in outpatient cardiology, gastroenterology, orthopedics, and urology between 2018 and 2019.^53^ Average VA wait times were lower than VA-paid VCP wait times for cardiology (33.0 [SD 8.7] days vs 38.0 [SD 9.2] days), gastroenterology (53.9 [SD 15.9] vs 60.3 ([SD 16.0] days), orthopedics (36.2 [SD 9.3] vs 43.6 [SD 12.9] days), urology (36.1 [SD 9.5] vs 50.5 [SD 14.5] days), and overall (41.1 [SD 15.9] vs 49.0 [SD 15.5] days).

In the fourth study,^54^ the authors examined VA Corporate Data Warehouse data to analyze differences in VA and VA-paid community care wait times in primary, mental health, and all other specialty care. They found that mean wait times were lower for VA versus VA-paid community care in unadjusted analyses for primary care (29 [SD 5.5] days vs 38.9 [SD 8.2] days), mental health care (33.6 [SD 4.6] days vs 43.9 [SD 9.0] days), and all other specialty care (35.4 [SD 2.7] days vs 41.9 [SD 5.9] days). In Veterans Integrated Service Network (VISN)-level adjusted analyses, VA wait times were shorter in 15 of 18 VISNs for primary care, in 16 of 18 VISNs for mental health care, and in 17 of 18 VISNs for all other specialty care.

In the last study,^19^ time to colonoscopy was significantly longer in VA (83.8 days, 95% CI [45.2, 122.4]) compared to VA-paid community care (58.4 days, 95% CI [24.7, 92.1]; p < 0.0001).

#### Patient-Reported Access Outcomes

Patient-reported access to care was mixed in 4 studies. Three studies were of good quality, and 1 was of fair quality.^18^

Vanneman and co-authors used VA’s 2016-17 Survey of Healthcare Experience of Patients (SHEP) to analyze differences in patient-reported access outcomes between VA and VA-paid CC patients receiving outpatient primary, specialty, and mental health care.^55^ In the second quarter of 2016, patients rated access to care as better in VA-paid CC, as evaluated by multivariate models adjusting for patient and facility characteristics. These evaluations of access in that quarter did not differ between VA and VA-paid CC for primary or mental health care. Access scores for specialty care increased by about 2% for both VA and VA-paid CC by the end of the study period in the fourth quarter of 2017. Scores for primary and mental health care did not change.

In another analysis of SHEP data, Davila and colleagues analyzed differences in patient-reported access among urban and rural Veterans receiving VA and VA-paid CC primary and specialty care from FY16–FY19.^56^ Compared with VA-paid CC primary care, rural Veterans reported greater satisfaction with access to VA primary care in FY16 (adjusted standardized mean difference [aSMD] = 0.17) and FY19 (aSMD = 0.21). Rural Veterans reported similar satisfaction with access to VA and VA-paid-CC specialty care. The study did not provide adjusted effect sizes for urban Veteran comparisons, but average access satisfaction scores were higher in both years for urban VA primary care compared with VA-paid CC primary care (FY16: 3.18 vs 2.91; FY19: 3.27 vs 3.12). Average scores were lower in both years for access to urban VA compared with VA-paid CC specialty care (FY16: 3.09 vs 3.17; FY19: 3.17 vs 3.28). Despite these differences, all average scores correspond to satisfaction scale ratings of “usually” to “always.” In a study previously included in quality, above, Bagshaw and colleagues compared CMS Star Rating scores for VA and non-VA hospitals.^40^ In the domain of timely and effective care, VA hospitals scored worse (mean standardized group score of −0.44 compared with 0.01) than non-VA hospitals.

In the last analysis, VA patients reported more access-related barriers to mental health care compared to patients receiving VA-paid community care (p < 0.001).^18^

#### Other Access Outcomes

A good quality study using VA health care record and cost data, VA-paid CC claims, and mapping software analyzed Veteran patient travel distance to and cost of percutaneous coronary intervention (PCI) and coronary artery bypass graft (CABG).^26^ Authors found that VA patients traveled farther than VA-paid CC patients for both PCI (90.8 miles vs 60.1 miles; p < 0.001) and CABG (123.2 miles vs 81.5 miles; p = 0.02). Patients also incurred higher travel costs in VA versus VA-paid CC for both PCI ($238 vs $198; p = 0.004) and CABG ($958 vs $630; p < 0.001).

In 2 final fair quality studies, VA patients lived farther away from kidney transplant centers than patients using Medicare or private insurance,^15^ and were more likely to report delays in seeking care than patients using Medicare, Medicaid, or commercial insurance.^17^

### Patient Experience

Ten studies reported patient experience outcomes. Two studies described ratings of providers, 3 studies reported various patient experience measures, 1 compared VA’s SHEP ratings with similar patient experience ratings from non-VA hospitals, 1 compared CMS Star Ratings for patient experience, 2 studies used SAIL and/or HCAPHPS scores, and another reported Yelp ratings of hospitals. VA care was better in 4 studies and equal or mixed compared to non-VA care in 4 studies. Four of these studies were good quality and 3 were fair quality.

#### Provider Ratings

The Vanneman study described above also used 2016-17 SHEP data to report differences in provider ratings between patients receiving VA and VA-paid CC.^55^ Provider ratings were higher in VA in the second quarter of 2016 for primary, specialty, and mental health care. VA and VA-paid CC ratings did not significantly change by the fourth quarter of 2017.

In the previously described Davila study, authors examined SHEP data to distinguish differences in provider ratings between rural Veterans receiving primary and specialty VA and VA-paid CC care during FY16 and FY19.^56^ Ratings for providers were higher for rural Veterans receiving primary and specialty care in VA compared to VA-paid CC in FY16 and FY19. Rural Veterans reported higher provider ratings for primary care (FY16 aSMD = 0.35; FY19 aSMD = 0.19) and specialty care (FY16 aSMD = 0.16; FY19 aSMD = 0.12) in VA compared to CC. Authors also provided data on provider ratings for urban Veterans but did not report adjusted effect sizes for VA and VA-paid CC comparisons. Average provider ratings (0-10, with 10 being the best) were higher for urban Veterans receiving VA care compared to those receiving VA-paid CC care for both primary (FY16: 8.83 vs 7.28; FY19: 8.92 vs 8.30) and specialty (FY16: 8.69 vs 8.46; FY19: 8.88 vs 8.70) care.

In a study based on responses by family members to the VA Bereaved Family Survey, Wachterman and colleagues compared data on Veterans receiving end-of-life (EOL) care in VA CLCs or in VA-contracted community nursing homes (CNH).^57^ On all 15 items in the survey, family members of Veterans receiving EOL care in CLCs rated the care as superior to families of Veterans treated in CNHs (such as “staff always took time to listen,” “staff were always kind, caring and respectful,” staff always provided enough emotional support,” etc). The findings, however, are limited by the low response rates (overall = 35%) to the survey.

#### SHEP or HCAHPS Outcomes

In a third study, authors analyzed 2014 VA SHEP and private sector Hospital Consumer Assessment of Healthcare Providers and Systems Hospital Survey (HCAHPS) data to examine differences in patient experience between VA and non-VA inpatient care.^38^ Each VA hospital was matched to 3 private sector non-VA hospitals using propensity score matching by bed size, geography, teaching hospital status, and urbanicity. Non-VA hospitals had higher ratings overall for hospital quietness, pain management, responsiveness of hospital staff, and communication with doctors or nurses. VA hospitals had higher ratings for communication about medicine, hospital cleanliness, and care transitions. Scores were very close for discharge information.’

In a fourth study, the authors used data from national surveys of patient experience using HCAHPS, the Hospital Consumer Assessment of Health Care Providers and Systems.^1^ Data are presented over the time period 2017-2021 and focus on results for certain patient groups. Here we focus primarily on data from 2021 and the overall population. Whereas in 2017, VA HCAHPS summary scores (from 127 VA hospitals) were significantly worse than the scores for non-VA hospitals (N = 4500 hospitals), in 2021 the VA HCAHPS summary score was significantly better for VA (N = 122 hospitals) than non-VA (N = 4,429 hospitals). This result was consistently seen regardless of patient subgroups by baseline health status and race.

#### Patient Experience Outcomes

The fifth study,^37^ previously described in the Quality and Safety section above, assessed national samples from VA and non-VA hospitals for patient-reported patient experience outcomes. About half of the 10 domains of patient experience had small but statistically significant better ratings for non-VA care, whereas there was no statistical difference in ratings for the other half of the domains.

In the sixth study, patient centeredness was not different (p = 0.243) between VA tele-mental health care and VA-paid, in-person mental health care in the community.^18^

#### Hospital Ratings

In a seventh study, authors analyzed differences in Yelp ratings between VA hospitals and their local university affiliates.^21^ After adjusting for bed size, teaching hospital and graduate medical education status, and The Joint Commission certification, VA and non-VA Yelp ratings did not differ.

A previously discussed study compared Medicare Star Ratings between VA and non-VA hospitals. VA hospitals tended to score better than non-VA hospitals in the domain of patient experience (mean standardized group score 0.64 vs −0.02).^40^

Lastly, one study used patient experience data from SAIL and from HCAHPS to compare a nationwide sample of 133 VA hospitals and 1,116 non-VA hospitals.^39^ In the overall hospital ratings, VA had a very slight but statistically significant better score (88.3 vs 87.7, p = 0.04).

### Cost/Efficiency

We identified 7 studies reporting on efficiency or cost outcomes: 1 study was about patients with cardiac disease,^26^ 1 study was about imaging in patients with prostate cancer,^58^ 1 study was about end-of-life care,^59^ 1 study was about hospitalization after dialysis,^34^ 1 study was about low-value PSA testing,^60^ 1 study was about hospitalizations for 6 common conditions,^29^ and 1 study was about tele-mental health care.^18^ Six studies were good quality studies, and the seventh was fair quality.^18^

#### Cardiac Disease

One study assessed many outcomes among nearly 20,000 Veterans less than age 65 who had elective coronary revascularization, either bypass surgery (N = 5,818) or a percutaneous coronary intervention (N = 13,273) at either a VA hospital or a community hospital with care paid for by VA.^26^ About 80% of patients received care at VA. Quality and access outcomes from this study are already reported in the appropriate sections of this report. Costs for VA care came from the VA Managerial Cost Accounting System, while costs for community care are what VA paid for the care. Costs were lower in VA than what VA paid for community care for patients receiving percutaneous coronary interventions ($15,683 vs $22,025) but higher in VA than what VA paid for community care for patients receiving bypass surgery ($63,144 vs $55,526).

#### Prostate Cancer Imaging

One study assessed agreement between guideline-suggested imaging in patients with prostate cancer among nearly 100,000 Veterans with prostate cancer.^58^ Patients were classified as receiving VA-only care (28% of the total), Medicare-only care (57%), or as dual users (14%). The comparison made was the rate of prostate cancer imaging in low-risk and high-risk patients, by the system of care. Comparing just the Medicare-only to the VA-only patients, low-risk prostate cancer patients in VA were less likely to receive guideline-discordant imaging (relative risk = 0.79, 95% CI [0.67, 0.92]), whereas VA patients with high-risk prostate cancer were no less likely to have imaging in VA compared to Medicare-only patients.

#### End-of-Life Care

One study assessed costs of care for 36,401 patients dying of cancer between 2010 and 2014 who were dually enrolled in Medicare and VA.^59^ In adjusted models, total costs of care were similar between patients who were Medicare reliant and those who were VA reliant.

#### Dialysis

In the fourth study, days of hospitalization after dialysis were similar in VA and non-VA settings.^34^

#### PSA Testing

In the fifth study, low-value PSA testing was associated with 9.9 fewer downstream services per 100 Veterans (95% CI [9.7, 10.1]) and $11.9 less spending per Veteran (95% CI [$7.6, $16.2]) in VA compared to non-VA care.^60^

#### Common Hospital Conditions

Yoon and colleagues^29^ (described above in clinical quality) used VA data and data from 11 states with all-payer hospital discharge data for non-VA care to compare costs and length of stay for Veteran patients discharged with 5 common conditions: acute myocardial infarction, gastrointestinal hemorrhage, heart failure, pneumonia, and stroke (as well as CABG, discussed under Quality of Surgical Care). Length of stay and costs were consistently higher for patients treated in VA as compared to non-VA hospitals.

#### Equity

We identified 2 studies assessing the equity of VA-delivered care compared to non-VA-delivered care.^61,62^ The study used the 2019-2020 National Health Interview Survey to assess the self-report of having received the influenza vaccine in the prior 12 months. Among 2,277 Veterans with VA coverage and 46,456 non-Veteran adults, statistically significant differences in the self-reported receipt of vaccine between the racial groups classified as White, Black, and Hispanic were seen for non-VA care but were small and statistically non-significant in VA-delivered care. The gap between Hispanic and White vaccination rates was statistically larger among non-Veterans compared to Veterans receiving VA care. Middle-income patients were less likely than high-income patients to be vaccinated among non-Veterans and Veterans in non-VA care. Low-income patients were less likely to be vaccinated across all categories. The gap in vaccination rates between low- and middle-income and high-income non-Veterans was larger than among Veterans in VA care.

A second study, which did not directly measure care but did assess long-term outcomes, used VA and California cancer registry data to assess 10-year survival, rate of metastatic disease, and prostate-cancer-specific mortality in patients who received care at the Greater Los Angeles VA Healthcare System or in non-VA community care in California.^62^ Outcomes in the community care cohort were worse for Black patients on all 3 dimensions, whereas within VA there were no statistically significant disparities in outcomes between Black and other racial/ethnic groups. The authors speculate that the differences in disparities between the 2 systems of care may be more than just clinical quality, and could possibly also reflect better access and short-term interventions aimed at social determinants of health.

#### Tele-Mental Health Care

In the last study, the numbers of encounters did not significantly differ (p = 0.276) between patients receiving VA tele-mental health care or VA-paid, in-person mental health care in the community.^18^

## QUALITY OF SURGICAL CARE

After dual review of identified publications, 24 met inclusion criteria (see Figure 1B), using national data with heterogenous designs and statistical methods to adjust for group differences with varying rigor (see Supplementary Materials). The majority of studies analyzed surgery- or patient-level outcomes on specific conditions or operations (22 of 24), while 2 studies reported hospital-level outcomes. The evidence reported orthopedic procedures (7 articles), cataract surgery (3 articles), pulmonary resections (2 articles), kidney transplant (2 articles), and CABG (2 articles). In addition, 2 studies analyzed all non-cardiac surgeries, 1 study assessed hernia repair, 1 study assessed colectomy, and another study evaluated access in urologic and orthopedic outpatient clinics.

Key findings from each study were organized into 4 quality domains and are presented in the following order: (1) quality and safety, (2) access, (3) patient experience, and (4) cost and efficiency. Most studies (13 of 19) reported outcomes in only 1 quality domain, while 4 studies covered 2 domains and 1 study reported 3 domains. The 5 studies that reported findings in multiple domains will appear in multiple sections below.

### Risk of Bias/Quality

Among the 24 included studies meeting all our risk of bias criteria, 4 were deemed fair quality studies, marginally meeting the criteria. Complete risk of bias ratings are provided in the Supplementary Materials.

Our overall results for surgical care are presented in the bubble plot/evidence map in Figure 3. The plot is organized in the same fashion as the non-surgical plot as follows: the domains of care are listed on the horizontal axis (quality/safety, access, patient experience, cost/efficiency), the results of the study are listed on the vertical axis (VA care is better than community care, VA care and community care are about equal, or results are mixed, and community care is better than VA care), and then each study is entered as a shape, with larger shapes being studies of better quality and representativeness than studies depicted by smaller shapes. The color of the shape indicates the type of comparison: blue for studies comparing Veterans getting care from VA to Veterans getting VA-paid care in the community; orange for studies comparing Veterans getting care from VA and non-Veterans, or a general population, getting care in the community; and yellow for studies comparing Veterans getting care from VA to Veterans getting community care not paid by VA. Next to each shape is a brief thumbnail of what the study was about, and inside the shape is the year of publication (’18 = 2018, ’19 = 2019, etc).

Figure 3 Evidence Map of Studies on the Quality of Surgical Care

This is a bubble plot of surgical care where each bubble represents an outcome reported in a study and they are classified into three categories: VA care is better than non-VA care for all or most outcomes; VA care and non-VA care are equal or there were mixed results; and non-VA care is better than VA care for all or most outcomes. The bubbles on this plot are about outcomes in all domains. There are 8 bubbles in the “VA care is better” category, 6 of which are in quality/safety and 2 of which are in access. There are 14 bubbles in the “equal or mixed results” category, 11 of which are in quality/safety, 2 of which are in access, and 1 of which is in patient experience. There are 9 bubbles in the “non-VA care is better” category, 2 of which are in quality/safety, 2 are in access, and 5 are in cost/efficiency.

### Quality and Safety

Eighteen studies reported quality and safety outcomes covering a broad range of procedures and will be discussed individually by surgical specialties including orthopedic (5 studies), lung resection (2), kidney transplant (2), CABG (2), hernia repair (1), cataract surgery (1), non-cardiac surgeries (2), and colectomy (1); 2 additional studies reported hospital-level patient safety indicators.

#### Orthopedic

Three studies reported outcomes for Veterans undergoing elective joint replacement (hip [THA] and knee [TKA]) and 1 for hip fracture repair, all meeting risk of bias criteria. While non-VA care was superior after hip fracture repair, outcomes for joint replacements were either equivalent between sites of care or reported some outcomes where VA care was better and others where CC/non-VA care was better (ie, mixed).

Harris et al reported that 24,407 VA CDW patients had about half of the odds of developing any complication (such as joint or wound infection, myocardial infarction, and pulmonary embolism) compared to 18,964 Veterans who underwent TKAs in VA-paid CC identified through Medicare claims over 2017–2019 (adjusted OR of any complication = 0.45, 95% CI [0.38, 0.54]).^63^ However, in their local facility-level comparison, the adjusted odds of complications were higher in 5 of 130 VA facilities compared to their CC site (approximate ORs = 1.8–2.6, 95% CIs [1.1, 4.6]).

The second study of joint replacement outcomes from 2016–2019 by Rosen et al reported considerably lower readmissions nationally among 25,384 Veterans compared to 19,990 Veterans in VA-paid CC using combined VA CDW and Medicare (adjusted OR for all-cause readmissions = 0.35, 95% CI [0.30, 0.40]).^64^ This trend varied at 3 individual CC sites that had lower readmissions compared to their corresponding VA (approximate ORs = 2.3–3.1, 95% CIs [1.0, 7.9]).

The third study of joint replacements found that VA care (N = 10,460) had substantially higher adjusted odds of complications (2.58, 95% CI [2.31, 2.89]) and readmissions (4.94, 95% CI [4.51, 5.41]) after elective primary TKA and THA at 30 days compared to 58,820 National Surgical Quality Improvement Program (NSQIP) database patients in 2014.^65^ While the study by Harris and colleagues compared VA care to care delivered in the community via CHOICE, this study compared VA care to care in hospitals participating in NSQIP, which is a voluntary program consisting mostly of academic medical center hospitals, which differ from other hospitals on a number of characteristics.^66^ Also, the methods for controlling for differences in patient characteristics and hospital setting were different between the 2 studies.

A study of timeliness of surgery and survival found that after hip fracture in patients 65 and older, the VA-NSQIP patients (N = 947) waited an average of 4 days more for surgery (mean admission date to date of surgery in VA = 5.64 [SD 43.25] and Medicare: 1.78 [SD 2.35]) compared to a propensity matched cohort of Medicare patients (N = 947) between 2003–2005. The Medicare cohort also had 70% higher odds of 30-day survival on average.^67^

A fifth study about joint replacement surgery compared the post-operative prescription of opioids. Between 2018 and 2021, there were 239 Veterans who received VA-paid care in the community and 323 Veterans who got surgery at the Salt Lake VAMC.^68^ The median number of opioids prescribed at discharge was 10 less at the VAMC (30.0, IQR = 10.0-47.5) compared to VA-paid community care (40.0, IQR = 30.0-60.0, p < 0.01).

#### Lung Resection

Two studies discussed quality and safety outcomes for Veterans undergoing pulmonary resection and/or non-small cell lung cancer (NSCLC) treatment. Both reported a measure of overall survival with VA based care experiencing superior or equal outcomes.

Heiden and colleagues found that Veterans in the VA CDW database had a small but significantly lower 30-day mortality rate (VA: 1.9% vs National Cancer Database [NCDB]: 2.8%, p < 0.001) that persisted at 90 days compared to a matched non-Veteran population in the NCDB between 2006–2016. Veterans in the VA also had longer adjusted median overall survival by about 6 months (71.4 vs 65.2 months, p < 0.001); they found no difference in unadjusted readmissions.

In a second study designed to assess racial disparities in management and outcomes of stage I NSCLC between Black and White patients, Williams et al compared 7,895 Veterans in VA CDW data with 8,744 non-Veterans in the SEER-Medicare database from 2001–2009.^69^ They found that Black patients were 27% and 43% less likely to receive surgery in VA and non-VA cohorts, respectively. When they adjusted for treatment received and other patient-level covariates, there was no disparity in 5-year overall survival between Black and White patients in either setting.

#### Kidney Transplant

Two studies of kidney transplant quality and safety outcomes used data from the Scientific Registry of Transplant Recipients database; both studies met all our risk of bias criteria.

Augustine et al analyzed transplant rates, mortality, and delisting in 2,905 VA patients across 4 VA transplant centers with 3,751 privately insured and 3,109 Medicare patients from 2004 to 2016.^15^ Compared to privately insured patients, VA patients had a lower adjusted hazard ratio (aHR) for deceased and living donor transplants combined (aHR = 0.72, 95% CI [0.65, 0.79]), slightly higher hazard ratio for delisting (aHR = 1.23, 95% CI [1.003, 1.50]), but no difference in adjusted mortality rates. Compared to Medicare patients, VA patients had a lower hazard ratio for mortality (aHR = 0.81, 95% CI [0.68, 0.96]) and were less likely to be removed from the waitlist (aHR = 0.82, 95% CI [0.68, 0.99]).

Kesseli et al found significantly lower observed versus expected (O:E) 30-day kidney transplant mortality rate in the 7 VA centers (N = 1,508) versus 286 non-VA centers (N = 117,680) (O:E VA = 0.27, 95% CI [0.05, 0.65]; O:E VA vs non-VA = 1.00, 95% CI [0.95, 1.06], p = 0.03).^70^ Three-year mortality and graft survival, however, were not different between the VA and matched non-VA centers.

#### CABG

Barnett et al studied elective coronary revascularization in Veterans under 65 years old for 4,866 patients in VA hospitals and 952 Veterans in VA-paid CC sites using VA claims data.^26^ Mortality and readmissions at 30 days after CABG were not different between VA care and CC. A second study by Yoon and colleagues compared CABG at VA and non-VA settings in 11 states; 30-day operative mortality was not significantly different, and 30-day all-cause readmission rates favored VA.^29^

#### Hernia Repair

Mull et al assessed nationwide the outcome of postoperative complications for patients getting hernia repair in VA and Veterans getting hernia repair in the community in 2018–2019.^71^ Among 7,991 procedures nationwide, just under 10% were done in the community (772). Unadjusted comparisons showed postoperative complications were higher for community care patients than patients operated on at VA (6.6% vs 4.0%), but this difference was no longer present after adjusting for patient comorbidities, complexity of the hernia repair, and the historical pattern of community care referrals.

#### Colectomy

Simmonds et al used data from VASQIP and NSQIP to compare the outcomes of colectomy surgery.^72^ After excluding emergency cases, there were 235,097 cases in NSQIP and 11,115 cases in VASQIP. In the non-emergency cases, there was no statistically significant difference in adjusted 30-day mortality (1.2% vs 1.4%, p = 0.145) but overall morbidity favored care at VA (17.7% vs 22%, p < 0.001). In unadjusted results, some outcomes favored VA (organ space infection, post-operative pneumonia, DVT, UTI) while others favored non-VA care (return to OR, wound dehiscence, prolonged use of ventilator, cardiac arrest, post-operative sepsis). Stratified analysis showed greater variability in outcomes after open surgery between VA and non-VA care compared to laparoscopic cases.

#### Non-Cardiac Surgery

George and colleagues^73^ compared mortality after noncardiac surgery between VA NSQIP (N = 3,174,274) and NSQIP (N = 736,477).^11^ The authors found that VA care was associated with lower risk of overall postoperative death (adjusted relative risk 0.59, 95% CI [0.47, 0.75]; p < 0.001) and lower risk of postoperative death after a complication (adjusted relative risk 0.55, 95% CI [0.44, 0.68]). More recently, these authors updated this analysis to focus only on women Veterans, and observed similar results: adjusted relative risk of 30-day mortality was lower in VA (0.41, 95% CI [0.23, 0.76]; p < 0.001) and adjusted relative risk for failure to rescue was also lower in VA (0.41, 95% CI [0.18, 0.92]; p < 0.001).^74^

#### Cataract Surgery

One study reported similar adjusted 90-day complications for Veterans undergoing cataract surgery in the VA (N = 44,546) compared to Veterans obtaining VA-paid community care (N = 17,203) in FY 2015 following complex and routine cataract surgeries (OR = 0.92, 95% CI [0.77, 1.10]).^75^

#### Cochlear Implant Surgery

Tripathi and colleagues compared outcome of cochlear implant surgery between 83 Veterans receiving care at a single VA facility with 83 non-Veterans receiving care at non-VA hospitals.^76^ The outcomes were several measures of hearing, the Consonant-Nucleus-Consonant Score, and the Arizona Biomedical Institute recognition score. At multiple time points, there were no statistically significant differences in scores between groups.

#### Patient Safety Indicators

Two studies used Hospital Compare data to evaluate VA hospital patient safety indicators (PSIs) with those reported by non-VA hospitals. Only Blay et al met all our criteria for risk of bias given its larger sample size.^37^ They found lower postoperative inpatient deaths from a treatable complication in the 129 VA hospitals compared to 4010 non-VA hospitals between 2012–2015 (VA: 105.8 deaths per 1000 discharges, 95% CI [96.7, 114.92]; non-VA: 136.34 deaths per 1000 discharges, 95% CI [135.42, 137.26]) and found a slightly lower postoperative VTE rate by about 1 per 1000 discharges, but no difference in wound dehiscence rates.

The second study by Eid et al^41^ reported lower postoperative inpatient deaths from treatable complications in the VA hospitals (N = 34) compared to non-VA hospitals (N = 319), similar to Blay et al. There was no difference in VTE rates but lower wound dehiscence rates among VA hospitals.

### Access

We identified 6 articles reporting health care access. Three studies described time to care (2 on time to surgery, 1 wait time to specialty appointment) and 3 studies measured geographic access in terms of distance to the provider; all met risk of bias criteria.

#### Time to Care

Wu and colleagues measured the proportion of 1,917,254 Veterans and 1,156,211 Medicare patients with documented cataract diagnoses who received cataract surgery within 1 and 5 years after diagnosis from 2002–2012.^77^ About one-third fewer Veterans underwent surgery for cataracts within 1 year (VA: 6.3% vs non-VA: 18.5%; adjusted OR for receiving surgery = 3.39, 95% CI [3.36, 3.41]) and 5 years (VA: 12.6%, non-VA: 35.9%; adjusted OR = 3.89, 95% CI [3.87, 3.91]) compared to Medicare patients. This study did not assess the reasons why patients did not undergo cataract surgery.

Griffith et al compared wait times to specialty appointments among Veterans at VA versus Veterans in VA-paid CC using VA administrative data from 2013–2019 (orthopedic patients, VA: 506,945 and non-VA: 139,827; urology patients, VA: 353,019 and non-VA: 37,089).^53^ Mean wait times declined over the study period, and on average were 6 days shorter in VA sites for orthopedics (VA: 36.2 days [SD 9.3] vs CC: 43.6 days [SD 12.9]) and 14 days shorter in VA sites for urology (VA: 36.1 days [SD 9.5] vs CC: 50.5 days [SD 14.5]).

The third study evaluated time from carpal tunnel referral to time of surgery. Due to a heterogenous comparison group that may overlap with the VA group, this study was deemed fair quality.^78^ Veterans treated only within the VA had shorter median time from primary care provider (PCP) referral to carpal tunnel release by about 200 days compared to the group with mixed VA plus VA-paid community care.

#### Geographic Access

Three national studies found travel distance to be longer for VA care; all of these studies met the risk of bias criteria.

Augustine et al (discussed above in Quality and Safety) reported median distance to the 4 matched kidney transplant centers from Veteran residences.^15^ Transplants at a VA required nearly 8-fold greater travel distance at 347.0 miles (interquartile range [IQR] = 196.9–701.8) versus 42.5 miles (IQR = 12.9–101.1) for privately insured patients and 55.6 miles (IQR = 16.4–102.6) for Medicare patients. Similarly, the study of elective CABG operations by Barnett et al (see above) found that net travel distance was 73.3 miles less for VA-paid CC Veterans compared to Veterans undergoing surgery at the VA hospital.^26^

In a study using 2015 CDW data, Pettey and colleagues calculated median travel distances nationally for Veterans undergoing cataract surgery to be 31.2 miles for VA versus 19.7 miles for VA-paid CC.^79^

### Patient Experience

One study describing patient experience was fair quality. Eid et al used Hospital Consumer Assessment of Healthcare Providers patient satisfaction scores in 2018 in 3 regions and found no differences in overall hospital rating, but the VA performed slightly worse when patients were asked if they would recommend the hospital compared to non-Veteran patients at non-VA hospitals.^80^

### Cost/Efficiency

Three studies reported cost outcomes for TKA, cataract surgery, and elective CABG. Three studies reported efficiency measures as length of stay. All study designs were previously described in results about other outcomes above.

#### Costs

A study by Wagner et al compared VA hospital versus CC TKAs and cataract surgeries using VA CDW data from 2017–2018.^81^ The mean total unadjusted inpatient cost of TKAs was substantially higher in VA care (6,179 VA patients: $28,969 [SD $10778] vs 6,337 VA-paid CC patients: $13,339 [SD $23,698]), and the pattern persisted after controlling for location of service and patient factors. Findings were the same for outpatient cataract surgeries, with the adjusted model demonstrating that, compared to VA-paid CC, VA hospital cataract procedures cost $2,680 more (standard error = 15.8).

Barnett and colleagues (described above) found a lower mean adjusted total cost of elective CABG in Veterans receiving VA-paid CC by $8,525, which included index procedure, readmission, and extra travel costs compared to VA care (VA: $65,264 [SD $47,978] for VA vs CC: $56,749 [SD $77,283] for CC, p < 0.01).^26^

The study by Yoon comparing CABG between VA and non-VA care in 11 states found higher costs in VA; for Veteran patients age 65 or over this difference was a mean of $76,200 in VA compared with $53,100 in non-VA care.^29^

#### Length of Stay

Veterans at VA hospitals experienced longer lengths of stays compared to non-Veterans in 4 studies. For example, mean length of stay after lung resection was about 1 day shorter among non-Veterans (VA: 8.12 days [SD 6.59]; non-VA: 7.08 days [SD 7.54], p > 0.001).^82^ Following elective THA, a higher proportion of patients had a length of stay 4 days or greater in the VA sample (47% vs 17%, p < 0.001).^65^ For CABG, the study by Yoon and colleagues found a mean length of stay for Veteran patients 65 and older of 11.7 days in VA compared with 9.6 days in non-VA settings.^29^

## THE QUALITY OF HOSPITAL-BASED CARE FOR ACUTE MEDICAL CONDITIONS

### Comparison of VA and Non-VA Hospital Care Delivered by Hospitalists

The VA currently spends over $19 billion annually on inpatient care and provides acute care services to more than one million Veterans each year.^83^ Despite this substantial investment, little is known about how the processes and outcomes of hospitalist-delivered care within VA facilities compare to those in nearby non-VA hospitals. Addressing this evidence gap is essential for informing the VA’s decisions about when to deliver care internally (“make”) versus refer patients to community providers (“buy”). For example, should the VA invest in expanding the workforce at smaller, rural VA hospitals, or consider closing these facilities and referring patients to community hospitals? In particular, understanding differences in access, patient experience, quality, clinical outcomes, and cost of care is critically important in the care of hospitalized patients. To our knowledge, no comprehensive review has been conducted to evaluate the existing literature on hospital medicine within the VA health system.

Because the original articles rarely if ever characterize the individual treating physician, to help inform this question we focus on studies of conditions that are most likely cared for on inpatient general medicine wards (conditions like heart failure, diabetes, chronic obstructive pulmonary disease, stroke, and pneumonia), as well as hospital-wide measures, reasoning that most patients within a hospital are cared for on medicine wards rather than other wards (surgery, neurology, etc). Such inpatient general medicine wards are the care delivery site most likely to be staffed by hospitalists. Due to the focus on hospitalist care, for the 2 studies that had outcomes that were composites of multiple measures,^37,38^ we disaggregated them and included those most relevant to hospitalist care and excluded measures not relevant to hospitalist care. Examples of measures relevant to hospitalist care include 30-day mortality for pneumonia or heart failure, 30-day readmission for myocardial infarction, COPD, or heart failure, prescription at discharge if indicated of aspirin, statin, or an ACE inhibitor or ARB inhibitor, rates of central line infections, iatrogenic pneumothorax, etc. Examples of measures judged not reflective of hospitalist care include perioperative venous thromboembolism, postoperative sepsis, postoperative wound dehiscence, unrecognized abdominopelvic accidental puncture/laceration, prophylactic antibiotic received within 1 hour of surgical incision, prophylactic antibiotic discontinued within 24 hours after surgery end time, cardiac surgery patients with controlled 6 AM postoperative blood glucose, etc. This in turn necessitates 2 versions of the evidence map, one for studies with single or global measures of quality and another for the disaggregated measures. Studies can appear in both maps. Finally, because the 2018 VA MISSION Act could impact access and quality of care to VA hospitals, we highlight our findings relative to its implementation.

#### Results

In our searches we identified 13 studies that met the above criteria. Six of these were about hospital-wide measures,^1,37–40,50^ 2 studies were about groups of conditions (1 study about acute myocardial infarction, heart failure, and pneumonia;^27^ and the other about acute myocardial infarction, heart failure, gastrointestinal bleed, pneumonia, and stroke^29^), and 5 studies were about specific conditions (2 studies about chronic obstructive pulmonary disease,^41,42^ 1 study about heart failure,^23^ 1 study about acute myocardial infarction,^30^ and 1 study about end-of-life care).^59^

Figures 4 and 5 present the results for studies with a single or global measure of quality (Figure 4) and for studies with composites that we disaggregated decoupled (as described above; Figure 5). The high-level findings are similar to the findings from the overall quality of care maps: Most of the evidence is about clinical quality and safety (with 10 symbols on Figure 4) and there is less known about access (1 symbol on Figure 4), patient experience (3 symbols on Figure 4), and cost/efficiency (2 symbols on Figure 4); and VA care is usually better or about the same as community care, rarely is VA care worse than community care.

What follows is more in-depth information about these 13 studies.

##### Studies with Hospital-Wide Measures

We identified 6 published studies of hospital-wide assessments of care. Two of these used national databases explicitly created to publicly present performance measures, namely Hospital Compare and the Medicare Star Rating System.^37,40^ One study used several other standard performance measure databases (detailed below).^38^ Two studies used data from the Hospital Consumer Assessment of Health Care Providers and Systems (HCAHPS) patient experience survey.^1,39^ Lastly, 1 study was focused on changing admission patterns since the passage of the MISSION Act, and as part of that presented data on readmissions.^50^

In the first study, Blay and colleagues used data in Hospital Compare to assess care at 129 VA hospitals and 4,010 non-VA hospitals on 9 patient safety measures, 4 mortality measures, 4 readmission measures, 10 patient experience measures, and 9 behavioral health measures.^37^ The study dates were 2012-2015, in the pre-MISSION Act period. Some of these measures concern care not delivered by hospitalists, such as death among surgical patients, peri- and post-operative events, etc, and are not mapped or presented here. For 3 of 4 patient safety measures relevant to hospitalist care, VA hospitals had significantly better performance than non-VA hospitals (pressure ulcer, iatrogenic pneumothorax, and catheter-associated blood stream infection rate). On all measures of 30-day mortality and 30-day re-admission rate for patients with AMI, heart failure, or COPD, VA hospitals had significantly better performance than non-VA hospitals. For patient experience measures, non-VA hospitals had significant better performance on 6 of 10 measures (nursing communication, physician communication, responsiveness, pain management, quietness, and recommendation of the hospital to others).

Bagshaw and colleagues used the 2023 Medicare Star Rating reports (which use data from Hospital Compare) to compare the overall rating (5 star, 4 star, 3 star, etc) and individual domains of performance between VA hospitals and non-VA hospitals.^40^ Across more than 100 hospitals (the sample varies across star rating domains), VA facilities were more likely to be rated 4 star and 5 star and less likely to be rated 2 star or 3 star than 2,962 non-VA hospitals. Among the star rating domains, VA hospitals scored better than non-VA hospitals in mortality and patient experience, but worse in timely and effective care and readmissions. This study period was about a decade after the data used in the Blay and colleagues study, after implementation of the MISSION Act, thus 1 potential explanation for differences in results between the Blay study and Bagshaw’s findings is true change over time.

Anhang Price and colleagues^38^ used data from a number of sources, including the Healthcare Effectiveness Data and Information Set (HEDIS), HCAHPS, SHEP to compare 135 VA hospitals and 402 matched non-VA hospitals using data from 2014 (pre-MISSION Act). Compared to non-VA hospitals, VA hospital care scored the same or significantly better on all measures of inpatient safety, inpatient mortality, and inpatient effectiveness but significantly worse on measures of readmission. Results on individual HCAHPS measures were mixed.

Axon and colleagues used data from VA and Medicare between 2016 and 2021 to investigate changing patterns of Veteran hospitalization during implementation of the MISSION Act.^50^ While the primary focus of the article was about shifting sites of hospitalization toward VA-paid community care and away from VA-delivered care and Medicare-paid care, the analyses presented do include numerous comparisons of 7-day and 30-day readmission rates (unadjusted and adjusted) over time up to 2022. Depending on which outcome and which time point, readmissions for Veterans with community care hospitalizations paid by VA were about 19% to 47% higher than for Veterans with VA hospital care. Veterans getting care from non-VA sources, paid by Medicare, had about 30% to 50% higher readmission rates than either of the other 2 groups. Post-discharge visits to the emergency department were about the same between Veterans getting care in VA and Veterans getting care through Medicare, but 11% higher in VA-treated patients than in VA-paid community care.

Elliott and colleagues used data from national surveys of patient experience using HCAHPS.^1^ Data are presented over the time period 2017-2021, spanning the MISSION Act implementation period, and focus on results for certain patient groups. Here we focus primarily on data from 2021 and the overall population. Whereas in 2017, VA HCAHPS summary scores (from 127 VA hospitals) were significantly worse than the scores for non-VA hospitals (N = 4500 hospitals), in 2021 the VA HCAHPS summary score was significantly better for VA (N = 122 hospitals) than non-VA (N = 4,429 hospitals). This result was consistent regardless of patient subgroups by baseline health status and race.

Lastly, while a study by Eid and colleagues^39^ primarily focused on surgical care – and was therefore not included in this focused assessment about hospitalist care – it did assess factors contributing to patient satisfaction. Using data from 2018 (pre-MISSION Act), the authors reported a comparison of the HCAHPS “would you recommend” rating between 133 VA hospitals and 1,116 non-VA hospitals. There was no significant difference found.

##### Studies with Groups of Measures

We identified 2 published assessments of clinical quality for patients with a group of conditions comparing Veterans receiving VA care to non-Veterans getting care in the community. Nuti and colleagues^27^ used Medicare fee-for-service data and VA administrative data to compare mortality and readmission rates between men aged 65 and older who received care in an urban VA hospital versus receiving care in a geographically nearby non-VA hospital. Patients had to have been hospitalized for AMI, heart failure, or pneumonia between July 2010 and June 2013 (pre-MISSION ACT). The numbers of hospitals and patients included varied based on hospital discharge diagnosis and outcome assessed, but in general consisted of 100+ VA hospitals and approximately 1,500 non-VA hospitals and between 10,000-200,000 patients. Using hierarchical logistic regression analyses that controlled for various patient demographic and clinical characteristics, the risk-standardized 30-day mortality rate was slightly but significantly better in VA hospitals than non-VA hospitals for AMI and heart failure (30-day mortality rate for AMI in VA hospitals = 13.52%, in non-VA hospitals = 13.69%; p = 0.02; 30-day mortality for heart failure in VA hospitals = 11.43%, in non-VA hospitals = 11.87%, p < 0.001) but slightly worse in pneumonia (30-day mortality in VA hospitals = 12.63%, in non-VA hospitals = 12.17%, p = 0.0450). Thirty-day readmission rates were consistently 0.50%–1.0% higher in VA hospitals compared to non-VA hospitals.

Yoon and colleagues performed a similar assessment of VA care to non-VA care,^29^ except this time all patients were Veterans. The study by Yoon and colleagues also differed from the study by Nuti and colleagues in several ways. First, in addition to the conditions of AMI, heart failure, and pneumonia, the study population included gastrointestinal hemorrhage, stroke, and coronary artery bypass surgery (the latter being a condition not treated by hospitalists and is not discussed here). Second, Yoon and colleagues’ data are more recent, encompassing 2012 through 2017 (pre-MISSION Act). Third, instead of being national in scope, the data come from 11 geographically diverse states. Patients included both men (98% of the sample) and women, and patients under age 65 were included. The study population consisted of 593,578 hospitalizations experienced by 414,861 Veterans. Adjusted differences in 30-day mortality outcomes varied by condition and age group, with nonsignificant differences between groups for patients with AMI, gastrointestinal hemorrhage, and pneumonia, and better outcomes for VA-treated patients with heart failure and with stroke. Thirty-day readmission rates were in general lower in VA-treated patients (7 of 10 comparisons). Length of stay was higher in VA hospitals compared to care in non-VA hospitals for 9 or 10 comparisons (by between 0.5 and 2.3 days), as were costs, which may in part be due to longer length of stay. Differences in costs in unadjusted comparisons were between $3000-$7000.

#### Studies of Specific Conditions

We identified 5 published studies focusing on specific conditions commonly treated by hospitalists. These conditions include heart failure (first leading cause of hospitalization in the VA), chronic obstructive pulmonary disease (sixth leading cause), and acute myocardial infarction (seventh leading cause).

##### Acute Myocardial Infarction

Weeda and colleagues used national VA and Medicare data to compare outpatient medication prescribing among Veterans treated at VA hospitals and Veterans treated at non-VA hospitals treated for AMI between 2013 and 2018 (pre-MISSION Act).^30^ The primary outcome was omissions of outpatient medications in patients with compelling indications filled within 30 days of discharge. As most of these patients could have or should have these outpatient medications written by the inpatient team at the time of hospital discharge, we judged this to be sufficiently relevant to include in an assessment of hospitalist care. There were a total 118,456 Veterans hospitalized for AMI, of which 102,209 were treated in non-VA hospitals and 16,247 were treated at VA hospitals. Relevant medications included angiotensin-converting enzyme inhibitor/angiotensin receptor blockers, beta-blockers, statins, high-intensity statins, and P2Y12 drugs such as clopidogrel. Across all classes of medications, Veterans treated in VA hospitals were statistically significantly more likely to have received the medications than were Veterans treated at non-VA hospitals (example: 47% of Veterans treated at non-VA hospitals had a beta-blocker omission compared to 24% of Veterans treated at VA hospitals.) Duplications in medications and delays in getting medications filled were also greater among Veterans treated at non-VA hospitals.

##### Heart Failure

Axon and colleagues compared readmission rates during 2007-2011 (pre-MISSION ACT) for Veterans discharged with a heart failure diagnosis from a South Carolina VA hospital to those who were discharged from non-VA facilities in South Carolina.^23^ Although the focus of the study was comparing VA users to dual-use Veterans and also included assessments of ED use, the comparison considered here is readmissions following hospitalization for patients with an index hospitalization for heart failure between VA users and non-VA users. Sample sizes are not listed for patients with hospitalizations, but for hospitalizations and ED visits combined there were 2,242 VA users and 8,825 non-VA users. Restricting just to patients with a heart failure hospitalization, adjusted analyses showed that both all-cause and heart failure-specific 30-day readmission rates were about 50% lower in Veterans getting care at non-VA hospitals.

##### Chronic Obstructive Pulmonary Disease

We identified 2 published studies that compared care for patients with COPD in VA and non-VA hospitals. In the first study, LaBedz and colleagues^41^ used national Hospital Compare data to assess readmission and mortality rates following a VA or non-VA discharge for COPD between 2015-2018 (pre-MISSION Act). Data came from 126 VA hospitals and 3,523 non-VA hospitals. The difference in risk-adjusted 30-day readmission rate was −4.1% (95% CI [04.5, −3.9]) favoring VA hospitals, while the difference in risk-adjusted 30-day mortality rate also favored VA hospitals (difference = −2.6%, 95% CI [−2.8, −2.4]). In the second study, Vercammen-Grandjean and colleagues^42^ used national data from VA and from Medicare to assess care for patients discharged with a qualifying diagnosis of COPD during 2007-2011 at VA hospitals (N = 32,856 patients) or non-VA hospitals (N = 158,137 patients). The primary outcome was the receipt of at least 1 pulmonary rehabilitation session. Use of pulmonary rehabilitation was very low in each group, being 1.5% in VA care and 2.0% in non-VA care, a difference that was statistically significant.

##### End-of-Life Costs of Care

Gidwani and colleagues used national VA and Medicare data to compare costs of end-of-life care between Veterans cared for in VA and Veterans getting care outside VA between 2010 and 2014^59^ (pre-MISSION Act). Although the study assessed inpatient, outpatient, and drug costs, we focused on inpatient costs. Also, patients were categorized as “VA-reliant” or “Medicare-reliant,” meaning 75% or more of care was obtained within that system. Over the course of 12 months prior to death, there were similar trajectories of care as measured by inpatient hospital spending for both VA and non-VA treated Veterans.

Figure 4 Evidence Map of Hospital-Based Care for Acute Medical Conditions (Composite Outcomes Plotted as One Bubble or Not Plotted)

This is a bubble plot of hospital care for acute medical conditions where each bubble represents an outcome reported in a study and they are classified into three categories: VA care is better than non-VA care for all or most outcomes; VA care and non-VA care are equal or there were mixed results; and non-VA care is better than VA care for all or most outcomes. The bubbles on this plot are about outcomes in all domains. There are 18 bubbles in the “VA care is better” category, 17 of which are in quality/safety and 1 in patient experience. There are 5 bubbles in the in the “equal or mixed results” category, 3 of which are in quality/safety, and 1 each in patient experience and cost/efficiency. There are 5 bubbles in the “non-VA care is better” category, 3 of which are in quality/safety, and 1 each in access and cost/efficiency.

Figure 5 Evidence Map of Hospital-Based Care for Acute Medical Conditions (Composite Outcomes Disaggregated)

This is a bubble plot of hospital care for acute medical conditions where each bubble represents an outcome reported in a study and they are classified into three categories: VA care is better than non-VA care for all or most outcomes; VA care and non-VA care are equal or there were mixed results; and non-VA care is better than VA care for all or most outcomes. The bubbles on this plot are about outcomes in all domains. There are 18 bubbles in the “VA care is better” category, 17 of which are in quality/safety and 1 in patient experience. There are 13 bubbles in the in the “equal or mixed results” category, 9 of which are in quality/safety, 3 in patient experience and 1 in cost/efficiency. There are 7 bubbles in the “non-VA care is better” category, and 1 in cost/efficiency.

This is a bubble plot of hospital care for acute medical conditions where each bubble represents an outcome reported in a study and they are classified into three categories: VA care is better than non-VA care for all or most outcomes; VA care and non-VA care are equal or there were mixed results; and non-VA care is better than VA care for all or most outcomes. The bubbles on this plot are about outcomes in all domains. There are 18 bubbles in the “VA care is better” category, 17 of which are in quality/safety and 1 in patient experience. There are 13 bubbles in the in the “equal or mixed results” category, 9 of which are in quality/safety, 3 in patient experience and 1 in cost/efficiency. There are 7 bubbles in the “non-VA care is better” category, and 1 in cost/efficiency.