# METHODS

## REGISTRATION AND REVIEW

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD42022314154 (https://www.crd.york.ac.uk/prospero/display_record.php?ID=CRD42022314154)). A draft of the original version of this report and a draft of the current update including a comparison of VA and non-VA care for hospital care of acute medical conditions were reviewed by external peer reviewers; their comments and author responses are provided in the Supplementary Materials.

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following key questions were the focus of this review:

- Key Question 1 (KQ1): What is the evidence comparing VA care to non-VA care on quality, access, patient experience, cost, and equity, for Veterans or the general population getting community care, paid for or not paid for by VA?
- Key Question 2 (KQ2): What is the evidence comparing VA and non-VA hospital-based care for acute medical conditions, in the above categories?

Eligible studies were required to assess outcomes in any Institute of Medicine health care domain (clinical quality, safety, efficiency, access, patient experience, or equity^5^) among Veterans receiving care in VA, and to compare outcomes in this population to those of 1) Veterans receiving care in the community (either VA-paid or not VA-paid) or 2) members of the general population receiving care in the community. Health care costs and length of stay were considered efficiency outcomes for the purposes of this review. Studies were permitted to use any research design but must have been conducted in the United States (ie, compared VA care to another US health care provider/setting).

## SEARCHING AND SCREENING

To identify relevant articles, a research librarian conducted broad searches using terms relating to Veterans health and community health services or private sector in the PubMed, APA PsycINFO, and Web of Science databases (1/1/2015–4/20/2025). Complete search strategies are provided in the Appendix. The start date was chosen to match the end date of the most recent review by O’Hanlon.^4^ Additional citations were identified from hand-searching reference lists and consultation with content experts. We limited the search to published and indexed articles involving human subjects available in the English language.

Two sets of team members (1 team specializing in surgical titles and the other specializing in non-surgical titles) working independently screened the titles of retrieved citations for relevance. For titles deemed relevant by at least 1 person, abstracts were then screened independently in duplicate by team members. All disagreements were reconciled through group discussion. Full-text review was conducted in duplicate by independent team members with any disagreements resolved through discussion.

## DATA ABSTRACTION AND RISK OF BIAS ASSESSMENT

At the abstract stage, information on the medical or surgical condition, type of outcome reported, populations under comparison, and years of data were collected. Articles meeting inclusion criteria underwent a second screening and additional information was abstracted: whether study years were contemporaneous, sampling approach, geographic representativeness, similarity of outcomes between the comparison groups, sample size, years of data collected, control variables, outcomes, findings, and statistical methods. All data abstraction and internal validity ratings were first completed by 1 reviewer and then checked by another; disagreements were resolved by consensus or discussion with an additional reviewer.

The risk of bias for studies eligible for this review centers around the representativeness of the samples being assessed and whether the measures of performance are valid and applied equally across both groups. For this review we adapted the 4 items originally used in the 2010 review to the following:

1) Whether the time frames for the measurement are contemporaneous for both groups;
2) Whether the samples are national or representative for both groups;
3) Whether the quality measures used to assess care in both groups are identical or nearly identical;
4) Whether the analysis had enough sample size and appropriate statistical methods to test the hypothesis.

Studies could fully meet a criterion, partially meet a criterion, or fail a criterion. Studies fully meeting all of these criteria were considered to be “good” quality and given greater weight than studies not meeting all of the criteria, which were considered to be “fair” quality. Studies failing 1 or more criteria were not included in the analysis (see Supplementary Materials for risk of bias ratings).

## SYNTHESIS

We narratively synthesized available evidence because studies differed too substantially in comparison groups, outcome domains, and/or procedure types or health conditions to allow for meta-analysis. Studies were first classified by the domain(s) of reported outcomes (quality and safety, access, patient experience, efficiency/cost, and equity). Within domains, studies were grouped by surgical discipline or by clinical condition (cardiovascular, mental health, etc). If multiple cost outcomes were reported, total cost was abstracted. Studies were grouped into 2 categories based on their quality assessment: those that had no obvious flaws limiting their internal validity (risk of bias) or external validity (generalizability), and those that had some flaws limiting internal or external validity. Studies with serious internal validity flaws were not included in the synthesis (see Supplementary Materials).