# BACKGROUND

The Department of Veterans Affairs (VA) is the nation’s largest integrated health care system, providing care for millions of US military Veterans. Providing high quality care is a commitment VA makes to Veterans. Comparisons of VA-delivered care to care delivered in non-VA settings are central to assessing the quality of VA care. Prior reviews comparing outcomes between VA and non-VA care included data through 2014, and found that VA care performed similarly to or better than non-VA care in most, but not all, aspects of quality.^3–5^

Since that time, concerns about access to care led to the Veteran Access, Choice, and Accountability (“Choice”) Act of 2014, which allowed Veterans to seek medical care in the community if the VA was unable to schedule a visit within 30 days or if the Veteran lived greater than 40 miles from their closest VA. This program also required independent performance assessments of VA’s health care services related to access and available expertise.^6^ Choice Act funding ended in 2017 and was followed by the VA Maintaining Internal Systems and Strengthening Integrated Outside Networks (MISSION) Act of 2018 that further addressed concerns regarding Veteran access to care by expanding eligibility for VA-reimbursed community care (CC) options.^7^ Even more recently have been changes to increase community care access and to extend the duration of community care authorizations.^8,9^

These acts greatly expanded the potential for care delivered to Veterans and paid for by VA to be from community providers, raising additional questions about comparisons of quality of care. To address these gaps, the VA Office of the Assistant Under Secretary for Health for Quality and Patient Safety requested a systematic review of evidence comparing quality and safety, access, patient experience, and cost between VA and non-VA care settings. The first such review^3,10^ was published in 2010 and 2011, was updated by non-VA investigators in 2017,^4^ and was subsequently updated 4 times by the Evidence Synthesis Program in 2022–2024.^11,12^ The current update now includes a comparison not included in all prior reviews, namely a comparison of VA and non-VA care for hospital care of acute medical conditions.