# Supplementary Materials

- Peer Review Feedback – Sep 2025 (XLSX)
- Peer Review Feedback – Nov 2022 (XLSX)
- Excluded Studies (Non-Surg) (XLSX)
- Excluded Studies (Surg) (XLSX)
- Studies with Unrepresentative.. (XLSX)
- Study Characteristic (Non-Surg) (XLSX)
- Study Characteristic (Surgical) (XLSX)
- RoB (Non-Surg) (XLSX)
- RoB (Surgical Care) (XLSX)

## VA Related Documents

Supplementary Materials (XLSX)