# REFERENCES

1 Trivedi RB, Post EP, Sun H, . Prevalence, comorbidity, and prognosis of mental health among US veterans. American journal of public health. 2015;105(12):2564–2569.26474009
2 Trivedi RB, Post EP, Piegari R, . Mortality among veterans with major mental illnesses seen in primary care: results of a national study of veteran deaths. Journal of general internal medicine. 2020;35(1):112–118.31667746
3 National strategy for preventing veteran suicide 2018-2028. U.S. Department of Veterans Affairs, Office of Mental Health and Suicide Prevention. https://www.mentalhealth.va.gov/suicide_prevention/docs/Office-of-Mental-Health-and-Suicide-Prevention-National-Strategy-for-Preventing-Veterans-Suicide.pdf
4 Karlin BE, Cross G. From the laboratory to the therapy room: National dissemination and implementation of evidence-based psychotherapies in the U.S. Department of Veterans Affairs Health Care System. Am Psychol. Jan 2014;69(1):19–33. doi:10.1037/a0033888 24001035
5 Valenstein-Mah H, Greer N, McKenzie L, . Effectiveness of training methods for delivery of evidence-based psychotherapies: a systematic review. Implement Sci. May 27 2020;15(1):40. doi:10.1186/s13012-020-00998-w 32460866
6 Goldsmith ES, Koffel E, Ackland PE, . Evaluation of Implementation Strategies for Cognitive Behavioral Therapy (CBT), Acceptance and Commitment Therapy (ACT), and Mindfulness-Based Stress Reduction (MBSR): a Systematic Review. J Gen Intern Med. Sep 2023;38(12):2782–2791. doi:10.1007/s11606-023-08140-4 37012538
7 VA/DOD Clinical Practice Guidelines. U.S. Department of Veterans Affairs. Accessed 8/21/2025, 2025. https://www.healthquality.va.gov/guidelines/MH/
8 Steuer J. Defining virtual reality: Dimensions determining telepresence. Journal of communication. 1992;42(4):73–93.
9 Mütterlein J. The three pillars of virtual reality? Investigating the roles of immersion, presence, and interactivity. 2018;
10 Rauschnabel PA, Felix R, Hinsch C, Shahab H, Alt F. What is XR? Towards a framework for augmented and virtual reality. Computers in human behavior. 2022;133:107289.
11 Bailey AL, Haywood T. VA Immersive Executive Roundtable 2023. US Department of Veterans Affairs. https://innovation.va.gov/hil/assets/documents/va-immersive-executive-roundtable-final.pdf
12 DistillerSR. DistillerSR Inc. https://www.distillersr.com/
13 Cochrane Handbook for Systematic Reviews of Interventions. Updated August 22, 2023. https://training.cochrane.org/handbook
14 Sterne JAC, Savovic J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. Aug 28 2019;366:l4898. doi:10.1136/bmj.l4898 31462531
15 Persky S, Colloca L. Medical Extended Reality Trials: Building Robust Comparators, Controls, and Sham. J Med Internet Res. Nov 22 2023;25:e45821. doi:10.2196/45821 37991836
16 metafor: Meta-Analysis Package for R. https://cran.r-project.org/web/packages/metafor/index.html
17 GRADEpro GDT. https://www.gradepro.org/
18 Guyatt GH, Oxman AD, Kunz R, . GRADE guidelines 6. Rating the quality of evidence–imprecision. J Clin Epidemiol. Dec 2011;64(12):1283–93. doi:10.1016/j.jclinepi.2011.01.012 21839614
19 Santesso N, Glenton C, Dahm P, . GRADE guidelines 26: informative statements to communicate the findings of systematic reviews of interventions. J Clin Epidemiol. Mar 2020;119:126–135. doi:10.1016/j.jclinepi.2019.10.014 31711912
20 Difede J, Rothbaum BO, Rizzo AA, . Enhancing exposure therapy for posttraumatic stress disorder (PTSD): a randomized clinical trial of virtual reality and imaginal exposure with a cognitive enhancer. Transl Psychiatry. Jul 27 2022;12(1):299. doi:10.1038/s41398-022-02066-x 35896533
21 Beidel DC, Frueh BC, Neer SM, Lejuez CW. The efficacy of Trauma Management Therapy: A controlled pilot investigation of a three-week intensive outpatient program for combat-related PTSD. J Anxiety Disord. Aug 2017;50:23–32. doi:10.1016/j.janxdis.2017.05.001 28545005
22 McLay RN, Baird A, Webb-Murphy J, . A Randomized, Head-to-Head Study of Virtual Reality Exposure Therapy for Posttraumatic Stress Disorder. Cyberpsychol Behav Soc Netw. Apr 2017;20(4):218–224. doi:10.1089/cyber.2016.0554 28394217
23 Reger GM, Koenen-Woods P, Zetocha K, . Randomized controlled trial of prolonged exposure using imaginal exposure vs. virtual reality exposure in active duty soldiers with deployment-related posttraumatic stress disorder (PTSD). J Consult Clin Psychol. Nov 2016;84(11):946–959. doi:10.1037/ccp0000134 27606699
24 Miyahira SD, Folen RA, Hoffman HG, Garcia-Palacios A, Spira JL, Kawasaki M. The effectiveness of VR exposure therapy for PTSD in returning warfighters. Stud Health Technol Inform. 2012;181:128–32.22954842
25 McLay RN, Wood DP, Webb-Murphy JA, . A randomized, controlled trial of virtual reality-graded exposure therapy for post-traumatic stress disorder in active duty service members with combat-related post-traumatic stress disorder. Cyberpsychol Behav Soc Netw. Apr 2011;14(4):223–9. doi:10.1089/cyber.2011.0003 21332375
26 Lacey C, Frampton C, Beaglehole B. A self-guided virtual reality solution for social anxiety: Results from a randomized controlled study. J Psychiatr Res. Dec 2024;180:333–339. doi:10.1016/j.jpsychires.2024.10.032 39515186
27 Stefaniak I, Hanusz K, Mierzejewski P, Bienkowski P, Parnowski T, Murawiec S. Preliminary Study of Efficacy and Safety of Self-Administered Virtual Exposure Therapy for Social Anxiety Disorder vs. Cognitive-Behavioral Therapy. Brain Sci. Sep 13 2022;12(9)doi:10.3390/brainsci12091236
28 Kim MK, Eom H, Kwon JH, Kyeong S, Kim JJ. Neural effects of a short-term virtual reality self-training program to reduce social anxiety. Psychol Med. May 2022;52(7):1296–1305. doi:10.1017/S0033291720003098 32880252
29 Zainal NH, Chan WW, Saxena AP, Taylor CB, Newman MG. Pilot randomized trial of selfguided virtual reality exposure therapy for social anxiety disorder. Behav Res Ther. Dec 2021;147:103984. doi:10.1016/j.brat.2021.103984 34740099
30 Ma L, Kruijt AW, Nojd S, Zetterlund E, Andersson G, Carlbring P. Attentional Bias Modification in Virtual Reality - A VR-Based Dot-Probe Task With 2D and 3D Stimuli. Front Psychol. 2019;10:2526. doi:10.3389/fpsyg.2019.02526 31798495
31 Bouchard S, Dumoulin S, Robillard G, . Virtual reality compared with in vivo exposure in the treatment of social anxiety disorder: a three-arm randomised controlled trial. Br J Psychiatry. Apr 2017;210(4):276–283. Comment in: Br J Psychiatry. 2018 Oct;213(4):617<ovid:br/> PMID: 30247117 [https://www.ncbi.nlm.nih.gov/pubmed/30247117]<ovid:br/> <ovid:br/>Comment in: Br J Psychiatry. 2018 Oct;213(4):617<ovid:br/> PMID: 30741144 [https://www.ncbi.nlm.nih.gov/pubmed/30741144]. doi:10.1192/bjp.bp.116.184234 27979818
32 Kampmann IL, Emmelkamp PM, Hartanto D, Brinkman WP, Zijlstra BJ, Morina N. Exposure to virtual social interactions in the treatment of social anxiety disorder: A randomized controlled trial. Behav Res Ther. Feb 2016;77:147–56. doi:10.1016/j.brat.2015.12.016 26752328
33 Anderson PL, Price M, Edwards SM, . Virtual reality exposure therapy for social anxiety disorder: a randomized controlled trial. J Consult Clin Psychol. Oct 2013;81(5):751–60. doi:10.1037/a0033559 23796315
34 Robillard G, Bouchard S, Dumoulin S, Guitard T, Klinger E. Using virtual humans to alleviate social anxiety: preliminary report from a comparative outcome study. Stud Health Technol Inform. 2010;154:57–60.20543270
35 Kan C, Wang Y, Hu R, Chen K, Zhang Y. Convenient virtual reality exposure self-training for social anxiety: a randomized controlled study. 2024;
36 Triscari MT, Faraci P, Catalisano D, D’Angelo V, Urso V. Effectiveness of cognitive behavioral therapy integrated with systematic desensitization, cognitive behavioral therapy combined with eye movement desensitization and reprocessing therapy, and cognitive behavioral therapy combined with virtual reality exposure therapy methods in the treatment of flight anxiety: a randomized trial. Neuropsychiatr Dis Treat. 2015;11:2591–8. doi:10.2147/NDT.S93401 26504391
37 Tortella-Feliu M, Botella C, Llabres J, . Virtual reality versus computer-aided exposure treatments for fear of flying. Behav Modif. Jan 2011;35(1):3–30. doi:10.1177/0145445510390801 21177516
38 Krijn M, Emmelkamp PM, Olafsson RP, . Fear of flying treatment methods: virtual reality exposure vs. cognitive behavioral therapy. Aviat Space Environ Med. Feb 2007;78(2):121–8.17310883
39 Rothbaum BO, Anderson P, Zimand E, Hodges L, Lang D, Wilson J. Virtual reality exposure therapy and standard (in vivo) exposure therapy in the treatment of fear of flying. Behav Ther. Mar 2006;37(1):80–90. doi:10.1016/j.beth.2005.04.004 16942963
40 Maltby N, Kirsch I, Mayers M, Allen GJ. Virtual reality exposure therapy for the treatment of fear of flying: a controlled investigation. J Consult Clin Psychol. Oct 2002;70(5):1112–8. doi:10.1037//0022-006x.70.5.1112 12362961
41 Rothbaum BO, Hodges L, Smith S, Lee JH, Price L. A controlled study of virtual reality exposure therapy for the fear of flying. J Consult Clin Psychol. Dec 2000;68(6):1020–6. doi:10.1037//0022-006x.68.6.1020 11142535
42 Wiederhold BK, Gevirtz RN, Spira JL. Virtual reality exposure therapy vs. imagery desensitization therapy in the treatment of flying phobia. Towards cyberpsychology: Mind, cognition and society in the internet age. 2001:253–272.
43 Hernandez-Serrano O, Ghita A, Figueras-Puigderrajols N, . Predictors of Changes in Alcohol Craving Levels during a Virtual Reality Cue Exposure Treatment among Patients with Alcohol Use Disorder. J Clin Med. Sep 18 2020;9(9)doi:10.3390/jcm9093018
44 Kim DY, Lee JH. The Effects of Training to Reduce Automatic Action Tendencies Toward Alcohol Using the Virtual Alcohol Approach-Avoidance Task in Heavy Social Drinkers. Cyberpsychol Behav Soc Netw. Dec 2019;22(12):794–798. doi:10.1089/cyber.2019.0121 31794239
45 Figueras-Puigderrajols N, Fernandez-Ruiz J, Ferrer-Garcia M, . Virtual reality-cue exposure therapy for the treatment of alcohol use disorder: Preliminary results. Annual Review of CyberTherapy and Telemedicine. 2020;18:261–264.
46 Ji X, Tang Y, Jing L, . Effects of a virtual reality-based motivational reinforcement + desensitization intervention program on psychological craving and addiction memory in female MA-dependent young adults. Front Psychiatry. 2023;14:1114878. doi:10.3389/fpsyt.2023.1114878 37559915
47 Wang YG, Liu MH, Shen ZH. A virtual reality counterconditioning procedure to reduce methamphetamine cue-induced craving. J Psychiatr Res. Sep 2019;116:88–94. doi:10.1016/j.jpsychires.2019.06.007 31226580
48 Qiu T, Zhang G, Zhou F, Jiang H. Application of virtual reality to enhance therapeutic Tai Chi for depression in elderly people. Acta Psychol (Amst). Aug 2024;248:104316. doi:10.1016/j.actpsy.2024.104316 39025032
49 Paul M, Bullock K, Bailenson J, Burns D. Examining the Efficacy of Extended Reality-Enhanced Behavioral Activation for Adults With Major Depressive Disorder: Randomized Controlled Trial. JMIR Ment Health. Apr 15 2024;11:e52326. doi:10.2196/52326 38437873
50 Cieslik B, Juszko K, Kiper P, Szczepanska-Gieracha J. Immersive virtual reality as support for the mental health of elderly women: a randomized controlled trial. Virtual Real. May 7 2023:1–9. doi:10.1007/s10055-023-00797-w
51 Wu JJ, Zheng MX, Hua XY, . Altered effective connectivity in the emotional network induced by immersive virtual reality rehabilitation for post-stroke depression. Front Hum Neurosci. 2022;16:974393. doi:10.3389/fnhum.2022.974393 35982688
52 Kiper P, Przysiezna E, Cieslik B, . Effects of Immersive Virtual Therapy as a Method Supporting Recovery of Depressive Symptoms in Post-Stroke Rehabilitation: Randomized Controlled Trial. Clin Interv Aging. 2022;17:1673–1685. doi:10.2147/CIA.S375754 36447623
53 Szczepanska-Gieracha J, Cieslik B, Serweta A, Klajs K. Virtual Therapeutic Garden: A Promising Method Supporting the Treatment of Depressive Symptoms in Late-Life: A Randomized Pilot Study. J Clin Med. May 1 2021;10(9)doi:10.3390/jcm10091942
54 Lee BM, Kim SW, Lee BJ, . Effects and safety of virtual reality-based mindfulness in patients with psychosis: a randomized controlled pilot study. Schizophrenia (Heidelb). Sep 13 2023;9(1):57. doi:10.1038/s41537-023-00391-8 37704650
55 Nijman SA, Pijnenborg GHM, Vermeer RR, . Dynamic Interactive Social Cognition Training in Virtual Reality (DiSCoVR) versus Virtual Reality Relaxation (VRelax) for People With a Psychotic Disorder: A Single-Blind Multicenter Randomized Controlled Trial. Schizophr Bull. Mar 15 2023;49(2):518–530. doi:10.1093/schbul/sbac166 36413388
56 Shen ZH, Liu MH, Wu Y, Lin QQ, Wang YG. Virtual-reality-based social cognition and interaction training for patients with schizophrenia: A preliminary efficacy study. Front Psychiatry. 2022;13:1022278. doi:10.3389/fpsyt.2022.1022278 36465308
57 Li S, Liu R, Sun B, . Effect of Virtual Reality on Cognitive Impairment and Clinical Symptoms among Patients with Schizophrenia in the Remission Stage: A Randomized Controlled Trial. Brain Sci. Nov 18 2022;12(11)doi:10.3390/brainsci12111572
58 Wang X, Kou X, Meng X, Yu J. Effects of a virtual reality serious game training program on the cognitive function of people diagnosed with schizophrenia: A randomized controlled trial. Front Psychiatry. 2022;13:952828. doi:10.3389/fpsyt.2022.952828 35911215
59 Vass E, Simon V, Csukly G, Fekete Z, Kis B, Simon L. Virtual reality-based theory of mind intervention in schizophrenia: Preliminary efficacy results. Compr Psychiatry. Nov 2022;119:152350. doi:10.1016/j.comppsych.2022.152350 36272240
60 Cella M, Tomlin P, Robotham D, . Virtual Reality Therapy for the Negative Symptoms of Schizophrenia (V-NeST): A pilot randomised feasibility trial. Schizophr Res. Oct 2022;248:50–57. doi:10.1016/j.schres.2022.07.013 35939920
61 Liang N, Li X, Guo X, . Visual P300 as a neurophysiological correlate of symptomatic improvement by a virtual reality-based computer AT system in patients with auditory verbal hallucinations: A Pilot study. J Psychiatr Res. Jul 2022;151:261–271. doi:10.1016/j.jpsychires.2022.04.027 35512620
62 Freeman D, Lambe S, Kabir T, . Automated virtual reality therapy to treat agoraphobic avoidance and distress in patients with psychosis (gameChange): a multicentre, parallel-group, single-blind, randomised, controlled trial in England with mediation and moderation analyses. Lancet Psychiatry. May 2022;9(5):375–388. doi:10.1016/S2215-0366(22)00060-8 35395204
63 Dellazizzo L, Potvin S, Phraxayavong K, Dumais A. One-year randomized trial comparing virtual reality-assisted therapy to cognitive-behavioral therapy for patients with treatment-resistant schizophrenia. NPJ Schizophr. Feb 12 2021;7(1):9. doi:10.1038/s41537-021-00139-2 33580033
64 Pot-Kolder R, Geraets CNW, Veling W, . Virtual-reality-based cognitive behavioural therapy versus waiting list control for paranoid ideation and social avoidance in patients with psychotic disorders: a single-blind randomised controlled trial. Lancet Psychiatry. Mar 2018;5(3):217–226. Comment in: Lancet Psychiatry. 2018 Mar;5(3):189–191<ovid:br/> PMID: 29429949 [https://www.ncbi.nlm.nih.gov/pubmed/29429949]. doi:10.1016/S2215-0366(18)30053-1 29429948
65 Park KM, Ku J, Choi SH, . A virtual reality application in role-plays of social skills training for schizophrenia: a randomized, controlled trial. Psychiatry Res. Sep 30 2011;189(2):166–72. doi:10.1016/j.psychres.2011.04.003 21529970
66 Fusco C, Di Nunzio M, Moccia A. Progressive muscle relaxation training: classic technique and virtual reality for psychotic patients. Minerva Psichiatrica. 2018;59(4):177 EP - 180. doi:10.23736/s0391-1772.18.01987-8
67 Shin B, Oh J, Kim BH, . Effectiveness of Self-Guided Virtual Reality-Based Cognitive Behavioral Therapy for Panic Disorder: Randomized Controlled Trial. JMIR Ment Health. Nov 22 2021;8(11):e30590. doi:10.2196/30590 34813486
68 Perez-Ara MA, Quero S, Botella C, . Virtual reality interoceptive exposure for the treatment of panic disorder and agoraphobia. Stud Health Technol Inform. 2010;154:77–81.20543274
69 Botella C, García-Palacios A, Villa H, . Virtual reality exposure in the treatment of panic disorder and agoraphobia: A controlled study. Clinical Psychology & Psychotherapy. 2007;14(3):164–175. doi:10.1002/cpp.524
70 Choi YH, Vincelli F, Riva G, Wiederhold BK, Lee JH, Park KH. Effects of group experiential cognitive therapy for the treatment of panic disorder with agoraphobia. Cyberpsychol Behav. Aug 2005;8(4):387–93. doi:10.1089/cpb.2005.8.387 16092896
71 Pelissolo A, Zaoui M, Aguayo G, . Virtual reality exposure therapy versus cognitive behavior therapy for panic disorder with agoraphobia: a randomized comparison study. Journal article. Journal of cyber therapy and rehabilitation. 2012;5(1):35–43.
72 Lorenzo Gonzalez M, Castro WP, Pitti Gonzalez CT, Bethencourt Perez JM, de la Fuente Portero JA, Marco RG. Efficacy of virtual reality exposure therapy combined with two pharmacotherapies in the treatment of agoraphobia. Health & Mental Health Treatment & Prevention 3300. International Journal of Clinical and Health Psychology. 2011;11(2):189–203.
73 Pitti CT, Penate W, de la Fuente J, . The combined use of virtual reality exposure in the treatment of agoraphobia. Actas Esp Psiquiatr. Jul–Aug 2015;43(4):133–41.26150057
74 Quero S, Pérez-Ara MÁ, Bretón-López J, García-Palacios A, Baños RM, Botella C. Acceptability of virtual reality interoceptive exposure for the treatment of panic disorder with agoraphobia. British Journal of Guidance & Counselling. 2013;42(2):123–137. doi:10.1080/03069885.2013.852159
75 Castro WP, Sanchez MJR, Gonzalez CTP, Bethencourt JM, de la Fuente Portero JA, Marco RG. Cognitive-behavioral treatment and antidepressants combined with virtual reality exposure for patients with chronic agoraphobia. Health & Mental Health Treatment & Prevention 3300. International Journal of Clinical and Health Psychology. 2014;14(1):9–17. doi:10.1016/S1697-2600%2814%2970032-8
76 Meyerbroeker K, Morina N, Kerkhof GA, Emmelkamp PM. Virtual reality exposure therapy does not provide any additional value in agoraphobic patients: a randomized controlled trial. Psychother Psychosom. 2013;82(3):170–6. doi:10.1159/000342715 23548832
77 Shiban Y, Schelhorn I, Pauli P, Muhlberger A. Effect of combined multiple contexts and multiple stimuli exposure in spider phobia: A randomized clinical trial in virtual reality. Behav Res Ther. Aug 2015;71:45–53. doi:10.1016/j.brat.2015.05.014 26072451
78 Jiang MYW, Upton E, Newby JM. A randomised wait-list controlled pilot trial of one-session virtual reality exposure therapy for blood-injection-injury phobias. J Affect Disord. Nov 1 2020;276:636–645. doi:10.1016/j.jad.2020.07.076 32871696
79 Gujjar KR, van Wijk A, Kumar R, de Jongh A. Efficacy of virtual reality exposure therapy for the treatment of dental phobia in adults: A randomized controlled trial. J Anxiety Disord. Mar 2019;62:100–108. doi:10.1016/j.janxdis.2018.12.001 30717830
80 Michaliszyn D, Marchand A, Bouchard S, Martel MO, Poirier-Bisson J. A randomized, controlled clinical trial of in virtuo and in vivo exposure for spider phobia. Cyberpsychol Behav Soc Netw. Dec 2010;13(6):689–95. doi:10.1089/cyber.2009.0277 21142994
81 Garcia-Palacios A, Hoffman H, Carlin A, Furness TA, 3rd, Botella C. Virtual reality in the treatment of spider phobia: a controlled study. Behav Res Ther. Sep 2002;40(9):983–93. doi:10.1016/s0005-7967(01)00068-7 12296495
82 Shiban Y, Brutting J, Pauli P, Muhlberger A. Fear reactivation prior to exposure therapy: does it facilitate the effects of VR exposure in a randomized clinical sample? J Behav Ther Exp Psychiatry. Mar 2015;46:133–40. doi:10.1016/j.jbtep.2014.09.009 25460259
83 Alvarez-Perez Y, Rivero F, Herrero M, . Changes in Brain Activation through Cognitive-Behavioral Therapy with Exposure to Virtual Reality: A Neuroimaging Study of Specific Phobia. J Clin Med. Aug 9 2021;10(16)doi:10.3390/jcm10163505
84 Miloff A, Lindner P, Dafgard P, . Automated virtual reality exposure therapy for spider phobia vs. in-vivo one-session treatment: A randomized non-inferiority trial. Behav Res Ther. Jul 2019;118:130–140. doi:10.1016/j.brat.2019.04.004 31075675
85 Emmelkamp PM, Krijn M, Hulsbosch AM, de Vries S, Schuemie MJ, van der Mast CA. Virtual reality treatment versus exposure in vivo: a comparative evaluation in acrophobia. Behav Res Ther. May 2002;40(5):509–16. doi:10.1016/s0005-7967(01)00023-7 12038644
86 Freeman D, Haselton P, Freeman J, . Automated psychological therapy using immersive virtual reality for treatment of fear of heights: a single-blind, parallel-group, randomised controlled trial. Lancet Psychiatry. Aug 2018;5(8):625–632. Comment in: Lancet Psychiatry. 2018 Aug;5(8):606–607<ovid:br/> PMID: 30007518 [https://www.ncbi.nlm.nih.gov/pubmed/30007518]. doi:10.1016/S2215-0366(18)30226-8 30007519
87 Krijn M, Emmelkamp PM, Biemond R, de Wilde de Ligny C, Schuemie MJ, van der Mast CA. Treatment of acrophobia in virtual reality: the role of immersion and presence. Behav Res Ther. Feb 2004;42(2):229–39. doi:10.1016/S0005-7967(03)00139-6 14975783
88 Hodges LF, Kooper R, Meyer TC, . Virtual environments for treating the fear of heights. Computer. 1995;28(7):27–34.
89 Pericot-Valverde I, Secades-Villa R, Gutierrez-Maldonado J. A randomized clinical trial of cue exposure treatment through virtual reality for smoking cessation. J Subst Abuse Treat. Jan 2019;96:26–32. doi:10.1016/j.jsat.2018.10.003 30466545
90 Goldenhersch E, Thrul J, Ungaretti J, Rosencovich N, Waitman C, Ceberio MR. Virtual Reality Smartphone-Based Intervention for Smoking Cessation: Pilot Randomized Controlled Trial on Initial Clinical Efficacy and Adherence. J Med Internet Res. Jul 29 2020;22(7):e17571. doi:10.2196/17571 32723722
91 Girard B, Turcotte V, Bouchard S, Girard B. Crushing virtual cigarettes reduces tobacco addiction and treatment discontinuation. Cyberpsychol Behav. Oct 2009;12(5):477–83. doi:10.1089/cpb.2009.0118 19817561
92 Schroder B, Kroczek A, Kroczek LOH, Ehlis AC, Batra A, Muhlberger A. Cigarette craving in virtual reality cue exposure in abstainers and relapsed smokers. Sci Rep. Mar 30 2024;14(1):7538. doi:10.1038/s41598-024-58168-7 38553517
93 Bordnick PS, Traylor AC, Carter BL, Graap KM. A Feasibility Study of Virtual Reality-Based Coping Skills Training for Nicotine Dependence. Res Soc Work Pract. May 2012;22(3):293–300. doi:10.1177/1049731511426880 25484549
94 Malbos E, Borwell B, Einig-Iscain M, . Virtual reality cue exposure therapy for tobacco relapse prevention: a comparative study with standard intervention. Psychol Med. Aug 2023;53(11):5070–5080. doi:10.1017/S0033291722002070 35924727
95 Malbos E, Borwell B, Cantalupi R, Lancon C. Virtual reality cue exposure for smoking relapse prevention: A comparative trial. Annual Review of CyberTherapy and Telemedicine. 2018;2018(16):124–130.
96 Machulska A, Eiler TJ, Kleinke K, . Approach bias retraining through virtual reality in smokers willing to quit smoking: A randomized-controlled study. Behav Res Ther. Jun 2021;141:103858. doi:10.1016/j.brat.2021.103858 33862407
97 Sancassiani F, Perra A, Galetti A, . Alexithymia and Bipolar Disorder: Virtual Reality Could Be a Useful Tool for the Treatment and Prevention of These Conditions in People with a Physical Comorbidity. J Clin Med. Oct 18 2024;13(20)doi:10.3390/jcm13206206
98 Carta MG, Kurotschka PK, Machado S, . A Virtual Reality Cognitive Stimulation Program as an Effective Tool Against Residual/Prodromal Depressive Symptoms in Bipolar Disorders. J Clin Med. Aug 11 2024;13(16)doi:10.3390/jcm13164714
99 Primavera D, Urban A, Cantone E, . The Impact on Anxiety Symptoms of an Immersive Virtual Reality Remediation Program in Bipolar Disorders: A Randomized Clinical Trial. J Clin Med. Jul 18 2024;13(14)doi:10.3390/jcm13144203
100 Primavera D, Migliaccio GM, Garau V, . Improving Quality of Life in Bipolar Disorders with an Immersive Virtual Reality Remediation Training Randomized Controlled Trial (RCT). J Clin Med. Jul 2 2024;13(13)doi:10.3390/jcm13133886
101 Perra A, Galetti A, Zaccheddu R, . A Recovery-Oriented Program for People with Bipolar Disorder through Virtual Reality-Based Cognitive Remediation: Results of a Feasibility Randomized Clinical Trial. J Clin Med. Mar 9 2023;12(6)doi:10.3390/jcm12062142
102 Popa CO, Sava FA, Muresan S, . Standard CBT versus integrative and multimodal CBT assisted by virtual-reality for generalized anxiety disorder. Front Psychol. 2022;13:1008981. doi:10.3389/fpsyg.2022.1008981 36248526
103 Navarro-Haro MV, Modrego-Alarcon M, Hoffman HG, . Evaluation of a Mindfulness-Based Intervention With and Without Virtual Reality Dialectical Behavior Therapy((R)) Mindfulness Skills Training for the Treatment of Generalized Anxiety Disorder in Primary Care: A Pilot Study. Front Psychol. 2019;10:55. doi:10.3389/fpsyg.2019.00055 30745888
104 Javaherirenani R, Mortazavi SS, Shalbafan M, Ashouri A, Farani AR. Virtual reality exposure and response prevention in the treatment of obsessive-compulsive disorder in patients with contamination subtype in comparison with in vivo exposure therapy: a randomized clinical controlled trial. BMC Psychiatry. Nov 28 2022;22(1):740. doi:10.1186/s12888-022-04402-3 36443695
105 Rizzo A, Reger G, Perlman K, . Virtual reality posttraumatic stress disorder (PTSD) exposure therapy results with active duty OIF/OEF service members. 2011;
106 Verdi EK, Katz AC, Gramlich MA, Rothbaum BO, Reger GM. Impact of dissociation on exposure therapy for PTSD outcomes and Adherence among U.S. Military service members. J Psychiatr Res. Oct 2023;166:86–91. doi:10.1016/j.jpsychires.2023.09.011 37751659
107 Reger GM, Smolenski D, Edwards-Stewart A, Skopp NA, Rizzo AS, Norr A. Does Virtual Reality Increase Simulator Sickness During Exposure Therapy for Post-Traumatic Stress Disorder? Telemed J E Health. Sep 2019;25(9):859–861. doi:10.1089/tmj.2018.0175 30379634
108 Kim H, Kim BH, Kim MK, Eom H, Kim JJ. Alteration of resting-state functional connectivity network properties in patients with social anxiety disorder after virtual reality-based self-training. Front Psychiatry. 2022;13:959696. doi:10.3389/fpsyt.2022.959696 36203841
109 Ma L, Kruijt AW, Ek AK, . Seeking neutral: A VR-based person-identity-matching task for attentional bias modification - A randomised controlled experiment. Internet Interv. Sep 2020;21:100334. doi:10.1016/j.invent.2020.100334 32904341
110 Ngai I, Tully EC, Anderson PL. The course of the working alliance during virtual reality and exposure group therapy for social anxiety disorder. Behav Cogn Psychother. Mar 2015;43(2):167–81. doi:10.1017/S135246581300088X 24131567
111 Price M, Anderson PL. Outcome expectancy as a predictor of treatment response in cognitive behavioral therapy for public speaking fears within social anxiety disorder. Psychotherapy (Chic). Jun 2012;49(2):173–9. doi:10.1037/a0024734 21967073
112 Price M, Anderson PL. The impact of cognitive behavioral therapy on post event processing among those with social anxiety disorder. Behav Res Ther. Feb 2011;49(2):132–7. doi:10.1016/j.brat.2010.11.006 21159328
113 Anderson PL, Edwards SM, Goodnight JR. Virtual Reality and Exposure Group Therapy for Social Anxiety Disorder: Results from a 4–6 Year Follow-Up. Cognitive Therapy and Research. 2016;41(2):230–236. doi:10.1007/s10608-016-9820-y
114 Klein H, Bartnicki J, Brown JE, . Consequences for Norway from a hypothetical accident at the Sellafield reprocessing plant: Atmospheric transport of radionuclides. J Environ Radioact. Oct 2021;237(2):106703. doi:10.1016/j.jenvrad.2021.106703 34274887
115 Anderson P, Jacobs CH, Lindner GK, . Cognitive behavior therapy for fear of flying: sustainability of treatment gains after September 11. Behav Ther. Mar 2006;37(1):91–7. doi:10.1016/j.beth.2005.05.001 16942964
116 Wiederhold BK, Wiederhold MD. Three-year follow-up for virtual reality exposure for fear of flying. Cyberpsychol Behav. Aug 2003;6(4):441–5. doi:10.1089/109493103322278844 14511458
117 van der Stouwe ECD, Booij SH, Geraets CNW, . Daily-life stress reactivity and recovery following virtual-reality-based cognitive behavioral therapy in patients with a psychotic disorder. Front Psychiatry. 2024;15:1360165. doi:10.3389/fpsyt.2024.1360165 38745779
118 Leff J, Williams G, Huckvale M, Arbuthnot M, Leff AP. Avatar therapy for persecutory auditory hallucinations: What is it and how does it work? Psychosis. 2014;6(2):166–176.24999369
119 Leff J, Williams G, Huckvale MA, Arbuthnot M, Leff AP. Computer-assisted therapy for medication-resistant auditory hallucinations: proof-of-concept study. Br J Psychiatry. Jun 2013;202(6):428–33. doi:10.1192/bjp.bp.112.124883 23429202
120 Du Sert OP, Potvin S, Lipp O, . Virtual reality therapy for refractory auditory verbal hallucinations in schizophrenia: a pilot clinical trial. Schizophrenia research. 2018;197:176–181.29486956
121 Basant, Pradhan P, Pinninti N, Rathod S. Chapter 4 AVATAR Therapy for Refractory Auditory Hallucinations. Springer International Publishing; 2016.
122 Singh K. ISO 14155: clinical investigation of medical devices for human subjects. Medical device guidelines and regulations handbook. Springer; 2022:1–18.
123 Ronaghi MH, Ronaghi M. How Does Virtual Reality Technology Affect Suicidal Ideation in Society? Int J Ment Health Nurs. Feb 2025;34(1):e13443. doi:10.1111/inm.13443 39394638
124 Loucks L, Yasinski C, Norrholm SD, . You can do that?!: Feasibility of virtual reality exposure therapy in the treatment of PTSD due to military sexual trauma. Journal of anxiety disorders. 2019;61:55–63.30005843
125 Loucks L, Rizzo A, Rothbaum BO. Virtual reality exposure for treating PTSD due to military sexual trauma. Journal of Clinical Psychology. 2025;81(2):81–92.39526899
126 Emmelkamp PMG, Meyerbroker K. Virtual Reality Therapy in Mental Health. Annu Rev Clin Psychol. May 7 2021;17(1):495–519. doi:10.1146/annurev-clinpsy-081219-115923 33606946
127 Rothbaum BO, Hodges L, Alarcon R, . Virtual reality exposure therapy for PTSD Vietnam Veterans: a case study. J Trauma Stress. Apr 1999;12(2):263–71. doi:10.1023/A:1024772308758 10378165
128 Hodges LF, Rothbaum BO, Kooper R, Opdyke D, Meyer T. Virtual environments for exposure therapy. IEEE Computer Journal, July. 1995:27–34.
129 Rizzo A, Koenig S, Lange B. Clinical virtual reality: The state of the science. 2023; doi:10.1037/0000308-023
130 Rizzo A. CBITs Digital Mental Health Lecture Series featuring Skip Rizzo Title of Talk: Clinical Virtual Reality: A Brief Review of the Future! Accessed 8/21/2025. https://www.youtube.com/watch?v=2CuwpVrB0XY
131 Rizzo AS, Koenig ST. Is clinical virtual reality ready for primetime? Neuropsychology. Nov 2017;31(8):877–899. doi:10.1037/neu0000405 29376669
132 Allen EN, Chandler CI, Mandimika N, Leisegang C, Barnes K. Eliciting adverse effects data from participants in clinical trials. Cochrane Database Syst Rev. Jan 16 2018;1(1):MR000039. doi:10.1002/14651858.MR000039.pub2 29372930
133 Dewar M, Paradis A, Fortin CA. Identifying trajectories and predictors of response to psychotherapy for post-traumatic stress disorder in adults: A systematic review of literature. The Canadian Journal of Psychiatry. 2020;65(2):71–86.31535576