# ACKNOWLEDGMENTS

The authors are grateful to Amy Claussen, MLIS for expertise and execution of the literature search for this review, Steffi Yang for data abstraction efforts, Timothy Wilt, MD, MPH for conceptualization, methodology, and supervision, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Anne Lord Bailey, PharmD
  Executive Director, Strategic Initiatives Lab
  VA Immersive Lead
  Digital Health Office

- Pearl McGee-Vincent, PsyD
  National Manager for Digital Mental Health
  VA Office of Mental Health

- Sonya Norman, PhD
  Director
  PTSD Consultation Program
  Professor of Psychiatry
  University of California San Diego

- Eric Hawkins, PhD
  Director
  Seattle Center of Excellence in Substance Addiction Treatment and Education

- Eric Hermes, MD
  Director, Psychotropic Drug Safety Initiative
  VA Office of Mental Health

- Paula Schnurr, PhD
  Executive Director, National Center for PTSD
  VA Office of Mental Health

- Tamara Campbell, MD
  Executive Director
  VA Office of Mental Health

## Technical Expert Panel

To ensure robust, scientifically relevant work, the technical expert panel (TEP) guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members included:

- Brian Kiluk, PhD
  Director, Technology-Based Interventions
  Associate Professor of Psychiatry
  Yale School of Medicine

- James McKay, PhD
  Director
  Philadelphia VA Center of Excellence in Substance Addiction Treatment and Education (CESATE)
  Professor, Psychiatry
  Perelman School of Medicine, University of Pennsylvania

- Susan Persky, PhD
  Director, Immersive Simulation Program
  National Human Genome Research Institute, Social and Behavioral Research Branch

- Albert “Skip” Rizzo, PhD
  Director of Medical Virtual Reality, Institute for Creative Technologies
  Research Professor
  University of Southern California

- Barbara Rothbaum, PhD
  Director, Emory Healthcare Veterans Program
  Associate Vice Chair, Clinical Research
  Department of Psychiatry, Emory School of Medicine