# Executive Summary

KEY FINDINGS

### Characteristics of studies evaluating virtual reality (VR) for treatment of posttraumatic stress disorder (PTSD), flying phobia, alcohol use disorder, stimulant use disorder, depression, and schizophrenia spectrum disorders (Key Question [KQ] 1)

- Most VR interventions were conducted in supervised health care or laboratory settings (k = 42); only 2 studies evaluated a VR intervention for home use (1 for social anxiety disorder, 1 for depression).
- There was substantial variation in VR session number and the total duration of interventions.
- Young and middle-aged adults (mean age <65) comprised the main study population across various disorders, except for depression studies.
- Studies evaluating VR exposure therapy interventions dominated the evidence base, comprising all studies for PTSD, specific phobia of flying, alcohol use disorder, and stimulant use disorder.
- VR interventions to treat depression primarily involved relaxation and exercise for older adults.
- For schizophrenia spectrum disorders, VR interventions varied in content, including social cognition training (k = 6), cognitive behavioral therapy (CBT, k = 2), personified voices therapy (k = 2), and others.
- No study evaluated whether VR characteristics (embodiment, interactivity, or multisensory stimulation) impacted VR intervention effects or engagement.

### Effects of VR interventions for select mental health disorders (as noted above, KQ1)

- Compared with non-VR prolonged exposure (PE) therapy, VR PE therapy for PTSD may result in less symptom severity improvement immediately post-intervention, and little to no difference at 3 months post-intervention (both low certainty of evidence [COE]). VR PE therapy probably results in less treatment response immediately post-intervention (moderate COE).
- For social anxiety disorder, the evidence is very uncertain on the effects of VR exposure therapy alone, or of CBT plus VR exposure therapy, on symptom severity (all very low COE) as compared to waitlist or to CBT plus non-VR exposure therapy.
- For specific phobia of flying, the evidence is very uncertain on the effect of VR exposure on symptom severity or flight completion, compared with either non-VR exposure or waitlist (very low COE).
- For alcohol use disorder, the 2 studies were too heterogeneous and COE was not assessed.
- For stimulant use disorder, VR exposure therapy may result in less craving immediately post-intervention (low COE) as compared to treatment as usual.
- The evidence is very uncertain on the effect of VR relaxation and exercise on depressive symptoms immediately post-intervention, compared with exercise and non-VR relaxation (very low COE).
- For schizophrenia spectrum disorders, the evidence is very uncertain on the effect of VR CBT on psychotic symptom severity immediately post-intervention, as compared to treatment as usual (very low COE). The evidence is also very uncertain on the effect of VR personified voices therapy on psychotic symptom severity, immediately post-intervention and at 3 months post-intervention, as compared to non-VR CBT (both very low COE).
- Adverse events were often not assessed, and when reported, not systematically assessed for all arms. This contributed to the uncertainty in adverse effects of VR interventions across mental health disorders.

### Effects of VR interventions for suicide prevention (KQ2)

- Only 1 eligible RCT evaluated a VR intervention for suicide prevention; this Iranian study was rated high RoB due to substantial methodological concerns and only reported limited findings on suicide ideation (assessed by unclear measures).

Over one quarter of Veterans in VA care have a diagnosed mental health disorder. Depressive disorders, PTSD, and substance use disorders (SUD) are most prevalent, and co-occurrence of diagnoses is common. Along with serious mental illnesses such as schizophrenia, all of these mental health disorders are associated with increased risks of hospitalization, premature death, and suicide among Veterans. Suicide prevention remains a high priority for VA. Evidence-based psychotherapies for mental health conditions, such as prolonged exposure therapy for PTSD, are effective yet remain underutilized in VHA clinical settings, prompting multiple VA initiatives to implement evidence-based psychotherapies for mental health conditions. Interest in delivering psychotherapies through virtual reality technology is rising, and systematic assessment is necessary to determine the evidence base for rollout of these interventions in VA.

VR provides a technological means of delivering a range of health interventions by situating a participant in a computer-generated virtual environment. A key aspect of VR is immersion: its capacity to make a participant feel present in the created virtual environment rather than in their physical environment. VR properties that can contribute to a person’s sense of being present in that immersive environment include interactivity (participants’ ability to take actions that have impact on the virtual experience) and multisensory stimulation (such as olfactory or tactile effects). In recent years, VR technology has become more affordable and more capable of producing realistic environments, and clinical applications are proliferating. VA’s clinical use of immersive VR technology has expanded from 5 clinical sites in 2017 to 160 sites across all 50 states, Guam, Puerto Rico, and American Samoa as of 2023, with a focus on use for mental health conditions including PTSD, SUD, and depression. Expansion of VR in clinical settings is partially driven by the perception of patient enthusiasm for the technology.

The conceptual basis for VR’s therapeutic effects depends on the interventions’ core elements and proposed mechanisms of action. For example, VR environments can create exposure scenarios within exposure therapy for PTSD or for specific phobias. VR characteristics such as multisensory stimulation and therapist control of stimuli distinguish VR exposure from imaginal exposure, while elements of both therapist and participant control within pre-programmed scenarios distinguish VR exposure from in vivo exposure. Whether VR exposure scenarios differ in benefits and harms from non-VR exposure approaches is an empirical question specific to the therapeutic approach, the comparison groups, the mental health conditions being treated, and the population involved. Use of VR may also have important implications for participant engagement. Finally, consideration of broad VR application requires consideration of harms and adverse events.

The VA Office of Mental Health and VA Office of Innovation and Learning, with operational partners including the VA Digital Health Office and the VA National Center for PTSD, requested this review of available evidence on VR interventions for mental health conditions and suicide prevention. The goal of this review is to inform VR implementation efforts in VA mental health care and identify evidence gaps to inform future research efforts.

In this systematic review, we synthesize evidence on the benefits and harms of fully immersive VR interventions for treating mental health disorders and for suicide prevention. We present findings by mental health disorder, beginning with PTSD. Within each condition, we provide results by VR intervention type, then by comparator type.

## CURRENT REVIEW

The a priori protocol for this review was registered on the Open Science Framework (https://doi.org/10.17605/OSF.IO/RXWBH). We searched MEDLINE, Embase, CENTRAL, and PsycINFO from inception to December 2024, using key words and subject headings for virtual reality and eligible mental health disorders. Additional citations were identified from hand-searching reference lists and consultation with content experts. Clinical trial registries (Clinical Trials, Australian and New Zealand Trials Registry, and ISRCTN (http://www.isrctn.com/)) were also searched for recently completed and ongoing trials.

Eligible studies included individuals diagnosed with specific mental health disorders (eg, being treated in a mental health clinic), used clinician-assessed measures to determine the diagnosis, or used participant-reported measures that had been validated for diagnostic accuracy. Many disorders of interest were included, such as PTSD, depressive disorders, social anxiety disorder, and others. Outcomes of interest were symptom severity, treatment response and recovery, suicidal ideation and/or behaviors, adverse events, health-related quality of life, and treatment engagement. Studies were required to be randomized controlled trials (RCTs); observational cohorts with ≥ 1 concurrent comparator group; or a single-arm observational cohort (only if including ≥ 100 participants and reporting results on adverse events).

With input from the technical expert panel, we prioritized the following disorders for detailed abstraction of study characteristics and findings: PTSD, social anxiety, specific phobia of flying, alcohol use disorder, stimulant use disorder, depressive disorders, and schizophrenia spectrum and other psychotic disorders. Abstracted data included participant characteristics and eligibility criteria, intervention characteristics (eg, content, duration and frequency of sessions), study design and settings, and findings for outcomes of interest, as noted above. For synthesis of findings, we first grouped studies by mental health disorder and then by intervention and comparator characteristics. We conducted meta-analyses when there were ≥ 3 studies for a given disorder that evaluated sufficiently similar interventions and comparators, and reported the same outcome (eg, comparable measures of symptom severity). Otherwise, we provided narrative syntheses of study characteristics and findings.

For efficacy outcomes, we focused on between-group comparisons of the mean scores at follow-up time points.

We used the Grading of Recommendations, Assessment, Development, and Evaluation (GRADE) methodology to rate overall COE as high, moderate, low, or very low. We systematically evaluated 5 domains: study limitations (risk of bias [RoB]), imprecision (limitations in precision of effect estimates), inconsistency (in direction and magnitude of effects across studies), indirectness (applicability of the results), and other considerations (including publication bias). For imprecision, we also considered the optimal information size (OIS) for efficacy outcomes and adverse events.

We screened 5,341 unique citations and reviewed the full texts for 424 publications. Of these, we identified 100 eligible articles reporting 84 unique primary studies (83 RCTs, 1 observational study). The 84 eligible RCTs addressed a variety of mental health disorders for KQ1, with about a fourth focusing on specific phobias (k = 20). Overall, 45 studies evaluated VR interventions for prioritized disorders: PTSD (k = 6), social anxiety disorder (k = 10), specific phobia of flying (k = 7), alcohol use disorder (AUD) (k = 2), stimulant use disorder (k = 2), depressive disorders (k = 6), and schizophrenia spectrum disorders (k =12). The remaining studies focused on other disorders, including agoraphobia and/or panic disorder (k =10), other specific phobias (k = 12), tobacco use disorder (k = 8), bipolar disorder (k = 5), general anxiety disorder (k = 2), and obsessive compulsive disorder (k = 1). KQ1 studies were generally small but some included more than 100 participants (k = 11). These were conducted in various countries around the world, with nearly half occurring in Europe (k = 44), a fourth in North America (k = 20), and fewer in Asia (k = 16), Australia/New Zealand (k = 2), and South America (k = 1). The most commonly reported outcomes were symptom severity and treatment response or recovery, whereas quality of life and suicidal ideation and/or behaviors were rarely assessed.

Among studies addressing KQ1 prioritized disorders, the most frequently evaluated use of VR within an intervention was VR exposure therapy (with or without CBT), including most studies for PTSD (k = 6), social anxiety disorder (k = 9), specific phobia of flying (k = 7), alcohol use disorder (k = 2), and stimulant use disorder (k = 2). In contrast, studies addressing depressive symptoms or schizophrenia spectrum disorders evaluated a variety of VR interventions not necessarily based on evidence-based psychotherapies, with a focus on skills training in the majority of schizophrenia spectrum studies (k = 8). Characteristics of VR varied across studies, with embodiment, interactivity, and multisensory stimulation most consistently present in VR exposure therapy for PTSD. Comparators for evaluated VR interventions also varied across studies, with comparisons to analogous non-VR therapies (ie, therapy content similar to that of the VR intervention) most common in phobia of flying interventions (k = 8). Most studies were conducted in supervised health care or laboratory settings (k = 44).

### KQ1 Benefits and Harms of VR Interventions for Prioritized Mental Health Disorders

ES Table 1 summarizes certainty of evidence for included outcomes evaluated in KQ1 studies.

ES Table 1 Summary of Key Findings for KQ1 Outcomes

Disorder | Comparison | Outcome | Total N (# Studies) | Certainty of Evidence | Summary Statement
PTSD | VR Prolonged Exposure vs Non-VR Prolonged Exposure | Symptom Severity | 277 (3) | ⊕⊕◯◯; Low | VR prolonged exposure may result in less improvement in symptom severity immediately post-intervention. There may be little to no differences at 3 months.
PTSD | VR Prolonged Exposure vs Non-VR Prolonged Exposure | Treatment Response/Recovery | 194 (2) | ⊕⊕⊕◯; Moderate | VR prolonged exposure probably results in less treatment response post-intervention.
PTSD | VR Prolonged Exposure vs Non-VR Prolonged Exposure | Adverse Events | 300 (2) | ⊕⊕◯◯; Low | VR prolonged exposure may result in little to no difference in adverse events.
Social anxiety disorder | VR Exposure vs Waitlist | Symptom Severity | 187 (4) | ⊕◯◯◯; Very low | The evidence is very uncertain on the effect of VR exposure on symptom severity post-intervention.
Social anxiety disorder | VR Exposure vs Waitlist | Adverse Events | 197 (4) | ⊕◯◯◯; Very low | The evidence is very uncertain on the effect of VR exposure on adverse events.
Social anxiety disorder | CBT + VR Exposure vs Waitlist | Symptom Severity | 244 (4) | ⊕◯◯◯; Very low | The evidence is very uncertain on the effect of CBT coupled with VR exposure on symptom severity post-intervention.
Social anxiety disorder | CBT + VR Exposure vs Waitlist | Adverse Events | 157 (2) | ⊕◯◯◯; Very low | The evidence is very uncertain on the effect of CBT coupled with VR exposure on adverse events.
Social anxiety disorder | CBT + VR Exposure Therapy vs CBT + Non-VR Exposure Therapy | Symptom Severity | 192 (4) | ⊕◯◯◯; Very low | The evidence is very uncertain on the effect of CBT coupled with VR exposure therapy on symptom severity post-intervention.
Social anxiety disorder | CBT + VR Exposure Therapy vs CBT + Non-VR Exposure Therapy | Adverse Events | 95 (2) | ⊕◯◯◯; Very low | The evidence is very uncertain on the effect of CBT coupled with VR exposure on adverse events.
Specific phobia of flying | VR Exposure vs Non-VR Exposure | Symptom Severity | 65 (2) | ⊕◯◯◯; Very low | The evidence is very uncertain on the effect of VR exposure on symptom severity immediately post-intervention.
Specific phobia of flying | VR Exposure vs Non-VR Exposure | Treatment Response | 65 (2) | ⊕◯◯◯; Very low | The evidence is very uncertain on the effect of VR exposure on flight completion immediately post-intervention.
Specific phobia of flying | CBT + VR Exposure vs CBT + Non-VR Exposure | Symptom Severity | 184 (2) | ⊕◯◯◯; Very low | The evidence is very uncertain on the effect of VR exposure on symptom severity immediately post-intervention, at 6 months, and at 12 months.
Specific phobia of flying | CBT + VR Exposure vs CBT + Non-VR Exposure | Treatment Response | 135 (3) | ⊕◯◯◯; Very low | The evidence is very uncertain on the effect of VR exposure on flight completion post-intervention.
Specific phobia of flying | VR Exposure vs Waitlist | Symptom Severity | 87 (2) | ⊕◯◯◯; Very low | The evidence is very uncertain on the effect of CBT and VR exposure on symptom severity post-intervention.
Specific phobia of flying | VR Exposure vs Waitlist | Treatment Response | 80 (2) | ⊕⊕◯◯; Low | CBT and VR exposure may lead to higher flight completion post-intervention.
Stimulant use disorder | VR Exposure vs TAU | Symptom Severity | 119 (2) | ⊕⊕◯◯; Low | VR exposure therapy may result in lower craving post-intervention.
Depressive disorders | VR Relaxation and Exercise vs Non-VR Relaxation and Exercise | Symptom Severity | 343 (4) | ⊕◯◯◯; Very low | The evidence is very uncertain about the effect of VR relaxation and exercise on symptom severity post-intervention.
Schizophrenia spectrum disorders | VR CBT + TAU vs TAU alone | Symptom Severity | 125 (2) | ⊕◯◯◯; Very low | The evidence is very uncertain on the effect of VR CBT + TAU on psychotic symptom severity post-intervention.
Schizophrenia spectrum disorders | VR CBT + TAU vs TAU alone | Adverse Events | 125 (2) | ⊕◯◯◯; Very low | The evidence is very uncertain on the effect of VR CBT + TAU on adverse events post-intervention.
Schizophrenia spectrum disorders | VR Personified Voices Therapy vs Non-VR CBTp | Symptom Severity | 120 (2) | ⊕◯◯◯; Very low | The evidence is very uncertain on the effect of VR personified voices therapy on psychotic symptom severity post-intervention and 3 months.

Notes. GRADE Working Group grades of evidence:

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Abbreviations. CBT=cognitive behavioral therapy; CBTp=cognitive behavioral therapy for psychosis; TAU=treatment as usual; VR=virtual reality.

### KQ2 Benefits and Harms of VR Interventions for Suicide Prevention

Only 1 study evaluated a VR intervention for suicide prevention, a 3-arm Iranian RCT that was rated high risk of bias, primarily due to substantial concerns regarding lack of reported information on intervention completion and loss to follow-up, and whether analytic methods accounted for these issues. This study compared VR-based education and counselling versus non-VR education and counselling versus no intervention. Although authors reported that there were greater reductions in these scores for the VR group (compared with both non-VR education and counseling, and the no treatment arms), it is unclear that this indicated any meaningful change in suicide ideation given the lack of information regarding assessment and scoring. No other eligible outcomes were assessed.

### Evidence Gaps and Future Research

For PTSD, specific phobia of flying, alcohol use disorder, and stimulant use disorder, all VR interventions involved exposure therapy. Despite sharing the same underlying conceptual basis for effectiveness, unanswered questions remain about effects and mechanisms of VR exposure therapy across the varying target populations. For example, all studies of VR prolonged exposure therapy for PTSD included exposure to combat trauma, and found that VR exposure may have effects similar to standard imaginal exposure at long-term follow-up. In these interventions, VR exposure involved virtual combat scenarios meant to emulate combat service in Iraq and/or Afghanistan. While therapists controlled the delivery of many features of stimuli within scenarios, some fundamental elements of scenarios (such as specific combat environment visuals and sounds) were preset and unchangeable at point of care. Findings from this specific combat-exposure VR setup may not generalize to other combat scenarios, and arguably cannot generalize to PTSD caused by non-combat traumas. Similarly, included studies used VR interventions designed to be specific both to the sociocultural context of use for both alcohol use and stimulant use disorders, and it is not clear that findings would generalize to other substances and sociocultural settings.

VR exposure scenarios require substantial tailoring to address specific clinical situations, including the type of mental health disorder (eg, PTSD vs social anxiety disorder). The development and testing of VR interventions to treat mental health disorders has required the dedication and committed efforts of multidisciplinary teams with both expertise in rapidly evolving VR technologies and clinical experience with mental health disorders. Thus, in all the studies included here, VR scenarios were largely preset with limited customization at the time a therapist is considering how exposure therapy should be applied for individual participants. In the future, advancements in VR technology may increase the level of flexibility and customization that can be accomplished by clinics or mental health professionals at the time they would be initiating treatments, thus leading to greater efficiencies and usability (by avoiding the need to acquire and learn entirely new VR systems for specific disorders and clinical situations). However, to understand whether these potential improvements in VR technology actually lead to better outcomes (or greater access) for patients, future research will be needed to compare these treatments to other forms of therapy, particularly non-VR exposure (eg, imaginal or in vivo exposure).

Additionally, mechanistic research to clarify the underlying key contributions of virtual exposure remains key for determining the added value of VR interventions. It remains unclear when VR exposure may replace either imaginal or in vivo exposure across multiple disorders, or when and how VR exposure may lead to greater efficacy by functioning in ways different from both imaginal and in vivo exposure. For example, while it has been proposed that VR exposure adds value to real-world exposure therapy by allowing finer therapist control of stimuli delivery and processing, included studies did not specifically address how this would be the potential mechanism (as distinct from other treatment differences) between VR and non-VR arms, or indicate under what circumstances (or for which patients) this element of therapist control would have been most beneficial.

VR technology has advanced quickly in recent years, but the ability of technology to improve efficacy depends on the mechanistic role of the VR characteristics that future technological progress can offer. Within exposure therapies, VR characteristics such as interactivity (a measure of participant control) and multisensory stimulation varied, but we found no studies comparing VR exposure therapies that differed regarding these key elements. Studies evaluating effects in relation to such mechanistically relevant VR characteristics could clarify when and how VR can add value to specific types of exposure therapy.

Beyond exposure therapy for above disorders, VR relaxation and exercise interventions were evaluated for depression in older adults and demonstrated some potential for greater improvement of symptoms, compared with non-VR analogous interventions. However, the COE was very low due to concerns with study methodology and the applicability of findings from these specific populations to the greater diversity of adults with depression. Future work is needed to demonstrate whether these VR interventions may work well for young and middle-aged adults, and to investigate comparative efficacy against other treatments, both pharmacological and psychological.

The schizophrenia spectrum disorder studies, in contrast, comprised a wide array of VR-delivered therapy types, most in early phases of development, for participants with psychoses. The majority of studies leveraged VR environments to build participants’ social and/or cognition skills, with elements of therapist control and/or participant control that are infeasible in the real world (such as therapists determining virtual entities’ appearance or behaviors to allow participants to build social interaction skills, or participants expressing emotion perception by choosing a virtual entity’s facial expression). VR personified voices therapy, in contrast, stands out as an example of a therapy in which VR enables a therapeutic approach—creating a naturalistic, therapist-controlled entity that personifies a patient’s audiovisual hallucinations—whose fundamentals cannot be achieved in the real world. This use of VR is distinct from approaches that seek to leverage VR as a means of delivery for therapies that have a strong evidence base as non-VR treatments, and was unique among VR therapies identified in this review. For such new approaches that leverage elements available only in VR space, studies evaluating the impact of presence versus absence of key VR characteristics (such as elements of therapist control, or levels of interactivity and/or multisensory stimulation) could be key both to understanding effects and maximizing feasibility of implementation.

Most included studies did not use clear and systematic methods to evaluate adverse events for VR interventions and comparator groups. This is an important gap for future research to address because this information will inform clinician decision-making, promote shared decision-making with well-informed patients, and potentially impact prioritization of limited medical resources. Trials should assess adverse events for each treatment arm using open-ended questions and/or checklists administered to all participants on a regular basis. Additionally, studies should clearly define the severity of adverse events (eg, serious events can be defined as life threatening, requiring hospitalization, or resulting in persistent disability) and rates of events that led to discontinuation of the treatment. Evaluation of adverse events will likely also require larger studies that are adequately powered to detect differences in adverse event rates across groups.

Research on heterogeneity of treatment effects may be key to understanding when and how VR delivery can improve either therapy effectiveness or participant engagement, and when and how it may have additional risks. We did not identify consistent trends with respect to VR’s impact on therapy attendance in included studies, and most studies did not evaluate any other measures of patient engagement with VR. Few included studies evaluated relationships between participant characteristics and clinical outcomes of VR interventions. Heterogeneity of VR intervention effects, in terms of both clinical outcomes and treatment engagement, is an area broadly in need of study. Future studies should be designed and powered to assess outcomes in prespecified subgroups with variation in key characteristics relevant to the potential mechanisms of effect; the most rigorous study design would be randomized trials with sufficient power and stratified sampling to detect potential differences in efficacy.

With respect to low-touch therapies (which may be more appropriate for lower severity depressive symptoms, fear of public speaking, or phobia of flying), it is theoretically possible that VR interventions could enable immersive therapies—potentially with therapist control of key elements—to be delivered in home settings. Our review identified only 2 studies of VR interventions for home use (VR pleasant activities to treat depressive disorder and VR exposure to treat social anxiety disorder). If an important goal is to increase reach of psychotherapies by using VR as a means of enhancing treatments delivered via telehealth or independent home use, then effectiveness and safety of home use must be evaluated for these future VR interventions.

Finally, there is a profound evidence gap regarding VR interventions for suicide prevention. Future work is needed to understand whether VR interventions can reduce suicide risk, and where these may be useful in the context of adequate evaluation and treatment for specific mental health disorders.

### Implications for Policy and Practice

For PTSD, social anxiety disorder, specific phobia of flying, alcohol use disorder, and stimulant use disorder, the reviewed comparative effectiveness evidence indicated that VR exposure therapy interventions performed similarly to non-VR evidence-based psychotherapies. As studied, these therapies also require substantial therapist involvement, and involve preset content with limited customizability at point of care. The rationale for implementing VR exposure therapy interventions in widespread clinical contexts remains unclear, pending identification of subpopulations or contexts in which VR may add value in terms of effectiveness and/or patient engagement in therapy.

VR interventions for depressive symptoms were mostly targeting community populations of older adults with depressive symptoms, and may be useful for improving access to self-management treatments (such as relaxation and exercise) for these populations. Before focusing resources on implementing these, it may be best to evaluate how they compare with other low-touch interventions that address mental health for older adults.

For schizophrenia spectrum disorders, novel VR interventions are in early phases of development, and benefits and harms require more definitive study before clinical implementation.

## CONCLUSIONS

VR exposure therapy for PTSD may be less effective, or have little to no difference in effect, when compared with non-VR exposure therapy. For stimulant use disorder, VR exposure therapy may result in less craving, compared to treatment as usual. The evidence is uncertain regarding the effects of VR therapies for social anxiety disorder, flying phobia, depression, and schizophrenia spectrum disorders. The evidence is also very uncertain regarding adverse events of VR interventions across prioritized disorders, and there is a lack of evidence on VR interventions for suicide prevention. In addition to the need for higher quality studies addressing the areas lacking evidence, future research should focus on clarifying the impacts of key VR characteristics on treatment effects, and how population characteristics may be important for both effectiveness and engagement.