# DISCUSSION

## SUMMARY OF KEY FINDINGS

### Characteristics of Evidence Base for KQ1 Prioritized Disorders

- Most VR interventions were conducted in supervised health care or laboratory settings (k = 42); only 2 studies evaluated a VR intervention for home use (1 for social anxiety disorder, 1 for depression). There was substantial variation in VR session number and the total duration of interventions.
- Young and middle-aged adults (mean age <65) comprised the main study population across various disorders, except for depression studies.
- Studies evaluating VR exposure therapy interventions dominated the evidence base, comprising all studies for PTSD, specific phobia of flying, alcohol use disorder, and stimulant use disorder.
- VR interventions to treat depression primarily involved relaxation and exercise for older adults.
- For schizophrenia spectrum disorders, VR interventions varied in content, including social cognition training (k = 6), CBT (k =2), personified voices therapy (k=2), and others.
- No study evaluated whether VR characteristics (embodiment, interactivity, or multisensory stimulation) impacted VR intervention effects or engagement.

### Effects of VR Interventions for KQ1 Prioritized Disorders

- Compared with non-VR PE therapy, VR PE therapy for PTSD may result in less symptom severity improvement immediately post-intervention, and little to no difference at 3 months post-intervention (both low COE). VR PE therapy probably results in less treatment response immediately post-intervention (moderate COE).
- For social anxiety disorder, the evidence is very uncertain on the effects of VR exposure therapy alone, or of CBT plus VR exposure therapy, on symptom severity (all very low COE) as compared to waitlist or to CBT plus non-VR exposure therapy.
- For specific phobia of flying, the evidence is very uncertain on the effect of VR exposure on symptom severity or flight completion, compared with either non-VR exposure or waitlist (very low COE).
- For alcohol use disorder, the 2 studies were too heterogeneous and COE was not assessed.
- For stimulant use disorder, VR exposure therapy may result in less craving immediately post-intervention (low COE) as compared to treatment as usual.
- The evidence is very uncertain on the effect of VR relaxation and exercise on depressive symptoms immediately post-intervention, compared with exercise and non-VR relaxation (very low COE).
- For schizophrenia spectrum disorders, the evidence is very uncertain on the effect of VR CBT on psychotic symptom severity immediately post-intervention, as compared to treatment as usual (very low COE). The evidence is also very uncertain on the effect of VR personified voices therapy on psychotic symptom severity, immediately post-intervention and at 3 months post-intervention, as compared to non-VR CBT (both very low COE).
- Adverse events were often not assessed, and when reported, not systematically assessed for all arms. This contributed to the uncertainty in adverse effects of VR interventions across mental health disorders.

### VR Interventions for Suicide Prevention (KQ2)

- One eligible RCT evaluated a VR intervention for suicide prevention; this Iranian study was rated high RoB due to substantial methodological concerns and only reported limited findings on suicide ideation (assessed by unclear measures)

## EVIDENCE GAPS AND FUTURE RESEARCH

For PTSD, specific phobia of flying, alcohol use disorder, and stimulant use disorder, all VR interventions involved exposure therapy. The earliest studies were of specific phobia of flying, with VR exposure therapy expanding in recent years into other mental health disorders. Despite sharing the same underlying conceptual basis for effectiveness, unanswered questions remain about effects and mechanisms of VR exposure therapy across the varying target populations. For example, all studies of VR PE for PTSD included exposure to combat trauma, and found that VR exposure may have effects similar to standard imaginal exposure at long-term follow-up. In these interventions, VR exposure involved virtual combat scenarios meant to emulate combat service in Iraq and/or Afghanistan. While therapists controlled the delivery of many features of stimuli within scenarios, some fundamental elements of scenarios (such as specific combat environment visuals and sounds) were preset and unchangeable at point of care. Findings from a bespoke combat-exposure VR setup may not generalize to other combat scenarios, and arguably cannot generalize to PTSD caused by non-combat traumas. For example, studies evaluating PTSD treatment effectiveness of bespoke VR exposure scenarios related to sexual violence are ongoing (without results in time for this report).^124,125^ Similarly, evaluated alcohol and stimulant use VR interventions were designed to be specific both to the substances used and the sociocultural context of use, and it is not clear that findings would generalize to other substances and settings.^126^

VR exposure scenarios require substantial tailoring to address specific clinical situations, including the type of mental health disorder (eg, PTSD vs social anxiety disorder). The development and testing of VR interventions to treat mental health disorders has required the dedication and committed efforts of multidisciplinary teams with both expertise in rapidly evolving VR technologies and clinical experience with mental health disorders. Thus, in all the studies included here, VR scenarios were largely preset with limited customization at the time a therapist is considering how exposure therapy should be applied for individual participants. In the future, advancements in VR technology may increase the level of flexibility and customization that can be accomplished by clinics or mental health professionals at the time they would be initiating treatments, thus leading to greater efficiencies and usability (by avoiding the need to acquire and learn entirely new VR systems for specific disorders and clinical situations). However, to understand whether these potential improvements in VR technology actually lead to better outcomes (or greater access) for patients, future research will be needed to compare these treatments to other forms of therapy, particularly non-VR exposure (eg, imaginal or in vivo exposure).

Additionally, mechanistic research to clarify the underlying key contributions of virtual exposure remains key for determining the added value of VR interventions. It remains unclear when VR exposure may replace either imaginal or in vivo exposure across multiple disorders,or when and how VR exposure may lead to greater efficacy by functioning in ways different from both imaginal and in vivo exposure. For example, while it has been proposed that VR exposure adds value to real-world exposure therapy by allowing finer therapist control of stimuli delivery and processing,^126–130^ included studies did not specifically address how this would be the potential mechanism (as distinct from other treatment differences) between VR and non-VR arms, or indicate under what circumstances (or for which patients) this element of therapist control would have been most beneficial.

VR technology has advanced quickly in recent years, and one could question whether findings from studies employing earlier technologies may generalize to state-of-the art VR interventions. The ability of technology to improve efficacy depends on the mechanistic role of the VR characteristics that future technological progress can offer. Within exposure therapies, VR characteristics such as interactivity (a measure of participant control) and multisensory stimulation varied, but we found no studies comparing VR exposure therapies that differed regarding these key elements. Studies evaluating effects in relation to such mechanistically relevant VR characteristics could clarify when and how VR can add value to specific types of exposure therapy.

Beyond exposure therapy for above disorders, VR relaxation and exercise interventions were evaluated for depression in older adults, and demonstrated some potential for greater improvement of symptoms, compared with non-VR analogous interventions. However, the COE was very low due to concerns with study methodology and the applicability of findings from these specific populations to the greater diversity of adults with depression. Future work is needed to demonstrate whether these VR interventions may work well for young and middle-aged adults, and to investigate comparative efficacy against other treatments, both pharmacological and psychological.

The schizophrenia spectrum disorder studies, in contrast, comprised a wide array of VR-delivered therapy types, most in early phases of development, for participants with psychoses. The majority of studies leveraged VR environments to build participants’ social and/or cognition skills, with elements of therapist control and/or participant control that are infeasible in the real world (such as therapists determining virtual entities’ appearance or behaviors to allow participants to build social interaction skills, or participants expressing emotion perception by choosing a virtual entity’s facial expression in response to communication). VR personified voices therapy, in contrast, stands out as an example of a therapy in which VR enables a therapeutic approach—creating a naturalistic, therapist-controlled entity that personifies a patient’s audiovisual hallucinations—whose fundamentals cannot be achieved in the real world. This use of VR is distinct from approaches that seek to leverage VR as a means of delivery for therapies that are evidence based in the physical world,^131^ and was unique among VR therapies identified in this review. As this new therapeutic concept remains actively under development for a population with severe mental illness refractory to evidence-based psychotherapies, benefits and harms remain in question and are still under study. For such new approaches that leverage elements available only in VR space, studies evaluating the impact of presence versus absence of key VR characteristics (such as elements of therapist control, or levels of interactivity and/or multisensory stimulation) could be key both to understanding effects and maximizing feasibility of implementation.

Most included studies did not use clear and systematic methods to evaluate adverse events for VR interventions and comparator groups. This is an important gap for future research to address because this information will inform clinician decision-making, promote shared decision-making with well-informed patients, and potentially impact prioritization of limited medical resources. Trials should assess adverse events for each treatment arm using open-ended questions and/or checklists administered to all participants on a regular basis.^132^ Additionally, studies should clearly define the severity of adverse events (eg, serious events can be defined as life threatening, requiring hospitalization, or resulting in persistent disability) and rates of events that led to discontinuation of the treatment. Evaluation of adverse events will likely also require larger studies that are adequately powered to detect differences in adverse event rates across groups.

Research on heterogeneity of treatment effects may be key to understanding when and how VR delivery can improve either therapy effectiveness or participant engagement, and when and how it may have additional risks. We did not identify consistent trends with respect to VR’s impact on therapy attendance in included studies, and most studies did not evaluate any other measures of patient engagement with VR. Few included studies evaluated relationships between participant characteristics and clinical outcomes of VR interventions. One notable example^20^ found that VR PE therapy was more effective for PTSD symptom severity among participants with depression, while non-VR PE was more effective among participants without depression, prompting further research questions about how VR may enhance exposure therapy for people with comorbid PTSD and depression, who tend to have worse PTSD outcomes in current care contexts.^133^ Findings suggest that heterogeneity of VR intervention effects, in terms of both clinical outcomes and treatment engagement, is an area broadly in need of study. This requires studies designed and powered to assess outcomes in prespecified subgroups with variation in key characteristics relevant to the potential mechanisms of effect; the most rigorous study design would be randomized trials with sufficient power and stratified sampling to detect potential differences in efficacy.

The severity of the mental health condition, which is often associated with the intensity of therapy and the need for clinician oversight, also informs the types of studies needed to build the VR evidence base. With respect to clinician-intensive therapies for mental health conditions with high acuity, it is essential to establish benefits and harms of VR approaches, and to determine whether VR adds value given the need for clinician presence regardless of technological approach. With respect to low-touch therapies (for appropriate conditions and symptom severity, such as low-intensity depressive symptoms, fear of public speaking, or phobia of flying), it is theoretically possible that VR interventions could enable immersive therapies—potentially with therapist control of key elements—to be delivered in home settings, which is arguably a potential benefit. Strikingly, our review identified only 2 studies of VR interventions for home use (VR pleasant activities to treat depressive disorder and VR exposure to treat social anxiety disorder). If an important goal is to increase reach of psychotherapies by using VR as a means of enhancing treatments delivered via telehealth or independent home use, then effectiveness and safety of home use must be evaluated for these future VR interventions.

Finally, there is a profound evidence gap regarding VR interventions for suicide prevention. We identified only a single, poor-quality study that reported findings that were challenging to understand and interpret. Future work is needed to understand whether VR interventions can reduce suicide risk, and where these may be useful in the context of adequate evaluation and treatment for specific mental health disorders.

## IMPLICATIONS FOR POLICY AND PRACTICE

For PTSD, social anxiety disorder, specific phobia of flying, alcohol use disorder, and stimulant use disorder, the reviewed comparative effectiveness evidence indicated that VR exposure therapy interventions performed similarly to non-VR evidence-based psychotherapies. As studied, these therapies also require substantial therapist involvement, and involve preset content with limited customizability at point of care. The rationale for implementing VR exposure therapy interventions in widespread clinical contexts remains unclear, pending identification of subpopulations or contexts in which VR may add value in terms of effectiveness and/or patient engagement in therapy.

VR interventions for depressive symptoms were mostly targeting community populations of older adults with depressive symptoms, and may be useful for improving access to self-management treatments (such as relaxation and exercise) for these populations. Before focusing resources on implementing these, it may be best to evaluate how they compare with other low-touch interventions that address mental health for older adults.

For schizophrenia spectrum disorders, novel VR interventions are in early phases of development, and benefits and harms require more definitive study before clinical implementation.

## LIMITATIONS

We limited eligibility to VR interventions that were fully immersive (ie, virtual environments that visually separated participants entirely from the physical environment), and therefore cannot comment on augmented reality approaches that visually incorporate virtual elements into the physical environment. We limited eligibility to English-language studies, and thus relevant studies published in other languages may have been missed. However, we note that included studies were conducted in a great variety of locations and non-English speaking countries.

## CONCLUSIONS

VR exposure therapy for PTSD may be less effective, or had little to no difference in effect, when compared with non-VR exposure therapy. For stimulant use disorder, VR exposure therapy may result in less craving, compared to treatment as usual. The evidence is uncertain regarding the effects of VR therapies for social anxiety disorder, flying phobia, depression, and schizophrenia spectrum disorders. The evidence is also very uncertain regarding adverse events of VR interventions across prioritized disorders, and there is a lack of evidence on VR interventions for suicide prevention. In addition to the need for higher quality studies addressing the areas lacking evidence, future research should focus on clarifying the impacts of key VR characteristics on treatment effects, and how population characteristics may be important for both effectiveness and engagement.