# RESULTS

## OVERVIEW OF INCLUDED STUDIES

We screened 5,341 unique citations and reviewed the full texts for 424 publications (Figure 1). Of these, we identified 100 eligible articles reporting 84 unique primary studies (83 RCTs, 1 observational study). A full list of excluded studies is provided in the Supplementary Materials. Eighty-four eligible studies addressed a variety of mental health disorders for KQ1, with about a fourth focusing on specific phobias (k = 20; Figure 1 and Table 2). Overall, 45 studies evaluated VR interventions for prioritized disorders: PTSD (k = 6),^20–25^ social anxiety disorder (k = 10),^26–35^ specific phobia of flying (k = 7),^36–42^ alcohol use disorder (AUD, k = 2),^43–45^ stimulant use disorder (k = 2),^46,47^ depression (k = 6),^48–53^ and schizophrenia spectrum disorders (k = 12).^54–66^ The remaining studies focused on other disorders, including agoraphobia and/or panic disorder (k = 10),^67–76^ other specific phobias (k = 12),^77–88^ tobacco use disorder (k =8),^89–96^ bipolar disorder (k = 5),^97–101^ general anxiety disorder (k = 2),^102,103^ and obsessive compulsive disorder (k = 1).^104^ KQ1 studies were generally small but some included more than 100 participants (k = 11). These were conducted in various countries around the world, with nearly half occurring in Europe (k = 44), a fourth in North America (k = 20), and fewer in Asia (k = 16), Australia/New Zealand (k = 2), and South America (k = 1). The most commonly reported outcomes were symptom severity and treatment response or recovery, whereas quality of life and suicidal ideation and/or behaviors were rarely assessed.

Among studies addressing KQ1 prioritized disorders, the most frequently evaluated use of VR within an intervention was VR exposure therapy (with or without cognitive behavioral therapy [CBT]), including most studies for PTSD (k = 6), social anxiety disorder (k = 9), specific phobia of flying (k = 7), alcohol use disorder (k = 2), and stimulant use disorder (k = 2) (Figure 2). In contrast, studies addressing depressive symptoms or schizophrenia spectrum disorders evaluated a variety of VR interventions not necessarily based on evidence-based psychotherapies, with a focus on skills training in the majority of schizophrenia spectrum studies (k = 8). Characteristics of VR varied across studies, with embodiment, interactivity and multisensory stimulation most consistently present in VR exposure therapy for PTSD (Figure 3). Comparators varied across studies, including analogous non-VR therapies (ie, therapy content similar to that of the VR intervention) most common in phobia of flying interventions (k = 8) (Figure 4). Most studies were conducted in supervised health care or laboratory settings (k = 35). Detailed study characteristics and RoB ratings are provided in the Supplementary Materials.

Below, we first present KQ1 findings for the prioritized mental health disorders, grouped by VR intervention and comparator characteristics within each disorder. We then describe results for the single study that evaluated a VR intervention for suicide prevention (KQ2).

Figure 1 Literature Flow Diagram

Notes. *Number of unique studies; ^†^Schizophrenia, schizoaffective and schizophreniform disorders; ^‡^38 studies addressing non-prioritized disorders for KQ1: bipolar disorder, obsessive compulsive disorder, generalized anxiety disorder, agoraphobia and/or panic disorder, other specific phobias, and tobacco use disorder.

Literature flow diagram summarizing results of study selection process.

Figure 2 VR Intervention Content by Prioritized Mental Health Disorder (KQ 1)

Notes. *Including Attentional Bias Modification, behavioral activation, rehabilitation, and personified voices.

Figure 2 is a bar plot of VR intervention content by mental health condition. VR intervention categories include exposure, skills training, relaxation and movement, and other therapies. For PTSD, social anxiety disorder, specific phobia of flying, alcohol use disorder, and stimulant use disorder, VR interventions consisted almost entirely of exposure therapy (only 1 VR intervention for social anxiety disorder was not exposure). No VR interventions for depressive disorders and schizophrenia spectrum disorders included exposure therapy content. Four of six VR interventions for depressive disorders consisted of relaxation and movement, and eight of thirteen VR interventions for schizophrenia spectrum disorders consisted of skills training.

Figure 3 VR Characteristics by Prioritized Mental Health Disorder (KQ 1)

Figure 3 is a bar plot of VR characteristics by mental health condition. VR characteristics include embodiment, interactivity, and multisensory stimulation. Interactivity is the most common VR characteristic, appearing in all mental health conditions. Multisensory stimulation appears in PTSD, specific phobia of flying, alcohol use disorder, and depressive disorders. Embodiment appears in PTSD, depressive disorders, and schizophrenia spectrum disorders. Stimulant use disorder VR interventions do not have any of these VR characteristics.

Figure 4 Comparator Arms for VR Interventions by Prioritized Mental Health Disorders (KQ 1)

Notes. Number of arms exceeds number of studies per condition due to trials evaluating more than 2 arms.

*VR = VR-delivered intervention with different content from the VR intervention under investigation; ^†^Non-VR Analogous = therapy content similar to that of the VR intervention, but delivered without VR; ^‡^Non-VR, Non-Analogous = therapy content different from that of the VR intervention, delivered without VR; ^§^TAU/Waitlist = treatment as usual and/or waitlist for VR intervention under investigation.

Figure 4 is a bar plot of comparator arms for VR interventions by mental health conditions. Comparators include VR, non-VR analogous, non-VR, non-analogous, and treatment as usual/waitlist. Non-VR analogous comparators are the most common, followed by treatment as usual/waitlist, VR, and non-VR, non-analogous.

Table 2 Overview of Characteristics of Eligible Studies for KQ1

Study Characteristic | Characteristic Category | PTSD (k = 6) | Social Anxiety Dis. (k = 10) | Specific Phobia of Flying (k = 7) | Alcohol Use Dis. (k = 2) | Stimulant Use Dis. (k = 2) | Depression (k = 6) | Schizophrenia Spectrum Dis. (k = 12) | Agoraphobia and/or Panic Dis. (k = 10) | Other Specific Phobia (k = 12) | Tobacco Use Dis. (k = 8) | Other Dis.^a^ (k = 8)
Sample size | <50 | 2 | 3 | 3 | 1 | – | 3 | 3 | 4 | 8 | – | 2
Sample size | 51-100 | 1 | 5 | 4 | 1 | 2 | 2 | 7 | 6 | 3 | 5 | 6
Sample size | >100 | 2 | 2 | – | – | – | 1 | 2 | – | 1 | 3 | –
Location | Asia | – | 2 | – | 1 | 2 | 2 | 5 | 2 | 1 | – | 1
Location | Australia/New Zealand | – | 1 | – | – | – | – | – | – | 1 | – | –
Location | Europe | – | 3 | 3 | 1 | – | 3 | 6 | 8 | 8 | 5 | 7
Location | North America | 6 | 4 | 4 | – | – | 1 | 1 | – | 2 | 2 | –
Location | South America | – | – | – | – | – | – | – | – | – | 1
Age (mean or median), y | <30 | 1 | 2 | – | 1 | 1 | – | 2 | 6 | – | 1 | –
Age (mean or median), y | 30-64 | 4 | 5 | 7 | 1 | 1 | 3 | 10 | 2 | 5 | – | 7
Age (mean or median), y | 65+ | – | – | – | – | – | 3 | – | – | 6 | 8 | –
Age (mean or median), y | NR | 1 | 3 | – | 0 | – | – | – | 2 | 1 | – | 1
Outcome Reported | Symptom severity | 5 | 10 | 7 | 2 | 2 | 6 | 12 | 10 | 12 | 7 | 6
Outcome Reported | Treatment response/Recovery | 4 | 2 | 5 | 1 | – | 1 | – | 3 | 8 | 5 | 4
Outcome Reported | Quality of life | – | 1 | – | – | – | – | 3 | 1 | 1 | 2 | 1
Outcome Reported | Attendance | 5 | 1 | 4 | 1 | 1 | 4 | 7 | 1 | 6 | 2 | –
Outcome Reported | Adherence | 3 | 2 | 4 | – | – | – | – | – | – | 1 | –
Outcome Reported | Other engagement | 2 | 4 | 4 | – | – | 1 | 4 | 3 | 3 | 2 | 1
Outcome Reported | Adverse events | 3 | 7 | 2 | – | – | 2 | 10 | 1 | 5 | 4 | 2
Outcome Reported | Suicidal ideation and/or behaviors | 1 | – | – | – | – | – | 2 | – | – | – | –

Notes.

a Includes 5 studies addressing bipolar disorder, 2 on generalized anxiety disorder, and 1 on obsessive compulsive disorder.

Abbreviations. NR=not reported.

## KQ1 PTSD (k = 6)

### Overview

We identified 5 RCTs (reported in 7 articles) and 1 observational study evaluating the use of VR interventions in the treatment of PTSD (Table 3). In each of the trials, VR was used to deliver exposure therapy for combat-related trauma to active-duty service members or Veterans with PTSD in the United States. The VR exposure was part of formally designated prolonged exposure (PE) therapy (k = 2),^20,23^ a similarly structured exposure therapy protocol with essential elements of PE (k = 2),^22,25^ or an exposure therapy protocol with some elements of PE (k = 1).^24^ The observational study evaluated VR exposure therapy for PTSD as part of an intensive outpatient program with no comparison group, and was included in this review due to reporting of adverse events.^21^

Below, we present findings from the 5 RCTs and 1 observational study evaluating VR exposure therapy. No studies reported quality of life outcomes. Below, we describe study characteristics and outcome findings for all included studies. Detailed study characteristics and outcome findings are located in the Supplementary Materials.

Table 3 Summary Characteristics of PTSD Studies (k = 6)

Author, Year; Study Design; Risk of Bias; Total N Key Participant Characteristics | Intervention Characteristics | Comparator Characteristics
Difede, 2022^20^; RCT; Some concerns; N = 192; Mean age: 34.3-35.0 years; 88.4-90.7% male; U.S. Service Members (of any duty status) and Veterans with combat-related PTSD | VR Prolonged Exposure Therapy; - Prolonged exposure therapy using VR equipment to conduct in-session exposure.; - Virtual combat scenarios customized by therapist during sessions; - Beginning in session 3, D-cycloserine or placebo given before each session; - No other medications with predominantly central nervous system activity; - 9 × 90-minute sessions; 9 weeks; Hardware: HMD (device NR); Embodiment: Yes; Interactivity: Yes; Multisensory stimulation: Yes | Non-VR Prolonged Exposure Therapy; - Traditional imaginal exposure (imagine scenes of trauma) during sessions; - Beginning in session 3, D-cycloserine or placebo given before each session; - No other medications with predominantly central nervous system activity; - 9 × 90-minute sessions; 9 weeks
Reger, 2016^23^; RCT; Some concerns; N = 162; Mean age: 29.5-30.9 years; 94-98% male; Active Duty U.S. Service Members with deployment-related PTSD | VR Prolonged Exposure Therapy; - Prolonged exposure therapy using VR equipment to conduct in-session exposure.; - Virtual combat scenarios customized by therapist; - No medication changes over 3 preceding months or during intervention; no other psychotherapy; - 10 × 90-120-minute sessions; 5-10 weeks; Hardware: eMagin z800 HMD; Embodiment: Yes; Interactivity: Yes; Multisensory Stimulation: Yes | Non-VR Prolonged Exposure Therapy; - Standard Prolonged Exposure protocol; - Imaginal exposure in session and in vivo exposures between sessions; - No medication changes over 3 preceding months or during intervention; no other psychotherapy; - 10 × 90-120-minute sessions; 5-10 weeks; Waitlist; - 5-week waiting period with assessments; - Began active treatment of choice after waiting period
McLay, 2017^22^; RCT; Some concerns; N = 81; Mean age: 32.5 years; 90-93% male; Active Duty U.S. Service Members with deployment-related PTSD | VR Prolonged Exposure Therapy; - VR exposure therapy adherent to essential prolonged exposure elements; - 2 sessions of assessment and psychoeducation; - VR exposure customized to the Veteran’s experience; - In vivo exposures between sessions; - No other individual psychotherapy; could continue group psychotherapy and/or medications; - 8-12 × 90-minute sessions / 9 weeks; Hardware: HMD (device NR); Embodiment: Yes; Interactivity: Yes; Multisensory Stimulation: Yes | Non-VR Prolonged Exposure Therapy; - Same protocol as VR exposure therapy; - In-session exposure involved looking at a 2D still image of the VR intervention (or real still image of Afghanistan or Iraq) chosen by participant from options provided; - No other individual psychotherapy; could continue group psychotherapy and/or medications; - 8-12 × 90-minute sessions; 9 weeks
McLay, 2011^25^; RCT; High; N = 20; Mean age: 28.0-28.8 years; 90-100% male; Active Duty U.S. Service Members with combat-related PTSD | VR Exposure Therapy; - VR exposure therapy adherent to essential prolonged exposure elements; - 2 sessions of intake, treatment rationale, teaching relaxation and attentional control training; - VR exposure to wartime situations with increasing intensity and realism; - Cognitive restructuring after each exposure; - No other individual psychotherapy; could continue group psychotherapy and/or medications; - 4-20 sessions (duration NR); 10 weeks; Hardware: HMD (device NR); Embodiment: Yes; Interactivity: Yes; Multisensory Stimulation: Yes | TAU; - Any type of mental health treatment received at study hospitals; - 3-38 sessions (duration NR); 10-46 weeks
Miyahira, 2012^24^; RCT; High; N = 22; Mean age: NR; % male NR; Active Duty U.S. Service Members with PTSD symptoms who participated in military operations in Iraq or Afghanistan | VR Exposure Therapy; - VR exposure therapy (with elements similar to prolonged exposure); - 1 session of orientation to treatment, review of traumatic memory, and breathing training; - VR exposure to a combat environment customized by study therapist; - No information on other treatments permitted during study; - 10 sessions, NR; 5 weeks; Hardware: HMD (device NR); Embodiment: NR; Interactivity: No; Multisensory Stimulation: Yes | Waitlist; - 5-week waitlist with brief phone assessments every 2 weeks; - Offered VR exposure treatment after waiting period
Beidel, 2017^21^; Observational; N = 112; Mean age: 37.1 years; 95% male; U.S military Veterans and active duty personnel | Trauma Management Therapy Intensive Outpatient Program + VR Exposure Therapy; - 3-week trauma management therapy IOP; - VR exposure therapy; - No benzodiazepines; any SSRI dose required to be stable 2 weeks prior to study; no medication changes during study; - Other program components included: in vivo exposure practice; social and emotional rehabilitation, social reintegration, anger management, and brief behavioral activation; Hardware: HMD (device NR); Embodiment: Yes; Interactivity: Yes; Multisensory Stimulation: Yes | No comparator

Abbreviations. HMD=head-mounted device; NR=not reported; TAU=treatment as usual; VR=virtual reality.

### VR Exposure

Five RCTs evaluated VR exposure therapy for combat-related PTSD, all using versions of the Virtual Iraq/Afghanistan System.^20,22–25,105^ Sample size ranged from 20-192 and study participants were primarily male (88–100%) and in early to middle adulthood (mean age from 28.4 to 34.6 years). Interventions comprised 4–20 total sessions over a duration of 5–10 weeks. Three studies compared VR prolonged exposure to non-VR prolonged exposure (N = 81–192).^20,22,23^ Reger 2016 also included a minimal attention waitlist comparator.^23^ All 3 studies were rated some concerns for RoB. The fourth RCT (McLay 2011) compared VR prolonged exposure to treatment as usual (TAU) (N = 20)^25^ and was rated high for RoB due to study team and participant having knowledge of the group allocation (participants pulled slip of paper from an envelope to assign them to a group) and deviations from the intended interventions (participants in TAU group could seek other treatment and VR exposure group could participate in group but not individual treatment). The fifth RCT (Miyahira 2012) compared VR exposure to a minimal attention waitlist (N = 22) and was rated high RoB due to deviations from the intended interventions and missing outcome data (48% of randomized participants did not complete treatment).^24^ One single-arm pre-post study of a VR exposure therapy was included for assessment of adverse events only.^21^

All VR exposure interventions included in the meta-analysis contained essential elements of prolonged exposure (PE) therapy. These 3 VR interventions incorporated embodiment, interactivity with the virtual environment, and multisensory stimulation (eg, tactile and olfactory stimuli). VR interventions and non-VR comparators varied with respect to customization of the VR environment and therapist/participant control.^23^ The VR exposure groups in Reger 2016 and Difede 2022 observed a virtual environment selected as relevant to a participant’s trauma and customized by the study therapist so that the scene and associated olfactory and tactile stimuli matched the participant’s memory.^20,23^ McLay 2017 compared VR exposure to a 2D-image exposure protocol. VR exposure included customization of the VR environment, with some elements of participant control (eg, choosing to add olfactory and tactile stimuli).^22^ The non-VR comparator involved observing a 2D image of the virtual environment or a still image of Iraq or Afghanistan while recounting a memory.

McLay 2011 evaluated a VR exposure intervention which they referred to as VR-graded exposure therapy.^25^ The VR environment was customized to match a participant’s traumatic memory, then adapted throughout treatment to increase intensity based on a participant’s reactivity. The comparator was a TAU condition in which participants could receive any PTSD services offered at study hospitals (including evidence-based treatments such as PE, cognitive processing therapy, and psychiatric medication management). Unique to this study was the documented high variation in dosing, or number of treatment sessions attended in both arms (VR exposure therapy arm: VR sessions mean = 8.8, range = 4–20; other mental health sessions mean = 3.3, range = 1–8; TAU arm: mental health sessions mean = 13.8, range = 3–38).

Miyahira 2012 tested the effectiveness of VR exposure in active-duty service members compared to a minimal attention waitlist.^24^ The intervention consisted of 10 sessions over 5 weeks. The first session consisted of information about the treatment, review of the traumatic event, and training in a breathing exercise. In sessions 2–10, participants took part in VR exposure to a virtual combat environment which could be customized by the study therapist to reflect aspects of the participant’s trauma memory.

Beidel 2017 was a single arm study examining effectiveness of VR Exposure Trauma Management Therapy without a comparison group.^21^ This intervention was a 3-week intensive outpatient program incorporating daily individual sessions completing customized VR exposure (via the Virtual Iraq/Afghanistan System) with the assistance of a therapist, with daily group therapy covering topics like social skills, anger management, and behavioral activation, and in-vivo exposure assignments.

#### Symptom Severity

VR PE may improve symptom severity at post-intervention less than non-VR PE (low COE). VR PE compared to non-VR PE may result in little to no difference in symptom severity at 3-months follow-up (low COE). Three studies evaluated VR PE versus a non-VR PE and measured PTSD symptom severity using the Clinician-Administered PTSD Scale (CAPS).^20,22,23^ Due to studies’ conceptual similarity and very low heterogeneity in random effects meta-analyses (see Appendix Figure 1), we estimated meta-analyses with fixed effects and referenced the fixed effects models for GRADE (Figure 5). Two of these studies also measured symptom severity using the patient-reported PTSD Checklist (PCL) and found no significant differences between arms at post-intervention and at 3-months follow-up.^20,23^ Difede et al^20^ also stratified randomization by presence of major depressive disorder and found that VR PE was more effective among participants with depression (VR PE vs non-VR PE post-treatment mean CAPS difference = 3.51, 95% CI [1.17, 5.86], p = 0.004) while non-VR PE was more effective among participants without depression (mean difference = −8.87, 95% CI [−11.33, −6.40], p < 0.001).

Not included in the meta-analysis were McLay 2011 and Miyahira 2012, both of which had comparators that did not involve exposure. McLay 2011 compared a VR exposure therapy to TAU rather than to a non-VR exposure therapy arm.^25^ While this study found no significant between-arm difference in mean CAPS scores post-intervention, the VR exposure arm had a significantly higher mean CAPS change score (35.4) than TAU (9.4) (p < 0.05). Miyahira 2012 found no significant difference in CAPS scores at post-intervention between VR exposure therapy and a minimal attention waitlist. Reger 2016 compared VR PE to non-VR PE (included in meta-analysis) and also to a waitlist.

In comparison with the waitlist, Reger 2016 found the VR PE arm had significantly lower post-intervention scores on the CAPS and PCL.

Figure 5 Forest Plots Showing SMD in CAPS After VR Prolonged Exposure versus Non-VR Prolonged Exposure Therapy for PTSD

Notes. Models estimated using fixed effects.

(a) Post-intervention

Figure 5a is a forest plot visualizing a meta-analysis using data from 3 studies. The plot visualizes data at post-intervention. All studies favor non-VR PE. All studies have a confidence interval that crosses the null. The overall pooled analysis favors Non-VR PE, with a confidence interval that crosses the null (SMD 0.22 [−0.02, 0.46]).

(b) 3 months post-intervention

Figure 5b is a forest plot visualizing a meta-analysis using data from 3 studies. The plot visualizes data at 3 months post-intervention. Two studies favor VR PE and one study favors non-VR PE. All studies have a confidence interval that crosses the null. The overall pooled analysis of all studies showed no difference between VR PE and non-VR PE, with a confidence interval that crosses the null (SMD 0.02 [−0.24, 0.29]).

#### Treatment Response/Recovery

VR PE probably results in less treatment response immediately post-intervention, compared with non-VR PE (moderate COE; Table 4). Two trials used different criteria to define treatment response. Reger 2016 evaluated “reliable and clinically significant change” in PTSD symptoms as measured by the CAPS weekly (see Table 4 for definition).^23^ McLay 2017 defined treatment response as ≥30% improvement in CAPS.^22,25^ Both Reger 2016 and McLay 2017 reported lower proportions of improvement in the VR PE arm versus non-VR PE (eg, 50.0% vs 33.3% in Reger 2016) post-intervention, but did not test between-arm differences for statistical significance.^22,23^ McLay 2017 found no statistically significant difference in treatment response rates between the groups at 3 months follow-up (30% vs 36%).^22^ In an additional report derived from Reger 2016, authors reported that baseline dissociative symptoms did not impact between-group difference in treatment response.^106^

McLay 2011 compared VR exposure therapy versus TAU and reported greater response (defined as ≥30% improvement in CAPS) in the VR exposure arm than in the TAU arm (70.0% vs 12.5%).^25^

#### Treatment Engagement

All studies reported on aspects of treatment engagement including session attendance and treatment discontinuation,^20–24,106^ treatment preference,^20^ and treatment satisfaction.^20,23^ No homework was assigned and so treatment adherence was not relevant.

##### Attendance

Difede 2022 found no significant difference in proportion of participants discontinuing treatment between VR PE (27.8%) and non-VR PE (34.7%).^20^ Reger 2016 also found no significant difference in the proportion of participants discontinuing treatment between VR PE (44.4%) and non-VR PE (40.7%), and no significant difference in session attendance (VR PE mean = 7.11, non-VR PE mean = 7.50).^23^ A secondary analysis found no significant association between baseline dissociative symptoms and either treatment discontinuation or session attendance, but did not compare between treatment arms.^106^ In McLay 2017, 7 VR PE participants (16%) discontinued treatment before completing a post-intervention assessment, while no non-VR PE participants discontinued. Study authors did not test for statistical difference.^22^ There was no significant difference between arms in the mean number of treatment sessions attended (VR exposure mean = 10.28, non-VR exposure mean = 9.24). McLay 2011 reported that all participants completed treatment.^25^ In Miyahira 2012, 48% of participants (17 of 29 in the VR exposure arm and 3 of 12 on waitlist) did not complete treatment, and no information was available on reasons for discontinuation.^24^ In Beidel 2017, 2 of 112 participants discontinued treatment, and 10 more participants were administratively removed from the study before receiving the intervention. Participants were reportedly removed due to protocol deviation (n = 3), malingering (n = 4), and primary diagnosis determined not to be PTSD (n = 3).^21^

##### Other Engagement Measures

Difede 2022 assessed treatment preference (using a form developed by the study team and administered prior to treatment) and found that most participants (76.7%) preferred VR PE to non-VR PE at baseline.^20^ Treatment satisfaction was assessed post-intervention by the Client Satisfaction Questionnaire (CSQ-8) and did not significantly differ based on whether participants received their preferred treatment. Treatment satisfaction by arm was not reported or compared, but there was no significant difference in treatment satisfaction between participants who completed treatment (mean total score = 28.58) and those who discontinued (mean total score = 27.23). Neither treatment preference nor treatment satisfaction were associated with post-intervention symptom severity outcome (CAPS). Reger 2016 also assessed treatment satisfaction post-intervention using mean item score on the CSQ-8.^23^ Both treatment arms reported high treatment satisfaction, with no significant difference between arms (VR PE mean item score = 3.47, non-VR PE mean item score = 3.52).

#### Adverse Events

VR PE compared to non-VR PE may have little to no difference in adverse events (low COE). Three of the 5 trials^20,23,25^ and 1 observational study^21^ reported on adverse events using different measures of different domains. Reger 2016^23^ and Difede 2022^20^ contributed to GRADE. Published results of the other 2 trials did not indicate presence or absence of adverse events.^22,24^

In Reger 2016, simulator-related side effects were measured in both study arms. An adapted version of the Simulator Sickness Questionnaire (SSQ) was administered in each session of imaginal or virtual exposure.^23^ A secondary data analysis of Reger 2016 reported the frequency of moderate or severe adverse symptoms (eg, dizziness, headache, “sickness in the stomach”).^107^ There was no significant difference between arms in the prevalence of side effects before the first exposure session and side effects declined at a similar rate throughout treatment. Difede 2022 noted that no adverse events were reported, and did not define adverse events.^20^

McLay 2011 reported no hospitalizations or emergency interventions and no study discontinuations due to adverse events (not otherwise defined) and noted that no participants had to stop VR sessions due to “discomfort caused by the equipment (cybersickness).”^25^

Beidel 2017 reported no instances of adverse events (not defined) in the single arm during the 3-week intensive outpatient treatment or during the 6-month follow-up period.^21^

##### Suicidal Ideation and/or Behavior

Beidel 2017 reported no instances of suicide attempts in the single arm during the 3-week intensive outpatient treatment or during the 6-month follow-up period.^21^

Table 4 PTSD Certainty of Evidence: VR Prolonged Exposure versus Non-VR Prolonged Exposure

Outcome; Measure | Follow-Up; Total N (# of Studies) | SMD Pooled Estimate; (95% CI) | Anticipated Absolute Effects on Mean Score or Event Rate at Follow-Up | | | Certainty | What Happens
Outcome; Measure | Follow-Up; Total N (# of Studies) | SMD Pooled Estimate; (95% CI) | VR Prolonged Exposure | Non-VR Prolonged Exposure | Difference | Certainty | What Happens
Symptom Severity; CAPS | Post-intervention; N = 277 (3 RCTs)^20,22,23^ | SMD: 0.22; (−0.02, 0.46) | 56.3; (50.1, 62.5) | 50.6^*^ | 5.7; (−0.5, 11.9) | ⊕⊕◯◯; Low^a,b^ | VR prolonged exposure may result in less improvement in symptom severity post-intervention.
Symptom Severity; CAPS | 3 months post-intervention; N = 234 (3 RCTs)^20,22,23^ | SMD: 0.02; (−0.24, 0.29) | 50.9; (43.8, 58.3) | 50.4^*^ | 0.5; (−6.6, 7.9) | ⊕⊕◯◯; Low^a,c^ | VR prolonged exposure may result in little to no difference in symptom severity at 3 months post-intervention.
Treatment Response/Recovery; Varied threshold for change in CAPS score^‡^ | Post-intervention; N = 194 (2 RCTs)^22,23^ | — | 33% | 50%^†^ | 17% | ⊕⊕⊕◯; Moderate^a^ | VR prolonged exposure probably results in less treatment response post-intervention.
Adverse Events; SSQ; NR | During intervention; N = 300 (2 RCTs)^20,23^ | — | 0 | 0^§^ | — | ⊕⊕◯◯; Low^a,d^ | VR prolonged exposure may result in little to no difference in adverse events.

Notes.

* Values for mean follow-up scores for symptom severity for comparator arms from Difede 2022^20^;

† Values for mean follow-up scores for treatment response in intervention and comparator arms from Reger 2016^23^;

‡ McLay 2017^22^ calculated treatment response as ≥30% improvement in CAPS score. Reger 2016^23^ calculated treatment response as above the threshold for reliable and clinically significant change. Clinically significant change was defined as at least the total baseline mean less twice the baseline standard deviation (SD). Reliability was defined as (s_t_^2^ – S_E_^2^)/s_t_^2^, where s_t_ equals the time or difference-specific SD, and S_E_ equals the standard error of the mean derived from the baseline mean and internal consistency of the previous week’s CAPS score among all study participants;

§ Difede 2022^20^ selected as reference for adverse events. Study did not report how adverse events were operationalized or measured;

a Downgraded 1 level for study limitations (1 or more studies rated some concerns for RoB);

b Downgraded 1 level for imprecision (CI crosses the null);

c Downgraded 1 level for imprecision (CI crosses thresholds for small effects in both directions);

d Downgraded 1 level for indirectness (1 study did not describe how or which adverse events were assessed).

Abbreviations. CAPS=Clinician-Administered PTSD Scale; NR=not repoted; RoB=risk of bias; SMD=standardized mean difference; SSQ=Simulator Sickness Questionnaire; VR=virtual reality.

## KQ1 SOCIAL ANXIETY DISORDER (k = 10)

### Overview

Ten eligible RCTs (reported in 16 articles) evaluated VR interventions for treating social anxiety disorder (Table 5).^26–35,108–113^ Four trials were conducted in North America,^29,31,33,34^ 3 in Europe,^27,30,32^ 2 in Asia,^28,35^ and 1 in New Zealand.^26^ Six studies allowed participants to be on mental health medications if on stable doses (minimum of 6 weeks to 6 months),^27,30–33,35^ and one of these excluded individuals who were receiving other psychotherapy.^35^ Two studies excluded participants receiving any other mental health treatments (psychotherapy or medications).^29,31^ Four studies compared VR exposure with waitlist,^29,32,35,108^ and one of these also included a non-VR exposure comparator arm.^32^ Five studies investigated CBT and VR exposure.^26,27,31,33,34^ Three of these were 3-arm trials comparing CBT + VR exposure versus CBT and non-VR exposure versus waitlist.^31,33,34^ The fourth was also a 3-arm trial but compared CBT and VR exposure versus CBT and non-VR exposure versus VR exposure only (no CBT arm).^27^ The final study examining CBT and VR exposure only compared this treatment versus waitlist.^26^ The tenth study examining VR treatment for social anxiety evaluated different versions of dot-probe tasks for Attentional Bias Modification (ABM).^30^

Below, we present findings separately for various comparisons, beginning with VR exposure versus waitlist, and followed by CBT and VR exposure versus waitlist. We then focus on outcomes comparing VR treatments to active comparators, including CBT and VR exposure versus CBT and non-VR exposure, VR exposure versus non-VR exposure, and VR exposure versus CBT plus non-VR exposure. Lastly, we describe findings for the single study comparing various versions of VR dot-probe tasks for ABM. All eligible studies assessed symptom severity, and none reported findings regarding suicidal ideation and/or suicidal behavior. Detailed study characteristics and findings are provided in the Supplementary Materials.

Table 5 Summary Characteristics of Social Anxiety Disorder Studies (k = 10)

Author, Year; Study Design; Risk of Bias; Total N Key Participant Characteristics | Intervention Characteristics | Comparator Characteristics
Kan 2024^35^; High; N = 61; Mean age: 22-23; 86-88% female | VR Exposure; - VR social situations presented, followed by instructions and a response from participants; - Self-paced; - NR sessions (length NR); duration NR; Hardware: Thousand Wonders G04VR headset; Embodiment: No; Interactivity: NR; Multisensory stimulation: No | Waitlist; - 14 day waitlist then offered the VR Self-Training intervention
Kampmann, 2016^32^; Some concerns; N = 60; Mean age: 37 years; 63% women | VR Exposure; - Virtual social scenarios customized by therapist during sessions; - 2 sessions of therapy rationale and tailoring the virtual reality intervention to the participant; - Therapist led; - 10 × 65-minute sessions; 5 weeks; Hardware: nVisor SX HMD; Embodiment: No; Interactivity: No; Multisensory stimulation: No | Non-VR Exposure; - Real world social scenarios (eg, shopping); - 2 sessions of therapy rationale and anxiety hiearchy creation; - Therapist led; - 10 60-minute sessions; 5 weeks
Kampmann, 2016^32^; Some concerns; N = 60; Mean age: 37 years; 63% women | | Waitlist; - 5 week waitlist then rerandomized to one of the other arms
Kim, 2022^28,108^; High; N = 41; Mean age: 24 years; 62-65% female; 35-38% male | VR Exposure; - Virtual social scenarios (eg, school or work); - Each scenario had four levels of difficulty; - Self-paced; - 8 sessions (length NR); 2 weeks; Hardware: Samsung Galaxy S6 on Samsung Gear VR HMD powered by Oculus; Embodiment: No; Interactivity: No; Multisensory stimulation: No | Waitlist; - No treatment for 3 weeks
Zainal, 2021^29^; Some concerns; N = 44; Mean age: 23 years; 77% female | VR Exposure; - Virtual social scenarios (party or interview); - Increasingly more anxiety provoking; - Self-paced; - 4 × 50-60-minute sessions; 2 weeks; Hardware: Pico Goblin VR HMD; Embodiment: No; Interactivity: Yes; Multisensory stimulation: No | Waitlist; - 4 week waitlist then received VR exposure therapy
Anderson, 2013^33,^ ^110–113^; Some concerns; N = 97; Mean age: 39 years; 62% female | CBT + VR Exposure; - CBT with virtual social scenarios exposure (eg, conference room or classroom); - Virtual environments had increasingly larger audiences; - Therapist led; - 8 sessions (length NR); duration NR; Hardware: NR; Embodiment: NR; Interactivity: NR; Multisensory stimulation: NR | CBT + Non-VR Exposure; - Participants gave speeches in front of a real life audience; - Therapist led; - 8 sessions (length NR); duration NR
Anderson, 2013^33,^ ^110–113^; Some concerns; N = 97; Mean age: 39 years; 62% female | | Waitlist; - 8 week waitlist then rerandomized to one of the other arms
Bouchard, 2017^31^; Some concerns; N = 54; Mean age: 31-37 years; 55-88% female | CBT + VR Exposure; - CBT with virtual social scenarios exposures (eg, interviews or public speaking); - Therapist led; - 14 × 1-hour long sessions; 14 weeks; Hardware: eMagin z800 HMD and an InterSense Inertia Cube motion tracker; Embodiment: NR; Interactivity: Yes; Multisensory stimulation: No | CBT + Non-VR Exposure; - CBT with real world social scenarios (eg, making mistakes in public or giving a speech to staff members); - Therapist led; - 14 1-hour long sessions; 14 weeks
Bouchard, 2017^31^; Some concerns; N = 54; Mean age: 31-37 years; 55-88% female | | Waitlist; - 12 week waitlist then offered a combined treatment
Lacey, 2024^26^; High; N = 120; Mean age: 34-36 years; 75-88% female | CBT + VR Exposure; - CBT with virtual social scenarios; - Modules 1-4 taught coping methods for social anxiety; - Modules 5-6 involved creating a fear hierarchy, progressing through increasingly challenging social scenarios, and preventing relapse; - Therapist led; - 6 sessions (length NR); 6 weeks; Hardware: oVRcome HMD; Embodiment: No; Interactivity: No; Multisensory stimulation: No | Waitlist; - No treatment
Robillard, 2010^34^; High; N = 45; Mean age: 35 years; 71% female | CBT + VR Exposure; - CBT with virtual social scenarios (not further described); - Therapist led; - 16 sessions (length NR); 16 weeks; Hardware: eMagin z800 3D Visor HMD; Embodiment: NR; Interactivity: NR; Multisensory stimulation: NR | CBT + Non-VR Exposure; - CBT with real world social scenarios (not further described); - Therapist led; - 16 sessions (length NR); 16 weeks
Robillard, 2010^34^; High; N = 45; Mean age: 35 years; 71% female | | Waitlist; - 16 week waitlist then offered a treatment distinct from the other arms
Stefaniak, 2022^27^; High; N = 91; Mean age: 31-32 years; 56-58% female | CBT + VR Exposure; - CBT with virtual social scenarios (eg, interview, public speaking); - Therapist led; - 12 × 45-minute sessions; 6 weeks; Hardware: HTC VIVE virtual helmet HMD; Embodiment: NR; Interactivity: NR; Multisensory stimulation: NR; VR Exposure; - Virtual social scenarios; - Self-paced; - 12 sessions (duration NR); 6 weeks; Hardware: HTC VIVE virtual helmet HMD; Embodiment: NR; Interactivity: NR; Multisensory stimulation: NR | CBT + Non-VR Exposure; - CBT with real world social scenarios; - Therapist led; - 12 45-minute sessions; 6 weeks
Ma, 2019^30,^ ^109^; High; N = 100; Mean age: 38-43 years; 44-74% female | ABM Training VR 3D Active Dot-Probe Task; - Dot-probe task using 3D image of a face with either a neutral or disgusted expression; - 1 session (length NR); duration NR; Hardware: Oculus Rift HMD; Embodiment: No; Interactivity: No; Multisensory stimulation: No | ABM Training VR 2D Active Dot-Probe Task; - Dot-probe task using 2D image of a face with either a neutral or disgusted expression; - 1 session (length NR); duration NR
Ma, 2019^30,^ ^109^; High; N = 100; Mean age: 38-43 years; 44-74% female | | ABM Training VR 2D Sham Dot-Probe Task; - Dot-probe task with a 2D sham stimulus; - 1 session (length NR); duration NR
Ma, 2019^30,^ ^109^; High; N = 100; Mean age: 38-43 years; 44-74% female | | ABM Training VR 3D Sham Dot-Probe Task; - Dot-probe task with a 2D sham stimulus; - 1 session (length NR); duration NR

Abbreviations. 2D=2-dimensional; 3D=3-dimensional; ABM=Attentional Bias Modification; CBT=cognitive behavioral therapy; HMD=head-mounted device; NR=not reported; VR=virtual reality.

### VR Exposure versus Waitlist

Four RCTs (reported in 5 articles) evaluated VR exposure compared with waitlist.^28,29,32,108^ Study characteristics are summarized in Table 5. Studies were small (total N = 40-61) and enrolled young and middle-aged adults (average age = 22.3–36.9 years, 57%–88% women). Interventions comprised 4–10 total sessions over a duration of 2–5 weeks. Two studies^29,32^ were appraised as some concerns for RoB and 2 studies^28,35^ were appraised high RoB, due to methodological concerns, including lack of information on if participants adhered to the intervention for the duration of the study and loss to follow-up that was not balanced between study arms.

VR exposure intervention contained similar content across studies. Participants had to speak to a virtual audience in different virtual social settings (eg, interview or dinner party). Settings were designed to provoke varying degrees of anxiety, for example, by having more or fewer virtual audience members. Kampmann 2016 had therapists guiding VR exposure sessions,^32^ while Kan 2024, Kim 2022, and Zainal 2021 had participants pace themselves through the VR sessions.^28,29,35^ VR experiences did not provide a sense of embodiment or multisensory stimulation. Only Zainal 2021 had reported interactivity, with the VR program able to detect speech and provide prompts when the participant was not speaking.^29^

#### Symptom Severity

The evidence is very uncertain on the effect of VR exposure on symptom severity, compared with waitlist, primarily due to concerns about methodological limitations and inconsistency (very low COE; Table 6). The meta-analysis included data from 4 studies^28,29,32,35^ and the pooled estimated favored VR exposure (SMD = −0.73 [−1.43, −0.03]; Figure 6). Studies measured symptom severity using either the Liebowitz Social Anxiety Scale (LSAS) or the Social Phobia Diagnostic Questionnaire (SPDQ).^28,29,32,35^ Studies also measured symptom severity using the Brief Fear of Negative Evaluation (FNE-B), Hospital Anxiety and Depression Scale (HADS), Patient Health Questionnaire (PHQ), Penn State Worry Questionnaire, Social Interaction Anxiety Scale (SIAS), and Social Phobia Inventory (see Supplementary Materials for point estimates).^28,29,32,108^

Figure 6 Social Anxiety Disorder: Effect of VR Exposure versus Waitlist on Symptom Severity Immediately Post-Intervention

Figure 6 is a forest plot visualizing a meta-analysis using data from 7 studies. The overall pooled analysis of all studies favors VR. Subgroup analyses were done for VR exposure versus waitlist and CBT plus VR exposure versus waitlist. Both subgroup analyses individually favor VR, with inconsistency between studies. One study in each subgroup has a confidence interval that crosses the null, and the other studies favor VR.

#### Treatment Response/Recovery

Only Kampmann 2016 assessed treatment response as “reliable change” in LSAS from pre- to post-intervention (not further defined). There were no differences between arms (47% in the VR group vs 50% in the waitlist arm; p = 0.873).^32^

#### Quality of Life

Only Kampmann 2016 evaluated quality of life, reporting participants in the VR arm had a larger increase in EUROHIS Quality of Life Scale scores over time (EUROHIS-QOL, follow-up mean = 25.74, SD = 6.85), compared with waitlist group (follow-up mean = 27.28, SD = 5.44) immediately post-intervention (p = 0.018).^32^

#### Engagement

Three studies reported attendance,^28,29,32^ and one of these also assessed adherence and other measures of engagement.^29^

##### Attendance

Participants in Zainal 2021 completed an average of 18 (SD = 14) VR scenes, with 58% (n = 15) reaching the highest difficulty level (not further defined) of the VR scenes.^29^ All 3 studies reported discontinuation rates of each treatment with no statistical comparisons. Kampmann 2016 reported that 6 (20%) in the VR exposure arm and 2 (10%) in the waitlist arm discontinued treatment. Kim 2022 reported 3 (11%) participants discontinued treatment in the VR exposure arm, while 8 (33%) discontinued in the waitlist arm. Zainal 2021 reported 3 (12%) in the VR exposure arm and 2 (11%) in the waitlist arm discontinued. ^28,29,32^

##### Adherence and Other Engagement Measures

Participants in Zainal 2021 were assigned in vivo exposure therapy homework to complete between VR exposure therapy sessions, and 80% (n = 21) were noted to have completed at least 1 in vivo exposure between sessions (mean number of in vivo exposures between sessions = 3.96, SD = 4.27).^29^ Zainal 2021 also assessed engagement in the VR arm using the iGroup Presence Questionnaire and found that participants’ spatial presence in VR increased over time (p = 0.019) Additionally, 85% of participants would recommend VR exposure therapy to others with social anxiety disorder.^29^

#### Adverse Events

The evidence is very uncertain on the effect of VR exposure on adverse events, compared with waitlist (very low COE; Table 6). Four RCTs reported adverse events only in the VR exposure arm, using different measures including the SSQ and undefined assessments.^28,29,32,35^ Kan 2024 stated that “no participants reported physical discomfort experienced after viewing virtual reality imagery.”^35^ Kampmann reported 1 participant in the VR exposure therapy arm discontinued the intervention due to motion sickness.^32^ Kim 2022 reported no discontinuation of VR exposure therapy due to simulator sickness and a mean SSQ score of 27.7 (SD = 7.37).^28^ Zainal 2021 stated that cybersickness decreased over time within the VR exposure therapy group, as assessed using the SSQ.^29^

Table 6 Social Anxiety Disorder Certainty of Evidence: VR Exposure versus Waitlist

Outcome; Measure | Follow-Up; Total N (# of Studies) | SMD Pooled Estimate; (95% CI) | Anticipated Absolute Effects on Mean Score or Event Rate at Follow-Up | | | Certainty | What Happens
Outcome; Measure | Follow-Up; Total N (# of Studies) | SMD Pooled Estimate; (95% CI) | VR Exposure | Waitlist | Difference | Certainty | What Happens
Symptom Severity; LSAS, SPDQ | Post-intervention; N = 187 (4 RCTs)^28,29,32,35^ | SMD: −0.73; (−1.43, −0.03) | 9.5; (6.6, 12.4) | 12.5^*^ | −3.0; (−5.9, −0.1) | ⊕◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of VR exposure on symptom severity post-intervention.
Adverse Events; SSQ, NR | During intervention; N = 197 (4 RCTs)^28,29,32,35^ | — | 16.39; (11.51)^†^ | — | — | ⊕◯◯◯; Very low^a,c^ | The evidence is very uncertain on the effect of VR exposure on adverse events.

Notes.

* Values for mean follow-up scores for intervention and/or comparator arms from Zainal 2021.^29^ Differences calculated by review team;

† SSQ scores in VR Exposure Therapy group from Zainal 2021^29^;

a Downgraded 2 levels for study limitations (1 or more studies rated high RoB);

b Downgraded 1 level for inconsistency (direction of effects inconsistent across studies);

c Downgraded 1 level for indirectness (3 studies did not describe how or which adverse events were assessed, 1 study only assessed outcome for 1 arm).

Abbreviations. LSAS=Liebowitz Social Anxiety Scale; NR=not reported; RoB=risk of bias; SMD=standardized mean difference; SPDQ=Social Phobia Diagnostic Questionnaire; SSQ=Simulator Sickness Questionnaire; VR=virtual reality.

### CBT + VR Exposure versus Waitlist

Four RCTs evaluated CBT + VR exposure compared with waitlist for social anxiety disorder.^26,31,33,34^ Study characteristics are summarized in Table 5. Study sample sizes ranged from 29–120, average age from 33.2–39.03 years, and 62%–81% were female.^31,33,34^ Interventions comprised 8–16 total sessions over a duration of 6–16 weeks. Two studies were appraised as some concerns RoB.^31,33^ Lacey 2024 and Robillard 2010 were appraised as high RoB due to methodological concerns, including the number of participants lost to follow-up.

#### Symptom Severity

The evidence is very uncertain on the effect of CBT + VR exposure on symptom severity, compared with waitlist (very low COE; Table 7. The meta-analysis used data from all 4 studies (either FNE-B or LSAS scores)^31,33,34^ and the pooled estimate indicated a moderate effect favoring CBT + VR exposure, when compared with waitlist (SMD = −0.66 [−1.17, −0.15]; Figure 6). Symptom severity was also measured using the SPS, SIAS, Personal Report of Confidence as a Speaker (PRCS), clinician ratings of global improvement, and Appraisal of Social Concerns (see Supplementary Materials for these findings).

#### Engagement

Three studies reported attendance data^26,31,33^ and 2 studies reported data on other engagement measures.^26,31^

##### Attendance

Three studies reported on participant attendance. Anderson 2013 reported 1 (3%) in the CBT + VR exposure arm and 3 (11%) in the waitlist withdrew,^33^ and Bouchard 2017 stated 2 (12%) and 4 (20%) dropped out in the CBT + VR exposure and waitlist arms, respectively.^31^ Lacey reported 25 (42%) in the CBT + VR exposure and 15 (25%) in the waitlist arm withdrew.^26^

##### Other Engagement Measures

Bouchard 2017 reported engagement with the CBT + VR exposure intervention using the Presence Questionnaire, the Gatineau Presence Questionnaire, and treatment credibility.^31^ Lacey 2024 also used the Gatineau Presence Questionnaire to assess for degree of realism.^26^ Neither provided comparisons within the VR arms across time points.

#### Adverse Events

The evidence is very uncertain on the effect of CBT + VR exposure on adverse events, compared to waitlist (very low COE; Table 7). Bouchard 2017 found no significant increase in SSQ scores over time (p > 0.2) in the VR arm, but did assess for adverse events in the waitlist arm.^31^ Lacey 2024 measured motion sickness using the Fast Motion Sickness Scale (FMS) and found that average FMS score was 8.1 at the last VR treatment (scale of 0–20, with 20 being “frank sickness”).^26^ No participants withdrew due to motion sickness, and authors also stated “no adverse events were reported and no participant requested assistance from a clinical psychologist.”

Table 7 Social Anxiety Disorder Certainty of Evidence: CBT + VR Exposure versus Waitlist

Outcome; Measure | Follow-Up; Total N (# of Studies) | SMD Pooled Estimate; (95% CI) | Anticipated Absolute Effects on Mean Score or Event Rate at Follow-Up | | | Certainty | What Happens
Outcome; Measure | Follow-Up; Total N (# of Studies) | SMD Pooled Estimate; (95% CI) | CBT + VR Exposure | Waitlist | Difference | Certainty | What Happens
Symptom Severity; FNE-B | Post-intervention; N = 244 (4 RCTs)^26,31,33,34^ | −0.66; (−117, −0.15) | 35.6; (30.3, 40.9) | 42.5^*^ | −6.9; (−12.2, −1.6) | ⊕◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of CBT coupled with VR exposure on symptom severity post-intervention.
Adverse Events; FMS, SSQ, NR | During intervention; N = 157 (2 RCTs)^26,31^ | — | 0.57; (0.79)^†^ | — | — | ⊕◯◯◯; Very low^a,c^ | The evidence is very uncertain on the effect of CBT coupled with VR exposure on adverse events.

Notes.

* Values for mean follow-up scores for intervention and/or comparator arms from Anderson 2013.^33^ Differences calculated by review team;

† SSQ scores in VR Exposure Therapy group from Bouchard 2017^31^;

a Downgraded 2 levels for study limitations (1 or more studies rated high RoB);

b Downgraded 1 level for inconsistency (direction of effects inconsistent across studies);

c Downgraded 1 level for indirectness (1 study did not describe how or which adverse events were assessed, 1 study only reported outcome for 1 arm).

Abbreviations. CBT=cognitive behavioral therapy; FNE-B=Brief Fear of Negative Evaluation; FMS=Fast Motion Sickness Scale; NR=not reported; RoB=risk of bias; SMD=Standardized Mean Difference; SSQ=Simulator Sickness Questionnaire; VR=virtual reality.

### CBT + VR Exposure versus CBT + Non-VR Exposure

Four RCTs compared CBT + VR exposure with CBT + non-VR exposure for social anxiety disorder.^27,31,33,34^ Study characteristics are summarized in Table 5. Study sample sizes ranged from 30–69, average age from 31.7–36.5 years, and 57%–83% were women.^27,31,34^ Interventions comprised 8–16 total sessions over a duration of 6–16 weeks. Two studies^31,33^ were appraised as some concerns RoB and 2 studies^27,34^ were appraised as high RoB, in part due to a large number of participants who did not receive the intervention.

All 4 RCTs used the same CBT sessions in both the VR and non-VR exposure arms. VR characteristics, including embodiment, interactivity, and multisensory stimulation, of the intervention were infrequently reported or not included, though Bouchard 2017 did have a component of interactivity (participants could interact with objects in the virtual environment).^31^

#### Symptom Severity

The evidence is very uncertain on the effect of CBT + VR exposure on symptom severity, compared with CBT and non-VR exposure (very low COE; Table 8). The meta-analysis used data from all 4 studies (LSAS^27,31,34^ and FNE-B scores^33^) and pooled estimates indicate no difference between arms (SMD 0.01[−0.45; 0.47]; Figure 7). Symptom severity was also measured using Appraisal of Social Concerns, Beck Depression Inventory (BDI), Clinician Global Impressions of Improvement, SIAS, PRCS, and Social Phobia Scale (SPS) (see Supplementary Materials for detailed findings).

Figure 7 Social Anxiety Disorder: Effect of CBT + VR Exposure versus CBT + Non-VR Exposure on Symptom Severity at Post-Intervention

Figure 7 is a forest plot visualizing a meta-analysis using data from 4 studies. There is inconsistency between studies, with 2 favoring VR and 2 favoring non-VR. All studies have confidence intervals that cross the null. The pooled SMD favors VR, with a confidence interval that crosses the null.

#### Treatment Response/Recovery

Only Anderson 2013 evaluated treatment response, reporting no significant differences using a chi-square test between arms at 3 months for participants in full remission, partial remission, and those who still met diagnostic criteria.^33^

#### Engagement

Two studies reported attendance data of participants,^27,31^ 1 study reported data on adherence,^33^ and 2 studies on other engagement measures. ^31,33^

##### Attendance

Two studies reported on attendance of participants but did not report comparisons between arms. Bouchard 2017 reported 2 (12%) and 4 (18%) participants in the CBT + VR exposure arm and CBT arm + non-VR arm, respectively, discontinued treatment.^31^ Stefaniak 2022 reported 2 (6%) discontinuations in the CBT + VR exposure arm, while 5 (17%) in the CBT + non-VR arm discontinued.^27^

##### Adherence

Anderson 2013 reported homework compliance at each treatment session (defined as participants completing half or more of homework). There was no statistically significant difference between groups at 7 of the 8 sessions.

##### Other Engagement Measures

Bouchard 2017 reported engagement in the CBT + VR exposure arm using the Presence Questionnaire, the Gatineau Presence Questionnaire, and treatment credibility. Participant’s sense of presence in VR increased over time, while treatment credibility remained similar throughout the VR intervention, though statistical comparisons over time and between arms were not reported.^31^ Anderson 2013 reported no difference in treatment satisfaction between arms at post-intervention (p = 0.2) or 12-month follow-up (p = 0.09).^33^

#### Adverse Events

The evidence is very uncertain on the effect of CBT + VR exposure on adverse events, compared to CBT + non-VR exposure (very low COE; Table 8). Two RCTs reported adverse events using the SSQ.^27,31^ Stefaniak 2022 reported 1 person in the CBT + VR exposure arm experienced simulator sickness symptoms and 4 people in the CBT + non-VR exposure arm experienced symptoms similar to simulator sickness^27^ Bouchard 2017 found no significant increase in SSQ scores after each VR session (p > 0.2) in the CBT + VR exposure arm, but did not assess for adverse events in the CBT + non-VR exposure arm.^31^

Table 8 Social Anxiety Disorder Certainty of Evidence: CBT + VR Exposure versus CBT + Non-VR Exposure

Outcome; Measure | Follow-Up; Total N (# of Studies) | SMD Pooled Estimate; (95% CI) | Anticipated Absolute Effects on Mean Score or Event Rate at Follow-Up | | | Certainty | What Happens
Outcome; Measure | Follow-Up; Total N (# of Studies) | SMD Pooled Estimate; (95% CI) | CBT + VR Exposure | CBT + non-VR Exposure | Difference | Certainty | What Happens
Symptom Severity; LSAS | Post-intervention; N = 192 (4 RCTs)^27,31,34,113^ | 0.01; (−0.45, 0.47) | 56.3; (44.6, 67.9) | 56.0^*^ | 0.3; (−11.4, 11.9) | ⊕◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of CBT coupled with VR exposure therapy on symptom severity post-intervention.
Adverse Events; SSQ | During intervention; N = 95 (2 RCTs)^27,31^ | — | 0.57; (0.79)^†^ | — | — | ⊕◯◯◯; Very low^a,c^ | The evidence is very uncertain on the effect of CBT coupled with VR exposure on adverse events.

Notes.

* Values for mean follow-up scores for intervention and/or comparator arms from Bouchard 2017.^31^ Differences calculated by review team;

† SSQ scores in VR Exposure Therapy group from Bouchard 2017^31^;

a Downgraded 2 levels for study limitations (1 or more studies rated high RoB);

b Downgraded 1 level for imprecision (CI crosses thresholds for small effects in both directions);

c Downgraded 1 level for indirectness (outcome not measured for all arms).

Abbreviations. CBT=cognitive behavioral therapy; LSAS=Liebowitz Social Anxiety Scale; RoB=risk of bias; SMD=standardized mean difference; SSQ=Simulator Sickness Questionnaire; VR=virtual reality.

### VR Exposure versus Non-VR Exposure

One study, Kampmann 2016, compared VR exposure with non-VR exposure. The sample size was 40, with a mean age of 38.6, and 70% of participants were female. The intervention comprised 10 total sessions over a duration of 5 weeks. The study was appraised as some concerns RoB due to loss to follow-up being imbalanced across arms. Non-VR and VR exposure sessions were 60 and 65 minutes long, respectively, for 10 sessions over a period of 5 weeks. Both exposure therapies were led by a therapist. Non-VR exposure consisted of participants engaging in social situations in the real world (eg, a supermarket or a café), while the VR exposure had similar social situations occur in a virtual environment.^32^

Symptom severity was assessed at 5 weeks and 3 months using the LSAS and the FNE-B. Non-VR exposure was found to have a statistically significant decrease versus VR exposure at both 5 weeks and 4 months on both the LSAS (p = 0.006 and p = 0.001) and the FNE-B (p = 0.008 and p = 0.007).^32^ Kampmann 2016 found “reliable change” in treatment response from pre- to post-intervention using the LSAS. While VR and non-VR exposure achieved reliable change in 47% and 78% of participants, respectively, the difference was not statistically significant (p = 0.057). For quality of life, Kampmann 2016 found significant difference in the change from pre-intervention at post-intervention between VR exposure (mean = 25.74, SD = 6.85) and non-VR exposure (mean = 29.78, SD = 4.47) as measured by EUROHIS-QOL (p = 0.004). There was no statistically significant difference between VR exposure (mean = 25.00, SD = 9.12) and non-VR exposure (mean = 28.92, SD = 6.46) at 3 months (p = 0.253). For attendance, Kampmann 2016 reported 6 (20%) in the VR exposure and 4 (14%) in the non-VR exposure arm discontinued treatment. Kampmann 2016 also reported adverse events; 1 participant in the VR exposure group discontinued the intervention due to motion sickness.^32^

### VR Exposure versus CBT Plus Non-VR Exposure

One study, Stefaniak 2022, also compared VR exposure with CBT plus non-VR exposure (as 2 of the 3 included arms).^27^ In the VR exposure arm, participants experienced 9 virtual scenarios (eg, speaking at a meeting or buying a train ticket) with varying levels of difficulty. The CBT plus non-VR exposure arm has been described above.

Symptom severity was assessed at 7 weeks using the LSAS, BDI, and Clinician Global Impressions of Improvement. There was a statistically significant change in LSAS (p = 0.008) and BDI scores (p = 0.002) when comparing VR exposure and CBT plus non-VR exposure at 7 weeks from baseline, but there was no statistically significant change in Clinician Global Impressions of Improvement (p-value not reported). For adverse events, 3 participants in the VR arm experienced simulator sickness symptoms and 4 in the CBT plus non-VR exposure arm experienced symptoms similar to simulator sickness.

### VR Attentional Bias Modification (ABM) Dot Probe Task

Ma 2019 compared 4 arms of ABM using a dot-probe task against each other (3D active, 3D sham, 2D active, 2D sham).^30,109^ The study enrolled 100 participants, 58.3% were female, and the average age was 40.8. All treatments were a single session each and were intended to reduce preferential focus on threatening faces and increase attention towards neutral faces. All arms used a VR head-mounted device. Two of the arms showed 3D rendered faces and 2 showed 2D rendered faces; 1 arm within each pair (3D or 2D) was considered active because it attempted to direct attention towards the neutral face using dots. The study was appraised as high ROB due to concerns about randomization, assignment to the intervention, missing outcome data, measurement of the outcome, and selection of reported results.

Symptom severity was assessed using LSAS and GAD. On the LSAS, mean (SD) scores at 3-month follow-up were as follows: 59.48 (23.18) (3D active), 43.76 (24.77) (3D sham), 56.65 (21.67) (2D active), and 49.48 (20.51) (2D sham). A mixed effects model found no significant differences between 2D/3D or active/sham in LSAS. No analyses were reported for GAD. All participants completed the intervention.

## KQ1 SPECIFIC PHOBIA OF FLYING (k = 7)

### Overview

Seven eligible RCTs (reported in 10 publications) evaluated VR interventions for specific phobia of flying (Table 9).^36–42^ All of these used VR exposure therapies, with half also including CBT. Four studies were conducted in the US^39–42,114–116^ and 3 were conducted in Europe (Spain,^37^ Italy,^36^ and the Netherlands^38^). Two studies permitted continuation of antidepressants or other medications (at stable doses),^36,38,41^ and 1 excluded individuals who had any other ongoing psychological or medication treatments for mental health disorders.^37^

We next present findings from the 6 RCTs comparing VR exposure therapy versus non-VR exposure, first focusing on the 2 trials evaluating only VR exposure therapy,^37,42^ then followed by the 4 studies using CBT plus VR exposure.^36,38,39,41^ Lastly, we describe the single study comparing VR exposure therapy with supportive group therapy.^40^ No studies reported findings on quality of life or suicidal ideation and/or suicidal behavior. Detailed study characteristics and findings may be found in the Supplementary Materials.

Table 9 Summary Characteristics of Specific Phobia of Flying Studies (k = 7)

Author, Year; Study Design; Risk of Bias; Total N Key Participant Characteristics | Intervention Characteristics | Comparator Characteristics
Tortella-Feliu, 2011^37^; Some concerns; N = 60; Mean age: 36-38 years; 52-75% female | VR Exposure; - VR scenarios preparing for flying, in airport, and during flight, with progression from easiest to most difficult; - Therapists guided sessions, use of cognitive strategies; - 6 × 60-minute sessions; 3 weeks; Hardware: 5DT HDM 800 HMD; Embodiment: No; Interactivity: Yes; Multisensory stimulation: No | Non-VR Exposure (with therapist); - 2-dimensional photos (on computer screen) and sounds for same types of scenarios as VR arm, provided additional exposures based on participant fear ratings; - Therapists present but did not guide treatment; - 6 × 60-minute sessions; 3 weeks
Tortella-Feliu, 2011^37^; Some concerns; N = 60; Mean age: 36-38 years; 52-75% female | | Non-VR Exposure (self-administered); - 2-dimensional computer-based program, same as comparator above, but therapist not present except during first and last sessions; - 6 × 60-minute sessions; 3 weeks
Wiederhold, 2001^42^; High; N = 36; Mean age: 36-44 years; 30-60% male; 40-70% female* | VR Exposure (no physiologic feedback); - VR graded exposure therapy, initial training in relaxation techniques; - 8 × 30-minute sessions; 8 weeks; Hardware: MRG4 (Liquid Image Inc.) HMD; Embodiment: No; Interactivity: Yes; Multisensory stimulation: Yes | Non-VR Exposure; - Graded imaginal exposure therapy, initial training in relaxation techniques; - 8 × 30-minute sessions; 8 weeks
Wiederhold, 2001^42^; High; N = 36; Mean age: 36-44 years; 30-60% male; 40-70% female* | VR Exposure (with physiologic feedback); - VR graded exposure therapy (with physiologic data displayed in virtual settings), initial training in relaxation techniques; - 8 × 30-minute sessions; 8 weeks; Hardware: MRG4 (Liquid Image Inc.) HMD; Embodiment: No; Interactivity: Yes; Multisensory stimulation: Yes | Non-VR Exposure; - Graded imaginal exposure therapy, initial training in relaxation techniques; - 8 × 30-minute sessions; 8 weeks
Krijn, 2007^38^; High; N = 86; Mean age: 39 years; 39% men; 61% women* | CBT + VR Exposure; - VR scenarios in airport and on airplanes; - CBT group sessions; - 4 × 60-minute sessions; 4 weeks; Hardware: Cybermind Visette Pro HMD; Embodiment: No; Interactivity: Yes; Multisensory stimulation: Yes | CBT + Non-VR Exposure; - Individual sessions using imaginal exposure (and sitting on aircraft seat in office setting); - CBT group sessions; - 4 × 60-minute sessions; 4 weeks
Krijn, 2007^38^; High; N = 86; Mean age: 39 years; 39% men; 61% women* | | Bibliotherapy; - Encouraged to read book to help address phobia of flying (also provided to participants in other 2 arms)
Rothbaum, 2000^41^; High; N = 49; Mean age: 41 years; 71% female | CBT + VR Exposure; - Individual sessions on cognitive restructuring, coping skills; - VR scenarios in airplane and during flights, therapist provided feedback and encouragement; - 8 × 60-90 minute sessions; 6 weeks; Hardware: Virtual Research VR6 HMD; Embodiment: No; Interactivity: No; Multisensory stimulation: Yes | CBT + non-VR Exposure; - Individual sessions on cognitive restructuring, coping skills; - In vivo exposure in airport and airplane (not in flight); - 8 × 60-90 minute sessions; 6 weeks
Rothbaum, 2000^41^; High; N = 49; Mean age: 41 years; 71% female | | Waitlist; - No active treatment
Rothbaum, 2006^39^; High; N = 83; Mean age: 37-45 years; 76-84% female | CBT + VR Exposure; - Individual sessions on cognitive restructuring, coping skills; - VR scenarios in airplane and during flights, therapist guided exposures, provided feedback and encouragement; - 8 × 60-90 minute sessions; 6 weeks; Hardware: IISVR-VFX3D HMD; Embodiment: No; Interactivity: No; Multisensory stimulation: Yes | CBT + non-VR Exposure; - Individual sessions on cognitive restructuring, coping skills; - In vivo and imaginao exposure in airport; - 8 × 60-90 minute sessions; 6 weeks
Rothbaum, 2006^39^; High; N = 83; Mean age: 37-45 years; 76-84% female | | Waitlist; - No active treatment
Triscari, 2015^36^; Some concerns; N = 65; Mean age: 42-46 years; 24-36% men; 64-76% women | CBT + VR Exposure; - Individual sessions on cognitive restructuring, coping skills, in vivo and imaginal exposures; - VR scenarios NR; - 10 × 120-minute sessions; 10 weeks; Hardware: NR; Embodiment: NR; Interactivity: NR; Multisensory stimulation: NR | CBT + non-VR Exposure; - Individual sessions on cognitive restructuring, coping skills, in vivo and imaginal exposures; - Systematic desensitization (details NR); - 10 × 120-minute sessions; 10 weeks
Triscari, 2015^36^; Some concerns; N = 65; Mean age: 42-46 years; 24-36% men; 64-76% women | | CBT + Eye Movement Desensitization and Reprocessing Therapy; - Individual sessions on cognitive restructuring, coping skills, in vivo and imaginal exposures; - EMDR (details NR); - 10 × 120-minute sessions; 10 weeks
Maltby, 2002^40^; High; N = 45; Mean age: 45 years; 79% women | VR Exposure; - VR graded exposure therapy; - Therapist adjusted exposure intensity (eg, smooth versus turbulent flight); - 5 × 50-90 minute sessions; 3 weeks; Hardware: Virtual Research V6 HMD; Embodiment: No; Interactivity: Yes; Multisensory stimulation: No | Supportive Group Therapy; - Education about flight mechanics and safety, group sharing of flying experiences and fears; - 5 × 50-90 minute sessions; 3 weeks

Abbreviations. CBT=cognitive behavioral therapy; HMD=head-mounted display; NR=not reported; VR=virtual reality.

### VR Exposure versus Non-VR Exposure

Two RCTs compared VR exposure with non-VR exposure,^37,42^ with 1 of these including 2 VR treatment arms (with or without biofeedback).^42^ Both assessed symptom severity, treatment response or recovery, and participant engagement. Both were small (total N = 36–60) and enrolled young and middle aged adults (mean age = 36–44 years, 40%–75% women).^37,42^ Treatments comprised 6–8 total sessions over a duration of 3–8 weeks, and 1 specified therapist involvement.^37^ Tortella-Feliu 2011^37^ was rated some concerns for RoB, while Wiederhold 2001^42^ had high RoB due to a number of methodological concerns including allocation concealment, balance in non-protocol interventions, and adherence to assigned treatment.

#### Symptom Severity

The evidence is very uncertain on the effect of VR exposure on symptom severity immediately post-intervention, as compared with non-VR exposure therapy (very low COE; Table 10). Tortella-Feliu 2013 assessed symptom severity using the Fear of Flying Scale (FFS),^37^ and Wiederhold 2001 employed the Questionnaire on Attitudes toward Flying (QAF).^42^ The pooled estimate (using data from both VR exposure arms in Wiederhold 2001) indicated potentially small effect favoring VR exposure, but with 95% CI extending to very large effects in both directions (SMD = −0.19 [−1.29, 0.90]; Figure 8). Both studies reported improvement in all groups over time and no significant between-group differences immediately post-intervention. Tortella-Feliu 2013 also assessed symptom severity at 1 year, finding that all groups maintained improvements in symptoms and no between-group differences at longer term follow-up.^37^

Figure 8 Specific Phobia of Flying: Effect of VR Exposure versus Non-VR Exposure on Symptom Severity Immediately Post-Intervention

Notes. *VR exposure arms without biofeedback (Wiederhold, 2001a) or with biofeedback (Wiederhold, 2001b). Same mean and SD from non-VR exposure arm was used for each comparison, with N split between the 2 comparisons.

Figure 8 is a forest plot visualizing a meta-analysis using data from 7 studies. The overall pooled analysis shows no significant difference between VR and non-VR (SMD 0.06 [95% confidence interval −0.26, 0.37]). Subgroup analyses were done for VR exposure versus non-VR exposure (3 studies) and for CBT plus VR exposure versus CBT plus non-VR exposure (4 studies). Neither subgroup analysis favors VR or non-VR. Confidence intervals cross the null for all studies. There is consistency among the 3 studies comparing VR versus non-VR. The results for the 4 studies comparing CBT plus VR versus CBT plus non-VR are less consistent with Krijn 2007, Rothbaum 2006, and Triscari 2015 favoring non-VR and Rothbaum 2000 favoring VR.

#### Treatment Response/Recovery

The evidence is very uncertain on the effect of VR exposure on treatment response, compared with non-VR exposure therapy (very low COE; Table 10). Both studies assessed the proportion of participants who completed flights after treatment, finding higher rates of flight completion in the VR arms (Figure 9). Tortella-Feliu 2013 encouraged participants to take a flight on their own within 15 days post-intervention, and then assessed who had done so.^37^ Wiederhold 2001 also evaluated self-reported flight completion post-intervention, but did not specify the time period.^42^ The pooled estimate potentially indicated higher completion in the VR group but the 95% CI extended into effects favoring non-VR treatment (pooled RR = 1.37, 95% CI [0.95, 1.98]; Figure 9).

Figure 9 Specific Phobia of Flying: Effect of VR Exposure versus Non-VR Exposure on Flight Completion Post-Intervention

Notes. *VR exposure arms without biofeedback (Wiederhold, 2001a) or with biofeedback (Wiederhold, 2001b). Total of 7 events in non-VR group; events were divided and N split between the 2 comparisons.

Figure 9 is a forest plot visualizing a meta-analysis using data from 3 studies. The pooled analysis shows no significant difference between CBT plus VR and CBT plus non-VR. One study (Triscari 2015) favors VR, 1 study (Rothbaum 2000) favors non-VR, and the third study (Rothbaum 2006) found a risk ratio of 1.00 favoring neither group. Figure 10 is a forest plot visualizing a meta-analysis using data from 5 studies. The overall pooled analysis shows no significant difference between VR and non-VR (RR 1.08 [95% confidence interval 0.91, 1.21). Subgroup analyses were done for VR exposure versus non-VR exposure (2 studies) and for CBT plus VR exposure versus CBT plus non-VR exposure (3 studies). Neither subgroup favors VR or non-VR. Confidence intervals cross the null for all studies.

Using the Anxiety Disorders Interview Schedule for Diagnostic and Standards Manual-IV (ADIS-IV), Tortella-Feliu 2013 also assessed proportion of participants who no longer met criteria for flying phobia immediately post-intervention and at 1 year.^37^ There were no between-group differences either immediately post-intervention or at 1 year (eg, 68% in VR group vs 52%–60% non-VR post-intervention, p = 0.59).

#### Engagement

Both studies reported on discontinuation or completion of treatments, and 1 study also evaluated treatment satisfaction. Tortella-Feliu 2013 reported similar discontinuation across arms (1 participant in the VR exposure group, and 1 and 2 in each of the 2 non-VR exposure arms); reasons given were scheduling conflicts and illness unrelated to the study.^37^ Wiederhold 2001 found that drop-out was substantial in the non-VR exposure group (4 out of 10), whereas no one in the VR arms did so.^42^ Tortella-Feliu 2013 also assessed satisfaction, reporting this was greater for the VR exposure arm; satisfaction was assessed with an adapted Borkovec and Nan Credibility/Expectations Scale, but authors did not provide mean values.^37^ None of the studies assessed other measures of engagement.

Table 10 Specific Phobia of Flying Certainty of Evidence: VR Exposure versus Non-VR Exposure

Outcome; Measure | Follow-Up; Total N (# of Studies) | Pooled Estimate; (95% CI) | Anticipated Absolute Effects on Mean Score or Event Rate at Follow-Up | | | Certainty | What Happens
Outcome; Measure | Follow-Up; Total N (# of Studies) | Pooled Estimate; (95% CI) | VR Exposure | Non-VR Exposure | Difference | Certainty | What Happens
Symptom Severity; FFS; QAF | Post-intervention; N = 65 (2 RCTs)^37,42^ | SMD: −0.19; (−129, 0.90) | 44.3; (31.3, 57.3) | 46.6^*^ | −2.3; (−15.3, 10.7) | ⊕◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of VR exposure on symptom severity immediately post-intervention.
Treatment Response; Flight completion | N = 65 (2 RCTs)^37,42^ | RR: 1.37; (0.95, 1.98) | 77%; (53%, 100%) | 56%^*^ | 21%; (−3%, 44%) | ⊕◯◯◯; Very low^a,c^ | The evidence is very uncertain on the effect of VR exposure on flight completion post-intervention.

Notes.

* Mean FFS score for comparator arm and proportion who completed flights are both from Tortella-Feliu 2011^37^;

a Downgraded 2 levels for study limitations (1 or more studies rated high RoB);

b Downgraded 2 levels for imprecision (CI crosses threshold for small effects in opposing direction);

c Downgraded 1 level for imprecision (CI crosses into effect in opposing direction).

Abbreviations. FFS=Fear of Flying Scale; QAF=Questionnaire on Attitudes toward Flying; RoB=risk of bias; RR=rate ratio; SMD=standardized mean difference; VR=virtual reality.

### CBT and VR Exposure versus CBT and Non-VR Exposure

Four RCTs compared CBT and VR exposure with CBT and non-VR exposure.^36,38,39,41^ Study characteristics and interventions are summarized in Table 9. Studies were small (total N = 34–86), and enrolled young and middle-aged adults (mean age = 37–46 years, 61%–84% women). VR interventions comprised 4–10 sessions over a duration of 4–10 weeks. Triscari 2015^36^ had some concerns for RoB, while the other 3 studies all had high RoB due to substantial methodological concerns, including allocation concealment and loss to follow-up.^38,39,41^

Rothbaum 2000 and Rothbaum 2006 were conducted by the same research group, and both studies involved similar treatment protocols with 4 sessions of CBT that preceded exposure sessions (VR vs imaginal and in vivo exposures).^39,41^ Both of these trials also included a third waitlist arm; findings for comparisons between VR and waitlist arms will be described in the next section. Krijn 2007 evaluated treatment with VR exposure sessions that preceded final group CBT sessions; the comparator group had individual CBT sessions (incorporating imaginal exposures), followed by the same group CBT sessions.^38^ The fourth RCT, Triscari 2015, compared CBT plus VR exposure versus CBT plus non-VR exposure versus CBT plus eye movement desensitization and reprocessing therapy (EMDR); CBT sessions were the same in all 3 arms.^36^

#### Symptom Severity

The evidence is very uncertain on the effect of CBT plus VR exposure on symptom severity immediately post-intervention, compared with CBT plus non-VR exposure (very low COE; Table 11). All 4 studies assessed symptom severity using the Flight Anxiety Situations Questionnaire (FAS)^36,38^ or QAF.^39,41^ The pooled estimate showed no significant between-group effects, with the 95% CI extending from small effects favoring VR to moderate effects favoring non-VR exposure (SMD = 0.14 [−0.33, 0.61]; see Figure 8 above). The COE was reduced due to study methodological limitations and wide confidence interval (crossing small to moderate effects in both directions). Triscari 2015 also compared CBT plus VR exposure with CBT plus EMDR, reporting no significant between-group differences.^36^

The evidence is very uncertain on the effect of CBT plus VR exposure versus CBT plus non-VR exposure on symptom severity at 6 and 12 months post-intervention (very low COE; Table 11).Three studies reported longer-term findings on symptom severity at 12 months.^36,39,41^ The pooled estimate showed no significant between-group effects (SMD = 0.14 [−0.55, 0.83]; Figure 10). The COE was reduced due to study methodological limitations and wide confidence interval (crossing small to moderate effects in both directions). Two of these studies also assessed outcomes at 6 months, both reporting no between-group differences.^39,41^ Additionally, Triscari 2015 reported no significant between-group differences between CBT plus VR exposure and CBT plus EMDR groups at 12 months.^36^

Figure 10 Specific Phobia of Flying: Effect of CBT with VR Exposure versus CBT with Non-VR Exposure on Symptom Severity 12 Months Post-Intervention

Figure 10 is a forest plot visualizing a meta-analysis using data from 3 studies. The pooled analysis shows no significant difference between CBT plus VR and CBT plus non-VR with confidence intervals for all 3 studies crossing the null. One study (Rothbaum 2000) favors VR while the other 2 studies (Rothbaum 2006, Triscari 2015) favor non-VR. There is consistency among the 2 studies comparing VR versus non-VR. The results for the 3 studies comparing CBT plus VR versus CBT plus non-VR are less consistent with Rothbaum 2000 favoring CBT plus VR, Rothbaum 2006 favoring neither, and Triscari 2015 favoring CBT plus non-VR.

#### Treatment Response/Recovery

The evidence is very uncertain on the effect of CBT plus VR exposure on treatment response, compared with CBT plus non-VR exposure (very low COE; Table 11). Pooled effect estimate using data from 3 studies^36,39,41^ showed no differences between groups but 95% CI extended into potentially important differences in both directions (RR = 1.04 [0.89, 1.21]; Figure 9). Treatment response was assessed as flight completion in all 3 studies, with both Rothbaum 2000 and Rothbaum 2006 including the flights (1.5–2 hours) as part of the study assessment protocol.^39,41^ Tricari 2015 asked participants to report on flights they had completed on their own (outside of the study protocol), and also indicated there were no between-group differences between CBT plus VR exposure and CBT plus EMDR arms.^36^ Rothbaum 2000 also reported flight completion at 6 and 12 months post-intervention, finding no between-group differences at these later time points.^41,114^ Finally, Rothbaum 2006 found that similar proportions of individuals no longer met full criteria for flying phobia at 6 months, assessed using the Structured Clinical Interview for the DSM-IV (71% for VR group vs 76% for non-VR arm, p-value not reported).

Table 11 Specific Phobia of Flying Certainty of Evidence: CBT + VR Exposure versus CBT + Non-VR Exposure

Outcome; Measure | Follow-Up; Total N (# of Studies) | Pooled Estimate; (95% CI) | Anticipated Absolute Effects on Mean Score or Event Rate at Follow-Up | | | Certainty | What Happens
Outcome; Measure | Follow-Up; Total N (# of Studies) | Pooled Estimate; (95% CI) | CBT + VR Exposure | CBT + Non-VR Exposure | Difference | Certainty | What Happens
Symptom Severity; FAS QAF | Post-intervention; N = 184 (4 RCTs)^36,38,39,41^ | SMD: 0.14; (−0.33, 0.61) | 154.9; (126.1, 183.7) | 146.3^*^ | 8.6; (−20.2, 37.4) | ⊕◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of VR exposure on symptom severity immediately post-intervention.
Symptom Severity; FAS QAF | 6 months post-intervention; N = 96 (2 RCTs)^39,41^ | — | 161.3^*^ | 136.8^*^ | 24.5 | ⊕◯◯◯; Very low^a,c^ | The evidence is very uncertain on the effect of VR exposure on symptom severity at 6 months post-intervention.
Symptom Severity; FAS QAF | 12 months post-intervention; N = 127 (3 RCTs)^37,39,114^ | SMD: 0.14; (−0.55, 0.83) | 164.1; (106.0, 222.2) | 152.3^*^ | 11.8; (−46.3, 69.9) | ⊕◯◯◯; Very low^a,b,d^ | The evidence is very uncertain on the effect of VR exposure on symptom severity at 12 months post-intervention.
Treatment Response; Flight completion | Post-intervention; N = 135 (3 RCTs)^36,39,41^ | RR: 1.04; (0.89, 1.21) | 68%; (58%, 79%) | 66%^*^ | 2%; (−8%, 13%) | ⊕◯◯◯; Very low^a,e^ | The evidence is very uncertain on the effect of VR exposure on flight completion post-intervention.

Notes.

* Values for mean QAF scores and flight completion rates from Rothbaum 2006^39^;

a Downgraded 2 levels for study limitations (1 or more studies rated high RoB);

b Downgraded 2 levels for imprecision (CI crosses thresholds for small effects in opposing direction);

c Downgraded 1 level for imprecision (using OIS, studies were not powered to detect minimum SMD of 0.6; see Methods for more information);

d Downgraded 1 level for inconsistency (direction of effects inconsistent across studies);

e Downgraded 1 level for imprecision (CI includes potentially important effects in both directions).

Abbreviations. CBT=cognitive behavioral therapy; FAS=Flight Anxiety Situations Questionnaire; OIS=optimal information size; QAF=Questionnaire on Attitudes toward Flying; RoB=risk of bias; RR=rate ratio; SMD=standardized mean difference; VR=virtual reality.

#### Engagement

Three studies assessed treatment discontinuation, with both Rothbaum 2000^41^ and Rothbaum 2006^39^ reporting similar rates for CBT plus VR exposure and CBT plus non-VR exposure arms (eg, 12% for both VR exposure and non-VR exposure arms).^39^ Krijn 2007 found higher discontinuation in the CBT plus VR exposure arm (34%) compared with CBT plus non-VR exposure (11%); 1 discontinuation in the VR arm was due to simulation sickness.^38^ Both Rothbaum 2000 and Rothbaum 2006 also assessed treatment satisfaction using the CSQ-8, finding no differences between groups and generally high levels of satisfaction.^39,41^ None of the studies assessed other measures of engagement.

### CBT and VR Exposure versus Waitlist

As noted above, both Rothbaum 2000 and Rothbaum 2006 included a waitlist arm with no active treatments described.^39,41^ The evidence is very uncertain on the effect of CBT plus VR exposure on symptom severity post-intervention, compared with waitlist (very low COE; Table 12). As noted above, symptom severity was assessed with the QAF; both studies reported lower scores for CBT plus VR exposure compared with waitlist (eg, mean = 150.3 [SD = 60.6] for VR compared with mean = 205.9 [72.0] in the waitlist arm, pairwise p-value not reported).^39,41^ The COE was reduced due to study methodological limitations and insufficient power of studies to detect a minimum SMD of 0.6 (see OIS criteria described in Methods).

CBT plus VR exposure may lead to higher flight completion post-intervention, compared with waitlist (low COE; Table 12). Both studies reported higher flight completion rates in the CBT plus VR arm (eg, 66% versus 20% in the waitlist group).^39^

Table 12 Specific Phobia of Flying Certainty of Evidence: CBT + VR Exposure versus Waitlist

Outcome; Measure | Follow-Up; Total N (# of Studies) | SMD Pooled Estimate; (95% CI) | Anticipated Absolute Effects on Mean Score or Event Rate at Follow-Up | | | Certainty | What Happens
Outcome; Measure | Follow-Up; Total N (# of Studies) | SMD Pooled Estimate; (95% CI) | VR Exposure | Waitlist | Difference | Certainty | What Happens
Symptom Severity; QAF | Post-intervention; N = 87 (2 RCTs)^39,41^ | — | 150.3; (60.6)^*^ | 204.9; (72.0)^*^ | −54.6^*^ | ⊕◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of CBT and VR exposure on symptom severity post-intervention
Treatment Response; Flight completion | Post-intervention; N = 80 (2 RCTs)^39,41^ | — | 76%; (19/25)^*^ | 20%; (5/25)^*^ | 56%^*^ | ⊕⊕◯◯; Low^a^ | CBT and VR exposure may lead to higher flight completion post-intervention.

* Mean QAF scores (SD) and proportion with flight completion for both arms from Rothbaum 2006.^39^ Differences calculated by review team;

a Downgraded 2 levels for study limitations (1 or more studies rated high RoB);

b Downgraded 1 level for imprecision (using OIS, studies were not powered to detect minimum SMD of 0.6; see Methods for more information).

Abbreviations. CBT=cognitive behavioral therapy; OIS=optimal information size; QAF=Questionnaire on Attitudes toward Flying; RoB=risk of bias; SMD=standardized mean difference; VR=virtual reality.

### VR Exposure versus Supportive Group Therapy

Maltby 2002 compared VR exposure with supportive group therapy, randomizing 45 adults with mean age of 45 years, 79% being women.^40^ The intervention comprised 5 sessions over 3 weeks. This study was rated high RoB due to a number of concerns, including ack of information about allocation concealment and imbalance in number of drop-outs across groups.

Immediately post-intervention, the VR group had lower mean FAS scores for both in-flight and anticipatory domains, compared with the supportive therapy group (eg, in-flight 20.5 [SD = 9.1] for VR vs 28.9 [12.0] for supportive therapy, p < 0.01). However, there were no between-group differences in FAS scores at 6 months post-intervention. For treatment response, there were no between-group differences in the study proportion of participants who were able to complete a 10–15 minute flight (59% VR vs 57% supportive therapy, p-value not reported). Regarding engagement, 2 participants dropped out of the VR group and none from the supportive therapy group. No other aspect of engagement was reported. For adverse events, authors reported that 1 of the participants who withdrew from the study did so due to motion sickness during VR exposure treatment, but they did not describe whether other participants may have experienced any symptoms during treatment sessions. This study did not assess any other eligible outcomes.

## KQ1 ALCOHOL USE DISORDER (k = 2)

### Overview

We identified 2 studies (reported in 3 articles) evaluating the use of VR interventions in the treatment of patients with alcohol use disorder (AUD; Table 13). One trial in Spain combined a VR version of cue exposure therapy with TAU.^43,45^ The other trial in Korea combined VR exposure with alcohol approach-avoidance training.^44^ Neither study reported quality of life, adherence, other engagement, adverse events, or suicidal ideation and/or behaviors outcomes. Below, we describe study characteristics and outcomes for both studies for VR exposure. Detailed study characteristics and detailed findings are presented in the Supplementary Materials.

Table 13 Summary Characteristics of AUD Studies (k = 3)

Author, Year; Study Design; Risk of Bias; Total N Key Participant Characteristics | Intervention Characteristics | Comparator Characteristics
Hernandez-Serrano, 2020^43^; Figueras-Puigderrajols, 2020^45^; High; N = 79; Mean age: 54.6 years; 50% women; Patients in substance use clinic | VR Cue Exposure Therapy + TAU; - Virtual cue exposure therapy in environments (eg, restaurant, bar) that elicit cravings; - Olfactory stimuli included smells corresponding to alcohol types; - Progression through levels of increasing difficulty by craving ratings; - Individual + group psychotherapy, pharmacotherapy as per TAU; - No use of anti-craving medication (eg, naltrexone); - 6 × 50-minute VR sessions; 3 weeks; Hardware: Oculus Rift S HMD; Embodiment: Yes; Interactivity: Yes; Multisensory stimulation: Yes | TAU; - Pharmacotherapy (disulfiram, anxiolytics and/or antidepressants); - Individual + group psychotherapy; - Individual psychotherapy session dose not reported; - No use of anti-craving medication (eg, naltrexone); - 3–6 1.5-hour group sessions; 3 weeks
Kim, 2019^44^; High; N = 28; Mean age: 22-23 years; 39% female; College undergraduates; heavy social drinkers | VR Approach Avoidance Exposure Therapy; - Virtual social situations with and without alcohol, training in approach and avoidance cues to reduce automatic action tendencies toward alcohol; - Color signals instructed participants to use a joystick to approach alcohol-unrelated situations and avoid alcohol-related situations; - 3 1-hour sessions; 2-3 weeks; Hardware: NR; Embodiment: NR; Interactivity: Yes; Multisensory stimulation: No | VR Sham Approach Avoidance Exposure Therapy; - Sham training in which no association was assumed between alcohol-related situations and participant actions; - 3 1 hour sessions; 2-3 weeks; Hardware: NR; Embodiment: NR; Interactivity: Yes; Multisensory stimulation: No

Abbreviations. AUD=alcohol use disorder; HMD=head-mounted display; NR=not reported; TAU=treatment as usual; VR=virtual reality.

### VR Exposure

Two RCTs evaluated VR exposure therapy for AUD.^43–45^ Study characteristics and findings for VR interventions are summarized in Table 13. Both studies were small (total N = 28–79) and included young and middle-aged adults (mean ages = 22–57 years, 39%–50% women). However, while Hernandez-Serrano 2020 enrolled patients from addiction clinics in Spain,^43^ Kim 2019 recruited Korean college undergraduates who were “heavy social drinkers” (defined as >22 on Alcohol Use Disorders Identification Test [AUDIT]).^44^ VR interventions involved 3–5 sessions, each lasting about an hour long and delivered over 2–3 weeks. Both studies were rated high for RoB due to substantial loss to follow-up.

Hernandez-Serrano 2020 evaluated VR cue exposure therapy to desensitize participants to alcohol-related scenarios in the virtual environment as well as to olfactory inputs provided by the attending clinical staff, progressing through stages of increasing difficulty based on subjective cravings ratings.^43^ Participants also received debriefings intended to reduce levels of craving and anxiety, immediately following the exposure session. The VR group also received TAU, which consisted of pharmacotherapy, individual and group psychotherapy (based on CBT), and motivational interviewing; the comparator group received only TAU. Figueras-Puigderrajols 2020 reported an earlier pilot’s results (for 28 participants) that appeared to be part of this same study,^45^ although it was unclear whether the same participants may have been included in both reports. Therefore, we present findings mainly from Hernandez-Serrano 2020,^43^ as it was larger and had better described study outcomes.

Kim 2019 used VR to re-condition alcohol-related behaviors while the patient remained present in the virtual environment.^44^ Participants encountered virtual scenarios that did or did not have the presence of alcohol, and were trained with color signals to activate an approach or avoidance response depending on the presence or non-presence of alcohol. Patients in the comparator arm received a sham training modality, which operated on a similar approach/avoidance basis but was programmed to impart only a neutral association of avoidance with alcohol.^44^

#### Symptom Severity

Both trials assessed AUD symptoms in terms of craving for alcohol, but were not combined to assess CoE due to substantial differences in populations, VR interventions, and comparators.^43–45^ Hernandez-Serrano 2020 assessed craving for alcohol with a modified version of the Multidimensional Craving Scale (MACS).^43^ MACS scores by study arm at baseline and follow-up were not presented, and no between-group statistical analyses were reported; however, authors stated that there were significant reductions only in the VR arm.^43^ Kim 2019 assessed participants cravings using the Alcohol Use Questionnaire (AUQ), and post-intervention AUQ scores did not differ significantly between arms.^44^

#### Treatment Response

Hernandez-Serrano 2020 also evaluated treatment response, defined as post-intervention improvement in craving category. MACS scores were categorized as nonexistent, mild, moderate, or intense at baseline, and improvement post-intervention was defined as improvement (by at least 1 level).^43^ Cravings improved for 87% (13/15) of completers in the VR group, compared with 33% (9/27) in control group.

#### Engagement

Only Hernandez-Serrano 2020 evaluated engagement, reporting that 57% (20/35) of participants in the VR group and 39% (17/44) of the TAU group failed to complete the assigned intervention.^43^ No reasons for discontinuation were noted.

## KQ1 STIMULANT USE DISORDER (k = 2)

### Overview

We identified 2 RCTs evaluating the use of VR interventions in the treatment of patients with stimulant use disorder (Table 14). In both trials, VR was used to deliver exposure therapy to patients with methamphetamine dependence. Both trials were conducted in Asia. We describe these 2 VR exposure studies together. No studies reported treatment response/recovery, quality of life, adherence, other engagement, adverse events, or suicidal ideation and/or behaviors outcomes. Below, we describe study characteristics and outcome findings for the included VR exposure studies. Detailed study characteristics and detailed results are provided in the Supplementary Materials.

Table 14 Summary Characteristics of Stimulant Use Disorder Studies (k = 2)

Author, Year; Study Design; Risk of Bias; Total N Key Participant Characteristics | Intervention Characteristics | Comparator Characteristics
Wang, 2019^47^; Some concerns; N = 61; Mean age: 33–35 years 100% men; Patients in substance addiction clinic | VR Exposure Therapy + TAU; - Virtual scenarios of methamphetamine use followed by scenarios showing adverse consequences, designed to create an aversive response to methamphetamine use through counterconditioning; - TAU: conventional psychotherapy plus physical exercises; - 6 sessions (duration NR); 3 weeks; Hardware: HMD version 2.0, Hangzhou Seventh Science and Technology Co., Ltd; Embodiment: No; Interactivity: No; Multisensory stimulation: No | TAU; - Conventional psychotherapy plus physical exercises
Ji, 2023^46^; Some concerns; N = 60; Mean age: 23 years 100% women; Enrolled in compulsory drug rehabilitation center | VR Exposure Therapy + Motivational Reinforcement; - Motivational reinforcement initial phase to establish intent to cease methamphetamine use (3 sessions: 2 individual + 1 group); - Virtual methamphetamine cue scenarios designed to activate addiction memories and desensitize participants, followed by group relaxation skills training; - 6 × 60-minute VR sessions; 4 weeks; Hardware: PICO G2 HMD; Embodiment: No; Interactivity: NR; Multisensory stimulation: NR | TAU; - Regular detoxification management; - 8 sessions (duration NR); 4 weeks

Abbreviations. HMD=head-mounted display; NR=not reported; TAU=treatment as usual; VR=virtual reality.

### VR Exposure

Both studies evaluated VR exposure therapies for stimulant use disorder.^46,47^ Study characteristics and findings for VR interventions are summarized in Table 14. Both studies were conducted in China and included participants with diagnoses of amphetamine dependence who were receiving care through detoxification or drug rehabilitation centers. Inpatient versus outpatient status was unclear for both studies. Sample sizes were 60 and 61. One study recruited only women in early adulthood (mean age 23)^46^ and the other recruited only men (mean age 35).^47^ Interventions comprised 6 sessions over 3–4 weeks. Both studies compared a VR exposure intervention with TAU, and both were rated some concerns for RoB. Both studies reported symptom severity outcomes and 1 reported on engagement though only presented data for attendance.

Though both studies cite cue exposure therapy as fundamental to their approach, strategies used to produce a therapeutic effect through VR exposure differed. Ji 2023 focused primarily on the mechanism of desensitization through VR, after an initial motivational reinforcement phase. Patients were exposed to virtual cue scenarios which were then followed by group relaxation skills training intended to reduce psychological cravings for methamphetamine. Participants in the comparator arm received TAU, described as regular detoxification and drug rehabilitation management.^46^ Wang 2019 evaluated a counterconditioning VR exposure therapy intervention intended to instill an aversive response to methamphetamine use. Through interviews conducted with patients with methamphetamine dependence, authors identified common negative themes (eg, encounters with police, death) which were then incorporated in immersive methamphetamine-related VR videos intended to recondition patients to develop methamphetamine-aversive behaviors. Both the intervention and the comparator arm received TAU (ie, psychotherapy, physical exercise).^47^

#### Symptom Severity

VR exposure therapy to treat methamphetamine dependence may result in improved symptom severity post-intervention when compared to TAU (low COE; Table 15). Both studies compared a VR exposure intervention with TAU for a duration of 3–4 weeks and reported subjective craving for methamphetamine using visual analogue scale (VAS) scores asking patients to indicate their levels of craving (eg, “how much do you crave METH/ice right now?”).^47^ Wang 2019^47^ and Ji 2023^46^ both assessed craving immediately post-intervention. In Wang 2019, the VR exposure therapy arm had significantly lower mean craving post-intervention than the TAU arm (mean levels NR, p < 0.001). In Ji 2023, the VR exposure therapy arm also had significantly lower mean craving immediately post-intervention and at 1 month, compared with the TAU arm (eg, mean VAS craving 10.17 VR vs 27.67 control at 1 month, p < 0.0001).

#### Engagement

Only Ji 2023 evaluated engagement, reporting that 1 participant missed 4 treatment sessions due to work; authors excluded this patient from analyses.^46^

Table 15 Stimulant Use Disorder Certainty of Evidence: VR Exposure Therapy versus TAU

Outcome; Outcome Measure | Follow-Up; Total N (# of Studies) | Anticipated Absolute Effects (SD) | | | Certainty | What Happens
Outcome; Outcome Measure | Follow-Up; Total N (# of Studies) | VR Exposure Therapy | TAU | Difference | Certainty | What Happens
Symptom Severity; VAS Craving | Post-intervention; N = 119 (2 RCTs)^46,47^ | 7.59; (1.65)^*^ | 27.67; (3.99)^*^ | −20.08^*^ | ⊕◯◯◯; Low^a,b^ | VR exposure therapy may result in lower craving post-intervention.

Notes.

* Mean (SD) for intervention and comparator arms taken from Ji 2023,^46^ and difference calculated by review team;

a Downgraded 1 levels for study limitations (study rated some concerns for RoB);

b Downgraded 1 level for imprecision (using OIS, studies were not powered to detect minimum SMD of 0.6; see Methods for more information).

Abbreviations. SD=standard deviation; TAU=treatment as usual; VAS=Visual Analogue Scale; VR=virtual reality.

## KQ1 DEPRESSION (k = 6)

### Overview

Six eligible RCTs evaluated VR interventions to address depression, with 4 focusing on treatment of depressive symptoms in older adults (Table 16).^48,50,52,53^ These trials all used the Geriatric Depression Scale (GDS) to assess presence of substantial depressive symptoms, defined as GDS ≥ 10.^48,50,52,53^ Three of these studies compared combined VR relaxation and exercise versus non-VR relaxation and exercise, and were conducted in Europe by the same group of investigators^50,52,53^; 1 of these focused exclusively on post-stroke depression.^52^ The fourth trial was conducted in China and compared VR Tai Chi versus non-VR Tai Chi for treatment-naïve older adults with depression.^48^ Below, we first present findings from this group of 4 studies. Then, we separately describe results from the 2 remaining studies; 1 compared VR behavioral activation versus non-VR behavioral activation for adults with major depressive disorder (MDD),^49^ and the other evaluated a VR rehabilitation program for post-stroke depression.^51^ No studies reported quality of life, adherence, or suicidal ideation and/or behaviors. Detailed study characteristics and outcome findings are located in the Supplementary Materials.

Table 16 Summary Characteristics of Studies Evaluating VR Interventions for Depression (k = 6)

Author, Year; Study Design; Risk of Bias; Total N Key Participant Characteristics | Intervention Characteristics | Comparator Characteristics
Cieslik, 2023^50^; Some concerns; N = 60; Mean age: 68 years; 100% women; Members of community center for older women | Exercise + VR Relaxation; - VR garden with music, mandala coloring task; - Group-based low-intensity exercises; - 16 × 20-minute sessions; 8 weeks; Hardware: VRTierOne device, VR HTC VIVE goggles and controllers; Embodiment: No; Interactivity: Yes; Multisensory stimulation: No | Exercise + Non-VR Relaxation; - Group-based relaxation, psychoeducation; - Group-based low-intensity exercises; - 16 × 20-minute sessions; 8 weeks
Kiper, 2022^52^; High; N = 60; Mean age: 66 years; 43-57% female, 43-57% male; Post-stroke patients, academic medical rehabilitation center | Exercise + VR Relaxation; - VR garden with music, mandala coloring task; focus on breathing; - Personalized exercise and rehabilitation; - 10 × 20-minute sessions; 3 weeks for VR; Hardware: VR TierOne device, HTC VIVE PRO goggles and a controller; Embodiment: No; Interactivity: Yes; Multisensory stimulation: NR | Exercise + Non-VR Relaxation; - Relaxation through Schultz’s Autogenic Training (via audio recording); - Personalized exercise and rehabilitation; - 10 × 20-minute sessions; 3 weeks
Szczepanska-Gieracha, 2021^53^; Some concerns; N = 25; Mean age: 71 years; 100% women; Non-responders to therapeutic group program for depression at community center for older women | Exercise + VR Relaxation; - VR garden with music, mandala coloring task; focus on breathing; - Group-based fitness program, relaxation exercises, and psychoeducation; - 8 × 80-minute sessions; 4 weeks; Hardware: VRTierOne device, VR HTC VIVE goggles and two controllers plugged into a PC; Embodiment: No; Interactivity: Yes; Multisensory stimulation: Yes | Exercise + Non-VR Relaxation; - Group-based fitness program, relaxation exercises, and psychoeducation; - 8 × 60-minute sessions; 4 weeks
Qiu, 2024^48^; High; N = 300; Mean age: 62 years; 50% male, 50% female; Treatment-naïve patients of private medical center | VR Tai Chi; - Tai Chi in VR environment; - 24 sessions (duration NR); 6 months; Hardware: Oculus Quest 2 headset; Embodiment: Yes; Interactivity: Yes; Multisensory stimulation: No | Non-VR Tai Chi; - Tai Chi with in-person instructor, video clips; - 24 sessions (duration NR); 6 weeks
Qiu, 2024^48^; High; N = 300; Mean age: 62 years; 50% male, 50% female; Treatment-naïve patients of private medical center | VR Tai Chi; - Tai Chi in VR environment; - 24 sessions (duration NR); 6 months; Hardware: Oculus Quest 2 headset; Embodiment: Yes; Interactivity: Yes; Multisensory stimulation: No | Waitlist; - No intervention
Paul, 2024^49^; High; N = 26; Mean age: 50 years; 23% male, 73% female, 4% nonbinary/other; Community members | Behavioral Activation with VR Activities; - Self-selected pleasant activities from commercially available catalogue (standard for VR system), complete ≥ 4 activities per week in home setting; - Weekly therapist sessions; - 4 × 30-50-minute sessions; 4 weeks; Hardware: VR Meta Quest 2 headset; Embodiment: Yes; Interactivity: Yes; Multisensory stimulation: No | Non-VR Behavioral Activation; - Self-selected pleasant activities in real life, complete ≥ 4 activities per week; - Weekly therapist sessions; - 4 × 30-50-minute sessions; 4 weeks
Wu, 2022^51^; Some concerns; N = 44; Mean age: 51 years; 36-41% female, 59-64% male; Post-stroke patients, academic medical rehabilitation center | VR Rehabilitation; - Fruit selection task in 3D virtual living room; - Difficulty of task personalized prior to each session; - 20 × 20-minute sessions; 4 weeks; Hardware: Unity 3D engine run on a PC (CPU Intel I7 9700K) with VR VIVE Pro headset; Embodiment: No; Interactivity: Yes; Multisensory stimulation: No | 2D Rehabilitation; - Fruit selection task on computer screen; - 20 × 20-minute sessions; 4 weeks; Hardware: Fourier M2 rehabilitation system; Embodiment: No; Interactivity: Yes; Multisensory stimulation: No

Abbreviations. 2D=2-dimensional; 3D=3-dimensional; NR=not reported; PC=personal computer; VR=virtual reality.

### VR Relaxation and Exercise versus Non-VR Relaxation and Exercise

Three small Polish RCTs (total N = 25–60) were conducted by the same team of investigators and compared a similar VR relaxation and exercise program versus non-VR relaxation and exercise over 1–2 months.^50,52,53^ In the VR group, participants were immersed in a black and gray virtual garden scene (that saturated in color as sessions progressed) and asked to color in a mandala presented to them within the garden space. Two of these studies focused solely on older women (mean ages = 68–71 years) with depressive symptoms and excluded those who had any ongoing mental health treatment.^50,53^ The third study included both older women and men (50% each, mean age = 66 years) with post-stroke depressive symptoms, and did not specify exposure to other mental health treatment (in eligibility or baseline characteristics).^52^ The fourth study, Qiu 2024, was a 3-arm RCT conducted in China that enrolled 300 older women and men (50% each) with depressive symptoms and no previous or ongoing treatments; authors compared VR versus non-VR tai chi versus waitlist.^48^ In the non-VR tai chi group, participants were supervised by an instructor in person “in a designated space.”^48^ Interventions comprised 8–24 total sessions over a duration of 3–24 weeks. Three studies^48,50,53^ had some concerns for RoB, while Kiper 2022 was rated high RoB primarily due to very substantial loss to follow-up (overall 35%) that was furthermore unbalanced between groups.^52^

#### Symptom Severity

The evidence is very uncertain about the effect of VR relaxation and exercise on depressive symptom severity (very low COE; Table 17). All 4 studies assessed depressive symptoms with GDS and 3 of use also used the HADS.^50,52,53^ The pooled estimate for symptoms immediately post-intervention indicates that VR relaxation and exercise led to lower symptom severity (SMD = −0.90 [−1.30, −0.49], using GDS data) (Figure 11). Sensitivity analysis using HADS-depression subscale scores from the 3 available studies also showed similar results (SMD = −0.64 [−1.42, 0.13]) (see Appendix Figure 2). The COE is very low due to study methodological concerns (1 trial was rated high RoB)^52^ and limited applicability given these specific study populations (2 focused exclusively on older women,^50,53^ and 1 on post-stroke depressive symptoms in older adults^52^).

Figure 11 Depression: Effect of VR Relaxation and Exercise versus Non-VR Relaxation and Exercise on Symptom Severity Immediately Post-Intervention

Figure 11 is a forest plot visualizing a meta-analysis using data from 4 studies. The overall pooled analysis of all studies favors VR, with no studies or the pooled SMD crossing the null.

#### Treatment Response and Recovery

Only Kiper 2022 reported on treatment response, assessed as proportion of participants with GDS <10 post-intervention; the VR group had 73% (N = 22) below this threshold, compared with 43% (N = 13) in the non-VR arm.^52^

Table 17 Depression Certainty of Evidence: VR Relaxation + Exercise versus Non-VR Relaxation + Exercise

Outcome; Measure | Follow-Up; Total N (# of Studies) | SMD; (95% CI) | Anticipated Absolute Effects on Mean Score at Follow-Up | | | Certainty | What Happens
Outcome; Measure | Follow-Up; Total N (# of Studies) | SMD; (95% CI) | VR Relaxation and Exercise | Non-VR Relaxation and Exercise | Mean Difference | Certainty | What Happens
Symptom Severity; GDS | Post-intervention; N = 343 (4 RCTs)^48,50,52,53^ | SMD: −0.90; (−1.3, −0.49 ) | 7.3; (5.4, 9.3)^*^ | 11.6^*^ | −4.3; (−6.2, −2.3) | ⊕◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of VR relaxation and exercise on symptom severity post-intervention.

Notes.

* Values for mean follow-up scores for intervention and/or comparator arms from Cieslik 2023^50^;

a Downgraded 2 levels for study limitations (1 or more studies rated high RoB);

b Downgraded 1 level for indirectness (2 studies only included older women, 1 study included only those with post-stroke depressive symptoms).

Abbreviations. GDS=Geriatric Depression Score; RoB=risk of bias; SMD=Standardized Mean Difference; VR=virtual reality.

#### Engagement

Two studies reported that 100% of participants completed the assigned treatment in both arms.^50,53^ As noted above, Kiper 2022 reported high drop-outs in both arms (26% in VR group).^52^ The fourth study did not report on attendance or discontinuation rates.^48^ None of the studies assessed other measures of engagement.

#### Adverse Events

Only Kiper 2022 reported on adverse events, stating “no adverse events were reported…and no negative emotional effects were recorded, such as anxiety, discomfort or inconvenience associated with using the device…”^52^

### Other VR Interventions

#### VR Behavioral Activation versus Non-VR Behavioral Activation

Paul 2024 compared behavioral activation using VR pleasant activities at home versus non-VR activities (in real life) for 26 middle-aged adults with MDD.^49^ Participants were predominantly women (73%), with 23% men and 4% nonbinary or third gender. Treatment in both arms also had weekly sessions with a clinical psychologist over 4 weeks and were asked to complete ≥4 activities between sessions. Most participants were middle-aged women (73%, mean age = 50.3 years), and the majority (65%) had other ongoing mental health treatments. This trial was rated high RoB for concerns including substantial loss to follow-up and imbalance in important co-interventions (including other mental health treatments).

Depressive symptoms were assessed using the Patient Health Questionnaire-9 (PHQ-9) at baseline and immediately post-intervention, and there were no between-group differences in changes in PHQ-9 (p = 0.78). However, authors did not directly compare mean scores at follow-up time points (VR = 8.4 [SD = 3.7] vs non-VR = 10.7 [4.6]). There was a higher discontinuation rate in the VR arm (23% vs 15% in non-VR arm) and adherence was only assessed for participants in the VR group (number of headset uses per participant). The VR arm was assessed using the SSQ, with eyestrain being the most commonly reported symptom (exact proportion or number was not reported). Authors also reported there were no “serious adverse events” in either group but did not specify which events this would include.

### VR Rehabilitation versus 2-Dimensional Rehabilitation

Wu 2022 compared VR program involving fruit selection tasks (N = 22) with a 2D version of the same tasks on a computer screen (N = 22) to treat middle-aged adults (mean age = 51–52 years, 36%–41% women) with depressive symptoms post-stroke.^51^ Depression was assessed as Hamilton Depression Rating Scale (HAMD) ≥ 17, there was no specified requirement for upper extremity weakness or paresis, and use of mental health treatment was not described (either in eligibility or baseline characteristics). The VR setting was a living room and participants were prompted to “select” a piece of fruit. The intervention comprised 20 sessions over 4 weeks. This study was rated some concerns for RoB.

Wu 2022 only reported symptom severity, assessed using HAMD scores immediately post-intervention. The VR group had lower scores (mean = 18.3 [SD = 3.3]) than the 2D arm (mean = 21.1 [1.9], p < 0.001).

## KQ1 SCHIZOPHRENIA SPECTRUM AND PSYCHOTIC DISORDERS (k =12)

### Overview

We identified 12 RCTs (reported in 16 articles) evaluating the use of VR interventions in the treatment of schizophrenia spectrum disorders or disorders with psychotic episodes. The most common (k = 12) diagnoses were schizophrenia spectrum disorders (ie, schizophrenia, schizophreniform, and schizoaffective disorder), followed by other psychotic disorders (k = 4) including delusional disorder, brief psychotic disorder, and psychotic disorder not otherwise specified (NOS) or unspecified. Study characteristics are summarized in Table 18. A third of the studies evaluated VR social cognition training (VR SCT; k = 4). Two studies examined VR CBT, one of which aimed to reduce the impact of negative symptoms, while the other addressed avoidance behaviors due to paranoia. Two studies evaluated a VR intervention personifying a participant’s auditory hallucinations in the virtual environment. The remaining 5 trials addressed cognition training (k = 3) and relaxation/mindfulness (k = 2). Nearly all participants also received TAU, with TAU protocols varying slightly across studies.

Below, we first describe study characteristics and results for the 5 studies evaluating VR SCT, followed by studies of VR CBT, VR personified voices therapy, and lastly the other interventions (including VR cognition training + TAU, VR relaxation, and VR mindfulness therapy). No studies reported treatment response/recovery, quality of life, or adherence. Detailed study characteristics and outcome findings are located in the Supplementary Materials.

Table 18 Summary Characteristics of Schizophrenia Spectrum and Other Psychotic Disorders Studies (k = 12)

Author, Year;; Study Design;; Risk of Bias; Total N Randomized; Age; Sex/Gender; Key Participant Characteristics | Intervention | Comparator(s)
Nijman, 2023^55^; High; N = 83; Mean age: 36-40 years; 65-73% male; 27-35% female; Schizophrenia spectrum disorder, brief psychotic disorder, delusional disorder, or other psychotic disorder; inpatient and outpatient | VR Social Cognition Training + TAU; - Practiced with social stimuli and developed social strategies; - Role played with a therapist-controlled virtual entity; - Also received psychoeducation about social cognition; - 16 × 45-60-minute sessions; 8 weeks; Hardware: Oculus Rift HMD. Therapists controlled the environment and virtual entities through a tablet interface and viewed participants’ field of vision using a second monitor.; Embodiment: No; Interactivity: Yes; Multisensory stimulation: No | VR Relaxation + TAU; - Engaged in relaxation exercises (eg, breathing exercises, progressive relaxation) with audio guidance while looking at relaxing nature scenes; - Participants controlled the environment with their gaze; - Also received psychoeducation about stress and coping; - 16 45-60-minute sessions; 8 weeks; Hardware: Samsung Gear VR headset with a Samsung Galaxy S7 smartphone; Embodiment: No; Interactivity: Yes; Multisensory Stimulation: No
Park, 2011^65^; High; N = 91; Mean age: 28-31 years; 42-52% female; Schizophrenia; inpatient | VR Social Cognition Training; - Developed conversation, assertion, and emotional expression skills; - First, therapist modeled then participant role played followed by feedback from the therapists; - Repeated role play of the same scene and feedback; - Each session included 3 role plays with different scenes per participant; - Role plays occurred in virtual environments with therapist-controlled virtual entities; - Intensive psychiatric care for 2-4 weeks prior to SCT; - 10 × 90-minute sessions; 5 weeks; Hardware: Eye Trek FMD 250W, OLYMPUS head mounted display and a position tracker (InterTrax2, InterSense); Embodiment: No; Interactivity: Yes; Multisensory stimulation: No | Non-VR Social Cognition Training; - Same session structure as VR SCT; - Role plays occurred in physical environments with therapist actors; - Intensive psychiatric care for 2-4 weeks prior to SCT; - 10 90-minute sessions; 5 weeks
Shen, 2022^56^; Some concerns; N = 87; Mean age: 31 years; 65-67% male; 33-35% female; Schizophrenia; inpatient | VR Social Cognition Training + TAU; - Three phases, all in VR: (1) emotionperception training, (2) theory of mind deficits and attributional bias, and (3) applying social cognitive skills to choose reactions in role playing game; - Continued usual medical treatment; only atypical antipsychotics; - 10 sessions (duration NR); 3 weeks; Hardware: Pico Goblin2 All-In-One; Embodiment: No; Interactivity: Yes; Multisensory stimulation: No | Non-VR Social Cognition Training + TAU; - Three phases: (1) introduction and emotions, (2) figuring out situations, and (3) checking it out; - Received psychoeducation about social cognition and emotion; - Learned about attributional bias and developed strategies to avoid jumping to conclusions; - Practiced applying learned skills to cope with daily interpersonal problems; - Each session involved 6 inpatient participants; - Continued usual medical treatment; only atypical antipsychotics; - 10 sessions (duration NR); 5 weeks
Shen, 2022^56^; Some concerns; N = 87; Mean age: 31 years; 65-67% male; 33-35% female; Schizophrenia; inpatient | | Waitlist + TAU; - Continued usual medical treatment; - 3 weeks
Vass, 2022^59^; High; N = 43; Mean age: 37-42 years; 48-57% male; 43-52% female; Schizophrenia or schizoaffective disorder; outpatient | VR Social Cognition Training + TAU; - Interacted with a therapist-controlled virtual entity, which played pre-recorded audio and had facial expressions; - Afterward, used visual display to change the virtual entity’s facial expressions based on its perceived emotional state; - Discussed experience and its challenges with therapist; - Continued outpatient treatment; - 9 × 60-minute sessions; 9 weeks; Hardware: Samsung Gear Head Mounted Displays with a Samsung S7 or S8 smartphone and a Samsung Simple Controller; Embodiment: Yes; Interactivity: No; Multisensory stimulation: No | VR Sham + TAU; - Explored virtual environments in which they could build virtual entities and change locations.; - Participants were unable to interact with other users or with therapist in virtual environment; - Continued outpatient treatment; - 9 60-minute sessions; 9 weeks; Hardware: Samsung Gear Head Mounted Displays with a Samsung S7 or S8 smartphone and a Samsung Simple Controller; Embodiment: Yes; Interactivity: No; Multisensory stimulation: No
Cella, 2022^60^; RCT; High; N = 30; Mean age: 37 years; 70% male; 30% female; Schizophrenia or psychotic episode; outpatient | VR CBT + TAU; - Principles based on CBT and cognitive remediation therapy; - Performed tasks in preset virtual environments at differing levels of motivational challenge; - Also received TAU; - 12 sessions (duration NR); 12 weeks; Hardware: Oculus Rift-S with ear covering headphones for sound; Embodiment: Yes; Interactivity: Yes; Multisensory stimulation: No | TAU; - Regular contact with a care coordinator and medication management by a psychiatrist; - Session amount and treatment duration NR
Pot-Kolder, 2018^64^; Some concerns; N = 116; Mean age: 37-40 years; 69-72% male; 28-31% female; Schizophrenia, schizoaffective disorder, delusional disorder, psychotic disorder NOS; outpatient | VR CBT + TAU; - Communicated with therapist during personalized VR sessions to explore and challenge suspicious thoughts while engaging with 4 virtual social environments; - VR exercises comprised 2/3 of each session; reflection and planning with therapist comprised remaining 1/3; - Continued existing medication regimen; - 16 × 60-minute sessions; 8-12 weeks; Hardware: Sony HMZ-T1/T2/T3 Head Mounted Display with Logitech F310 Gamepad and a 3DOF tracker for head rotation; Embodiment: No; Interactivity: Yes; Multisensory stimulation: No | TAU; - Regular contact with a psychiatrist and a psychiatric nurse to improve self-care, daytime activities, and social and community functioning; - Continued existing medication regimen; - Session amount and treatment duration NR
Dellazizzo, 2021^63^; High; N = 74; Mean age: 41-44 years; 73-78% male; 22-27% female; Schizophrenia or schizoaffective disorder; outpatient | VR Personified Voices Therapy + TAU; - Engaged in dialogue with a therapistcontrolled virtual entity, which was meant to personify the abusive, critical, and hostile nature of AVHs; - Participant-virtual entity interactions became less abusive and more supportive as the sessions progressed; - Continued existing medication regimen; - 9 × 60-minute sessions; 9 weeks; Hardware: Samsung Gear VR HMD or Oculus Rift HMD; Embodiment: No; Interactivity: No; Multisensory stimulation: No | Non-VR CBT for Psychosis + TAU; - Learning modules and task assignments aimed to identify and develop new means to navigate hallucination experiences; - Continued existing medication regimen; - 9 60-minute sessions; 9 weeks
Liang, 2022^61^; High; N = 65; Mean age: 25-27 years; 44-52% male; 48-56% female; Schizophrenia; setting unclear | VR Personified Voices Therapy + TAU; - Spoke to a virtual entity meant to resemble the source of their AVHs; - Each session included 3 parts, during which the participant and therapist agreed on the focus of the dialogue, engaged in dialogue (with the therapist controlling the virtual entity) for 10-15 minutes, and shared feedback; - Continued existing medication regimen; - 7-9 × 60-minute sessions; 7-9 weeks; Hardware: HTC VIVE HMD. Unity 3D game engine and Blendshape were used to create virtual entities.; Embodiment: No; Interactivity: No; Multisensory stimulation: No | Non-VR CBT for Psychosis + TAU; - Completed daily log about AVHs; - Identified current strategies for coping with AVHs and explored new ways to manage them; - Re-evaluated negative beliefs based on disconfirming evidence; - Engaged in mindfulness exercises and practiced daily at home; - Developed plans to prevent relapse and maintain gains; - Continued existing medication regimen; - 7-9 60-minute sessions; 7-9 weeks
Freeman, 2022^62^; Some concerns; N = 346; Mean age: 37-38 years; 67% men; 31-33% women; 0-1% other gender; 0-1% prefer not to say; 0-1% missing gender; Schizophrenia spectrum disorder, delusional disorder, schizotypal disorder, brief psychotic disorder, unspecified psychosis, or affective diagnosis with psychotic symptoms; outpatient | VR Cognition Training + TAU; - Guided by a pre-programmed virtual coach through automated situational behavioral experiments; - Chose from 6 virtual social scenarios, each with 5 levels of difficulty; - Focused on treating agoraphobic-type fears impacting everyday interactions; - Also received usual care; - 6 × 30-minute sessions; 6 weeks; Hardware: HTC Vive Pro headset and Dell G5 15 5590 laptop; Embodiment: No; Interactivity: Yes; Multisensory stimulation: No | TAU; 6 weeks of prescription medication, visits from a mental health worker, and outpatient appointments with a psychiatrist
Li, 2022^57^; Some concerns; N = 68; Mean age: 46-47.5 years; 60-67% male; 33-40% female; Schizophrenia; inpatient | VR Cognition Training + TAU; - Completed different shopping tasks in a virtual supermarket; - Aimed to improve cognitive function; - Also received antipsychotic treatment; - 10 sessions (duration NR); 2 weeks; Hardware: NR; Embodiment: No; Interactivity: Yes; Multisensory stimulation: No | TAU; 2 weeks of antipsychotic treatment
Fusco, 2018^66^; High; N = 22; Mean age: 48 years; 60% male; 40% female; Schizophrenia spectrum disorder or other psychotic disorder; all participants recruited from a psychiatric rehabilitation program | VR Relaxation; - Learned about the effects of triggering psychosocial situations and progressive muscle relaxation techniques; - Immersed in a relaxing scenario on a beach by the ocean, accompanied by music and a voice guiding a progressive muscle relaxation exercise; - 10 × 10-minute sessions (duration NR); 2 months; Hardware: HMD and a pair of headphones; Embodiment: NR; Interactivity: NR; Multisensory stimulation: No | Non-VR Relaxation; - Learned about the effects of triggering psychosocial situations and progressive muscle relaxation techniques; - Entered a “classic relaxation setting” (not further specified) to apply techniques; - 10 10-minute sessions; 2 months
Lee, 2023^54^; Some concerns; N = 64; Mean age: 31-33 years; 45-46% male; 54-55% female; Schizophrenia spectrum disorder, psychotic disorder NOS, or delusional disorder; outpatient | VR Mindfulness Training + TAU; - Watched educational videos about mindfulness and self-awareness; - Engaged with therapeutic videos that guided meditation (eg, sense awareness, awareness, looking back at self, loving-kindness); - Received intermittent instructions during therapeutic meditation sessions; - Also received psychotherapy, psychoeducation, and pharmacotherapy; - 8 30-minute sessions; 8 weeks; Hardware: Oculus Rift CV1; Embodiment: No; Interactivity: No; Multisensory stimulation: No | VR Sham + TAU; - Watched 3D, virtual nature scenes; - Also received psychotherapy, psychoeducation, and pharmacotherapy; - 8 30-minute sessions; 8 weeks; Hardware: Oculus Rift CV1; Embodiment: No; Interactivity: No; Multisensory stimulation: No

Abbreviations. 3D=three-dimensional; AVH=audiovisual hallucination; CBT=cognitive behavioral therapy; HMD=head-mounted display; NOS=not otherwise specified; NR=not reported; SCT=social cognition training; TAU=treatment as usual; VR=virtual reality.

### VR Social Cognition Training

Four RCTs^55,56,59,65^ evaluated VR SCT for patients who had a diagnosis of schizophrenia or other disorders involving psychosis. Study characteristics including study population diagnoses are summarized in Table 18. Two studies enrolled only inpatients,^56,65^ while 1 study focused on outpatients,^59^ and another study included both inpatient and outpatient participants.^55^ Sample size ranged from 42–81, and study participants were primarily young to middle-aged men (mean age = 33 years, 48%–73% male). Comparators varied, with the most common being non-VR SCT (k = 2).^57,59^ Three trials^55–57^ were rated some concerns for RoB, while the other trials^59,65^ were rated high RoB.

All the studies evaluated similar VR SCT that utilized role play of social situations with a therapist to foster development of social skills (eg, conversing, expressing/recognizing emotion, and interpreting behavior).^55,56,59,65^ In Nijman 2023, the therapists spoke to the participants using a virtual entity whose appearance, voice, and behavior the therapist could control, along with environment.^55^ Therapists in Vass 2022^59^ could control the virtual entity’s movements and the timing of pre-recorded verbal responses.^59^ Park 2011^65^ and Shen 2022^56^ did not detail the therapist-controlled versus preset aspects of virtual entity behavior in the role plays.

#### Symptom Severity

Two studies^56,65^ evaluated VR SCT versus non-VR SCT in 10 sessions delivered over 3–5 weeks and measured symptom severity. Due to heterogeneity of outcome domains measured, these studies were not combined to assess certainty of evidence. Using the Positive and Negative Syndrome Scale (PANSS), Park 2011^65^ reported no between-arm differences in positive, negative, and general symptoms of psychosis immediately post-intervention.^65^ Using the Personal and Social Performance (PSP) scale, Shen 2022 found that both VR SCT (mean = 73.08, p = 0.001) and non-VR SCT (mean = 66.30, p = 0.005) had significantly higher social functioning than the waiting list arm (mean = 66.67) post-intervention, but no significant difference was reported between VR SCT and non-VR SCT.^56?^

The other 2 studies used 2 different comparators and were thus not combined to assess certainty of evidence.^55,59^ Nijman 2023 compared VR SCT with VR relaxation therapy, which aimed to reduce stress and improve coping through a combination of virtual relaxation and psychoeducation.^55^ None of the time by treatment interactions were statistically significant for outcomes including general psychotic symptoms, social cognition, social functioning, anxiety, and depression immediately post-intervention and at 3 months post-intervention. Vass 2022 used a VR sham comparator. Using the PANSS, Vass 2022 reported significantly better results for VR SCT than for VR sham in PANSS total score (mean = 42.76 vs 55.00, p ≤ 0.0001), PANSS negative symptoms (mean = 12.28 vs 16.14, p = 0.005) and PANSS cognitive symptoms (mean = 11.66 vs 14.90, p = 0.003) immediately post-intervention. At 3 months post-intervention, VR SCT continued to have significantly better results than VR sham in PANSS total score (mean = 42.57 vs 52.00, p ≤ 0.0001), negative symptoms (mean = 12.47 vs 16.15, p = 0.0005) and cognitive symptoms (mean = 11.52 vs 14.15, p ≤ 0.0001).^59^ There were no significant results for positive or affective symptoms at either time point.

#### Engagement

Four studies reported aspects of treatment engagement including attendance^55,56,59,65^ and participant VR experience.^59,65^

##### Attendance

Shen 2022 reported no significant difference in the overall treatment discontinuation proportions between the VR SCT and non-VR SCT groups at 3 weeks (2/28 VR participants vs 6/30 non-VR participants, p = 0.299) and 5 weeks (2/28 vs 7/30, p = 0.181), although this is difficult to compare between arms given the 3-week duration of VR SCT and the 5-week duration of non-VR SCT.^56^ Park 2011^65^ reported no difference in discontinuation proportions between VR and non-VR SCT groups, though they observed higher attendance in the VR SCT group compared with the non-VR SCT group (mean 95.3% vs 91.0%, p = 0.019).^65^

Nijman 2023 reported no significant difference in discontinuation proportions between VR SCT and VR relaxation.^55^ Vass 2022 reported that across the VR SCT and VR sham arms, only 1 VR SCT participant did not complete the allocated intervention due to an adverse event deemed unrelated to treatment.^59^

##### Other Engagement Measures

Park 2011 assessed participant SCT-related motivation and skills knowledge in the VR and non-VR arms at the end of each treatment session using study-developed measures, and found that the VR arm scored higher than the non-VR arm on average post-session interest in participation (mean = 81.5 vs 75.5, p = 0.09) and average post-session social cognition skills knowledge (mean = 88.0 vs 82.9, p = 0.033).^65^ Vass 2022 solicited feedback on the VR SCT experience and reported that most respondents found the intervention interesting (100%), entertaining (93.3%), realistic (86.7%), and important to their rehabilitation (78%).^59^ Most respondents felt safe using the VR devices (93.3%) and considered the virtual entity interactions pleasant (80%). Some participants found the Temporal Disc Controller aspect of VR SCT cumbersome (13.4%) and difficult (26.7%), while others reported anxiety related to treatment (20%).

#### Adverse Events

Three studies reported adverse events.^55,59,65^ Park 2011 assessed for simulator sickness in the VR SCT arm after each session, using a study-developed questionnaire which did not apply to the non-VR arm.^65^ They reported no symptoms related to the use of an immersive HMD (eg, nausea, sweating, and dizziness). Vass 2022 used the SSQ to monitor possible side effects, but did not report quantitative results.^59^ Authors stated that only mild symptoms were reported (eg, difficulty focusing, sweating, and blurred vision), and that all symptoms resolved within a few minutes. Nijman 2022^55^ also used the SSQ at the end of session 3. Nausea was reported significantly more often by VR SCT participants compared with VR relaxation participants (mean = 3.1 vs 2.0, p = 0.036), while there was no significant difference between groups in the oculomotor score (mean = 3.2 vs 4.26, p = 0.262).^55^ Furthermore, 2 serious adverse events (SAE) were reported in the VR SCT arm compared with 1 SAE in the VR relaxation arm, though all were deemed unrelated to study participation.^55^

### VR CBT + TAU

Two RCTs evaluated VR CBT + TAU for patients who had a diagnosis of a schizophrenia spectrum disorder or psychotic disorder or who had experienced a psychotic episode.^60,64^ Study characteristics are summarized in Table 18. Sample size ranged from 30–116 and study participants were primarily male (69%–-72%) in early to middle adulthood (mean age = 37.7 years). Both studies compared VR CBT plus TAU versus TAU alone. Cella 2022^60^ was rated high RoB and Pot-Kolder 2018^64^ was rated some concerns for RoB.

The interventions varied with respect to therapist/participant control. Cella 2022^60^ evaluated a CBT approach they called VR negative symptom therapy (and abbreviated as V-NeST) involving therapist-supported activities including psychoeducation, behavioral activation, and activity appraisal. This therapy was designed to help participants achieve personal recovery goals and improve negative symptoms. The intervention offered 5 preset VR environments (designed by study authors) with motivational challenges of varying difficulty. The authors described TAU as a multi-modal treatment approach including regular contact with a care coordinator and medication management by a psychiatrist. In Pot-Kolder 2018, VR CBT consisted of 4 VR social environments which participants could navigate using a gamepad.^64^ The intervention was designed to address paranoid thoughts during social encounters in an effort to improve social participation. Individualized case formulation guided the selection of social environmental cues to elicit fear, paranoid thoughts, and safety behaviors. Therapists could customize the experience by adjusting the number of human virtual entities present, their characteristics, their engagement with the participant, and their use of pre-recorded sentences. The authors described TAU as consisting of antipsychotic medication and regular contact with a psychiatric nurse to improve activities of daily living and quality of life.

#### Symptom Severity

The evidence is very uncertain on the effect of VR CBT + TAU on psychotic symptom severity compared with TAU alone (very low COE; Table 19). Both studies^60,64^ evaluated VR CBT + TAU versus TAU alone lasting 8–12 weeks (12–16 sessions) and measured psychotic symptom severity. Cella 2022^60^ monitored negative symptoms (Clinical Assessment Interview for Negative Symptoms (CAINS), while Pot-Kolder 2018^64^ assessed changes in paranoia symptoms (GPTS). Both studies reported treatment by time interactions that favored the VR CBT + TAU arms for all outcomes. Cella 2022 reported that pairwise comparisons between VR CBT + TAU and TAU, post-intervention and controlling for baseline scores, favored VR CBT+TAU for improving negative symptoms.^60^ Pot-Kolder 2018 found a significant treatment by time interaction favoring VR CBT+TAU in ideas of persecution (GPTS).^64^ By additional measures, Pot-Kolder 2018 also reported a significant reduction in momentary paranoia based on the Experience Sampling Method (ESM) in the VR CBT + TAU arm and a slight increase in the TAU arm, and found significant treatment arm by time interactions favoring VR CBT + TAU over TAU in momentary paranoia (ESM) and paranoid ideation (ESM) post-intervention and at 3 months follow-up.

#### Engagement

Both studies^60,64^ reported aspects of treatment engagement including attendance,^60,64^ adherence,^64^ and participant VR experience.^64^

##### Attendance

Cella 2022^60^ reported that 2 participants allocated to VR CBT did not receive the intervention due to moving (n = 1) or competing demands (n = 1). All participants in the TAU control group received treatment. Pot-Kolder 2018^64^ reported that 11 participants (19%) in the VR CBT group did not complete treatment, including 4 participants who did not start treatment. The other 7 participants discontinued for various reasons, including being too afraid (n = 1), not having enough time (n = 1), not willing to travel (n = 1), nausea (n = 1), unable to attend sober (n = 1), and finding the HMD too uncomfortable (n = 2).

##### Adherence

A secondary report of Pot-Kolder 2018^117^ reported that on average, participants completed 47.4 out of 70 diary entries. Participants completed more diary entries on average before treatment than after treatment (mean = 49.9 vs 45.4, no statistical comparison).

##### Other Measures of Engagement

Pot-Kolder 2018^64^ used the Igroup Presence Questionnaire to assess participants’ experience in the VR environments. Results show that participants felt satisfied with spatial presence (mean = 3.79), involvement (mean = 3.16), and realness (mean = 2.96).

#### Adverse Events

Both studies^60,64^ reported adverse events. The evidence is very uncertain on the effect of VR CBT + TAU on adverse events compared with TAU alone (very low COE; Table 19). In Cella 2022,^60^ 2 participants in the TAU control arm reported serious adverse events. There were 11 adverse events (7 in the VR CBT group and 4 in the TAU group), none of which authors deemed associated with study participation. Pot-Kolder 2018^64^ used the SSQ to assess cybersickness symptoms in the VR CBT group after sessions 4 and 8. One participant dropped out because of nausea, and authors stated that no other adverse events related to either VR CBT or TAU were reported.

Table 19 Schizophrenia Spectrum and Other Psychotic Disorders Certainty of Evidence: VR CBT + TAU versus TAU Alone

Outcome; Measure | Follow-Up; Total N (# of Studies) | Anticipated Absolute Effects on Mean Score or Event Rate at Follow-Up | | | Certainty | What Happens
Outcome; Measure | Follow-Up; Total N (# of Studies) | VR Exposure | Waitlist | Difference | Certainty | What Happens
Symptom Severity; CAINS;^60^ GPTS Ideas of persecution^64^ | Post-Intervention; N = 125 (2 RCTs)^60,64^ | 33.4^*^ | 38.2^*^ | −4.8^*^ | ⊕◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of VR CBT + TAU on psychotic symptom severity post-intervention.
Adverse events; NR | During intervention; N = 125 (2 RCTs)^60,64^ | 7 AEs^†^ | 4 AEs^†^ | — | ⊕◯◯◯; Very low^a,c^ | The evidence is very uncertain on the effect of VR CBT + TAU on adverse events post-intervention.

Notes.

* Values for mean follow-up scores for intervention and comparator arms taken from Pot-Kolder 2018.^64^ Differences calculated by review team;

† Values for adverse events for intervention and comparator arms from Cella, 2022.^60^

a Downgraded 2 levels for study limitations (one or more studies rated high RoB);

b Downgraded 1 level for imprecision (study measurement tool does not comprehensively assess psychotic or other schizophrenic symptoms);

c Downgraded 1 level for indirectness (outcome not measured consistently).

Abbreviations. AE=adverse event; CAINS=Clinical Assessment Interview for Negative Symptoms; CBT=cognitive behavioral therapy; GPTS=Green Paranoid Thoughts Scale; NR=not reported; RoB=risk of bias; TAU=treatment as usual; VR=virtual reality.

### VR Personified Voices Therapy

Two RCTs evaluated a VR intervention comprising role plays designed to teach participants to manage their paranoid hallucinations. Patients in these studies were diagnosed with schizophrenia or schizoaffective disorder.^61,63^ Study characteristics are summarized in Table 18. Sample size ranged from 58–62. In 1 study,^61^ the sample was half female and primarily young adults (mean age = 25.9 years). The other study^63^ enrolled primarily men (76%) in early to middle adulthood (mean age = 42.5 years). Both studies evaluated a VR intervention in which a therapist-controlled virtual entity was used for role playing participant responses to hallucinations, compared with non-VR CBT for psychosis (CBTp). Both trials were rated high RoB.

The VR intervention in these studies^118–121^ used a visual depiction of the participants’ audiovisual hallucinations (AVHs) in the form of a virtual entity visible and audible in the virtual environment, which the therapists controlled to engage in dialogue with the participants. The intervention was designed to help patients develop new strategies for interacting with the content of their AVHs, improved their emotional regulation, and modified their negative self-perceptions. Liang 2022^61^ described a collaborative process in which the therapist developed the virtual entity with the participant to ensure it resembled the most distressing aspects of their AVHs. The therapist controlled the virtual entity’s face and body during dialogue with the participant and used either the virtual entity’s voice or their own to offer guidance and feedback. Dellazizzo 2021^63^ did not describe the development of the virtual entity, though there was a similarly high degree of therapist control of the entity during dialogue therapy. Both studies used CBTp as the comparator, which was delivered in an individual format by a licensed psychologist or psychiatrist.

#### Symptom Severity

The evidence is very uncertain on the effect of VR personified voices therapy on psychotic symptom severity compared with non-VR CBTp, immediately post-intervention and at 3 months post-intervention (very low COE; Table 20). Both studies reported treatment by time interactions. In Liang 2022,^61^ there were no statistically significant differences between arms over time for auditory hallucination, positive, or negative symptoms. There were also no interaction effects for anxiety or depressive symptoms. Dellazizzo 2021^63^ measured PANSS, Psychotic Symptom Rating Scales (PSYRATS) and BDI at baseline, post-intervention, and 3 month follow-up, but did not test between-arm differences in means at any time point. Time by treatment effects across all 3 time points, however, were assessed for these measures and several subscales. Only PANSS anxio-depressive subscale was statistically significant, in favor of the VR personified voices therapy arm (p = 0.025).

#### Engagement

Both studies^60,63^ reported aspects of treatment engagement including discontinuation^61,63^ and participant experience.^63^

##### Attendance

In Liang 2022,^61^ 94% percent of VR personified voices therapy participants completed all treatment sessions, compared with 85% of CBTp participants. Two participants did not complete the VR personified voices intervention, compared with 5 CBTp participants. Authors cited reasons including failure to attend, adjustment to antipsychotic medication, or no desire to continue treatment. Dellazizzo 2021^63^ reported that 9 participants in the VR personified voices arm did not attend sessions or discontinued treatment, compared with 3 participants in the CBTp arm. Reasons for discontinuation included lack of motivation, not wanting to reduce their AVH voices, and moving away.

##### Other Measures of Engagement

Dellazizzo 2021^63^ used semi-structured interviews to assess the acceptance and feasibility of both interventions in a subsample of participants (n = 15). The questions asked about factors including content, sequence, dose, setting, mode of delivery, and materials used. Most participants rated the intervention aspects as adequate, though one-third found the dose to be too short or described the intervention as stressful, particularly related to VR personified voices therapy. Almost half the CBTp participants reported that the homework was uninteresting or unhelpful.

#### Adverse Events

Liang 2022^61^ stated that no adverse events attributed to either intervention occurred during the course of the study, and did not define adverse events. Dellazizzo 2021^63^ reported that no patients were re-hospitalized during the trial.

Table 20 Schizophrenia Spectrum and Other Psychotic Disorders Certainty of Evidence: VR Personified Voices Therapy versus Non-VR CBTp

Outcome; Outcome Measure | Follow-Up; Total N (# of Studies) | Anticipated Absolute Effects on Mean Score or Event Rate at Follow-Up | | | Certainty | What Happens
Outcome; Outcome Measure | Follow-Up; Total N (# of Studies) | VR Personified Voices Therapy | Non-VR CBTp | Difference | Certainty | What Happens
Symptom Severity; PANSS total | Post-Intervention; N = 120 (2 RCTs)^61,63^ | 70.3^*^ | 73.4^*^ | −3.1^*^ | ⊕◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of VR personified voices therapy on psychotic symptom severity post-intervention.
Symptom Severity; PANSS total | 3 months post-intervention; N = 120 (2 RCTs)^61,63^ | 67.5^*^ | 71.4^*^ | −3.9^*^ | ⊕◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of VR personified voices therapy on psychotic symptom severity at 3 months post-intervention.

Notes.

* Values for mean follow-up scores for intervention and comparator arms taken from Liang 2022.^61^ Differences calculated by review team;

a Downgraded 2 levels for study limitations (1 or more studies rated high risk of bias);

b Downgraded 1 level for imprecision (sample size did not meet OIS).

Abbreviations. CBTp=Cognitive Behavioral Therapy for psychosis; OIS=optimal information size; PANSS=Positive and Negative Syndrome Scale; VR=virtual reality.

### Other Interventions

#### VR Cognition Training Plus TAU versus TAU Alone

Three studies investigated VR cognition training plus TAU compared with TAU alone. Two studies included inpatients with a schizophrenia diagnosis,^57,58^ while the third study recruited outpatients with a diagnosis of a schizophrenia spectrum disorder or an affective disorder with psychotic symptoms.^62^ Study characteristics are summarized in Table 18. Sample size ranged from 64–346. In the study with N = 346,^62^ the average age of participants was 37.2 years, and 32% were female. The average age in the other 2 studies was 25–46 years and 33%–52% were female. Interventions comprised 7 to at least 20 sessions over a duration of 2–6 weeks. One study was rated as low RoB.^58^ The other 2 studies were appraised as some concerns RoB.^57,62^ All the studies investigated novel cognitive training interventions with the goal of improving cognitive function. Studies were not combined to assess certainty of evidence due to differences in intervention content and outcome measures (Table 18).

Freeman 2022^62^ assessed paranoia using the Green Paranoid Thoughts Scale (GPTS) and depressive symptoms using the PHQ-9, post-intervention and at 20 weeks post-intervention. They reported no significant between-arm differences in either outcome at either time point. Li 2022 found no significant treatment by time interactions for psychotic symptoms (PANSS) or social functioning (PSP) post-intervention.^57^ There was a significant interaction between time and treatment for cognitive function (p < 0.001).

Freeman 2022^62^ found no significant between-arm differences in suicidal ideation by the Columbia Suicide Severity Rating Scale (C-SSRS) post-intervention or at 20-week follow-up, and found no significant differences between groups in quality of life based on the EuroQol 5 Dimension 5 Level (EQ-5D-5L).^62^

Freeman 2022^62^ cited ISO14155:2011 guidelines for medical device trials as guidance in their SAE definition.^122^ Authors defined an adverse event as serious if it led to any of the following: death; life-threatening illness or injury; hospitalization or prolongation of existing hospitalization; persistent or clinically significant disability or incapacity; medical or surgical intervention to prevent any of the aforementioned outcomes; fetal distress or death, or congenital anomaly or birth defect; or “otherwise considered medically significant by the investigator.” Authors noted that an independent data monitoring and ethics committee chair rated whether any SAE was related to trial procedures. Freeman 2022 reported 12 SAEs (in 9 participants) in the VR cognition training + TAU group and 8 SAEs (in 7 participants) in the TAU alone group (no significant between-group difference). Authors stated that “we also checked medical notes for adverse events that were not serious,” without further definition of non-serious adverse events. Freeman 2022 reported 25 adverse events (in 21 participants) in the VR cognition training + TAU group and 29 adverse events (in 19 participants) in the TAU alone group (no significant between-group difference). In Li 2022, 1 participant in the VR cognition training + TAU arm reported feeling dizzy during treatment, but this did not impact their treatment completion.^57^ Authors stated that no other “uncomfortable feelings” or SAE were reported (without further definition).

Li 2022^57^ reported 2 participants in the TAU group did not receive the intervention (1 due to adjusting drug dosage, 1 due to being over the age of 55), and 4 in the VR cognition training + TAU did not start the intervention due to being unable to complete the initial cognitive battery.

#### VR Relaxation

One study, Fusco 2018,^66^ investigated VR relaxation (which they entitled progressive muscle relaxation) compared with non-VR relaxation in a sample of participants with a diagnosis of a schizophrenia spectrum or other psychotic disorder. Study characteristics are summarized in Table 18. The intervention arm received 10 sessions of VR relaxation over 2 months, while the control arm followed similar non-VR procedures. The average age of participants was 48 years and 41% were female. The study was appraised as some concerns RoB.

Fusco 2018^66^ did not report eligible psychotic symptom severity outcomes, but did assess anxiety using the Beck Anxiety Inventory (BAI), finding significantly lower mean anxiety scores in the VR relaxation arm than in the non-VR relaxation arm (17.54 vs 23.45, p < 0.01).

#### VR Mindfulness Therapy

One study, Lee 2023,^54^ investigated VR mindfulness + TAU compared with VR sham + TAU in a sample of participants with a diagnosis of a schizophrenia spectrum disorder or other psychotic disorder not otherwise specified. Study characteristics are summarized in Table 18. The intervention arm received 8 sessions of educational and therapeutic experiences over 8 weeks, while the control arm engaged with virtual nature scenes. Usual treatment including supportive psychotherapy, psychoeducation, and pharmacotherapy was provided to all participants during the trial. The average age of participants was 32 years and 54% were female. The study was appraised as some concerns RoB due to assignment to the intervention and measurement of the outcome.

Lee 2023^54^ found no significant between-arm differences in post-intervention means and no significant treatment arm by time interactions for measures assessing positive and negative symptoms (PANSS), delusions and auditory hallucinations (PSYRATS), and depressive symptoms (BDI). Authors also measured the motivation and pleasure domain of negative symptoms using the Motivation and Pleasure Scale-Self Report (MAP-SR), finding no significant between-arm differences in post-intervention means, and a significant treatment arm by time interaction only for the subscale assessing feelings and motivation about close, caring relationships (p = 0.027). There were no significant between-arm differences in suicidal ideation based on the C-SSRS post-intervention.

Lee 2023^54^ used the SSQ to assess cybersickness symptoms in both study arms (VR mindfulness and VR sham) after the first and eighth (final) session of treatment. In the VR mindfulness group (n = 33), the most common symptoms were difficulty with visual focus (77%), blurred vision (69%), and eye fatigue (69%). In the VR sham group (n = 28), the most common symptoms were blurred vision (67%), general discomfort (90%), and difficulty with visual focus (53%). There were no significant between-arm differences in incidence of cybersickness symptoms at either time point, and severity of symptoms was usually less than moderate in both groups.

## KQ2 BENEFITS AND HARMS OF VR INTERVENTIONS FOR SUICIDE PREVENTION

The single study evaluating an VR intervention for suicide prevention was a 3-arm RCT conducted in Iran that enrolled 189 young and middle-aged men and women (95% ≤ age 50 years, 59% women) who had at least 1 suicide attempt in the past year.^123^ Ronaghi 2024 compared 2 months of VR-based education and counselling with non-VR-based education and counseling, and no intervention.^123^ Duration of interventions, length of sessions, and further description of education or counseling content were not provided. Ronaghi 2024 also did not report any additional evaluation of participants for specific mental health disorders or whether participants may have been receiving other treatments. This study was rated high RoB due to substantial concerns regarding lack of reported information on intervention completion and loss to follow-up, and whether analytic methods accounted for these issues.

Ronaghi 2024 reported using the Beck Scale for Suicide Ideation (BSS) to assess participants at baseline and post-intervention, but did not report summary scores for any time point.^123^ Rather, scores were provided for “suicidal intent,” “suicidal ideation,” and “contemplated attempt” at baseline and follow-up, but authors did not describe how these were derived from BSS items. Although authors reported that there were greater reductions in these scores for the VR group (compared with both non-VR education and counseling, and the no treatment arms), it is unclear that this indicates any meaningful change in suicide ideation given the lack of information regarding assessment and scoring. No other eligible outcomes were reported.