# METHODS

## TOPIC DEVELOPMENT

Collaborating with representatives from the VA Digital Health Office, VA Office of Mental Health, VA National Center for PTSD, and our technical expert panel (TEP), we defined the scope, formulated key questions (KQs), and determined eligibility criteria. We defined the list of eligible mental health disorders through discussions with partners and the TEP, and we focused on VR technologies that are fully immersive (virtual environments that visually seal off the user from their local physical environment).

## REGISTRATION AND REVIEW

A preregistered protocol for this review can be found on the Open Science Framework Registries (https://doi.org/10.17605/OSF.IO/RXWBH). A draft version of this report was reviewed by external peer reviewers; their comments and author responses are provided in the Supplementary Materials.

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following key questions were the focus of this review:

- Key Question 1 (KQ1): What are the benefits and harms of VR interventions for treating mental health disorders?
- Key Question 2 (KQ2): What are the benefits and harms of VR interventions for suicide prevention?

Study eligibility criteria are shown in the table below.

Domain | Inclusion Criteria | Exclusion Criteria
Population | - KQ1:; - Adults with:; - [underlined: Prioritized]; - Posttraumatic stress disorder; - Social anxiety disorder (social phobia); - Specific phobia of flying Alcohol use disorder; - Substance use disorder; - Depressive disorders; - Schizophrenia; - Schizoaffective disorder; - Other schizophrenia spectrum and psychotic disorders; - [underlined: Non-prioritized]^a^; - Agoraphobia; - Bipolar disorder; - Dissociative disorders; - Generalized anxiety disorder; - Obsessive compulsive disorder; - Panic disorder; - Persistent depressive disorder (Dysthymia); - Premenstrual dysphoric disorder; - KQ2: Adults | —
Intervention | Fully immersive VR interventions (ie, virtual environments that visually seal off the user from their local physical environment) to treat mental health disorders (KQ1) or prevent suicide (KQ2) | —
Comparator | Any | —
Outcomes | - [underlined: Primary outcomes]^b^; - Symptom severity; - Treatment response; - Recovery; - Suicidal ideation and/or behaviors; - Adverse events; - [underlined: Secondary outcomes]; - Quality of life; - Treatment engagement (eg, attendance of sessions, adherence to practice) | —
Setting | Any | —
Study Design | RCTs with ≥ 10 participants per arm; observational studies ≥ 100 participants, if reporting adverse events or suicidal ideation and/or behaviors | Systematic reviews, study protocols, case reports, letters, conference abstracts, editorials, non-English studies (of any type), pre-clinical studies (in vitro or animal studies)

Notes.

a Non-prioritized studies were included but did not undergo full data abstraction;

b To be eligible, study had to address at least 1 primary outcome.

Abbreviations. VR=virtual reality.

## SEARCHING AND SELECTION

To identify articles relevant to the key questions, a medical research librarian searched MEDLINE, Embase, CENTRAL, and PsycINFO databases from inception to December 2024, using key words and subject headings for virtual reality and eligible mental health disorders. See Appendix for complete search strategies. Additional citations were identified from hand-searching reference lists and consultation with content experts. Clinical trial registries (Clinical Trials, Australian and New Zealand Trials Registry, and ISRCTN (http://www.isrctn.com/)) were also searched for recently completed and ongoing trials. For relevant completed trials found in those registries, we searched for associated publications using the protocol title, investigator names, and locations. Ongoing trials (without identified publications) are noted in the Supplementary Materials.

After removing duplicate search results, titles and abstracts were screened using DistillerSR version 2.35 (Evidence Partners, Ottawa, Canada).^12^ Two independent reviewers were required to exclude abstracts. Included abstracts then underwent full-text review by 2 reviewers, with inclusion of papers requiring consensus of both reviewers. Consensus was reached after discussion and/or with the involvement of a third reviewer. Pilot rounds were completed at both abstract screening and full-text review to clarify operationalization of the eligibility criteria. Studies had eligible populations for KQ1 if they included individuals diagnosed with the disorder (eg, being treated in a mental health clinic), used clinician-assessed measures to determine the diagnosis, or used participant-reported measures that had been validated for diagnostic accuracy (see the Supplementary Materials for information on these measures).

## DATA ABSTRACTION AND RISK OF BIAS ASSESSMENT

For all eligible studies, we abstracted the following information: study design, population, setting, intervention, comparator, and reported outcomes. With additional input from partners and TEP, we further prioritized the following disorders for detailed data abstraction and synthesis of KQ1 findings: PTSD, social anxiety, specific phobia of flying, alcohol use disorder, stimulant use disorder, depressive disorders, and schizophrenia spectrum disorders. The prioritization process involved a discussion of preliminary evidence map describing summary characteristics of eligible studies across all eligible mental health disorders, followed by individual surveys of partners and TEP members to elicit ratings for the top 3 highest priority disorders. As the partners and TEP members had diverse perspectives and interests, we mainly sought consensus by selecting the disorders with the highest ratings overall across all respondents. From these prioritized studies, we abstracted detailed characteristics of interventions and comparators, and findings for eligible outcomes (eg, effect measures, interview quotes). If findings were only reported in figures, we used PlotDigitizer (https://plotdigitizer.com/app) to derive numbers from figure images, per recommended practices.^13^ All data abstraction was completed by 1 reviewer and then checked by another.

The internal validity (risk of bias [RoB]) of each prioritized RCT was rated by 2 independent reviewers using Cochrane Risk of Bias 2.0.^14^ Disagreements (for domains and overall) were resolved by discussion and/or with input of a third reviewer (see the Supplementary Materials for detailed RoB ratings). We did not assess risk of bias for the 1 observational study that did not have concurrent comparators.

Demographics including sex or gender were abstracted using the terminology provided by authors (eg, woman or female). VR interventions were described using features from Persky 2023.^15^ Included features of VR were embodiment, interactivity, and multisensory stimulation. Embodiment is defined as “the ability for [VR] to make users feel as if they are existing within a digital body other than their own (eg, an avatar) enacting behaviors in the virtual environment.” Interactivity is defined as “response of [VR] environments to user input including physical movements and input from hand controllers.” Multisensory stimulation is originally defined as “[VR] can engage multiple senses such as visual (3D and stereoscopic), aural, olfactory, haptic, as well as senses not typically engaged by media (eg, proprioception);” due to the prevalence of visual and aural stimulation in included VR interventions, we defined interventions that stimulated senses beyond sight and sound as having multisensory stimulation.

## SYNTHESIS

We first grouped eligible studies for KQ1 by mental health disorder or category (eg, PTSD, Social Anxiety Disorder). We then further categorized studies by intervention and comparator components, including components of the intervention in addition to the VR (eg, education) and method of therapy utilized using VR technology (eg, prolonged exposure). We further stratified by comparator (eg, waitlist, active comparator).

We conducted meta-analyses when ≥3 sufficiently similar studies (based on populations, interventions and comparators) reported the same eligible outcome (eg, comparable measures of symptom severity). When meta-analyses could not be conducted, we provided qualitative syntheses of study characteristics and findings. For meta-analyses, we used random-effects models (with Hartung-Knapp-Sidik-Jonkman estimator) due to the anticipated heterogeneity in effects arising from variation in patient populations, interventions, and other study characteristics. We evaluated statistical heterogeneity using forest plots, τ^2^, and 95% prediction intervals (PI). We also estimated fixed-effects models when studies included the same participant population and evaluated essentially the same VR intervention and comparator; this was also evidenced by little to no heterogeneity in the random effects models. We planned to assess publication bias using funnel plots if there were ≥10 sufficiently similar studies (according to considerations described previously). We used meta and metafor packages and R version 4.3.1 (R Foundation for Statistical Computing, Vienna, Austria)^16^ to conduct meta-analyses and generate forest plots.

### Strength of Evidence

We used Grading of Recommendations, Assessment, Development, and Evaluation (GRADE) criteria to rate the strength of evidence for the following outcomes: symptom severity, treatment response, suicidal ideation and/or behaviors, and adverse events.^17,18^ Overall COE was rated as high, moderate, low, or very low (Table 1).^17,19^ These outcomes were selected with input from the TEP and topic nominators. We separately rated outcomes assessed immediately post-intervention and at 2–3 months. We did not determine strength of evidence if there was only a single applicable study (evaluating a particular VR intervention vs comparator for that mental health disorder) that reported an eligible outcome. GRADE assessment included evaluation of the evidence base across 5 domains: study limitations (RoB), inconsistency (in direction and magnitude of effect across studies), indirectness (applicability of results as a consideration of both population studied and outcome measures used), imprecision (limitations in precision of effect estimates), and other considerations (including publication bias). To assess imprecision when we did not have meta-analyses, we set thresholds for optimal information size (OIS) separately for efficacy and adverse events outcomes.^18^ For efficacy outcomes, we downgraded 1 level when a study did not have sufficient sample size n (for 2-tailed α = 0.05 and β = 0.2) to detect a standardized mean difference (SMD) of 0.6–0.7 (medium effect size) and 2 levels if not sufficient to detect 1 SMD (large effect size). For adverse events, we downgraded 1 level if a study did not have sufficient sample size in the VR intervention arm to detect events that occurred in ≥5% (N ~ 60) and 2 levels if it was not sufficient to detect events in ≥10% (N ~ 30).

Table 1 GRADE Certainty of Evidence Ratings: Definitions and Recommended Statements

Certainty of Evidence | Rating Definition | Recommended Statements (“What Happens”)
High | We are very confident that the true effect lies close to that of the estimate of the effect. | Intervention reduces/increases/improves outcome.; Intervention results in little to no difference in outcome.
Moderate | We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different. | Intervention probably reduces/increases/improves outcome.; Intervention probably results in little to no difference in outcome.
Low | Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect. | Intervention may reduce/increase/improve outcome.; Intervention may result in little to no difference in outcome.
Very Low | We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect. | The evidence is very uncertain about the effect of intervention on outcome.