# BACKGROUND

Over one quarter of Veterans in VA care have a diagnosed mental health disorder.^1^ Depressive disorders, posttraumatic stress disorder (PTSD), and substance use disorders (SUD) are most prevalent, and co-occurrence of diagnoses is common. Along with serious mental illnesses such as schizophrenia, all of these mental health disorders are associated with increased risks of hospitalization, premature death and suicide among Veterans.^1,2^ Suicide prevention remains a high priority for VA; current estimates indicate 20 Veterans die by suicide each day and suicide prevention will likely require multi-level efforts, including in health care settings.^3^ Evidence-based psychotherapies for mental health conditions, such as prolonged exposure therapy for PTSD, are effective yet remain underutilized in VHA clinical settings, prompting multiple VA initiatives to implement evidence-based psychotherapies for mental health conditions.^4–7^ Interest in delivering psychotherapies through virtual reality technology is rising, and systematic assessment is necessary to determine the evidence base for rollout of these interventions in VA.

Virtual reality (VR) provides a technological means of delivering a range of health interventions by situating a participant in a computer-generated virtual environment. A key aspect of VR is immersion: its capacity to make a participant feel present in the created virtual environment rather than in their physical environment.^8–10^ VR properties that can contribute to a person’s sense of being present in that immersive environment include interactivity (participants’ ability to take actions that have impact on the virtual experience) and multisensory stimulation (such as olfactory or tactile effects). In recent years, VR technology has become more affordable and more capable of producing realistic environments, and clinical applications are proliferating. The use of immersive VR technology in VA has expanded from 5 clinical sites in 2017 to 160 sites across all 50 states, Guam, Puerto Rico, and American Samoa as of 2023, with a focus on use for mental health conditions including PTSD, SUD, and depression.^11^ Expansion of VR in clinical settings is partially driven by the perception of patient enthusiasm for the technology.

The conceptual basis for VR’s therapeutic effects depends on the interventions’ core elements and proposed mechanisms of action. For example, VR environments can create exposure scenarios within exposure therapy for PTSD or for specific phobias. VR characteristics such as multisensory stimulation and therapist control of stimuli distinguish VR exposure from imaginal exposure, while elements of both therapist and participant control within pre-programmed scenarios distinguish VR exposure from in vivo exposure. Whether VR exposure scenarios differ in benefits and harms from non-VR exposure approaches is an empirical question specific to the therapeutic approach, the comparison groups, the mental health conditions being treated, and the population involved. Use of VR may also have important implications for participant engagement. Finally, consideration of broad VR application requires consideration of harms and adverse events.

The VA Office of Mental Health, Office of Innovation and Learning, and Digital Health Office requested this review of available evidence on VR interventions for mental health conditions and suicide prevention. The goal of this review is to inform VR implementation efforts in VA mental health care and identify evidence gaps to inform future research efforts.

In this systematic review, we synthesize evidence on the benefits and harms of fully immersive VR interventions for treating mental health disorders and for suicide prevention. We present findings by mental health disorder, beginning with PTSD. Within each condition, we provide results by VR intervention type, then by comparator type.