# Appendices

## SEARCH STRATEGIES

### MEDLINE (1946 TO DECEMBER 19, 2024)

# | Search Statement | Results
1 | Anxiety Disorders/ or Depression/ or exp Dissociative Disorders/ or exp Mood Disorders/ or exp Obsessive-Compulsive Disorder/ or Panic Disorder/ or exp Phobic Disorders/ | 376180
2 | (anxiet* or bipolar or cyclothymi* or depressi* or dysthymi* or mania* or moral injur* or neurocirculatory asthenia or neuros#s or obsessive-compulsive or OCD or panic attack* or phobia* or psychoneuros#s or ((postnatal or post-natal or postpartum or post-partum) adj1 dysphori*) or ((acute stress or adjustment or affective or depressive or dissociative or mood or panic or phobic or premenstrual dysphori* or neurotic or seasonal or vascular) adj3 disorder*)).ti,ab,kf. | 801528
3 | Suicidal Ideation/ or Suicide Prevention/ | 25265
4 | (suicidal ideation* or suicidality).ti,ab,kf. | 24635
5 | exp “Trauma and Stressor Related Disorders”/ | 53491
6 | (((posttraumatic or post-traumatic) adj3 (disorder* or neuros* or stress*)) or PTSD).ti,ab,kf. | 56833
7 | mental disorders/ or exp “schizophrenia spectrum and other psychotic disorders”/ | 335853
8 | (((delusional or paranoid or psychotic) adj3 disorder*) or psychos#s or ((serious or severe) adj2 mental adj2 (disorder* or illness*)) or schizo* or SMI).ti,ab,kf. | 231181
9 | Addiction Medicine/ or exp Substance-Related Disorders/ or Smoking Cessation/ or “Tobacco Use Cessation”/ or Vaping/ | 355635
10 | ((addict* adj (medicine or psychiatry)) or alcoholi* or ((alcohol or amphetamine? or cannabis or cocaine or drug? or glue or heroin or inhalant? or marijuana or methamphetamine? or morphine or narcotic? or nicotine or opioid? or opiate? or opium or PCP or phencyclidine? or substance or tobacco or vaping) adj3 (abuse* or addict* or dependen* or disorder* or habituation or misuse* or overuse or use*)) or SUD).ti,ab,kf. | 616337
11 | or/1-10 | 1898159
12 | augmented reality/ or haptic interfaces/ or exp Virtual Reality/ or Virtual Reality Exposure Therapy/ | 10004
13 | (((augmented or immersi* or simulat* or virtual) adj3 reality) or artificial reality or avatar* or extended reality or mixed reality or haptic interface? or haptic technolog* or virtual exposure or VR exposure or VR therap* or virtual world).ti,ab,kf. | 29921
14 | or/12-13 | 31163
15 | and/11,14 | 3607
16 | 15 not ((exp infant/ or exp child/ or adolescent/) not exp adult/) | 3306
17 | (adolescen* or child* or infant* or pediatric* or teen* or youth*).ti. | 1531760
18 | 16 not 17 | 3128
19 | exp animals/ not humans.sh. | 5291012
20 | 18 not 19 | 3117
21 | limit 20 to english language | 3050
22 | 21 not (comment/ or editorial/ or letter/ or news/ or exp consensus development conference/ or study guide/ or case reports/) | 2885
23 | 22 not (“review”/ or “systematic review”/) | 2313
| Total | 2313

### PSYCINFO (1806 TO DECEMBER 2024 WEEK 3)

# | Search Statement | Results
1 | exp affective disorders/ or anxiety disorders/ or exp dissociative disorders/ or generalized anxiety disorder/ or panic attack/ or panic disorder/ or exp phobias/ | 221393
2 | (anxiet* or bipolar or cyclothymi* or depressi* or dysthymi* or mania* or moral injur* or neurocirculatory asthenia or neuros#s or obsessive-compulsive or OCD or panic attack* or phobia* or ((postnatal or post-natal or postpartum or post-partum) adj1 dysphori*) or psychoneuros#s or ((acute stress or adjustment or affective or depressive or dissociative or mood or panic or phobic or premenstrual dysphori* or neurotic or seasonal or vascular) adj3 disorder*)).mp. | 618664
3 | mental disorders/ or psychosis/ or exp schizophrenia/ | 194140
4 | (((delusional or paranoid or psychotic) adj3 disorder*) or psychos#s or ((serious or severe) adj2 mental adj2 (disorder* or illness*)) or schizo* or SMI).mp. | 177296
5 | suicidal ideation/ or suicide prevention/ | 19846
6 | (suicidal ideation* or suicidality).mp. | 29531
7 | exp “stress and trauma related disorders”/ | 45761
8 | (((posttraumatic or post-traumatic) adj3 (disorder* or neuros* or stress*)) or PTSD).mp. | 70759
9 | Addiction Medicine/ or exp “substance use disorder”/ or smoking cessation/ or vaping/ | 132085
10 | ((addict* adj (medicine or psychiatry)) or alcoholi* or ((alcohol or amphetamine? or cannabis or cocaine or drug? or glue or heroin or inhalant? or marijuana or methamphetamine? or morphine or narcotic? or nicotine or opioid? or opiate? or opium or PCP or phencyclidine? or substance or tobacco or vaping) adj3 (addict* or abuse* or dependen* or disorder* or habituation or overuse* or misuse* or use*)) or SUD).mp. | 288587
11 | or/1-10 | 1040949
12 | augmented reality/ or avatars/ or virtual environment/ or virtual reality/ or virtual reality exposure therapy/ | 15487
13 | (((augmented or immersi* or simulat* or virtual) adj3 reality) or artificial reality or avatar* or extended reality or mixed reality or haptic interface? or haptic technolog* or virtual exposure or virtual world).mp. | 19482
14 | or/12-13 | 20082
15 | 11 and 14 | 3086
16 | 15 not ((adolescence 13 17 yrs or childhood birth 12 yrs) not adulthood 18 yrs older).ag. | 2913
17 | (adolescen* or child* or infant* or pediatric* or teen* or youth*).ti. | 522272
18 | 16 not 17 | 2836
19 | 18 not ((animals.mh. or Animal.po. or “Animal research”/ or exp invertebrates/ or exp vertebrates/ or exp “Plants (Botanical)”/) not (humans.mh. or human.po.)) | 2826
20 | limit 19 to english language | 2624
21 | limit 20 to (chapter or clarification or “column/opinion” or “comment/reply” or dissertation or editorial or encyclopedia entry or interview or letter or review-book) | 404
22 | 20 not 21 | 2220
| Total | 2220

### COCHRANE CENTRAL (NOVEMBER 2024)

# | Search Statement | Results
#1 | MeSH descriptor: [Anxiety Disorders] this term only | 6433
#2 | MeSH descriptor: [Dissociative Disorders] explode all trees | 188
#3 | MeSH descriptor: [Mood Disorders] explode all trees | 20674
#4 | MeSH descriptor: [Obsessive-Compulsive Disorder] explode all trees | 1563
#5 | MeSH descriptor: [Panic Disorder] this term only | 1117
#6 | MeSH descriptor: [Phobic Disorders] explode all trees | 2202
#7 | MeSH descriptor: [Suicidal Ideation] this term only | 1085
#8 | MeSH descriptor: [Suicide Prevention] this term only | 585
#9 | (acute stress or adjustment or anxiet* OR bipolar OR cyclothymi* OR depress* OR dissociative or dysthymi* OR mania* OR moral injur* OR neuros?s OR obsessive compulsive OR OCD OR panic attack* OR phobia*) NEAR/3 disorder*:ti,ab,kw (Word variations have been searched) | 58785
#10 | (postnatal OR postpartum OR premenstrual OR pregnan*) NEXT/3 dysphori*:ti,ab,kw | 321
#11 | MeSH descriptor: [Trauma and Stressor Related Disorders] explode all trees | 4811
#12 | (posttraumatic OR post-traumatic) NEAR/3 (stress* OR neuros*):ti,ab,kw | 8585
#13 | MeSH descriptor: [Mental Disorders] this term only | 5573
#14 | (serious OR severe) NEAR/3 mental NEAR/3 (disorder* OR illness*):ti,ab,kw | 2819
#15 | MeSH descriptor: [Schizophrenia] explode all trees | 10008
#16 | (schizoaffective OR schizophren*):ti,ab,kw | 21244
#17 | (delusional OR paranoid OR psycho* NEAR/3 disorder*):ti,ab,kw | 25867
#18 | (psychoses OR psychosis OR severe mental disorder* OR severe mental illness* OR serious mental disorder* OR serious mental illness*):ti,ab,kw | 16201
#19 | MeSH descriptor: [Addiction Medicine] this term only | 1
#20 | addiction NEXT (medicine OR psychiatry):ti,ab,kw | 95
#21 | MeSH descriptor: [Substance-Related Disorders] explode all trees | 21571
#22 | (alcohol use OR alcoholism OR alcoholic OR amphetamine? OR cannabis OR cocaine OR heroin OR inhal* OR huffing OR marijuana OR methamphetamine? OR morphine OR narcotic? OR nicotine OR opioid? OR opiate? OR opium OR PCP OR phencyclidine OR smoking OR substance OR tobacco OR vaping) NEAR/3 (addict* OR abuse* OR dependen* OR disorder* OR habituation OR overuse* OR misuse*):ti,ab,kw | 36210
#23 | {OR #1-#22} | 132511
#24 | MeSH descriptor: [Virtual Reality] explode all trees | 1307
#25 | MeSH descriptor: [Haptic Interfaces] this term only | 0
#26 | MeSH descriptor: [Augmented Reality] this term only | 125
#27 | (artificial reality or augmented reality OR avatar* OR extended reality OR haptic interface* OR haptic technolog* OR immersi* reality OR mixed reality OR simulat* reality OR virtual exposur* OR VR exposure OR virtual reality OR VR therap* OR virtual world):ti,ab,kw (Word variations have been searched) | 10732
#28 | {OR #24-#27} | 10732
#29 | {AND #23, #28} | 1490
#30 | english:la | 2122203
#31 | {AND #29-#30} in Trials (Word variations have been searched) | 1475
| Total | 1475

### EMBASE (1974 TO 2024 WEEK 51)

# | Search Statement | Results
1 | anxiety disorder/ or acute stress disorder/ or exp dissociative disorder/ or generalized anxiety disorder/ or exp mood disorder/ or exp obsessive compulsive disorder/ or panic/ or exp phobia/ | 848260
2 | (acute stress or adjustment or anxiet* or bipolar or cyclothymi* or depressi* or dissociative or dysthymi* or mania* or moral injur* or neuros#s or obsessive-compulsive or OCD or panic attack* or phobia* or ((postnatal or post-natal or postpartum or post-partum) adj dysphori*) or psychoneuros#s or ((acute stress or adjustment or affective or depressive or dissociative or mood or panic or phobic or premenstrual dysphoric or neurotic or seasonal or vascular) adj3 disorder*)).ti,ab,kf. | 1384848
3 | exp posttraumatic stress disorder/ | 89105
4 | (((posttraumatic or post-traumatic) adj3 (disorder* or neuros* or stress*)) or PTSD).ti,ab,kf. | 72726
5 | *mental disease/ or delusional disorder/ or exp paranoid psychosis/ or psychosis/ or exp paranoid psychosis/ or schizoaffective psychosis/ or exp schizophrenia/ or schizophrenia spectrum disorder/ | 407636
6 | (((delusional or paranoid or psychotic) adj3 disorder*) or psychos#s or ((serious or severe) adj mental adj2 (disorder* or illness*)) or schizo* or SMI).ti,ab,kf. | 299591
7 | addiction medicine/ or exp drug dependence/ | 295059
8 | ((addiction adj1 (medicine or psychiatry)) or alcoholi* or ((alcohol or amphetamine or cannabis or cocaine or drug or glue or heroin or inhalant or marijuana or methamphetamine? or morphine or narcotic or nicotine or opioid or opiate or opium or PCP or phencyclidine or substance or tobacco) adj3 (addict* or abuse* or dependence* or disorder* or habituation or overuse* or misuse* or use*)) or SUD).ti,ab,kf. | 720309
9 | suicidal ideation/ or suicide prevention/ | 37515
10 | (suicidal ideation* or suicidality).ti,ab,kf. | 32448
11 | or/1-10 | 2655197
12 | augmented reality/ or avatar/ or virtual reality/ or virtual reality exposure therapy/ or haptic technology/ | 35238
13 | (((augmented or immersi* or simulat* or virtual) adj3 reality) or artificial reality or avatar* or extended reality or mixed reality or haptic interface? or haptic technolog* or virtual exposure or VR exposure or VR therap* or virtual world).ti,ab,kf. | 36072
14 | or/12-13 | 47839
15 | 11 and 14 | 5913
16 | 15 not (exp juvenile/ not exp adult/) | 5362
17 | (adolescen* or child* or infant* or pediatric* or teen* or youth*).ti. | 1811485
18 | 16 not 17 | 5183
19 | 18 not ((exp animal/ or animal experiment/ or nonhuman/) not (exp human/ or human experiment/)) | 5129
20 | limit 19 to (books or chapter or conference abstract or conference paper or “conference review” or editorial or letter or note or “preprint (unpublished, non-peer reviewed)” or “review”) | 1999
21 | 19 not 20 | 3130
22 | limit 21 to (book or book series or conference proceeding or “preprint archive (unpublished, non-peer reviewed)” or trade journal) | 21
23 | 21 not 22 | 3109
24 | limit 23 to english language | 3033
25 | “scoping review”/ or “systematic review (topic)”/ or “review”/ or “conference review”/ or “systematic review”/ or “umbrella review”/ or “rapid review”/ or single case report/ | 3396954
26 | 24 not 25 | 2959
27 | book/ or exp conference paper/ or editorial/ or letter/ or note/ or short survey/ | 6905661
28 | 26 not 27 | 2939
| Total | 2939

APPENDIX FIGURE 1 FOREST PLOTS SHOWING STANDARDIZED MEAN DIFFERENCE IN CAPS AFTER VR PROLONGED EXPOSURE VERSUS NON-VR PROLONGED EXPOSURE THERAPY FOR PTSD (MODELS ESTIMATED USING RANDOM EFFECTS)

(a) Post-intervention

Appendix figure 1a is a forest plot visualizing a meta-analysis using data from 3 studies. The plot visualizes data at post-intervention. All studies favor non-VR PE. All studies have a confidence interval that crosses the null. The overall pooled analysis favors Non-VR PE, with a confidence interval that crosses the null (SMD 0.22 [−0.30, 0.74]).

(b) 3 months post-intervention

Appendix figure 1b is a forest plot visualizing a meta-analysis using data from 3 studies. The plot visualizes data at 3 months post-intervention. Two studies favor VR PE and one study favors non-VR PE. All studies have a confidence interval that crosses the null. The overall pooled analysis shows no difference between VR PE and non-VR PE, with a confidence interval that crosses the null (SMD 0.04 [−0.74, 0.82]).

APPENDIX FIGURE 2 FOREST PLOT SHOWING STANDARDIZED MEAN DIFFERENCE IN HADS-DEPRESSION AFTER VR RELAXATION AND EXERCISE VERSUS NON-VR RELAXATION AND EXERCISE FOR DEPRESSION IMMEDIATELY POST-INTERVENTION (MODELS ESTIMATED USING RANDOM EFFECTS)

Appendix figure 2 is a forest plot visualizing a meta-analysis using data from 3 studies. The plot visualizes data at post-intervention. All studies favor VR relaxation and exercise. Two studies have confidence intervals that do not cross the null; the third study’s confidence interval does cross the null. The overall pooled analysis favors VR relaxation and exercise, with a confidence interval that crosses the null (SMD −0.64 [−1.42, 0.13]).