# ABBREVIATIONS TABLE

Abbreviation: Definition
2D: 2-dimensional
3D: 3-dimensional
AAAT: Alcohol Approach-Avoidance Training
ABM: Attentional Bias Modification
ADIS-IV: Anxiety Disorders Interview Schedule for DSM-IV
AUD: Alcohol use disorder
AUQ: Alcohol Use Questionnaire
AVH: Audiovisual hallucination
BAI: Beck Anxiety Inventory
BDI: Beck Depression Inventory
BSS: Beck Scale for Suicide Ideation
CAINS: Clinical Assessment Interview for Negative Symptoms
CAPS: Clinician-Administered PTSD Scale
CBT: Cognitive behavioral therapy
CBTp: Cognitive behavioral therapy for psychosis
CI: Confidence interval
COE: Certainty of evidence
CSQ-8: Client Satisfaction Questionnaire
C-SSRS: Columbia Suicide Severity Rating Scale
DSM-IV: Diagnostic and Statistical Manual of Mental Disorders, Fourth Edition
DSM-V: Diagnostic and Statistical Manual of Mental Disorders, Fifth Edition
EMDR: Eye movement desensitization and reprocessing therapy
EQ-5D-5L: EuroQol 5 Dimension 5 Level
EUROHIS-QOL: Eurohis Quality of Life Scale
FAS: Flight Anxiety Situations Questionnaire
FFS: Fear of Flying Scale
FMS: Fast Motion Sickness Scale
FNE-B: Brief Fear of Negative Evaluation
GAD: General Anxiety Disorder 7-item Scale
GDS: Patient-Reported Geriatric Depression Scale
GPTS: Green Paranoid Thoughts Scale
GRADE: Grading of Recommendations, Assessment, Development, and Evaluation
HADS: Hospital Anxiety and Depression Scale
HAMD: Hamilton Depression Rating Scale
HMD: Head-mounted device
ICD-10: International Classification of Diseases, 10^th^ revision
ISRCTN: International Standard Randomized Controlled Trial Number
KQ: Key question
LSAS: Liebowitz Social Anxiety Scale
MACS: Multidimensional Craving Scale
MDD: Major depressive disorder
MEDLINE: Medical Literature Analysis and Retrieval System Online
NOS: Not otherwise specified
NR: Not reported
OIL: VA Office of Innovation and Learning
OIS: Optimal information size
OMH: VA Office of Mental Health
PANSS: Positive and Negative Syndrome Scale
PC: Personal computer
PCL: PTSD Checklist
PE: Prolonged exposure
PHQ: Patient Health Questionnaire
PHQ-9: Patient Health Questionnaire-9
PI: Prediction interval
PRCS: Personal Report of Confidence as a Speaker
PTSD: Posttraumatic stress disorder
QAF: Questionnaire on Attitudes toward Flying
RCT: Randomized controlled trial
RoB: Risk of bias
RR: Rate ratio
SAE: Serious adverse events
SCT: Social cognition training
SD: Standard deviation
SIAS: Social Interaction Anxiety Scale
SMD: Standardized mean difference
SPDQ: Social Phobia Diagnostic Questionnaire
SPS: Social Phobia Scale
SSQ: Simulator Sickness Questionnaire
SUD: Substance use disorder
TAU: Treatment as usual
TEP: Technical Expert Panel
VA: Veterans Affairs
VAS: Visual Analogue Scale
VR: Virtual reality