# Supplementary Materials

- Trial Characteristics (XLSX)
- Study Arm Characteristics (XLSX)
- Outcome Data (XLSX)
- Symptom Severity Measures (XLSX)
- Risk of Bias Assessments - RCT (XLSX)
- Non-Prioritized Characteristics (XLSX)
- Excluded Studies (XLSX)
- Underway Studies (XLSX)
- Peer Review Feedback (XLSX)

## VA Related Documents

Supplementary Materials (XLSX)