# REFERENCES

1 MedlinePlus. Movement Disorders. National Library of Medicine (US). https://medlineplus.gov/movementdisorders.html
2 Winkel D, Bernstein L. Movement Disorders. Med Clin North Am. May 2022;106(3):519–525. doi:10.1016/j.mcna.2022.02.002 35491071
3 Rajput A, Noyes E. Overview of Movement Disorders. Merck Manual. Updated 2024/02. 2024. https://www.merckmanuals.com/home/brain-spinal-cord-and-nerve-disorders/movement-disorders/overview-of-movement-disorders
4 Xing F, Marsili L, Truong DD. Parkinsonism in viral, paraneoplastic, and autoimmune diseases. J Neurol Sci. Feb 15 2022;433:120014. doi:10.1016/j.jns.2021.120014 34629181
5 Luo Y, Qiao L, Li M, Wen X, Zhang W, Li X. Global, regional, national epidemiology and trends of Parkinson’s disease from 1990 to 2021: findings from the Global Burden of Disease Study 2021. Original Research. Frontiers in Aging Neuroscience. 2025-January-10 2025;16doi:10.3389/fnagi.2024.1498756
6 Song P, Zhang Y, Zha M, . The global prevalence of essential tremor, with emphasis on age and sex: A meta-analysis. J Glob Health. Apr 10 2021;11:04028. doi:10.7189/jogh.11.04028 33880180
7 Education and Support: Resources for Veterans. American Parkinson Disease Association. https://www.apdaparkinson.org/resources-support/national-veteran-resources/
8 Camp Lejeune: Past Water Contamination. U.S. Department of Veterans Affairs. https://www.publichealth.va.gov/exposures/camp-lejeune/index.asp
9 Parkinson’s Disease Research, Education and Clinical Centers. U.S Department of Veterans Affairs. https://www.parkinsons.va.gov/
10 Macleod AD, Grieve JW, Counsell CE. A systematic review of loss of independence in Parkinson’s disease. J Neurol. Jan 2016;263(1):1–10. doi:10.1007/s00415-015-7847-8 26174653
11 van Munster M, Pedrosa AJ, Künkler C, Pedrosa DJ. The Quality in Quality of Life in Parkinson’s Disease: A Qualitative Meta-Synthesis. Mov Disord Clin Pract. Jul 2024;11(7):761–769. doi:10.1002/mdc3.14063 38715240
12 Armstrong MJ, Rastgardani T, Gagliardi AR, Marras C. Impact of Off Periods on Persons With Parkinson Disease and Care Partners: A Qualitative Study. Neurol Clin Pract. Jun 2021;11(3):e232–e238. doi:10.1212/cpj.0000000000000921 34484896
13 Gumber A, Ramaswamy B, Thongchundee O. Effects of Parkinson’s on employment, cost of care, and quality of life of people with condition and family caregivers in the UK: a systematic literature review. Patient Relat Outcome Meas. 2019;10:321–333. doi:10.2147/prom.S160843 31695537
14 Cong S, Xiang C, Zhang S, Zhang T, Wang H, Cong S. Prevalence and clinical aspects of depression in Parkinson’s disease: A systematic review and meta-analysis of 129 studies. Neurosci Biobehav Rev. Oct 2022;141:104749. doi:10.1016/j.neubiorev.2022.104749 35750224
15 Zhao N, Yang Y, Zhang L, . Quality of life in Parkinson’s disease: A systematic review and meta-analysis of comparative studies. CNS Neurosci Ther. Mar 2021;27(3):270–279. doi:10.1111/cns.13549 33372386
16 Gerbasi ME, Elble RJ, Jones E, . Associations Among Tremor Amplitude, Activities of Daily Living, and Quality of Life in Patients with Essential Tremor. Tremor Other Hyperkinet Mov (NY). 2024;14:22. doi:10.5334/tohm.877
17 Bhimani R. Understanding the Burden on Caregivers of People with Parkinson’s: A Scoping Review of the Literature. Rehabil Res Pract. 2014;2014:718527. doi:10.1155/2014/718527 25298895
18 Tan QY, Cox NJ, Lim SER, . The Experiences of Treatment Burden in People with Parkinson’s Disease and Their Caregivers: A Systematic Review of Qualitative Studies. J Parkinsons Dis. 2021;11(4):1597–1617. doi:10.3233/jpd-212612 34334419
19 Potel SR, Marceglia S, Meoni S, Kalia SK, Cury RG, Moro E. Advances in DBS technology and novel applications: focus on movement disorders. Current Neurology and Neuroscience Reports. 2022;22(9):577–588.35838898
20 Ferreira JJ, Mestre TA, Lyons KE, . MDS evidence-based review of treatments for essential tremor. Movement Disorders. 2019;34(7):950–958.31046186
21 Walters H, Shah BB. Focused ultrasound and other lesioning therapies in movement disorders. Current Neurology and Neuroscience Reports. 2019;19:1–7.30627880
22 Troncoso-Escudero P, Sepulveda D, Pérez-Arancibia R, . On the right track to treat movement disorders: promising therapeutic approaches for Parkinson’s and Huntington’s disease. Frontiers in aging neuroscience. 2020;12:571185.33101007
23 Miczak K G-CC, Segal M,. Rehabilitation for People with Movement Disorders. Practical Neurology. 2023;(Sept–Oct)
24 Lu G, Luo L, Liu M, . Outcomes and Adverse Effects of Deep Brain Stimulation on the Ventral Intermediate Nucleus in Patients with Essential Tremor. Neural Plast. 2020;2020:2486065. doi:10.1155/2020/2486065 32802034
25 Diseases and Conditions. Focused Ultrasound Foundation. https://www.fusfoundation.org/diseases-and-conditions/
26 VHA Office of Integrated Veteran Care Clinical Determination and Indication Magnetic Resonance-Guided Focused Ultrasound Thalamotomy (2024).
27 Administration USFaD. FDA approves first MRI-guided focused ultrasound device to treat essential tremor. https://www.fda.gov/news-events/press-announcements/fda-approves-first-mri-guided-focused-ultrasound-device-treat-essential-tremor#:~:text=The%20U.S.%20Food%20and%20Drug,beta%20blockers%20or%20anticonvulsant%20drugs
28 Insightec. Insightec Announces FDA Approval of Exablate Neuro for the Treatment of Parkinson’s Disease. https://insightec.com/news/insightec-announces-fda-approval-of-exablate-neuro-for-the-treatment-of-parkinsons-disease/
29 Insightec. Insightec Announces FDA Approval of Staged Bilateral Focused Ultrasound Treatment for Parkinson’s Disease. https://insightec.com/news/insightec-announces-fda-approval-of-staged-bilateral-focused-ultrasound-treatment-for-parkinsons-disease/
30 Agrawal M, Garg K, Samala R, Rajan R, Naik V, Singh M. Outcome and Complications of MR Guided Focused Ultrasound for Essential Tremor: A Systematic Review and Meta-Analysis. Front Neurol. 2021;12:654711. doi:10.3389/fneur.2021.654711 34025558
31 Rohani M, Fasano A. Focused Ultrasound for Essential Tremor: Review of the Evidence and Discussion of Current Hurdles. Tremor Other Hyperkinet Mov (N Y). 2017;7:462. doi:10.7916/d8z89jn1 28503363
32 Golfrè Andreasi N, Cilia R, Romito LM, . Magnetic Resonance-Guided Focused Ultrasound Thalamotomy May Spare Dopaminergic Therapy in Early-Stage Tremor-Dominant Parkinson’s Disease: A Pilot Study. Mov Disord. Nov 2022;37(11):2289–2295. doi:10.1002/mds.29200 36036203
33 van der Stouwe AMM, Jameel A, Gedroyc W, . Double lesion MRgFUS thalamotomy for essential tremor: 4.5-year outcomes and framework for assessing loss of efficacy and tremor progression. Br J Neurosurg. Jul 17 2024:1–4. doi:10.1080/02688697.2024.2354282
34 Elias WJ, Lipsman N, Ondo WG, . A Randomized Trial of Focused Ultrasound Thalamotomy for Essential Tremor. N Engl J Med. Aug 25 2016;375(8):730–9. doi:10.1056/NEJMoa1600159 27557301
35 Giordano M, Caccavella VM, Zaed I, . Comparison between deep brain stimulation and magnetic resonance-guided focused ultrasound in the treatment of essential tremor: a systematic review and pooled analysis of functional outcomes. J Neurol Neurosurg Psychiatry. Dec 2020;91(12):1270–1278. doi:10.1136/jnnp-2020-323216 33055140
36 Guidera JA, Kondapavulur S, Wang DD. A Systematic Review Comparing Radiofrequency versus Focused Ultrasound Pallidotomy in the Treatment of Parkinson’s Disease. Stereotactic and Functional Neurosurgery. 2024;102(5):325–342.39173595
37 Lin F, Wu D, Yu J, . Comparison of efficacy of deep brain stimulation and focused ultrasound in parkinsonian tremor: a systematic review and network meta-analysis. J Neurol Neurosurg Psychiatry. Jan 18 2021;doi:10.1136/jnnp-2020-323656
38 Shih LC, Tarsy D. Deep brain stimulation for the treatment of atypical parkinsonism. Mov Disord. Nov 15 2007;22(15):2149–55. doi:10.1002/mds.21648 17659638
39 Guyatt GH, Oxman AD, Vist GE, . GRADE: an emerging consensus on rating quality of evidence and strength of recommendations. Bmj. 2008;336(7650):924–926.18436948
40 Berkman ND, Lohr KN, Ansari M, . Grading the strength of a body of evidence when assessing health care interventions for the effective health care program of the Agency for Healthcare Research and Quality: an update. 2013.
41 Javdaneh N, Barati A, Shojaedin S, Mirzaei RM. Is chronic neck pain related to scapular dyskinesia? A systematic review. BMC Musculoskeletal Disorders. 2025;26:585.40604589
42 Boutet A, Gwun D, Gramer R, . The relevance of skull density ratio in selecting candidates for transcranial MR-guided focused ultrasound. J Neurosurg. Jun 1 2020;132(6):1785–1791. doi:10.3171/2019.2.Jns182571 31051458
43 Health Quliaty Ontario. Magnetic resonance-guided focused ultrasound neurosurgery for essential tremor: A health technology assessment. Ontario Health Technology Assessment Series. 2018;18(4):1–141.
44 Rohringer CR, Sewell IJ, Gandhi S, . Cognitive effects of unilateral thalamotomy for tremor: a meta-analysis. Brain Commun. 2022;4(6):fcac287. doi:10.1093/braincomms/fcac287 36440102
45 Iorio-Morin C, Yamamoto K, Sarica C, . Bilateral focused ultrasound thalamotomy for essential tremor (BEST-FUS trial): Safety and efficacy proof of principle. Movement Disorder. 2021;36(SUPPL 1):S589–S590. International Parkinson and Movement Disorder Society, MDS 2021. Virtual. doi:10.1002/mds.28794
46 Kaplitt MG, Krishna V, Eisenberg HM, . Safety and Efficacy of Staged, Bilateral Focused Ultrasound Thalamotomy in Essential Tremor: An Open-Label Clinical Trial. JAMA Neurol. Jul 29 2024;doi:10.1001/jamaneurol.2024.2295
47 Scantlebury N, Rohringer CR, Rabin JS, . Safety of Bilateral Staged Magnetic Resonance-Guided Focused Ultrasound Thalamotomy for Essential Tremor. Mov Disord Clin Pract. Oct 2023;10(10):1559–1561. doi:10.1002/mdc3.13882 37868927
48 Yamamoto K, Sarica C, Elias GJB, . Ipsilateral and axial tremor response to focused ultrasound thalamotomy for essential tremor: clinical outcomes and probabilistic mapping. J Neurol Neurosurg Psychiatry. Aug 22 2022;doi:10.1136/jnnp-2021-328459
49 Holcomb JM, Chopra R, Feltrin FS, . Improving tremor response to focused ultrasound thalamotomy. Brain Commun. 2023;5(4):fcad165. doi:10.1093/braincomms/fcad165 37533544
50 Jameel A, Gedroyc W, Nandi D, . Double lesion MRgFUS treatment of essential tremor targeting the thalamus and posterior sub-thalamic area: preliminary study with two year follow-up. Br J Neurosurg. Apr 2022;36(2):241–250. doi:10.1080/02688697.2021.1958150 34382881
51 Dallapiazza R, Huss D, Shah B, Harrison M, Elias WJ. A functional assessment of essential tremor treated with bilateral or unilateral surgery. Journal article; Conference proceeding. Stereotactic and functional neurosurgery. 2014;92:s13. doi:10.1159/000366073
52 Huss DS, Dallapiazza RF, Shah BB, Harrison MB, Diamond J, Elias WJ. Functional assessment and quality of life in essential tremor with bilateral or unilateral DBS and focused ultrasound thalamotomy. Mov Disord. Dec 2015;30(14):1937–43. doi:10.1002/mds.26455 26769606
53 Kim M, Jung NY, Park CK, Chang WS, Jung HH, Chang JW. Comparative Evaluation of Magnetic Resonance-Guided Focused Ultrasound Surgery for Essential Tremor. Stereotact Funct Neurosurg. 2017;95(4):279–286. doi:10.1159/000478866 28810261
54 Miller WK, Becker KN, Caras AJ, . Magnetic resonance-guided focused ultrasound treatment for essential tremor shows sustained efficacy: a meta-analysis. Neurosurg Rev. Feb 2022;45(1):533–544. doi:10.1007/s10143-021-01562-w 33978922
55 Mohammed N, Patra D, Nanda A. A meta-analysis of outcomes and complications of magnetic resonance-guided focused ultrasound in the treatment of essential tremor. Neurosurg Focus. Feb 2018;44(2):E4. doi:10.3171/2017.11.Focus17628
56 Langford BE, Ridley CJA, Beale RC, Caseby SCL, Marsh WJ, Richard L. Focused Ultrasound Thalamotomy and Other Interventions for Medication-Refractory Essential Tremor: An Indirect Comparison of Short-Term Impact on Health-Related Quality of Life. Value Health. Oct 2018;21(10):1168–1175. doi:10.1016/j.jval.2018.03.015 30314617
57 Ravikumar VK, Parker JJ, Hornbeck TS, . Cost-effectiveness of focused ultrasound, radiosurgery, and DBS for essential tremor. Mov Disord. Aug 2017;32(8):1165–1173. doi:10.1002/mds.26997 28370272
58 Buzaev IV, Galimova RM, Nabiullina DI, Illarioshkin SN, Zagidullin NS, Safin SM. Magnetic resonance imaging-guided focused ultrasound thalamotomy launch with remote telemedicine international proctorship. Chronic Dis Transl Med. Mar 2024;10(1):40–50. doi:10.1002/cdt3.92 38450308
59 Abbas A, Hassan MA, Shaheen RS, . Safety and efficacy of unilateral focused ultrasound pallidotomy on motor complications in Parkinson’s disease (PD): a systematic review and meta-analysis. Neurological Sciences. 2024;doi:10.1007/s10072-024-07617-2
60 Xu Y, He Q, Wang M, . Safety and efficacy of magnetic resonance imaging-guided focused ultrasound neurosurgery for Parkinson’s disease: a systematic review. Neurosurg Rev. Feb 2021;44(1):115–127. doi:10.1007/s10143-019-01216-y 31814058
61 Tian X, Hu R, He P, Ye J. Efficacy and safety of magnetic resonance-guided focused ultrasound for Parkinson’s disease: a systematic review and meta-analysis. Front Neurol. 2023;14:1301240. doi:10.3389/fneur.2023.1301240 38146437
62 Lennon JC, Hassan I. Magnetic resonance-guided focused ultrasound for Parkinson’s disease since ExAblate, 2016-2019: a systematic review. Neurol Sci. Feb 2021;42(2):553–563. doi:10.1007/s10072-020-05020-1 33389248
63 Ge Y, Gu F, Yang X, Chen Z, Dong W, Wang Z. Clinical application of magnetic resonance-guided focused ultrasound in Parkinson’s disease: a meta-analysis of randomized clinical trials. Neurological Sciences. 2021;42(9):3595–3604. doi:10.1007/s10072-021-05443-4 34216307
64 Peters J, Maamary J, Kyle K, . Outcomes of Focused Ultrasound Thalamotomy in Tremor Syndromes. Mov Disord. Jan 2024;39(1):173–182. doi:10.1002/mds.29658 37964429
65 Horisawa S, Yamaguchi T, Abe K, . Magnetic Resonance-Guided Focused Ultrasound Thalamotomy for Focal Hand Dystonia: A Pilot Study. Mov Disord. Aug 2021;36(8):1955–1959. doi:10.1002/mds.28613 34050695
66 Khu KJO, Jamora RDG, Aguilar JA, . Establishing and developing a magnetic resonance-guided focused ultrasound program in a resource-limited setting: the Philippine experience. Neurosurg Rev. Jul 30 2024;47(1):372. doi:10.1007/s10143-024-02624-5 39078417
67 Golfrè Andreasi N, Braccia A, Levi V, . The Optimal Targeting for Focused Ultrasound Thalamotomy Differs between Dystonic and Essential Tremor: A 12-Month Prospective Pilot Study. Mov Disord Clin Pract. Jan 2024;11(1):69–75. doi:10.1002/mdc3.13911 38291839
68 Cesarano S, Saporito G, Sucapane P, . Staged magnetic resonance-guided focused ultrasound thalamotomy for the treatment of bilateral essential tremor and Parkinson’s disease related tremor: a systematic review and critical appraisal of current knowledge. Front Neurol. 2024;15:1409727. doi:10.3389/fneur.2024.1409727 38966080
69 Kondapavulur S, Silva AB, Molinaro AM, Wang DD. A Systematic Review Comparing Focused Ultrasound Surgery With Radiosurgery for Essential Tremor. Neurosurgery. Sep 1 2023;93(3):524–538. doi:10.1227/neu.0000000000002462 37010324
70 Giammalva GR, Maugeri R, Umana GE, . DBS, tcMRgFUS, and gamma knife radiosurgery for the treatment of essential tremor: a systematic review on techniques, indications, and current applications. J Neurosurg Sci. Dec 2022;66(6):476–484. doi:10.23736/s0390-5616.22.05524-2 35301835
71 Dang TTH, Rowell D, Connelly LB. Cost-Effectiveness of Deep Brain Stimulation With Movement Disorders: A Systematic Review. Mov Disord Clin Pract. Jun 2019;6(5):348–358. doi:10.1002/mdc3.12780 31286004
72 Altinel Y, Alkhalfan F, Qiao N, Velimirovic M. Outcomes in Lesion Surgery versus Deep Brain Stimulation in Patients with Tremor: A Systematic Review and Meta-Analysis. World Neurosurg. Mar 2019;123:443–452.e8. doi:10.1016/j.wneu.2018.11.175 30500587
73 Schreglmann SR, Krauss JK, Chang JW, Bhatia KP, Kägi G. Functional lesional neurosurgery for tremor: a systematic review and meta-analysis. J Neurol Neurosurg Psychiatry. Jul 2018;89(7):717–726. doi:10.1136/jnnp-2017-316302 29326290
74 Cummins DD, Bernabei JM, Wang DD. Focused Ultrasound for Treatment of Movement Disorders: A Review of Non-Food and Drug Administration Approved Indications. Stereotact Funct Neurosurg. 2024;102(2):93–108. doi:10.1159/000535621 38368868
75 Fan H, Bai Y, Yin Z, . Which one is the superior target? A comparison and pooled analysis between posterior subthalamic area and ventral intermediate nucleus deep brain stimulation for essential tremor. CNS Neurosci Ther. Sep 2022;28(9):1380–1392. doi:10.1111/cns.13878 35687507
76 Pouratian N, Baltuch G, Elias WJ, Gross R. American Society for Stereotactic and Functional Neurosurgery position statement on magnetic resonance-guided focused ultrasound for the management of essential tremor. Neurosurgery. 2020;87(2):E126–E129.31832649
77 Healthcare M. Molina Clinical Policy Magnetic Resonance Guided Focused Ultrasound (MRgFUS) Ablation for Essential Tremor: Policy No. 312 https://www.molinaclinicalpolicy.com/molinaclinicalpolicy/-/media/Molina/PublicWebsite/PDF/Common/Molina-Clinical-Policy/Magnetic-Resonance-Guided-Focused-Ultrasound_MRgFUS_for-Essential-Tremor_R.pdf
78 Albanese A, Barnes M, Bhatia K, . A systematic review on the diagnosis and treatment of primary (idiopathic) dystonia and dystonia plus syndromes: report of an EFNS/MDS-ES Task Force. European journal of neurology. 2006;13(5):433–444.16722965
79 Bond AE, Shah BB, Huss DS, . Safety and Efficacy of Focused Ultrasound Thalamotomy for Patients With Medication-Refractory, Tremor-Dominant Parkinson Disease: a Randomized Clinical Trial. Journal article. JAMA neurology. 2017;74(12):1412–1418. doi:10.1001/jamaneurol.2017.3098 29084313
80 Krishna V, Fishman PS, Eisenberg HM, . Trial of Globus Pallidus Focused Ultrasound Ablation in Parkinson’s Disease. Journal article. New England journal of medicine. 2023;388(8):683–693. doi:10.1056/NEJMoa2202721 36812432
81 Martínez-Fernández R, Máñez-Miró JU, Rodríguez-Rojas R, . Randomized Trial of Focused Ultrasound Subthalamotomy for Parkinson’s Disease. Journal article. New England journal of medicine. 2020;383(26):2501–2513. doi:10.1056/NEJMoa2016311 33369354
82 Armengou-Garcia L, Sanchez-Catasus CA, Aviles-Olmos I, . Unilateral Magnetic Resonance-Guided Focused Ultrasound Lesion of the Subthalamic Nucleus in Parkinson’s Disease: A Prospective Study. Mov Disord. Dec 2024;39(12):2230–2241. doi:10.1002/mds.30020 39295191
83 Monteiro JDS, BB E S, de Oliveira RR, . Magnetic resonance-guided focused ultrasound ventral intermediate thalamotomy for Tremor-Dominant Parkinson’s disease: a systematic review and meta-analysis. Neurosurg Rev. Sep 27 2024;47(1):701. doi:10.1007/s10143-024-02948-2 39331247
84 Paschen S, Natera-Villalba E, Pineda-Pardo JA, . Comparative Study of Focused Ultrasound Unilateral Thalamotomy and Subthalamotomy for Medication-Refractory Parkinson’s Disease Tremor. Mov Disord. May 2025;40(5):823–833. doi:10.1002/mds.30159 40028918