# ACKNOWLEDGMENTS

The authors are grateful to Becky Baltich Nelson, MLS, MS, Gaelen Adam, MLIS, PhD, and Cheryl Banick, MLIS for literature searching and retrieval, external peer reviewers, and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Dawn McHale
  Program Specialist
  Philadelphia PADRECC
  National Coordinator
  National VA Parkinson’s Disease Consortium

- Pavan Vaswani, MD, PhD
  Attending Neurologist
  Philadelphia PADRECC

## Technical Expert Panel

To ensure robust, scientifically relevant work, the technical expert panel (TEP) guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members included:

- Wael Asaad, MD, PhD
  Neurosurgeon
  Brown- Rhode Island Hospital

- Amie Hiller, MD
  Neurologist
  Portland PADRECC

- Roshni Patel, MD
  Neurology Attending Physician
  Jesse Brown VAMC