# DISCUSSION

We identified 14 primary studies that reported on the comparative use of MRgFUS for the treatment of movement disorders. Nine of these were comparative studies focusing on ET, 1 was a comparative study focusing on PD, and 4 were single group studies that focused on other movement disorders. In addition, we identified 22 systematic reviews that reported on the use of MRgFUS for the treatment of movement disorders. Importantly, for ET and PD we focused only on studies that compared treatments, target locations, and laterality, or side. For other movement disorders, less is known about the effect of MRgFUS or FUS, so we included comparative and single group studies.

Key findings include the following:

## KEY FINDINGS

ET:

MRgFUS versus Other Treatments (3 Comparative Studies)

► Bilateral DBS compared to unilateral MRgFUS may provide better improvement of tremor-related outcomes and quality of life (low confidence).
► There was insufficient evidence to assess adverse events or other outcomes for studies that compared treatments (no conclusions), and no studies reported on functional outcomes.

Unilateral versus Bilateral MRgFUS (3 Comparative Studies)

► Bilateral treatment compared to unilateral treatment may provide better improvement of tremor-related outcomes (moderate confidence).
► There were no differences in functional outcomes between unilateral and bilateral treatments (low confidence).
► There is insufficient evidence for quality of life, adverse events, and other outcomes (no conclusions).

Target Location (2 Comparative Studies)

► MRgFUS targeting the PSA or targets with PSA compared to VIM alone may provide better improvement of tremor-related outcomes (low confidence).
► There is insufficient evidence for adverse events between target locations (no conclusion).
► No other outcomes were reported for this comparison.

Left versus Right Side Treatment (1 Comparative Study)

► Evidence was insufficient to make any conclusions about the effect of treatment side on tremor-related outcomes (no conclusion).
► No other outcomes were reported.

Results from the Systematic Reviews (7 Studies)

► MRgFUS for ET improves tremor-related symptoms, quality of life, and functional outcomes (single group and comparative data), but overall it was not clear how MRgFUS compared to other treatments for these outcomes (certainty of evidence not assessed).
► Results (single group and comparative data) were mixed for the effects of MRgFUS on adverse event for ET (certainty of evidence not assessed).

PD:

► Only 1 comparative study reported comparative data for PD. There was insufficient evidence to make any conclusions about the use of MRgFUS in these patients.

Results from the Systematic Reviews (7 studies)

► MRgFUS for PD improved tremor-related outcomes (single group and comparative data), but results were mixed when compared to other treatments (certainty of evidence not assessed).
► Results (single group and comparative data) were mixed for the effects of MRgFUS for PD on quality of life and adverse events (certainty of evidence not assessed).

Other Movement Disorders (4 Single Group Studies):

► Single group studies showed improvements in several outcomes of interest, but there was insufficient evidence to make any conclusions about the use of MRgFUS in patients with dystonia conditions.

Results from the Systematic Reviews (8 studies)

► MRgFUS improved tremor-related outcomes in cohorts of people with mixed conditions (single group and comparative data), but no differences were seen when compared to other treatments (certainty of evidence not assessed).
► For mixed condition studies, reviews favored MRgFUS over other treatments for quality of life, but adverse event outcomes were mixed (certainty of evidence not assessed).

Overall, bilateral compared to unilateral MRgFUS appears to improve tremor-related outcomes for people with ET. This finding may be because unilateral treatment only treats the contralateral side, so treating the other side may offer further benefit. In addition, targeting the PSA versus VIM alone is associated with improved tremor-related outcomes, and other studies have shown that the PSA target may also be superior for DBS in ET.^75^ Importantly, at present, bilateral MRgFUS is generally not recommended by the American Society for Stereotactic and Functional Neurosurgery, which may be due to concerns of increased risk of side effects.^76,^ ^77^ The current review concluded that there was insufficient evidence to assess differences in adverse events between unilateral and bilateral treatment for ET. There were sparse data on the effect of MRgFUS compared to other active treatments. Importantly, 1 meta-analysis of single group studies indirectly compared bilateral DBS to unilateral MRgFUS. The authors concluded that bilateral DBS may be more beneficial for tremor control though less so for post-operative quality of life, but again this was an indirect comparison and there were important baseline differences between patient groups.^35^ Although evidence was insufficient to draw conclusions about adverse events, 2 primary studies included in our review noted that adverse events were more common for MRgFUS compared to bilateral DBS or unilateral RF.^52,^ ^53^ By 12 months there were no meaningful differences in adverse events between MRgFUS and bilateral DBS or unilateral RF.

For PD, only 1 study directly compared target locations.^58^ This study found lower recurrence in individuals who received treatment of the PTT target compared to VIM. In this study, some individuals in the PTT group also received treatment of the VIM, making it challenging to interpret the findings. For the systematic reviews identified, overall the studies showed benefit of MRgFUS comparing baseline to follow-up data or comparing MRgFUS to sham.^63^ As a result, there is limited information on comparisons of MRgFUS to other treatments, use of different treatment targets, or other similar comparisons.

For other movement disorders, it appears that MRgFUS improves tremor-related outcomes, quality of life, and function, and that adverse effects generally dissipate by 12 months post-procedure. However, overall these studies were small, did not include comparison groups, and included a variety of conditions. Standard treatments for idiopathic dystonia, for example, include medications including botulinum toxin injections or other therapies, such as DBS.^78^ We identified no studies fitting our criteria that compared MRgFUS to other therapies. Several of the identified systematic reviews made indirect comparisons between MRgFUS and other treatments for patients with other movement disorders. Overall, these reviews showed varied results.^69,^ ^71,^ ^72^

Importantly, across all conditions and comparisons of interest, there was either no evidence or insufficient evidence to be able to assess differences in adverse events, which is a crucial component when considering appropriate treatment. Some of the systematic reviews we identified, which incorporated single group studies, may shed additional light on the evidence for differences in adverse events between treatment groups. For instance, the review by Giordano et al reported more gait disturbances, paresthesia, and nausea in patients who received MRgFUS compared to DBS, but fewer speech disturbances and local adverse symptoms. However, based on the larger literature base of single group studies and MRgFUS compared to sham, some side effects, such as head pain, dizziness, ataxia, and paresthesia, may be common in patients treated with MRgFUS.^30,^ ^31^ Individualized discussions with patients will be important when considering potential adverse events related to treatments.

Finally, costs were a prioritized outcome for this review, but none of the identified primary studies reported or compared costs between treatments. Three of the systematic reviews we identified indicated that MRgFUS compared to DBS may cost less. In addition, 1 systematic review indicated no difference in costs between SRS and MRgFUS,^57^ and another systematic review indicated that RF may be less costly than MRgFUS.^43^ It is difficult to act on the cost data without comparative data on clinical and patient centered outcomes.

## STRENGTHS AND LIMITATIONS OF THE SYSTEMATIC REVIEW PROCESS

This review employed rigorous methodology to capture studies that aligned with the key questions. However, there are several important limitations to the current review that should be considered. First, because MRgFUS has already been shown to be effective for ET and PD, for these conditions we focused only on studies that provided comparative results based on treatment, target location, or laterality. As a result, the literature base for these conditions was small and did not include several pivotal trials that compared MRgFUS to sham or best medical management.^34,^ ^79–81^ Much of the literature includes single group studies, and many of the systematic reviews and meta-analyses “compared” results from these single group studies. By focusing on comparative studies, we excluded single group studies that may have offered insight into potential adverse effects that may occur from MRgFUS. While single group studies were not included in our analyses of primary studies, we did provide a summary of identified systematic reviews that included single group studies. Notably, the systematic reviews concluded that adverse events were resolved by 12 months post-treatment.

Second, we also chose to only include studies that intentionally and prospectively targeted different treatment locations in the brain. We excluded several studies that conducted post hoc retrospective analyses of people who received treatments in different locations. We opted to exclude these studies due to a high concern of selection bias and unobserved confounding. While this helped to ensure intentionality in differing treatment targets, the omitted studies that examined lesion location post hoc may offer further insight into the outcome differences based on lesion location.

For comparisons of side or unilateral verses staged bilateral treatments, it was not explicitly stated across studies how side or laterality was determined. While there may be some assumption this could have been based on tremor severity, we could not confirm this information. From a clinical perspective, patient preference and safety decisions made by the surgeon would be the main factors.

Finally, for conditions other than ET and PD, we included single group studies. Data from single group studies did offer some insight into effectiveness of treatment; however, data from single group studies do not offer information on how treatment may compare to other treatments including usual medical management. Additionally, we only included a subset of conditions that cause secondary movement disorders as part of our search, so other studies on secondary movement disorders may not have been included.

## STRENGTHS AND LIMITATIONS OF THE LITERATURE BASE AND FUTURE RESEARCH NEEDS

Overall, the evidence base has several limitations. First, the available research made it challenging to directly examine comparisons of interest (eg, target locations, use of different treatments) due to potential difference in baseline patient risk factors or reasons for treatment allocation. No RCTs compared treatments, target location, laterality, or side for ET and PD. Nor were there any RCTs that compared MRgFUS to other treatments for all other movement disorders. Historical evolution of RCTs for surgical procedures is important to consider. When treatments are shown to be clinically beneficial, and as surgeons’ skills improve over time with improved patient outcomes, often they eventually become accepted as standard surgical procedures, which differs compared to drug trials. There can be ethical issues, patient preferences in the case of elective surgeries, and safety issues at the time of the procedure that are factors in the development of such trials. As a procedure matures, the expectation would be an increase in controlled and comparative trials, which reflects the typical trajectory of surgical intervention. Future studies should consider conducting RCTs to inform these questions when increased numbers of patients and better understanding of target physiology allow. In the interim, NRCS can provide valuable information, but they need to adjust for confounders such as patient characteristics and availability of treatment options and infrastructure.

Second, many included studies mentioned that slight target adjustments were made during procedures to ensure lesioning was effective. While this may be typical for treatment, this also may lead to inaccuracies when comparing treatment target locations. When treatment modality is dynamic and patient-centered outcomes including safety are the goals, these adjustments are likely unavoidable. Future studies should document when and how adjustments are made and consider approaches to control for adjustments in the analysis.

Third, given the limited number of studies included, we were also unable to examine outcomes based on patient characteristics that might be important for treatment, such as skull density ratio. Relatedly, the studies included in this review consisted of a heterogeneous group of disorders, all with smaller sample sizes. This makes it challenging to generalize results to any 1 disorder of interest. In addition, in studies that looked at different treatments, there were significant differences in baseline scores for a variety of outcomes, making it challenging to directly compare the changes in scores between these groups.

Finally, there were limited data surrounding the effects of different treatment comparators on adverse events. This is problematic, as it limits the ability to understand the full scope of treatments. While this may have been somewhat a reflection of the scope of the current review, limiting studies to only those that directly compare treatments of interest, future studies should focus on reporting adverse events in comparative studies. These studies should also consider potential differences in timing of adverse events that may arise from different treatment types. Since our literature search was conducted, several new studies on MRgFUS have been published.^82–84^ These and other future studies may be able to help lend additional evidence to differences in adverse events among comparators of interest.

## CONCLUSIONS

MRgFUS has emerged within the last decade as a viable and less invasive alternative for the treatment of movement disorders. For ET, bilateral DBS compared to unilateral MRgFUS may provide better improvement of tremor-related outcomes and quality of life; however, we cannot rule out that these differences are not based on unobserved patient characteristics, since comparative studies did not conduct adjusted analyses. We were unable to assess differences between other treatments and MRgFUS for tremor-related outcomes. Staged bilateral MRgFUS compared to unilateral treatment may improve tremor-related outcomes. MRgFUS treatments that target or include the PSA compared to VIM alone may improve tremor-related outcomes. There was insufficient evidence to assess adverse events or other outcomes for the above comparisons. Systematic reviews of single group studies and comparative data indicate that MRgFUS improves tremor-related symptoms, quality of life, and functional outcomes, but it was not clear how these outcomes compare to other treatments.

For PD, the single comparative study found insufficient evidence to make any conclusions regarding the use of MRgFUS when the VIM and/or PTT were targets. There were no direct head-to-head comparisons of MRgFUS targeting the subthalamus nuclear versus the globus pallidus internus for PD. However, systematic reviews of single group and comparative data indicate improved tremor-related outcomes but with mixed results when compared to other treatments for effects on quality of life and adverse events.

For other movement disorders—mainly dystonic conditions—single group studies showed improvements in several outcomes of interest, but there was insufficient evidence to make any conclusions about use of MRgFUS in patients with dystonia conditions. Systematic reviews of single group and comparative data indicate improved tremor-related outcomes in those with mixed conditions, but no differences were seen when compared to other treatments. MRgFUS was favored over other treatments for quality of life, but adverse event outcomes were mixed.

Future NRCS should adjust for baseline patient characteristics such as skull density ratios and tremor laterality and distribution. Adverse events have been reported in the larger literature of single group studies of MRgFUS and those of MRgFUS compared to sham. Evidence on adverse events from the comparative studies for the specific diseases discussed was insufficient to draw definitive conclusions. There is a need for well-designed RCTs that compare MRgFUS to other treatments and to understand the effect of different anatomical targets as well as longer-term outcomes of unilateral and bilateral procedures. As MRgFUS establishes itself in the treatment of movement disorders, these suggestions may allow for more robust studies to better guide patient care and improve outcomes.