# RESULTS

## LITERATURE FLOW DIAGRAM

The literature flow diagram summarizes the results of the study selection process. A full list of excluded studies is provided in the Supplementary Materials.

Notes. ^a^ References of identified systematic reviews were searched for potential additional primary studies, and we provide a narrative synthesis of the systematic reviews.

Literature flow diagram summarizing results of study selection process.

## OVERVIEW OF INCLUDED STUDIES

Of 3,856 records screened, 422 records underwent full text screening. Of these, 385 were excluded for not being a design of interest per KQ1 (N = 229), being a duplicate (N = 77), having no comparator of interest (for KQ1) (N = 28), sample size requirements not met or unclear (N = 15), not reporting results by condition (N = 10), not reporting outcomes of interest (N = 9), having no extractable data or results (N = 8), not including a treatment of interest (N = 7), and not being able to retrieve full text (N = 3). Upon reviewing the full text of records, 14 primary studies were eligible and included for KQ1 and/or KQ2. Additionally, we identified 22 systematic review or meta-analysis that were related to our KQs and we summarized the evidence from these reviews.

The 14 primary studies were conducted between 1995 to 2024 and included 497 patients. Nine studies focused on patients with ET, 1 study focused on patients with PD, and 4 studies focused on patients with dystonia conditions. Four studies used a crossover NRCS design (eg, patients received a preplanned first treatment and were assessed, then received a second preplanned treatment and were assessed), 6 NRCS compared 2 or more groups of patients, and 4 studies used a single group design. In 9 studies, mean age ranged from 43.2 to 74.7 years, 1 study reported a median age of 56 years, and 4 studies did not report extractable data on patient age. Males represented 53.0 to 87.0% of patients in 10 studies (4 studies did not report sex), and no studies reported patient race/ethnicity data. In 6 studies, the mean skull density ratio (which can impact energy transmission and focusing of the ultrasound wave^42^) ranged from approximately 0.37 to 0.58, 1 study reported a median skull density ratio of 0.50, and 7 studies did not report skull density ratio. Mean disease duration ranged from 9.8 to 38 years in 5 studies, and 1 study reported a median of 35 years. Three studies reported the mean number of sonications ranging from 7.1 to11, and 2 studies listed median sonications of 5.5 and 10. Six studies reported maximum temperature ranging from 50 to 62 degrees Celsius. Across all studies, 12 specified the use of MRgFUS and 2 indicated FUS without specifying MRI guidance. Table 2 provides select study details by condition of interest. Full details of the baseline characteristics, design details, and procedure characteristics for the studies can be found in the Supplementary Materials.

Table 2 Select Primary Study Details

Domain | Study Details | ET (N=9) | PD (N=1) | Other Conditions (N=4)
| Patients, N (Range) | 407 (10–98) | 40 (NA) | 50 (6–24)
Study design | Crossover NRCS | 4 | 0 | 0
Study design | NRCS | 5 | 1 | 0
Study design | Single group | 0 | 0 | 4
Comparator | Unilateral vs bilateral | 3 | 0 | 0
Comparator | Left vs right side | 1 | 0 | 0
Comparator | Target location vs target location | 2 | 1 | 0
Comparator | MRgFUS vs other treatment | 3 | 0 | 0
Comparator | None | 0 | 0 | 4
Outcomes | Tremor related | 7 | 3 | 2
Outcomes | Quality of life | 3 | 0 | 1
Outcomes | Function | 2 | 0 | 1
Outcomes | Adverse events | 4 | 0 | 3
Outcomes | Other | 3 | 1 | 2

Abbreviations. ET=essential tremor; MRgFUS=magnetic resonance-guided focused ultrasound; NRCS=nonrandomized comparative study; PD=Parkinson’s disease.

We identified 22 systematic reviews or meta-analyses published between 2017 and 2024 (see Supplementary Materials). These 22 systematic reviews or meta-analyses included 491 individual studies, with significant overlap in the studies included. Seven reviews focused exclusively on ET, 7 focused exclusively on PD, and 8 included multiple conditions (eg, PD, ET, MS, dystonia, rubral tremor). Importantly, most of the systematic reviews included single group studies, and most relied on indirect comparisons of MRgFUS to other treatments. These reviews reported on tremor-related outcomes (N = 19), quality of life (N = 10), function (N = 4), adverse events (N = 14), or other outcomes (N = 9). Of note, CRST Part C scores were used to assess both function and quality of life across these reviews. Only 2 systematic reviews used GRADE methodology to synthesize the evidence.43, 44

## ESSENTIAL TREMOR

### Comparative of Effects of MRgFUS for ET from Primary Studies

Nine studies (4 crossover NRCS and 5 NRCS) reported results for 407 patients with ET (see Supplementary Materials). The studies were conducted the US (N = 4), Canada (N = 3), Korea (N = 1) and the UK (N = 1) between 1995 and 2022. Three crossover studies compared unilateral to bilateral MRgFUS treatment, 3 NRCS compared MRgFUS to other treatments, 2 NRCS (1 NRCS and 1 crossover NRCS) compared target locations (eg, ventral intermedius [VIM] versus posterior subthalamic area [PSA]), and 1 NRCS compared side of treatment (ie, left versus right).

Four studies (all crossover NRCS) had no concerns (therefore, low risk of bias). The other 5 NRCS had high risk of bias due to use of crude analyses (N = 5), lack of or unclear blinding of the assessor (N = 4), concerns about comparator representativeness (N = 3), unclear representativeness of the cohort (N = 2), and concerns about adequacy of description of the intervention, lack of clear eligibility criteria, and lack of clear reporting (N = 1).

#### Comparative Effectiveness of Unilateral versus Bilateral

Three studies compared unilateral to bilateral MRgFUS treatment. In summary (Table 3), bilateral treatment compared to unilateral treatment was associated with improved tremor-related outcomes (moderate confidence), and there were no differences in functional outcomes between unilateral and bilateral treatments (low confidence). There were no conclusions for quality of life, adverse events, and other outcomes (insufficient evidence).

##### Tremor-Related Outcomes

Three crossover NRCS reported tremor-related outcomes for patients receiving unilateral then bilateral treatment. One study examined tremor-related outcomes post-first side treatment and post-second side treatment of MRgFUS in 10 patients.^45^ In this study, the first side (unilateral) was performed at 7 to 56 months before the second (bilateral) (median of 9 months). The study reported significant improvements in CRST A+B after treatment to the second side compared to first side (MD = −17.2, p < 0.001). There was also an improvement in CRST C (functional disability) scores at 3 months post-treatment on the second side compared to post (unclear time point) first side treatment (MD = −4.2, 95% CI [−6.8, −1.6], p = 0.005).

Another crossover NRCS included 51 patients who received MRgFUS on 1 side and then a second side.^46^ Mean time between treatments was 2.2 (standard deviation [SD] = 1.6) years. Tremor (CRST parts A and B tremor / motor function score) improved at 3 months and 12 months post-treatment on the second side compared to post-treatment (unclear time point) on the first side (3-month MD = −11.00, 95% CI [−12.47, −9.53], p < 0.001 and 12-month MD = −10.40, 95% CI [−11.91, −8.90], p < 0.001). Similarly, for CRST parts A (upper extremity posture tremor score), tremor improved at 3 months (MD = −1.90, 95% CI [−2.13, −1.67)], p < 0.001) and 12 months (MD = −1.90, 95% CI [−2.12, −1.68], p < 0.001) post-treatment on the second side compared to post-treatment on the first side. The same study reported that head tremor scores improved at 3 months (MD = −0.70, 95% CI [−0.95, −0.45]) and 12 months (MD= −0.90, 95% CI [−1.07, −0.73]) post-treatment on the second side compared to post-treatment on the first side. The study reported an improvement in CRST part C scores (functional disability) at 3 months (MD = −8.1, 95% CI [−9.22, 6.98], p < 0.001) and 12 months (MD = −7.9, 95% CI [−9.02, −6.78], p < 0.001) post-second side treatment compared to post-treatment on the first side. Finally, the study reported that head tremor scores improved at 3 months (MD = −0.70, 95% CI [−0.95, −0.45]) and 12 months (MD = −0.90, 95% CI [−1.07, −0.73]) post-treatment on the second side compared to post-treatment on the first side.

A third study reported on 16 patients who received MRgFUS on 1 side and then a second side. Bilateral treatment was performed within 1 year of the first side (unilateral). The study found that CRST scores improved after each treatment in the targeted hand (p < 0.001), while the untargeted tremor had not significantly changed.^47^

##### Quality of Life Outcomes

One crossover NRCS examined quality of life outcomes post-first side treatment and post-second side treatment of MRgFUS in 10 patients.^45^ Quality of Life in Essential Tremor Questionnaire (QUEST) scores declined (ie, an improvement) at 3 months post-treatment on the second side compared to post-treatment (unclear time point) on the first side treatment (MD = −19.7, 95% CI [−31.4, −8.0], p = 0.004). Similarly, EQ-5D-5L VAS improved at 3 months post-second side treatment compared to post-first side treatment (MD = 6.9, 95% CI [1.8, 11.6], p = 0.013).

##### Functional Outcomes

Two crossover NRCS comparing unilateral to bilateral treatment reported on functional outcomes. One study compared function post-first side treatment and post-second side treatment of MRgFUS in 10 patients.^45^ This study reported no significant difference in blinded evaluators’ assessment of patients’ ability to walk based on a repeated measures ANOVA from baseline (post-first procedure), and 2 hours, 1 month, and 3 months post-second procedure (F_3,27_ = 1.777, p = 0.176). Similarly, the authors found no significant differences in patients’ self-reported ability to walk (F_1.349,12.145_ = 0.199, p = 0.735) or speak (F_3,27_ = 1.855, p = 0.161) across these same time periods. The study reported a significant increase in missteps in a 6-m tandem walk across these same time periods (F_3,27_ = 0.629, p < 0.0005), and significant improvements in blinded evaluators’ assessment of speech using the NRS-11 (F_3,27_ = 7.364, p = 0.001). There were significant reductions in gait after treatment on the second side versus post-treatment on the first side impairment (RR = 0.25, 95% CI [0.07, 0.90]).

Another study of 16 patients who received MRgFUS on 1 side and then a second side reported no significant differences in processing speech (p = 0.271), attention/working memory (p = 0.250), executive function (p = 0.896), language (p = 0.991), verbal memory (p = 0.803), or visuospatial perception (p = 0.614) between treatment of the second side versus first side.^47^

##### Adverse Events

One crossover NRCS reported adverse events post-first side treatment and post-second side treatment of MRgFUS in 10 patients.^45^ There were significant reductions in dysesthesia after treatment on the second side versus post-treatment on the first side (RD = 0.30, 95% CI [0.02, 0.58]). There were no significant differences in any other reported adverse events.

##### Other Outcomes

One crossover study of 10 patients reported that 100% of patients indicated they would receive a second side treatment again by answering “given what I know now, I would do the second side again.”^45^

Table 3 Summary of Findings for Essential Tremor: Comparative Effectiveness of Unilateral versus Bilateral

Result | Studies (N); Design | Methodological Limitations | Indirectness | Imprecision | Inconsistency | Other Issues | Summary | Overall Confidence
Tremor-related outcomes | 3 (77); Crossover NRCS | Low | Direct | Imprecise^a^ | Consistent | N/A | All 3 studies reported significant improvements for bilateral vs unilateral | Moderate
Quality of life outcomes | 1 (10); Crossover NRCS | Low | Direct | Imprecise^b^ | N/A^c^ | Single study | Significant improvement for bilateral vs unilateral | Insufficient
Functional outcomes | 2 (26); Crossover NRCS | Low | Direct | Imprecise^a^ | Inconsistent^d^ | N/A | Overall, no clear difference in outcomes | Low
Adverse events | 1 (10); Crossover NRCS | Low | Direct | Imprecise^b^ | N/A^c^ | Single study | Significant reduction in dysesthesia after bilateral vs after unilateral | Insufficient
Other outcomes | 1 (10); Crossover NRCS | Low | Direct | Imprecise^b^ | N/A^c^ | Single study | All patients would have second side treatment again | Insufficient

Notes.

a Two of the studies had N < 20;

b Study only included 10 patients;

c Single study;

d One study reported mixed results and the other reported no difference.

Abbreviations. N/A=not applicable; NRCS=nonrandomized comparative study.

#### Comparative Effectiveness of Treatment Sides

Only 1 NRCS compared outcomes by treatment side. This study of 98 patients reported no significant difference in the proportion of patients who had ≥30% improvement in ipsilateral sub-score between those who received MRgFUS on the left side versus MRgFUS on the right side (RR = 1.26, 95% CI [0.33, 4.75]).^48^ Evidence was insufficient to make any conclusions (Table 4). No other outcomes were reported for this study.

Table 4 Summary of Findings for Essential Tremor: Comparative Effectiveness of Side

Result | Studies (N); Design | Methodological Limitations | Indirectness | Imprecision | Inconsistency | Other Issues | Summary | Overall Confidence
Tremor-related outcomes | N/A | N/A | N/A | N/A | N/A | N/A | N/A | N/A
Quality of life outcomes | N/A | N/A | N/A | N/A | N/A | N/A | N/A | N/A
Functional outcomes | N/A | N/A | N/A | N/A | N/A | N/A | N/A | N/A
Adverse events | N/A | N/A | N/A | N/A | N/A | N/A | N/A | N/A
Other outcomes | 1 (100); NRCS | High^a^ | Direct | Precise | N/A | Single study | No difference in ipsilateral sub score between left vs right side | Insufficient

Notes.

a High risk of bias due to lack of blinding of assessor, unclear representativeness of cohort and comparison group, and lack of adjustment for confounders.

Abbreviations. N/A=not applicable; NRCS=nonrandomized comparative study.

#### Comparative Effectiveness of Target Locations

Two NRCS compared target locations for MRgFUS in ET. In summary (Table 5), there was greater improvement in tremor-related outcomes for MRgFUS targeting the PSA or targets with PSA compared to VIM (low confidence). The studies provide insufficient evidence differences in adverse events between target locations (no conclusion). No other outcomes were reported for this comparison.

##### Tremor-Related Outcomes

Two NRCS compared MRgFUS for ET targeting 2 separate locations in the brain. One study compared 10 patients who received treatment targeted 1.2–1.5 mm superior to the AC-PC plane with FUS lesion extension into PSA (Group 1) to 10 other patients whose treatment targeted the standard 2.0 mm superior to AC–PC without FUS lesion extension into the PSA (Group 2).^49^ This study reported significantly greater improvement in Tremor Research Group Essential Tremor Rating Scale (TETRAS) postural tremor (NMD = −1.20, 95% CI [−1.71, −0.69]), kinetic tremor (NMD = −1.05, 95% CI [−1.57, −0.53]), and Archimedes spiral scores (NMD = −1.00, 95% CI [−1.58, −0.42]) for those who received treatment with extension in the PSA (Group 1) compared to those who did not (Group 2).

A second study was a crossover NRCS that compared tremor outcomes of 13 patients who received MRgFUS treatment at the VIM/ventral oralis posterior (VOP) to treatment in the PSA.^50^ The study reported a 30.1% improvement in BFS score from post anterior-VIM/VOP to post-PSA ablation (p < 0.001).

##### Adverse Event Outcomes

One NRCS compared 10 individuals who received treatment with lesion extension into PSA (Group 1) to 10 other individuals who received treatment without FUS lesion extension into the PSA (Group 2). The study reported no significant differences between groups in transient imbalance (RR = 2.00, 95% CI [0.64, 6.25]) or numbers at 3 weeks post-treatment (RD = −0.10, 95% CI [−0.29, 0.09]).^49^

No other outcomes were reported for studies comparing target locations.

Table 5 Summary of Findings for Essential Tremor: Comparative Effectiveness of Target Locations

Result | Studies (N); Design | Methodological Limitations | Indirectness | Imprecision | Inconsistency | Other Issues | Summary | Overall Confidence
Tremor-related outcomes | 2 (23); 1 Crossover NRCS; 1 NRCS | Moderate^a^ | Direct | Imprecise^b^ | Consistent | N/A | PSA targets or targets with PSA had greater improvement compared to VIM alone | Low
Quality of life outcomes | N/A | N/A | N/A | N/A | N/A | N/A | N/A | N/A
Functional outcomes | N/A | N/A | N/A | N/A | N/A | N/A | N/A | N/A
Adverse events | 1 (10); NRCS | High | Direct | Imprecise^c^ | N/A^d^ | Single study | No difference in transient imbalance or numbness between targets | Insufficient
Other outcomes | N/A | N/A | N/A | N/A | N/A | N/A | N/A | N/A

Notes.

a One was rated as low and the other was rated as high;

b Two of the studies had N < 20;

c Study only included 10 patients;

d Single study.

Abbreviations. N/A=not applicable; NRCS=nonrandomized comparative study.

#### Comparative Effectiveness of Treatments

Three NRCS reported outcomes comparing MRgFUS to other treatments for people with ET. In summary (Table 6), tremor-related outcomes and quality of life improved for patients who received bilateral DBS compared to unilateral MRgFUS, but confidence was low given baseline differences between groups. No conclusions were made for adverse events of other outcomes for studies that compared treatments (insufficient evidence), and no studies reported on functional outcomes.

##### Tremor-Related Outcomes

Two NRCS reported tremor-related outcomes for patients who received MRgFUS versus DBS. One study compared unilateral MRgFUS to bilateral DBS in 55 patients.^51^ This study reported significantly better total CRST scores in the DBS group compared to MRgFUS after surgery (timeframe not specified; p < 0.01), and larger improvement in scores for those in the DBS group compared to the MRgFUS group (NMD = 20.3, p NR). Importantly, baseline scores were better for those in the MRgFUS group. Significantly better total CRST scores were reported post-treatment for the DBS group compared to the MRgFUS group (p < 0.01), and larger improvements were reported for the DBS group when comparing follow-up scores to baseline (NMD = 12.05, p NR). Again, baseline scores were better in the MRgFUS group. CRST part B scores were significantly better after surgery (timeframe not specified) in the DBS group compared to the MRgFUS group (p < 0.01). This study also reported no significant differences between CRST C disabilities subscore after treatments (MD = 0.8, p = 0.34). Baseline scores for subscales were not reported. No differences were reported in hand tremor scores between unilateral FUS treatment (5.5 [treated hand score]) and bilateral DBS (4.6 and 3.9, p = 0.26 and 0.45).

A second NRCS compared unilateral MRgFUS to unilateral and bilateral DBS in 85 individuals with ET.^52^ This study reported significant improvements on total CRST scores from baseline to follow-up for all treatments (p < 0.005 for all, mean follow-up = 13.1, 8.6, and 11.8 months for bilateral DBS, unilateral DBS, and FUS, respectively). Changes were greater in the unilateral DBS (NMD = 6.5, p NR) and bilateral DBS (NMD = 14, p NR) compared to MRgFUS. Baseline scores were lower (better) for the MRgFUS group compared to people receiving other treatments. This study also reported significant improvements from baseline to post-treatment in CRST observed tremor scores for all treatments (p < 0.005 for all). Changes were greater in the unilateral DBS (NMD = 6, p NR) and bilateral DBS (NMD = 13.6, p NR) compared to MRgFUS. Baseline scores were lower (better) at baseline in the MRgFUS group compared to the other treatments. For CRST task scores, this study reported significant improvements from baseline to post-treatment for all treatments (p < 0.005 for all). Changes were greater in the unilateral DBS (NMD = 0.4, p NR) and bilateral DBS (NMD = 4.4, p NR) compared to MRgFUS. Baseline scores were lower (better) at baseline in the MRgFUS group compared to the bilateral DBS group.

There was no significant difference in change from baseline to follow-up for CRST axial score in the MRgFUS group (mean follow-up 11.8 months). There were significant improvements in CRST axial score from baseline to post-treatment for both unilateral and bilateral DBS (p < 0.005 for both, mean follow-up = 13.1 months for bilateral and 8.6 months for unilateral DBS). Changes were greater in the unilateral DBS (NMD = 2.9, p NR) and bilateral DBS (NMD= 5.5, p NR). Baseline scores were lower (better) at baseline in the MRgFUS group compared to the other treatments.

This study reported significant improvements in CRST disability scale scores from baseline to follow-up for all treatment groups (p < 0.05 for all, mean follow-up = 13.1, 8.6, and 11.8 months for bilateral DBS, unilateral DBS, and FUS, respectively. Changes were slightly greater in the unilateral DBS (NMD = 0.3, p NR) and bilateral DBS (NMD = 2.2, p NR) compared to MRgFUS.

For CRST scores in the treated hand, the study also reported significant improvements from baseline to post-treatment for all treatments (p < 0.005 for all). Changes were greater in the MRgFUS group compared to unilateral DBS (NMD = −1.8, p NR) but just slightly better in the bilateral DBS compared to MRgFUS (NMD = 0.5, p NR). Scores were lower (better) at baseline in the MRgFUS group compared to the other treatments. For the untreated hand, improvements from baseline to follow-up were only seen in the bilateral DBS group (p < 0.05). Changes were greater in the unilateral DBS (NMD = 9.5, p NR) and bilateral DBS (NMD = 21.1, p NR). Baseline scores were lower (better) at baseline in the MRgFUS group compared to the other treatments.

##### Quality of Life Outcomes

Two NRCS reported quality of life outcomes. One NRCS compared unilateral MRgFUS to bilateral DBS in 55 patients.^51^ This study reported improvements in QUEST scores from baseline to post-treatment for both groups (p NR). The change was greater in the bilateral DBS group compared to MRgFUS group (NMD = 13.5, p NR). Importantly, baseline scores were lower (better) for patients in the MRgFUS group.

A second NRCS compared unilateral MRgFUS to unilateral and bilateral DBS in 85 individuals with ET,^52^ but only reported quality of life scores for the MRgFUS versus bilateral DBS. This study reported significant improvements in total QUEST scores from baseline to follow-up for both groups (p < 0.05 for both, mean follow-up = 13.1 for bilateral DBS and for FUS). The change was greater in the bilateral DBS group compared to the MRgFUS group (NMD = 10.6, p NR), but scores were lower (better) at baseline for the MRgFUS group. Similar results were seen for QUEST work, hobbies, and physical and social subscales. There was no significant difference on communication subscales from baseline and follow-up for the MRgFUS group.

##### Functional Outcomes

No studies reported on functional outcomes.

##### Adverse Event Outcomes

One NRCS compared unilateral MRgFUS to unilateral and bilateral DBS in 85 individuals with ET.^52^ A significantly greater proportion of patients experienced paresthesia at 3 months post-treatment in the unilateral MRgFUS versus unilateral DBS group (RR = 12.53, 95% CI [1.75, 89.56]) or bilateral DBS group (RR = 26.73, 95% CI [6.36, 112.26]). At 12 months post-treatment, there was only a significant difference in the proportion of patients who experienced paresthesia between the MRgFUS versus bilateral DBS (RR = 11.36, 95% CI [1.39, 92.64]).

There were no significant differences in the proportion of patients with dysarthria at 3 months between groups, but there were significantly more cases of dysarthria in the bilateral DBS group compared to the MRgFUS group (RD = −0.11, 95% CI [−0.18, −0.03]) at 12 months post-procedure.

At 3 months follow-up, the proportion of people with gait instability was higher among those who received unilateral DBS compared to unilateral MRgFUS (RR = 0.39, 95% CI [0.17, 0.90]) but not at 12 months. No significant differences were seen between bilateral DBS and unilateral MRgFUS.

There were significantly higher proportions of headache (RD = 0.60, 95% CI [0.35, 0.85]), lightheaded/dizziness (RD = 0.73, 95% CI [0.51, 0.96]), and nausea/vomiting (RD = 0.53, 95% CI [0.28, 0.79]) in the MRgFUS group compared to unilateral DBS at 3 months follow-up, but no significant difference by 12 months follow-up.

Similarly, there were significantly higher proportions of headache (RD = 0.60, 95% CI [0.35, 0.85]) lightheaded/dizziness (RD = 0.73, 95% CI [0.51, 0.96]) and nausea/vomiting (RD = 0.53, 95% CI [0.28, 0.79]) in the MRgFUS group compared to bilateral DBS at the 3 month follow-up, but no significant difference by 12 months follow-up.

There were no significant differences in hemorrhage, flushed warmth, mental health status, weakness, dysphagia, or hardware-related MRI burn, lead erosion, or infection between any groups at any time point.

One NRCS compared unilateral MRgFUS to unilateral DBS and unilateral radiofrequency (RF) in 59 individuals with ET.^53^ A significantly larger proportion of people in the RF group compared to the MRgFUS group had an adverse event (defined as intracerebral hemorrhage near the lesion, cognitive deterioration, mild dysarthria, impaired eye movement, mild facial paresis, hypesthesia, loss of taste, balance problems, or muscle twitching) at 1 month follow-up (RR = 0.22, 95% CI [0.07, 0.68]). There were no significant differences in adverse events at 12 months. No significant difference was reported between unilateral DBS and MRgFUS groups. Further, no significant differences were reported between groups for any individual adverse event examined.

##### Other Outcomes

One NRCS compared unilateral MRgFUS to unilateral DBS and unilateral RF in 59 individuals with ET.^53^ No differences were reported between groups at 1 month or 12 months follow-up in the proportion of people with successful treatment or complete remission.

Table 6 Summary of Findings for Essential Tremor: Comparative Effectiveness of Treatments

Result | Studies (N); Design | Methodological Limitations | Indirectness | Imprecision | Inconsistency | Other Issues | Summary | Overall Confidence
Tremor-related outcomes | 2 (140); NRCS | High^a^ | Direct | Precise | Consistent | N/A | Bilateral DBS had better improvement compared to Unilateral MRgFUS | Low
Quality of life outcomes | 2 (140); NRCS | High^a^ | Direct | Precise | Consistent | N/A | Bilateral DBS had better improvement compared to Unilateral MRgFUS | Low
Functional outcomes | N/A | N/A | N/A | N/A | N/A | N/A | N/A | N/A
Adverse events | 2 (144); NRCS | High^a^ | Direct | Imprecise^b^ | Consistent^c^ | N/A | Greater AEs in MRgFUS group within 3 months of procedure, but generally no difference by 12 months post-procedure | Insufficient
Other outcomes | 1 (59); NRCS | High | Direct | Precise | N/A^d^ | Single study | Greater remission in Unilateral RF at 0-3m but no difference by 12 months | Insufficient

Notes.

a Both rated as high;

b Confidence intervals for several measures were wide;

c Measures varied across studies and were not consistent;

d Single study.

Abbreviations. N/A=not applicable; NRCS=nonrandomized comparative study.

### Results from Systematic Reviews for ET

Seven systematic reviews examined MRgFUS for ET. Overall, MRgFUS for ET may improve tremor-related symptoms, quality of life outcomes, and functional outcomes, but comparative effectiveness results were mixed, particularly when compared to DBS. Adverse event outcomes also showed mixed results. However, cost outcomes favored MRgFUS over DBS and RF.

#### Pre-Post

Four systematic reviews reported change in outcomes from before to after MRgFUS.^30,^ ^43,^ ^54,^ ^55^ All 4 systematic reviews concluded that there were improvements in tremor-related outcomes and quality of life (1 review using GRADE methodology concluded low certainty of evidence for tremor severity and very low certainty of evidence for recurrence).^43^ One of the 4 reviews also reported an improvement in function from before to after treatment.^43^

Another systematic review reported that a significant proportion of patients pooled across 9 individual studies experienced adverse events including in-procedure dizziness (pooled estimate = 43.4%), nausea/vomiting (pooled estimate = 26.8%). In addition, a significant proportion of patients across 9 studies experienced paresthesia or ataxia at 0 to 3 months (pooled estimates = 25.1% and 32.8%, respectively) or 12 months after treatment (pooled estimates = 15.3% and 10.5%, respectively).^55^

#### MRgFUS versus Deep Brain Stimulation

Four systematic reviews compared MRgFUS to DBS with mixed findings.^35,^ ^43,^ ^44,^ ^56^ One systematic review of 9 studies reported no difference in tremor outcomes between MRgFUS and DBS (GRADE: very low)^43^ Another systematic review of 45 studies reported worse tremor-related outcomes for MRgFUS compared to DBS (pooled average % improvement tremor severity, DBS = 60.1% [SD = 9.7] vs FUS = 55.6% [SD = 8.2], p NR).^35^ The same review reported significantly better outcomes for bilateral DBS compared to those receiving unilateral MRgFUS (pooled average % improvement tremor severity, bilateral DBS = 60.2% [SD = 5.2] vs FUS = 55.6% [SD = 8.2], p < 0.001). There was no significant difference in tremor-related outcomes for MRgFUS compared to unilateral DBS (pooled average % improvement tremor severity, unilateral DBS = 56.4% [SD = 9.7] vs FUS = 55.6% [SD = 8.2], p = 0.198).^35^ One systematic review of 46 articles narratively reported mixed results for tremor-related outcomes.^56^ Another systematic review of 32 studies reported significantly better tremor outcomes for those receiving MRgFUS versus DBS (p < 0.001).^57^

Two systematic reviews reported quality of life outcomes. One systematic review of 9 studies found better quality of life for MRgFUS compared to DBS (GRADE: very low), and the other systematic review of 45 studies found significantly better quality of life in the FUS group (percent improvement = 61.9% [SD = 7.9]) compared to the DBS group (52.5% [SD= 16.2], p < 0.001).^35^

One systematic review reported no difference in function or complications between MRgFUS and DBS (GRADE: very low for both).^43^ One review of 45 studies reported that a significantly higher proportion of patients experienced gait disturbances and/or muscle problems, paresthesia, and nausea for patients with ET after MRgFUS compared to any DBS (p < 0.001 for all). The same review reported significantly higher gait disturbances/muscle problems for patients who received MRgFUS compared to only those receiving unilateral DBS (p = 0.003). Those receiving any DBS (unilateral or bilateral) had a significantly higher prevalence of speech disturbances and local adverse symptoms (p < 0.001 for both). No deaths were reported in the MRgFUS group, while 1 surgery-related death was reported in the DBS group. There were more persistent complications in the MRgFUS group than in the DBS cohort (with persistent defined as present at the latest follow-up, with average follow-up of 16.6 [SD = 16.4] in the DBS group and 14.4 [SD = 7.3] in the MRgFUS group).^35^

Two systematic reviews reported lower costs for FUS compared to DBS.^43,^ ^57^ One reported that MRgFUS neurosurgery has a mean cost of $23,507 and a mean quality-adjusted survival of 3.69 quality-adjusted life-years, while the DBS group had mean costs and quality-adjusted life-years of $57,535 and 3.94 (HQO). The other review estimated a mean cost of treatment to be lower with MRgFUS ($20,593 [SD = $1,402]) versus DBS without staging ($27, 906 [SD = $524], p NR) or DBS with staging ($45,107 [SD = $614], p NR) (overall DBS vs MRgFUS p < 0.001).^57^

#### MRgFUS versus Other Treatments

One systematic review of 9 studies compared MRgFUS to RF. The review reported no difference in tremor-related outcomes between RF and MRgFUS (GRADE: very low). The same review reported lower total mean costs for patients who received MRgFUS compared to RF, and higher complications for RF compared to MRgFUS (GRADE: very low for both).^43^

One systematic review reported significantly better quality of life for FUS compared to SRS for quality of life effect and duration of effect (p < 0.001), but no significant difference in cost outcomes (p = 0.654).^57^ One systematic review compared FUS to “other” treatments and narratively reported favorable results for those treated with FUS.^43^

One systematic review reported improved CRST Part C scores and quality of life for patients who received MRgFUS compared to sham based on 1 RCT (GRADE: high for both).^43^

## PARKINSONS DISEASE

### Comparative of Effects of MRgFUS for PD from Primary Studies

One NRCS compared MRgFUS targeted at either the VIM or the pallidothalamic tract (PTT) in people with Parkinson’s disease (see Supplementary Materials).^58^ The 40-person study was conducted between 2020–2022 in Russia. Median follow-up time was 109.0 (inner quartile range [IQR] = 53, 231) days, with a maximum of 625 days. The full study included patients whose treatments were either telemedicine-proctored treatment (N = 27) or whose treatments were conducted independently without proctor supervision (N = 40). However, the study only reported results by target for those whose treatments were conducted independently; therefore, only these patients were included in this review. The median age of all participants in the independently treated group was 63.0 (IQR = 58.5, 69.5) years and 72.5% were male. The median skull density ratio for the independently treated group was 0.5 (IQR = 0.4, 0.6) and the median disease duration was 6.0 years (IQR = 5.0, 11.2). Patient characteristics were not reported by treatment target group. Importantly, 30 patients received treatment in the VIM nucleus target, and 25 of these patients received treatment in the PTT target, but 15 of the patients in the PTT group received treatment in both targets. Overall, patients received approximately 6.0 sonications (median; IQR = 5.0, 9.0).

The study was high risk of bias due to concerns about comparator representativeness, use of crude analyses, and lack of clarity for blinding of an outcome assessor and representativeness of the cohort (see Supplementary Materials).

The study only reported 1 outcome (recurrence of tremor) for the comparison of anatomical targets. Specifically, a smaller proportion of patients had recurrence of tremor 1 year after treatment for the PTT target group compared to the VIM target group (12% vs 22%, p NR). No other outcomes were reported for the comparison of anatomical targets in this group. We conclude that there was insufficient evidence to make conclusions about the effect of MRgFUS targeted at VIM or PTT in patients with Parkinson’s disease (Table 7).

Table 7 Summary of Findings for Parkinson’s Disease^a^

Result | Studies (N); Design | Methodological Limitations | Indirectness | Imprecision | Inconsistency | Other Issues | Summary | Overall Confidence
Tremor-related outcomes | N/A | N/A | N/A | N/A | N/A | N/A | N/A | N/A
Quality of life outcomes | N/A | N/A | N/A | N/A | N/A | N/A | N/A | N/A
Functional outcomes | N/A | N/A | N/A | N/A | N/A | N/A | N/A | N/A
Adverse events | N/A | N/A | N/A | N/A | N/A | N/A | N/A | N/A
Recurrence of tremor | 1 (40); NRCS | High^b^ | Direct | N/A^c^ | N/A^c^ | N/A | No conclusion | Insufficient

Notes.

a Comparing target location;

b Rated as high risk of bias due to unclear blinding of assessor, unclear representativeness of cohort, and concerns about comparator and use of crude analyses;

c Single study.

Abbreviations. N/A=not applicable; NRCS=nonrandomized comparative study.

### Results from Systematic Reviews for PD

Seven systematic reviews focused on PD patients treated with MRgFUS. Four reviews reported changes in outcomes from before FUS to after FUS. Two reviews looked at FUS more generally, while the rest focused specifically on MRgFUS. Three systematic reviews reported on tremor-related outcomes.

Overall, for tremor-related outcomes for PD, MRgFUS appeared to show benefit from before to after treatment. However, results were mixed when compared to RF of DBS. Results were mixed for quality of life, but 1 review showed improvement in function compared to sham. Results for adverse events compared with sham, RF, or no comparator were mixed.

#### Pre-Post

One systematic review of 5 studies reported significant improvements in tremor-related outcomes using the Unified Parkinson’s Disease Rating Scale (UPDRS)-II, III, IV, and Unified Dyskinesia Rating Scale (UDysRS) after FUS compared to before (pooled p < 0.001 for all).^59^ Another systematic review of 11 studies narratively reported favorable outcomes after FUS compared to before using the UPDRS-III.^60^ Another systematic review that included 20 studies reported favorable results or no difference in tremor outcomes (UPDRS-III) from before to after MRgFUS compared to baseline for those “on” medication (pooled standardized mean differences [SMDs] of 12.88 (95% CI [5.32, 20.44]) at 1 month and 20.65 (95% CI [12.15, 29.14]) at 1 year. Similar findings were reported when comparing people who received MRgFUS to those “off” medication (SMD = 11.45; 95% CI [−3.50, −26.40]) and SMD = 22.28 (95% CI [15.26, 29.30]) for those “off” medication).^61^

For adverse events, 1 systematic review of 5 studies reported a significant occurrence of dysarthria (p = 0.038) but no other significant adverse events after MRgFUS.^59^ Two other reviews provided information on adverse events from before to after, but no conclusions were made.^60,^ ^61^

One systematic review of 11 studies narratively reported favorable quality of life outcomes after compared to before MRgFUS.^60^ Of note, CRST Part C scores were included as part of the quality of life assessments in this review. Another review of 2 studies narratively reported that the only significant cognitive changes seen over time were visual memory and verbal fluency, but that otherwise there were minimal cognitive declines.^62^

A systematic review of 24 studies reported significant improvement in efficacy (defined as UPDRS III and UPDRS III items 20 and 21) after MRgFUS of the globus pallidus internus (GPi) (MD = 13.46, 95% CI [2.46, 25.10]).^37^

#### MRgFUS versus Other Treatments

A systematic review of 2 studies compared MRgFUS to sham and found significantly favorable tremor-related (pooled SMD = −1.20, 95% CI [−2.06, −0.34]) and functional outcomes (SMD = −0.86, 95% CI [−1.41, −0.32]), but no difference in quality of life (SMD = −0.43, 95% CI [−0.96, 0.10]) or “other” indications (pooled SMD NR). This same review reported that dizziness was significantly more common for people who received MRgFUS (OR = 4.68, 95% CI [1.20, 18.23]) but there were no other differences in adverse events.^63^

One systematic review included 40 studies (3 of these using FUS) to compare FUS with RF.^36^ This review reported a lower failure rate for RF compared to FUS (14% vs 24%, p NR), and no difference in post treatment UPDRS-III scores between RF and FUS (pooled MD = −1.1, 95% CI [−9.6, 7.4]). This same review reported mixed results for adverse events, with RF having significantly higher cognitive deficits (p = 0.004), but MRgFUS having significantly worse “other” adverse events (p < 0.001).

One systematic review of 24 studies generally found no significant difference in efficacy (defined as UPDRS III and UPDRS III items 20 and 21) between MRgFUS of the GPi or MRgFUS of the VIM to each other or DBS with various targets. However, significant differences were seen between DBS of the GPi compared to MRgFUS of the GPi (MD = −9.21, 95% CI [−16.44, −2.28]) or compared to MRgFUS of the VIM (MD = − 9.23, 95% CI [−18.19, −0.11]) for total UPDRS III scores who were “on medications.”^37^

## OTHER CONDITIONS

### Effects of MRgFUS for Dystonia Conditions from Primary Studies

Four single group studies reported results for 50 patients with dystonia conditions that were treated with MRgFUS. Conditions included dystonic tremor (N = 2), focal hand dystonia (FHD) (N = 1), and X-linked dystonia-parkinsonism (XDP) (N = 1) (see Supplementary Materials). The studies were conducted in Italy, Australia, Japan, and the Philippines between 2017 and 2024, and follow-up ranged from 12 to 36 months. The primary targets included the VIM (N = 2), ventro-oral (Vo) nucleus (N = 1), and the PTT (N = 1). Of note, 1 of the VIM studies noted that all patients received treatment in the VIM, but that some patients also received treatment at another target (PSA and/or ventro-oral anterior [VOA]). The mean number of sonications ranged from 7.1 to 11, and the average maximum temperature ranged from 56.6 to 60.3 degrees Celsius across the 4 studies.

In 2 studies, the average age of patients was 43.2 (SD = 9.8) and 70.9 (SD = 10.6), while the median age in a third study was 56 (IQR = 44, 66). In 3 studies, males comprised 62 to 90% of the study population, and none of the studies reported information on patient race/ethnicity. A fourth study did not report age of patients for those with XPD (Khu). In 2 studies, the mean skull density ratio of patients was 0.37 and 0.41, and a third study reported a median skull density ratio of 0.5. Mean disease duration was 9.8 and 20.5 years in 2 studies, and median disease duration was 35 years in a third study.

All studies were single group designs with no true comparator. Three were moderate risk of bias for having unclear or high risk of blinding of the outcome assessor, high risk of incomplete outcome data, or unclear representativeness of the cohort. The other study was low risk of bias (see Supplementary Materials).

In summary, there was insufficient evidence to make any conclusions about the use of MRgFUS in patients with dystonia conditions (Table 8).

#### Tremor-Related Outcomes

Three single group studies reported tremor-related outcomes. One single group study reported on patients with dystonic tremor who received MRgFUS targeted at the VIM, and potentially additional sonications in the PSA and/or VOA if tremor persisted after 3 treatments of the VIM. This study reported a significant reduction (improvement) in hand tremor score based on CRST Parts A & B at 1 month and 24 months compared to baseline (1-month aMD = −14.5, 95% CI [−17.7, −11.3], p < 0.001; 24-month aMD = −12.2, 95% CI [−15.6, −8.9], p < 0.001). The same study also reported a significant reduction (improvement) in total CRST scores at 1 month and 24 months compared to baseline (1-month aMD = −31.4, 95% CI [−38.1, −24.8], p < 0.001; 24-month aMD = −24.8, 95% CI [−32.5, −17.1]; p < 0.001).^64^

One single group study of patients with focal hand dystonia who received MRgFUS targeted at the Vo nucleus reported a significant decrease (improvement) in Writer’s Cramp Rating Scale at 12 months compared to baseline (MD = −4.3, 95% CI [−7.17, −1.43], p = 0.011). The same study also reported a significant increase (improvement) in Tubiana Musician’s Dystonia Scale scores at 1 month and 12 months follow-up compared to baseline (1-month MD = 3.4, 95% CI [2.7, 4.1]; 12-months MD = 3.6, 95% CI [3.2, 4.0], p < 0.0001). There was also a significant increase (improvement) on the Arm Dystonia Disability Scale scores at 1 month and 12 months compared to baseline (1-month MD = 29.2, 95% CI [18.3, 40.1]; 12-months MD = 22.9, 95% CI [6.2, 39.6], p = 0.025).^65^

A third single group study of patients with X-linked dystonia-parkinsonism received MRgFUS targeted at the PTT and reported a 14.1% to 15.3% improvement in X-linked dystonia-parkinsonism Movement Disorder Society of the Philippines (XDP-MDSP) total scores from baseline to a mean follow-up of 19.1 months (p NR).^66^

#### Quality of Life Outcomes

One single group study reported quality of life outcomes for patients with dystonic tremor who received MRgFUS targeted at the VIM or potentially sonications in the PSA and/or VOA if tremor persisted after 3 treatments of the VIM. This study reported a significant decrease (improvement) in QUEST scores at 1 month and 24 months compared to baseline (1-month aMD = −39.3, 95% CI [53.4, −25.2], p < 0.001; 24-months aMD = −22.4, 95% CI [−40.3, −4.4], p < 0.05).^64^

#### Functional Outcomes

One single group study of patients with dystonic tremor reported functional outcomes related to MRgFUS targeted at the VIM. There were significant reductions (improvements) in activities of daily living (MD = −16.67, 95% CI [−21.71, −11.62], p < 0.001), total performance scores (MD = −6.33, 95% CI [−11.68, −0.99], p < 0.01), and performance scores on the treated side (MD = −7.67, 95% CI [−9.59, −5.74], p < 0.001) at 12 months compared to baseline, all assessed using the TETRAS. There was no significant difference in axial performance scores at 12 months compared to baseline (MD = −1.67, 95% CI [−4.13, 0.80], p NR).^67^

#### Adverse Events

Three single group studies reported on adverse events related to MRgFUS targeted at the VIM. One single group study of 10 patients with dystonic tremor reported 1 instance of imbalance and 1 instance of dysarthria during the first 12 months after treatment, but neither persisted after 12 months. The study reported no instances of limb ataxia, oral paresthesia, or hand paresthesia.^67^

Another single group study of 10 patients with focal hand dystonia who received MRgFUS targeted at the Vo nucleus reported several adverse events that resolved by 12 months. Reported adverse events including periorbital edema (1 patient) unsteady gait (2 patients), facial palsy (2 patients), occipital sensory loss (3 patients), and nausea (3 patients). Headache related to stereotactic frame occurred in all 10 patients, as well as headache related to sonication, but all were resolved by the 12 month follow-up point. Dysarthria occurred in 3 patients, with 1 of these cases persisting after 12 months. One suicide attempt was reported but was likely unrelated to treatment.^65^

One single group study of patients with X-linked dystonia-parkinsonism who received MRgFUS targeted at the PTT reported that 1 out of 6 patients reported right side weakness 3 months post-procedure.^66^ This study indicated that there were no interoperative adverse events in these patients.

#### Other Outcomes

One single group study of patients with focal hand dystonia who received MRgFUS targeted at the Vo nucleus reported that 4 of 5 patients who were unemployed at baseline had returned to work by 12 months. The same study reported that 3 of 10 patients had symptom recurrence at 3 months.^65^

Another single group study of patients with X-linked dystonia-parkinsonism reported at all 6 patients reported symptom improvement after receipt of MRgFUS targeted at the PTT.^66^

Table 8 Summary of Findings for Dystonia Conditions

Result | Studies (N); Design | Methodological Limitations | Indirectness | Imprecision | Inconsistency | Other Issues | Summary | Overall Confidence
Tremor-related outcomes | 3 (40); Single group | Moderate^a^ | Direct | Imprecise^b^ | Consistent | All single group | All 3 studies reported improvements (2 significant; significance could not be assessed in the third based on reported data) | Insufficient
Quality of life outcomes | 1 (24); Single group | Low | Direct | Imprecise^b^ | N/A^c^ | Single study | Significant decrease (improvement) in QUEST scores | Insufficient
Functional outcomes | 1 (10); Single group | Moderate | Direct | Imprecise^b^ | N/A^c^ | Single study | Significant improvement in 3/4 scale measures of function | Insufficient
Adverse events | 3 (26); Single group | Moderate^d^ | Direct | Imprecise^b^ | Consistent | All single group | Occur in approximately 10-30% of patients for most adverse events (though higher for headache), and generally resolve by 12 months post procedure | Insufficient
Other outcomes | 2 (16); Single group | Moderate^d^ | Direct | Imprecise^b^ | Inconsistent^e^ | All single group | 4/5 patients who were not working at baseline were working at 12 months follow-up; 3/10 had symptoms recurrence; All (6/6) patients reported symptom improvement | Insufficient

Notes.

a Two rated as moderate risk, 1 as low risk of bias;

b Due to small sample size;

c Single study;

d All studies rated as moderate;

e Variety of outcomes so consistency not applicable.

Abbreviations. N/A=not applicable; NRCS=nonrandomized comparative study.

### Results from Systematic Reviews for Mixed or Other Conditions

Eight systematic reviews reported on multiple conditions. Six reviews focused on MRgFUS and 2 reviews reported on FUS more generally. Two of the 8 reviews included patients with just ET and PD^68,^ ^69^ and 6 included patients with a general combination of conditions (eg, PD, ET, multiple sclerosis [MS], dystonia, rubral tremor).

In summary, for mixed conditions, MRgFUS generally showed improvements in tremor-related outcomes, but no differences were seen when compared to RF, GK, DBS, or other lesioning surgeries based on 2 reviews, and 1 review reported favorable results for MRgFUS compared to SR. Two reviews reported that quality of life results favored MRgFUS over DBS, sham, or without a comparator group. One review reported no difference in function after MRgFUS. Overall adverse event outcomes were mixed.

#### ET and PD

One systematic review of 9 studies narratively found favorable results for tremor-related outcomes, quality of life, adverse events, and patient satisfaction after compared to before MRgFUS for patients with ET and PD (p NR).^68^ Of note, CRST part C scores were included as part of the quality of life measures. The other systematic review included mostly ET patients but noted that some PD patients were incidentally included within these studies. This review included 18 studies examining efficacy and 34 examining adverse events. The review found significant improvement in tremor-related outcomes for patients who received FUS compared to SRS (pooled net mean difference = 1.31, 95% CI [−2.96, 5.99]).^69^ However, the same review reported significantly more adverse events in the FUS group, including imbalance/gait disturbances (10.5% vs 0%, p NR) and sensory disturbances (8.3% vs 1.1%, p NR). This review also reported significantly higher imbalance/gait disturbances for people who received FUS in modified coordinates compared to classic coordinates (p = 0.0005).

#### Mixed Conditions

Two systematic reviews included patients with mixed conditions and reported changes in outcomes from before to after MRgFUS. One review of 8 studies reported no significant differences in functional outcomes from before to after MRgFUS (p = 0.39 to 0.81).^44^ One systematic review of 42 studies (16 include MRgFUS, as well as 15 DBS and 13 GK studies) just reported data about the procedures (eg, MRgFUS) and did not report treatment-related outcomes.^70^

One systematic review of 17 studies that compared MRgFUS to DBS in patients with ET, PD, and dystonia narratively reported that costs were higher for both unilateral and bilateral DBS compared to MRgFUS.^71^

One systematic review of mixed conditions (15 studies, 2 of which included MRgFUS) reported favorable results for tremor-related (SMD = 1.31; 95% CI [0.83, 1.80]) and quality of life outcomes (SMD = 1.25; 95% CI [0.75, 1.74]) for patients who received MRgFUS compared to sham.^72^ There were no significant differences in cognitive or neuropsychiatric function. Of note, CRST Part C scores were used as part of the quality of life assessments. The same systematic review found no significant difference in tremor-related outcomes between MRgFUS compared to DBS (p NR) but significantly greater quality of life for patients who received MRgFUS compared to DBS (p = 0.014). There was no difference in tremor-related outcomes between MRgFUS and other lesioning surgeries (p NR).

One systematic review that included patients with ET, PD, MS, and rubral tremor compared MRgFUS targets as well as different treatments.^73^ There were significant improvement in tremor-related outcomes after MRgFUS of the cerebellothalamic tract (CTT) (MD = −2.35, 95% CI [−2.51, −2.19]) and the VIM for patients with ET (MD = −2.08, 95% CI [−2.77, −1.39]). The same review found no significant differences in tremor outcomes for ET patients who received MRgFUS of either target to each other, or to RF of the VIM, or GK of the VIM. There were no significant differences in speech or swallowing difficulties (both defined as adverse events) for ET patients who received MRgFUS of the VIM compared to CTT (p NR). A higher proportion of ET patients who received MRgFUS of the VIM compared to CTT had sensory changes (not defined). There were no differences in adverse events between ET patients who received MRgFUS of the CTT compared to RF of the VIM. For MRgFUS of the VIM compared to RF of the VIM, there was no difference in speech or swallowing difficulties, but a higher percentage of sensory changes (not defined) in the MRgFUS of the VIM. MRgFUS of the CTT for ET patients had more favorable adverse event outcomes than GK of the VIM (significance not assessed), but MRgFUS of the VIM showed mixed results for adverse events.

The same systematic review narratively concluded that there were fewer adverse events for PD patients who received MRgFUS of the VIM compared to RF of the VIM. Similarly, the systematic review narratively found either fewer adverse events or no difference in adverse events for PD patients who received MRgFUS of the VIM compared to RF of the subthalamic nucleus (STN) or pallidum. The systematic review also narratively found no differences in adverse events between PD patients who received MRgFUS of the VIM compared to GK of the VIM.

A final systematic review of 25 studies reported results for the use of FUS for tremor with ataxia, multiple sclerosis, mixed tremor, post-stroke tremor, tremor plus dystonia, isolated and combined dystonia without tremor, subthalamotomy for PD, CTT-FUS for ET, and PTT-FUS for PD.^74^ The systematic review narratively concluded that there were improvements in tremor-related outcomes for all conditions expect post-stroke after FUS compared to before.