# METHODS

## REGISTRATION AND TOPIC DEVELOPMENT

A protocol for this review was registered on the PROSPERO international prospective register of systematic reviews (CRD42024611898). A draft version of this report was reviewed by external peer reviewers; their comments and author responses are provided in the Supplementary Materials.

Representatives from the VA PADRECC and a technical expert panel (TEP) were consulted to refine the key questions (KQ). We focused on studies that reported on the use of MRgFUS for the treatment of movement disorders in adults. For the purposes of this review, it was assumed that all FUS was MRI guided for the conditions of interest. Based on guidance from the TEP, it was determined that the effectiveness of MRgFUS versus sham is sufficiently established for the treatment of ET and PD. Therefore, KQ1 focuses on the comparative effectiveness of MRgFUS versus other surgical treatments. In contrast, the TEP and nominator noted that less is known about the benefits and harms of MRgFUS for other movement disorders of interest. Therefore, KQ2 focuses on the effectiveness of MRgFUS versus sham, best medical management, or no treatment.

While not originally part of our protocol, based on a request from our TEP members we also summarized the results of identified relevant systematic reviews, regardless of study designs included in these reviews.

## KEY QUESTIONS

The following KQs were the focus of this review:

KQ Number | Key Question
Key Question 1a | What is the comparative effectiveness of high-intensity focused ultrasound therapy^a^ versus other surgical treatments (eg, deep brain stimulation, stereotactic radiosurgery and other ablative treatments) applied to specific anatomic targets for the treatment of:; - essential tremor?; - Parkinson’s disease?
Key Question 1b | Does the comparative effectiveness vary by patient characteristics (including treatment history) and anatomic targets?
Key Question 2a | What are the benefits and harms of high-intensity focused ultrasound therapy applied to specific anatomic targets for the treatment of:; - other neurological conditions?; - dystonia?; - task-specific tremors?; - other movement disorders?
Key Question 2b | Do benefits and harms vary by patient characteristics (including treatment history) and anatomic targets?

Notes.

a Included studies that did and did not specify MRI-guided FUS.

## SEARCHING AND SCREENING

We searched PubMed, EMBASE, Cochrane, and ClinicalTrials.gov (http://clinicaltrials.gov) from inception to August 26, 2024 (see Appendix for complete search strategies). We used medical subject headings (MeSH) and free text terms specific to high intensity focused ultrasound, magnetic resonance imaging, and movement disorders (including Parkinson’s disease, essential tremor, dystonia, and others). We ensured that known relevant publications were captured by our searches. Additional citations were sought from hand-searching reference lists of relevant systematic and non-systematic reviews and consultation with content experts.

Citations were uploaded into EndNote and deduplicated. We screened citations in Systematic Review Data Repository-Plus (SRDR+ (https://srdrplus.ahrq.gov/projects/5980/)). A pilot round of 200 citations was run to ensure a common understanding of the eligibility criteria, where all team members screened the title and abstract of the same citations. The remaining citations were screened by 2 members of the research team and conflicts were resolved by group discussion. Abstracts accepted at the screening phase underwent full-text review by 2 independent reviewers. In the case of conflicts between reviewers during full text-review, an additional team member was consulted as necessary.

Table 1 lists the study eligibility criteria. For KQ1, we focused on individuals with ET or PD who were treated with MRgFUS ablation of brain tissue. Studies included randomized controlled trials (RCTs) and nonrandomized comparative studies (NRCS). Comparisons of interest included unilateral versus bilateral treatment (including different timing of treating the second side), different treatment procedures (DBS, stereotactic radiosurgery [SRS], gamma knife [GK], and other noninvasive or surgical ablations), and comparisons of anatomical targets. We required studies to include a minimum of 10 patients at baseline per arm. We excluded studies that compared people who received a treatment at a single target to those who received a second target due to initial failure of the first treatment. We also excluded studies that conducted only post hoc comparisons of target location. That is, studies that compared anatomical locations were required to have intentionally targeted different anatomical areas prospectively (rather than assess difference in outcomes based on where people were found to have lesions). For KQ1, we excluded studies that compared HIFU only with best medical management or sham comparators, non-comparative (ie, single group) studies, and studies that compared data from cohorts of different studies and did not include an adjusted analysis.

For KQ2, we focused on other neurological conditions that involved movement disorders (such as dystonia). Study designs included RCTs, NRCSs, and single group studies, since the overall benefits and harm of MRgFUS for these conditions are unknown. Comparators for KQ2 included those used for KQ1 in addition to best medical management or sham treatments, and studies comparing baseline to follow-up. Due to the expected sparseness of eligible studies, we required a minimum of 5 patients at baseline per arm for these studies (a lower threshold than for KQ1).

For both KQs, outcomes of interest included condition- or procedure-related outcomes (including tremor severity, required other treatments, and cost), patient-specific outcomes (eg, quality of life, patient satisfaction), and harms. Intermediate outcomes were not included. For both KQs, we excluded studies focused on atypical parkinsonism, since current evidence does not support use of MRgFUS in atypical parkinsonian syndromes which have different pathophysiologic mechanisms.^37,^ ^38^ We also excluded modeling studies, case reports, case series, qualitative studies, non-systematic reviews, and studies that did not report results by condition and/or anatomical target.

Table 1 Eligibility Criteria

Domain | Inclusion Criteria | Exclusion Criteria
Population | KQ1 & KQ2: Adults aged 18 and older; KQ1: Essential tremor or Parkinson’s disease; KQ2: Other movement related disorders, including dystonia, task-specific tremors, and other movement disorders | KQ1 & KQ2: Atypical parkinsonism
Exposure | KQ1 & KQ2: High-intensity focused ultrasound ablation of brain tissue, including unilateral, staged bilateral, non-staged bilateral
Comparator | KQ1 & KQ2:; - Unilateral, staged bilateral, non-staged bilateral focused ultrasound ablation, including comparisons between these treatments, as well as comparisons between anatomical targets; - Deep brain stimulation; - Different timing of ultrasound (including timing of 2^nd^ treatment for bilateral treatment); - Stereotactic radiosurgery; - Gamma knife; - Invasive or surgical ablations; KQ2:; - Any (eg, best medical management or sham treatment) or no comparator | KQ1: Studies comparing focused ultrasound to best medical management or sham treatment
Outcomes | KQ1 & KQ2:; Disease/condition or procedural outcomes:; - Tremor severity; - Required follow-up treatments for procedure; - Required other treatments or change in other treatments; - Recovery outcomes; - Cost; Patient-Specific Outcomes; - Quality of life; - Function; - Patient satisfaction; - Caregiving measures (reported in the specified studies); Harms; - Adverse events/side effects; - Complications from procedure; - Cognitive decline or impairment | KQ1 & KQ2:; - Intermediate outcomes (eg, electroencephalogram readings, imaging measures); - Studies that do not report results by condition and anatomical target
Timing | KQ1 & KQ2: Any
Setting | KQ1 & KQ2: Any
Study Design | KQ1; - RCT; - NRCS; - Systematic reviews; KQ2:; - RCT; - NRCS; - Single group; - Systematic reviews | KQ1 & KQ2:; - Modeling studies; - Case reports or case series; - Qualitative studies; - Non-systematic reviews; KQ1: Single group studies
Other | KQ1: [underlined: ≥]10 patients per arm (per condition); KQ2: [underlined: ≥]5 patients per arm (per condition)

Notes. KQ=key question; NRCS=nonrandomized comparative studies; RCT=randomized controlled trials.

## DATA EXTRACTION AND RISK OF BIAS ASSESSMENT

Data were extracted into SRDR+. All data extraction was first completed by 1 reviewer and then confirmed by a second reviewer. Other team members were consulted if conflicts arose. For both KQs, we extracted the following data from eligible studies: study design, details of procedures used, sample size and population characteristics at baseline, and outcomes. Procedure outcomes included available details on anatomical targets, target coordinates, tractography used (visualization and mapping technique), number of sonications (or number of individuals treatment applications to a particular target tissue), ultrasound intensity, average and maximum temperature reached, and other available details. For studies that included comparative data, we extracted whether these were comparing treatments, target locations, or side of treatment. For adverse events, we did not extract severity data. For studies with multiple time points, we extracted data at a short-term and long-term time point (up to 24 months post procedure) for each outcome.

Study risk of bias was independently assessed by 1 reviewer using questions derived from the Cochrane Risk of Bias tool for RCTs and the Risk of Bias In Non-randomized Studies – of Interventions tool for other study designs (see Supplementary Materials). We also evaluated whether each article adequately defined patient eligibility criteria, interventions, and outcomes assessed, and whether it was free of discrepancies. Risk of bias assessments were confirmed by a second reviewer.

## SYNTHESIS AND CERTAINTY OF EVIDENCE

We conducted a narrative synthesis of the evidence. We aimed to meta-analyze quantitative data, but this was not feasible due to the variation in conditions and comparisons. Results in study groups were compared using risk ratios (RR) for dichotomous outcomes. When a study had 0 events in 1 group, we calculated risk differences (RD) instead. Continuous data were compared using mean differences (MD) between interventions or time points for single group studies. We assessed certainty of evidence following the GRADE (Grading of Recommendations Assessment, Development and Evaluation) approach.^39^ The GRADE approach takes into account risk of bias, imprecision, inconsistency, indirectness, and other issues that the study may present in order to help synthesize results from a body of literature.^40,^ ^41^ We assessed each of these aspects for each of the examined outcomes in order to assess the confidence of our conclusions. Importantly, we considered the Fahn-Tolosa-Marín Clinical Rating Scale for Tremor (CRST) Part C scores as tremor-related outcomes (some studies described CRST Part C as quality of life [QOL] or function). We compiled evidence profiles based on key findings from the included literature, which provide the basis for determination of certainty of evidence and summary conclusions for outcomes. Within each outcome, we considered the study design, the number of studies and participants, methodological limitations, directness of the evidence, precision of the findings, consistency across studies, and other issues. For outcomes with insufficient evidence, the summary finding for that outcome is “no conclusion.” Although we summarize findings from existing systematic reviews, we do not include the findings of these systematic reviews as part of our GRADE approach.