# BACKGROUND

Movement disorders are a group of neurological conditions that cause problems with movement, including changes in movement frequency, speed, or control.^1^ Typically, these disorders involve involuntary movements that present as either decreased or slowing of movement (hypokinesis) or increased or excessive movements (hyperkinesis).^2^ Movement disorders result from damage or dysfunction in the brain due to neurodegeneration, stroke, autoimmune conditions, infections, or toxic/metabolic issues, among other causes.^1,^ ^3,^ ^4^ The most common movement disorders include Parkinson’s disease (PD) and essential tremor (ET), which affect approximately 11.8 and 24.9 million people globally, respectively.^5,^ ^6^ Other common movement disorders include dystonia (abnormal posture movements due to sustained or intermittent muscle contraction), ataxia (poorly coordinated movement), chorea (involuntary, jerky, irregular movements), and tic disorders.^1,^ ^2^

Veterans are at an increased risk for movement disorders compared to the general US population due to age, brain injuries, and exposure to chemicals (eg, Agent Orange).^7,^ ^8^ To better serve Veterans, the VHA created six Parkinson’s Disease Research, Education, and Clinical Centers (PADRECCs) in 2001 that specialize in the management of these movement disorders.^9^ The PADRECCs annually serve approximately 110,000 Veterans through education, interdisciplinary care, and research.^9^

Movement disorders can severely impact a person’s physical and cognitive function, independence, and quality of life.^10,^ ^11^ People with a movement disorder may encounter difficulties in activities of daily life including maintaining employment, driving, or self-care.^12,^ ^13^ Movement disorders can also impact important non-motor functions including sleep patterns and can be associated with depression and anxiety.^14–16^ People diagnosed with movement disorders may require substantial caregiving from family, friends, or other caregivers,^17,^ ^18^ and it is not uncommon for caregivers to experience stress and burnout.12, 13

Treatment options for movement disorders include medications, neurorehabilitation therapy, surgical therapies such as deep brain stimulation (DBS), and more research-based interventions such as stem cell replacement or gene therapies.^19–23^ Appropriate treatments vary by condition, patient and provider preferences, and individual responses to less invasive methods. More aggressive methods, such as invasive lesioning or stimulation therapies, are generally used as second- or third-line treatments after best medical management; however, aggressive therapies are associated with risks of serious adverse events (eg, infection, hemorrhage, stroke).^24^ More recently, high intensity focused ultrasound (HIFU) therapy, a noninvasive technique for targeted tissue ablation, has been shown to be effective for treating a variety of health issues including pain, certain cancers, fibroids, and also movement disorders.^25^ Magnetic resonance-guided focused ultrasound (MRgFUS) combines MRI and FUS to target and destroy tissue without damaging surrounding structures or requiring an open surgical approach.^26^ MRgFUS has been approved by the US Food and Drug Administration (FDA) for the treatment of ET and PD,^27,^ ^28^ and the FDA recently approved staged bilateral MRgFUS of the pallidothalamic tractotomy for PD.^29^ At the time of this report, MRgFUS has not received FDA approval for the treatment of other movement disorders.

While side effects have been reported from MRgFUS, such as headache, ataxia, or paresthesia,^30,^ ^31^ studies have also found improved outcomes for people with ET and PD treated with MRgFUS compared to sham or best medical management.^32–34^ Because of this, MRgFUS has already been approved by the FDA for ET and PD. While evidence for the FDA approvals come from RCTs that have compared MRgFUS to sham therapy, there is limited information about the comparative effectiveness of MRgFUS to other surgical treatments (eg, DBS) or the comparison of ablating different anatomical targets. To our knowledge, there have been no systematic reviews on the use of MRgFUS for PD or ET that have focused exclusively on comparative studies. Existing systematic reviews have only reported on indirect comparisons of available treatments.^35,^ ^36^ Generally, these have shown support for MRgFUS, but these vary by outcome, as well as condition and comparison of interest. There is minimal evidence about other comparative factors, such as anatomical target or unilateral versus bilateral treatments. Additionally, while MRgFUS is being explored for use in other movement-related conditions, such as dystonia, its efficacy to treat these conditions is still uncertain.

To help inform decisions about the use of MRgFUS within the VHA, the VA PADRECC requested a review of the available comparative evidence on the efficacy and safety of MRgFUS for movement disorders.