# Appendix

## SEARCH STRATEGIES

### COCHRANE (INCEPTION TO 08/26/2024)

# | Search Statement | Results
1 | ((High-Intensity Focused Ultrasound Ablation OR focused ultrasound* OR HIFU* OR MRgFUS*)):ti,ab,kw (Word variations have been searched) | 1755
2 | (Guided) AND ("focused ultrasound") | 199
3 | Magnetic Resonance Imaging | 36404
4 | MRI | 36806
5 | #3 OR #4 | 50578
6 | #2 AND #5 | 110
7 | ‘high intensity’ and focused and ultrasound and ablation | 194
8 | MR-guided focused ultrasound | 63
9 | insightec | 19
10 | #1 OR #6 OR #7 OR #8 OR #9 | 1794
11 | ((Essential Tremor OR Parkinson Disease OR essential tremor* OR familial tremor* OR parkinson*)):ti,ab,kw (Word variations have been searched) | 14903
12 | MeSH descriptor: [Parkinson Disease] explode all trees | 6149
13 | MeSH descriptor: [Essential Tremor] explode all trees | 203
14 | MeSH descriptor: [Chorea] explode all trees | 376
15 | MeSH descriptor: [Ataxia] explode all trees | 398
16 | MeSH descriptor: [Multiple Sclerosis] explode all trees | 5246
17 | MeSH descriptor: [Myoclonus] explode all trees | 93
18 | MeSH descriptor: [Tremor] explode all trees | 708
19 | MeSH descriptor: [Dystonia] explode all trees | 382
20 | MeSH descriptor: [Movement Disorders] explode all trees | 8907
21 | (Ataxia OR Chorea OR Dystonia OR Task specific OR tremor OR Fragile X Syndrome OR Hepatolenticular Degeneration OR Multiple Sclerosis OR Myoclonus OR Restless Legs Syndrome OR Supranuclear Palsy, Progressive OR Tardive Dyskinesia OR Tourette Syndrome OR atax* OR adiadochokines* OR cerebellar gait* OR cerebelloparenchymal disorder* OR coordination impairment* OR dyscoordination OR dysmetria* OR dyssynergia* OR hemitaxia* OR hypermetria* OR incoordination* OR rubral tremor* OR schut-haymaker OR SCA1* OR olivopontocerebellar OR spinocerebellar OR atroph* OR opca OR wadia-swami OR chorea* OR chorei* OR neuroacanthocytosis OR st* vitus* dance OR dystoni* OR fragile x OR marker x OR martin-bell OR fraxa OR fraxe OR hepatocerebral OR hepatolenticular OR neurohepatic OR progressive lenticular OR degeneration OR myoclon* OR polymyoclon* OR kinsbourne syndrome OR pseudosclerosis OR copper storage OR wilson OR westphal-strupell OR holmes tremor* OR huntington* OR sclerosis OR ms OR orofacial dyskinesia* OR tardive dyskinesia* OR restless leg* OR willis-ekbom OR wittmaack-ekbome OR progressive supranuclear OR ophthalmoplegia* or richardson* disease* OR richardson*syndrome*):ti,ab,kw (Word variations have been searched) | 77556
22 | #11 OR #12 OR #13 OR #14 OR #15 OR #16 OR #17 OR #18 OR #19 OR #20 OR #21 | 89897
23 | #10 AND #22 | 160
| Total | 160

### PUBMED (INCEPTION TO 08/26/2024)

# | Search Statement | Results
1 | ‘high intensity focused ultrasound’ | 6,053
2 | MR-guided focused ultrasound | 630
3 | (‘high intensity’) AND (focused) AND (ultrasound) AND (ablation) | 3,470
4 | (((((mrgfus*) OR (mrigfus*)) OR (MR-guided focused ultrasound)) OR (HIFU*)) OR (insightec*)) OR (focused ultrasound*) | 22,093
5 | (mr) OR (mri) OR (‘nuclear magnetic resonance imaging’) OR (‘magnetic resonance imaging’) | 979,151
6 | (guided) AND (‘focused ultrasound’) | 5,554
7 | (#5) AND (#6) | 2,710
8 | ((((#1) OR (#2)) OR (#3)) OR (#4)) OR (#7) | 22,823
9 | Essential Tremor/ or Parkinson Disease/ or (essential tremor* or familial tremor* or parkinson*) | 183,748
10 | exp Ataxia/ or exp Chorea/ or Dystonia/ or tremor/ or tremor or Task specific/ or Fragile X Syndrome/ or Hepatolenticular Degeneration/ or exp Multiple Sclerosis/ or exp Myoclonus/ or Restless Legs Syndrome/ or Supranuclear Palsy, Progressive/ or Tardive Dyskinesia/ or Tourette Syndrome/ OR dystonic tremor OR MS associated tremor OR position specific tremor OR primary writing tremor OR focal dystonia OR writer* cramp OR neuroleptic induced parkinsonism OR medication induced parkinsonism OR cerebellar tremor OR rubral tremor OR (atax* or adiadochokines* or cerebellar gait* or coordination impairment* or dyscoordination or dysmetria* or dyssynergia* or hemitaxia* or hypermetria* or incoordination* or rubral tremor* or schut-haymaker or SCA1* or ((olivopontocerebellar or spinocerebellar) adj1 atroph*) or opca or wadia-swami or chorea* or chorei* or neuroacanthocytosis or st vitus* dance or dystoni* or ((fragile x or marker x or martin-bell or fraxa or fraxe or fra?x? or mar?x?) adj1 syndrome*) or ((hepatocerebral or hepatolenticular or neurohepatic or progressive lenticular) adj1 degeneration) or myoclon* or polymyoclon* or kinsbourne syndrome or pseudosclerosis or ((copper storage or wilson*) adj1 disease) or holmes tremor* or huntington* or ((disseminated or multiple) adj1 sclerosis) or ms or ((orofacial or tardive) adj1 dyskinesia*) or restless leg or willis-ekbom or (progressive supranuclear adj1 (ophthalmoplegia* or pals*)) or (richardson* adj3 (disease* or syndrome*)) or tic disorder or tourette) | 894,166
11 | (exp Movement disorder/) OR (movement disorder*) | 137,983
12 | ((#9) OR (#10)) OR (#11) | 1,116,015
13 | (#8) AND (#12) | 1,441
| Total | 1,441

### EMBASE (INCEPTION TO 08/26/2024)

# | Search Statement | Results
1 | high intensity focused ultrasound’.mp. or high intensity focused ultrasound/ [mp=title, abstract, heading word, drug trade name, original title, device manufacturer, drug manufacturer, device trade name, keyword heading word, floating subheading word, candidate term word] | 8512
2 | (‘high intensity’ and focused and ultrasound and ablation).mp. [mp=title, abstract, heading word, drug trade name, original title, device manufacturer, drug manufacturer, device trade name, keyword heading word, floating subheading word, candidate term word] | 3830
3 | high intensity focused ultrasound.mp. or exp high intensity focused ultrasound/ | 8512
4 | MR-guided focused ultrasound.mp. or exp MR-guided focused ultrasound/ | 1759
5 | mrgfus*.mp. or exp MR-guided focused ultrasound/ | 2013
6 | exp MR-guided focused ultrasound/ | 1315
7 | mrigfus*.mp. | 57
8 | (mr or mri or ‘nuclear magnetic resonance imaging’ or ‘magnetic resonance imaging’).mp. [mp=title, abstract, heading word, drug trade name, original title, device manufacturer, drug manufacturer, device trade name, keyword heading word, floating subheading word, candidate term word] | 1421378
9 | (guided and ‘focused ultrasound’).mp. [mp=title, abstract, heading word, drug trade name, original title, device manufacturer, drug manufacturer, device trade name, keyword heading word, floating subheading word, candidate term word] | 4457
10 | 8 and 9 | 3457
11 | HIFU*.mp. or high intensity focused ultrasound/ | 8317
12 | insightec*.mp. | 533
13 | focused ultrasound*.mp. | 14788
14 | 1 or 2 or 3 or 4 or 5 or 6 or 7 or 10 or 11 or 12 or 13 | 15291
15 | chorea.mp. or exp chorea/ | 56915
16 | ataxia.mp. or exp ataxia/ | 106583
17 | Multiple Sclerosis.mp. or exp Multiple Sclerosis/ | 183109
18 | Myoclonus.mp. or exp Myoclonus/ | 30684
19 | tremor.mp. or exp Tremor/ | 72975
20 | Dystonia.mp. or exp Dystonia/ | 41208
21 | movement disorder.mp. or motor dysfunction/ | 108367
22 | (Task specific or Fragile X Syndrome or Hepatolenticular Degeneration or Restless Legs Syndrome or Supranuclear Palsy, Progressive or Tardive Dyskinesia or Tourette Syndrome or dystonic tremor or MS associated tremor or position specific tremor or primary writing tremor or focal dystonia or writer* cramp or neuroleptic induced parkinsonism or medication induced parkinsonism or cerebellar tremor or rubral tremor or atax* or adiadochokines* or cerebellar gait* or cerebelloparenchymal disorder* or coordination impairment* or dyscoordination or dysmetria* or dyssynergia* or hemitaxia* or hypermetria* or incoordination* or rubral tremor* or schut-haymaker or SCA1* or olivopontocerebellar or spinocerebellar or atroph* or opca or wadia-swami or chorea* or chorei* or neuroacanthocytosis or st* vitus* dance or dystoni* or fragile x or marker x or martin-bell or fraxa or fraxe or hepatocerebral or hepatolenticular or neurohepatic or progressive lenticular or degeneration or myoclon* or polymyoclon* or kinsbourne syndrome or pseudosclerosis or copper storage or wilson or westphal-strupell or holmes tremor* or huntington* or sclerosis or ms or orofacial dyskinesia* or tardive dyskinesia* or restless leg* or willis-ekbom or wittmaack-ekbome or progressive supranuclear or ophthalmoplegia* or richardson* disease* or richardson*syndrome*).mp. | 1672366
23 | Parkinson Disease.mp. or exp Parkinson disease/ | 209822
24 | exp essential tremor/ or essential tremor*.mp. | 9717
25 | familial tremor*.mp. | 65
26 | parkinson*.mp. | 273044
27 | 15 or 16 or 17 or 18 or 19 or 20 or 21 or 22 or 23 or 24 or 25 or 26 | 1950628
28 | 14 and 27 | 2004
| Total | 2004

### CLINICALTRIALS.GOV (INCEPTION TO 08/26/2024)

# | Search Statement | Results
1 | Condition/disease: tremor; Other terms:(Movement Disorders) OR (Parkinson’s); Intervention/Treatment:Ultrasound | 35
2 | Intervention/Treatment:Magnetic Resonance Guided Functional Ultrasound | 13
3 | Condition/disease: tremor; ; Intervention/Treatment:high-intensity Ultrasound | 2
4 | Condition/disease: movement; Intervention/Treatment:high-intensity Ultrasound | 6
5 | Condition/disease: Multiple Sclerosis; Intervention/Treatment:Ultrasound | 11
6 | Condition/disease: Dystonia ; Intervention/Treatment:Ultrasound | 17
7 | Condition/disease: tremor ; Other terms:(Movement Disorders) OR (Parkinson’s) OR (dystonia) OR (multiple sclerosis); Intervention/Treatment: (Ultrasound) OR (focused ultrasound) OR (HIFU) OR (MRgFUS) | 43
8 | Condition/disease: tremor; Other terms:(Movement Disorders) OR (Parkinson’s) OR (dystonia) OR (multiple sclerosis) OR (Ataxia) OR (Chorea) OR (Dystonia) OR (Fragile X Syndrome) OR (Hepatolenticular Degeneration) OR (Myoclonus) OR (Restless Legs Syndrome) OR (Palsy) OR (Tardive Dyskinesia) OR (Tourette Syndrome)OR (tic disorder); Intervention/Treatment: (Ultrasound) OR (focused ultrasound) OR (HIFU) OR (MRgFUS) | 43
9 | Condition/disease: (Movement Disorders) OR (Parkinson’s) OR (dystonia) OR (multiple sclerosis) OR (Ataxia) OR (Chorea) OR (Dystonia) OR (Fragile X Syndrome) OR (Hepatolenticular Degeneration) OR (Myoclonus) OR (Restless Legs Syndrome) OR (Palsy) OR (Tardive Dyskinesia) OR (Tourette Syndrome)OR (tic disorder); Intervention/Treatment: (Ultrasound) OR (focused ultrasound) OR (HIFU) OR (MRgFUS) | 241
| Total after deduplication | 251