# ABBREVIATIONS TABLE

Abbreviation: Definition
ANOVA: Analysis of variance
CRST: Fahn-Tolosa-Marín Clinical Rating Scale for Tremor
CTT: Cerebellothalamic tract
DBS: Deep brain stimulation
EQ-5D-5L VAS: 5 level EQ-5D visual analog scale
ET: Essential tremor
FDA: US Food and Drug Administration
FUS: Focused ultrasound
GK: Gamma knife
GPi: Globus pallidus internus
GRADE: Grading of Recommendations Assessment, Development and Evaluation
HIFU: High intensity focused ultrasound
IQR: Inner quartile range
KQ: Key question
MD: Mean difference
MRgFUS: Magnetic resonance-guided focused ultrasound
MRI: Magnetic resonance imaging
MS: Multiple sclerosis
NMD: Net mean difference
NR: Not reported
NRCS: Nonrandomized comparative studies
NRS-11: Numeric rating scale 11
PADRECC: Parkinson’s Disease Research, Education, and Clinical Centers
PD: Parkinson’s disease
PSA: Posterior subthalamic area
PTT: Pallidothalamic tract
QOL: Quality of life
QUEST: Quality of Life in Essential Tremor Questionnaire
RCT: Randomized controlled trials
RD: Risk differences
RF: Radiofrequency
RR: Risk ratio
SD: Standard deviation
SMD: Standardized mean difference
SR: Stereotactic radiosurgery
SRDR+: Systematic Review Data Repository-Plus
STN: Subthalamus nuclear
TEP: Technical expert panel
TETRAS: Tremor Research Group Essential Tremor Rating Scale
UPDRS: Unified Parkinson’s disease rating scale
VHA: Veterans Health Administration
VIM: Ventral intermedius
Vo: Ventro-oral
VOA: Ventro-oral anterior
VOP: Ventral oralis posterior
XPD: X-linked dystonia-parkinsonism
XDP-MDSP: X-linked dystonia-parkinsonism Movement Disorder Society of the Philippines